# REFERENCES

### Overview

1 Gardner JW, Sanborn JS. Years of potential life lost (YPLL)--what does it measure? Epidemiology 1990;1:322–9. https://www.ncbi.nlm.nih.gov/pubmed/2083312 [abstract]. Accessed December 6, 2021.2083312
2 Wide-ranging online data for epidemiologic research (WONDER). Atlanta, GA: CDC, National Center for Health Statistics; 2020. http://wonder.cdc.gov. Accessed December 6, 2021.
3 Rural Health Information Hub. Critical Access Hospitals. https://www.ruralhealthinfo.org/topics/critical-access-hospitals. Accessed December 6, 2021.
4 Zhang X, Lin D, Pforsich H, Lin VW. Physician workforce in the United States of America: forecasting nationwide shortages. Hum Resour Health 2020;18(1):8. https://pubmed.ncbi.nlm.nih.gov/32029001/. Accessed December 6, 2021.32029001
5 Machado SR, Jayawardana S, Mossialos E, Vaduganathan M. Physician density by specialty type in urban and rural counties in the U.S., 2010 to 2017. JAMA Netw Open. 2021 Jan 4;4(1):e2033994. 10.1001/jamanetworkopen.2020.33994. Accessed December 16, 2021.33481030
6 Health Resources and Services Administration. Projecting Health Workforce Supply and Demand. https://bhw.hrsa.gov/data-research/projecting-health-workforce-supply-demand. Accessed December 16, 2021.
7 Arora S, Thornton K. Novel models of hepatitis C virus care delivery: telemedicine, Project ECHO, and integrative care. Clin Liver Dis (Hoboken). 2020 Jul 21;16(1):5–7. 10.1002/cld.912. Accessed December 16, 2021.32714515
8 Ibe CA, Wilson LM, Brodine J, Monroe D, Boonyasai RT, Meza B, Tschudy MT, McArthur K, Robinson KA. Impact of Community Health Worker Certification on Workforce and Service Delivery for Asthma and Other Selected Chronic Diseases. Technical Brief No. 34. (Prepared by the Johns Hopkins University Evidence-based Practice Center under Contract No. 290-2015-00006-I/290-320011-T.) Rockville, MD: Agency for Healthcare Research and Quality; March 2020. AHRQ Publication No. 20-EHC004-EF. https://effectivehealthcare.ahrq.gov/products/health-worker-certification/technical-brief. Accessed December 16, 2021.
9 Wasserman M, Bender D, Lee SY. Use of preventive maternal and child health services by Latina women: a review of published intervention studies. Med Care Res Rev. 2007 Feb;64(1):4–45. 10.1177/1077558706296238. Accessed December 16, 2021.17213456
10 Bassuk EL, Hanson J, Greene RN, Richard M, Laudet A. Peer-delivered recovery support services for addictions in the United States: a systematic review. J Subst Abuse Treat. 2016 Apr;63:1–9. 10.1016/j.jsat.2016.01.003. Accessed December 16, 2021.26882891
11 Wetterhall S, Burrus B, Shugars D, Bader J. Cultural context in the effort to improve oral health among Alaska Native people: the dental health aide therapist model. Am J Public Health. 2011 Oct;101(10):1836–40. 10.2105/AJPH.2011.300356. Accessed December 16, 2021.21852624
12 Snyder CR, Frogner BK, Skillman SM. Facilitating racial and ethnic diversity in the health workforce. J Allied Health 2018;47(1):58–65. https://pubmed.ncbi.nlm.nih.gov/29504021/. Accessed December 6, 2021.29504021
13 Brown T, Liu JX, Scheffler RM. Does the under- or overrepresentation of minority physicians across geographical areas affect the location decisions of minority physicians? Health Serv Res 2009;44:1290–1308. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2739029/. Accessed December 6, 2021.19467025
14 Day JC, Christnacht C. Women Hold 76% of All Health Care Jobs, Gaining in Higher-Paying Occupations. Suitland, MD: U.S. Census Bureau; August 14, 2019. https://www.census.gov/library/stories/2019/08/your-health-care-in-womens-hands.html. Accessed December 6, 2021.
15 Greenwood BN, Carnahan S, Huang L. Patient–physician gender concordance and increased mortality among female heart attack patients. PNAS 2018 Aug 21;115(34):8569–74. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6112736/. Accessed December 6, 2021.30082406
16 Peabody MR, Eden AR, Douglas M, Phillips RL. Board certified family physician workforce: progress in racial and ethnic diversity. J Am Board Fam Med 2018 Nov;31(6):842–3. https://www.jabfm.org/content/31/6/842. Accessed December 6, 2021.30413540
17 Malhotra J, Rotter D, Tsui J, Llanos AAM, Balasubramanian BA, Demissie K. Impact of patient-provider race, ethnicity, and gender concordance on cancer screening: findings from Medical Expenditure Panel Survey. Cancer Epidemiol Biomarkers Prev 2017;26(12):1804–11. https://cebp.aacrjournals.org/content/26/12/1804.long. Accessed December 6, 2021.29021217
18 Garcia RI, Blue Spruce G, Sinkford JC, Lopez MJ, Sullivan LW. Workforce diversity in dentistry - current status and future challenges. J Public Health Dent 2017 Mar;77(2):99–104. Epub 2017 May 12. https://pubmed.ncbi.nlm.nih.gov/28497850/. Accessed December 6, 2021.28497850
19 American Dental Education Association. U.S. Dental School Applicants and First-Time, First-Year Enrollees, 2000 to 2020. https://www.adea.org/data/students/Applicants-2020-Entering-Class/. Accessed December 14, 2021.
20 Phillips JM, Malone B. Increasing racial/ethnic diversity in nursing to reduce health disparities and achieve health equity. Public Health Rep 2014;129 Suppl 2(Suppl 2):45–50. https://pubmed.ncbi.nlm.nih.gov/24385664/. Accessed December 6, 2021.24385664
21 Health Resources and Services Administration, National Center for Health Workforce Analysis. Sex, Race, and Ethnic Diversity of U.S. Health Occupations (2011–2015). Rockville, MD: U.S. Department of Health and Human Services; August 2017. https://bhw.hrsa.gov/sites/default/files/bureau-health-workforce/data-research/diversity-us-health-occupations.pdf. Accessed December 6, 2021.
22 Bush AA. A conceptual framework for exploring the experiences of underrepresented racial minorities in pharmacy school. Am J Pharm Educ 2020 Jan;84(1):7544. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7055416/. Accessed December 6, 2021.32292197
23 O’Neil E, Dower C. Primary care health workforce in the United States. Synth Proj Res Synth Rep 2011;(22):72579. https://pubmed.ncbi.nlm.nih.gov/22041996/. Accessed December 6, 2021.22041996
24 Naylor MD, Kurtzman ET. The role of nurse practitioners in reinventing primary care. Health Aff (Millwood) 2010;29(5):893–9. 10.1377/hlthaff.2010.0440. Accessed December 6, 2021.20439877
25 Crowe RP, Krebs W, Cash RE, Rivard MK, Lincoln EW, Panchal AR. Females and minority racial/ethnic groups remain underrepresented in emergency medical services: a ten-year assessment, 2008–2017. Prehosp Emerg Care 2020 Mar–Apr;24(2):180–7. Epub 2019 Jul 24. https://pubmed.ncbi.nlm.nih.gov/31225772/. Accessed December 6, 2021.31225772
26 Kleinpell RM, Grabenkort WR, Kapu AN, Constantine R, Sicoutris C. Nurse practitioners and physician assistants in acute and critical care: a concise review of the literature and data 2008–2018. Crit Care Med. 2019 Oct;47(10):1442–49. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6750122/. Accessed December 6, 2021.31414993
27 Rotenstein LS, Reede JY, Jena AB. Addressing workforce diversity - a quality-improvement framework. N Engl J Med. 2021 Mar 25;384(12):1083–86. 10.1056/NEJMp2032224. Accessed December 6, 2021.33764706
28 Beck AJ, Manderscheid RW, Buerhaus P. The future of the behavioral health workforce: optimism and opportunity. Am J Prev Med 2018;54(6):S187–S189. https://www.ajpmonline.org/article/S0749-3797(18)31627-1/fulltext. Accessed December 6, 2021.29779540
29 Health Resources and Services Administration, National Center for Health Workforce Analysis; Substance Abuse and Mental Health Services Administration, Office of Policy, Planning, and Innovation. National Projections of Supply and Demand for Behavioral Health Practitioners: 2013–2025. Rockville, MD: U.S. Department of Health and Human Services; 2015. https://bhw.hrsa.gov/sites/default/files/bhw/health-workforce-analysis/research/projections/behavioral-health2013-2025.pdf. Accessed December 6, 2021.
30 Olfson M. Building the mental health workforce capacity needed to treat adults with serious mental illnesses. Health Aff (Millwood) 2016;35(6):983–90. 10.1377/hlthaff.2015.1619. Accessed December 6, 2021.27269013
31 Substance Abuse and Mental Health Services Administration. National Survey on Drug Use and Health: 2018. https://www.samhsa.gov/data/sites/default/files/cbhsq-reports/Assistant-Secretary-nsduh2018_presentation.pdf. Accessed December 6, 2021.
32 Substance Abuse and Mental Health Services Administration. 2018 National Survey on Drug Use and Health: Asians/Native Hawaiian and Other Pacific Islanders (NHOPI). https://www.samhsa.gov/data/report/2018-nsduh-asiansnative-hawaiians-and-other-pacific. Accessed December 6, 2021.
33 Substance Abuse and Mental Health Services Administration. 2018 National Survey on Drug Use and Health: African Americans. https://www.samhsa.gov/data/report/2018-nsduh-african-americans. Accessed December 6, 2021.
34 Substance Abuse and Mental Health Services Administration. 2018 National Survey on Drug Use and Health: Hispanics, Latino or Spanish Origin or Descent. https://www.samhsa.gov/data/report/2018-nsduh-hispanics-latino-or-spanish-origin-or-desce. Accessed December 6, 2021.
35 Eylem O, de Wit L, van Straten A, Steubl L, Melissourgaki Z, Danışman GT, de Vries R, Kerkhof AJFM, Bhui K, Cuijpers P. Stigma for common mental disorders in racial minorities and majorities a systematic review and meta-analysis. BMC Public Health 2020;20(1):1–20. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7278062/. Accessed December 6, 2021.31898494
36 Substance Abuse and Mental Health Services Administration, Center for Mental Health Services; National Institute of Mental Health. Mental Health: Culture, Race, and Ethnicity: A Supplement to Mental Health: A Report of the Surgeon General. Washington, DC: Department of Health and Human Services, Public Health Service, Office of the Surgeon General; August 2001. https://www.ncbi.nlm.nih.gov/books/NBK44243/. Accessed December 6, 2021.
37 Wahowiak L. Addressing stigma, disparities in minority mental health: access to care among barriers. Nation’s Health 2015 Feb;45 (1):1–20. https://www.thenationshealth.org/content/45/1/1.3. Accessed December 6, 2021.
38 Santiago CD, Miranda J. Progress in improving mental health services for racial-ethnic minority groups: a ten-year perspective. Psychiatr Serv 2014;65(2):180–5. 10.1176/appi.ps.201200517. Accessed December 6, 2021.24178249
39 Alegría M, Roter DL, Valentine A, Chen CN, Li X, Lin J, Rosen D, Lapatin S, Normand SL, Larson S, Shrout PE. Patient-clinician ethnic concordance and communication in mental health intake visits. Patient Educ Couns 2013 Nov;93(2):188–96. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3800470/. Accessed December 6, 2021.23896127
40 U.S. Bureau of Labor Statistics. Occupational Outlook Handbook: Psychologists. Last modified September 1, 2020. https://www.bls.gov/ooh/life-physical-and-social-science/psychologists.htm. Accessed December 6, 2021.
41 Hines AL, Cooper LA, Shi L. Racial and ethnic differences in mental healthcare utilization consistent with potentially effective care: the role of patient preferences. Gen Hosp Psychiatry; 2017 May:14–19. https://pubmed.ncbi.nlm.nih.gov/28622809/. Accessed December 6, 2021.
42 Centers for Medicare & Medicaid Services. National Health Expenditures by Type of Service and Source of Funds, CY 1960–2017. Last modified December 17, 2019. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical. Accessed December 6, 2021.
43 Centers for Medicare & Medicaid Services. National Health Expenditure Accounts: Methodology Paper, 2018: Definitions, Sources, and Methods. https://www.cms.gov/files/document/definitions-sources-and-methods.pdf. Accessed December 6, 2021.

### Access to Healthcare

1 Institute of Medicine, Committee on Monitoring Access to Personal Health Care Services. Access to Health Care in America. Millman M, ed. Washington, DC: National Academies Press; 1993. https://www.ncbi.nlm.nih.gov/books/NBK235882/. Accessed December 6, 2021.
2 Office of Disease Prevention and Health Promotion. HealthyPeople.gov. Access to Health Services. https://www.healthypeople.gov/2020/topics-objectives/topic/Access-to-Health-Services. Accessed December 6, 2021.
3 National Academies of Science, Engineering, and Medicine. Communities in Action: Pathways to Health Equity. Washington, DC: National Academies Press; 2017. https://www.nap.edu/catalog/24624/communities-in-action-pathways-to-health-equity. Accessed December 6, 2021.
4 Sommers BD, Maylone B, Blendon RJ, Orav EJ, Epstein AM. Three-year impacts of the Affordable Care Act: improved medical care and health among low-income adults. Health Aff 2017;36(6): 1119–28. https://pubmed.ncbi.nlm.nih.gov/28515140/. Accessed December 6, 2021.
5 Buchmueller TC, Levy HG. The ACA’s Impact on Racial and Ethnic Disparities in Health Insurance Coverage and Access to Care. Health Aff. 2020 Mar 1;39(3):395–402. 10.1377/hlthaff.2019.01394. Accessed December 6, 2021.
6 Seu K, Hall K, Moy E. Emergency Department Visits for Dental-Related Conditions, 2009. HCUP Statistical Brief #143. 2012. Agency for Healthcare Research and Quality, Rockville, MD. Available at https://hcup-us.ahrq.gov/reports/statbriefs/sb143.jsp. Accessed December 6, 2021.
7 Oral Health in America: A Report of the Surgeon General. Rockville, MD: National Institute of Dental and Craniofacial Research, National Institutes of Health; 2000. https://www.nidcr.nih.gov/research/data-statistics/surgeon-general. Accessed December 6, 2021.
8 Patel N, Fils-Aime R, Li C, Lin M, Robison V. Prevalence of past-year dental visit among U.S. adults aged 50 years or older, with selected chronic diseases, 2018. Prev Chronic Dis. 2021;18:200576. https://www.cdc.gov/pcd/issues/2021/20_0576.htm. Accessed December 1, 2021.
9 Stephens MB, Wiedemer JP, Kushner GM. Dental problems in primary care. Am Fam Physician 2018;98(11):654–60. https://www.aafp.org/afp/2018/1201/p654.html. Accessed December 6, 2021.30485039
10 Committee on Optimizing Scheduling in Health Care; Institute of Medicine. Kaplan K, Hamilton Lopez M, McGinnis JM, eds. Transforming Health Care Scheduling and Access: Getting to Now. Washington, DC: National Academies Press; 2015. https://www.ncbi.nlm.nih.gov/books/NBK316132/. Accessed December 6, 2021.
11 Brunner J, Rose DE, Chuang E, Canelo I, Yano EM. The role of healthcare system hassles in delaying or forgoing care. Healthc (Amst) 2020 Feb 29:100411. https://pubmed.ncbi.nlm.nih.gov/32127306/. Accessed December 6, 2021.32127306
12 Sommers BD, Gawande AA, Baicker K. Health insurance coverage and health – what the recent evidence tells us. N Engl J Med 2017;377;6:586–93. https://pubmed.ncbi.nlm.nih.gov/28636831/. Accessed December 6, 2021.28636831
13 Chen J, Vargas-Bustamante A, Mortensen K, Ortega AN. Racial and ethnic disparities in health care access and utilization under the Affordable Care Act. Med Care 2016;54:140–6. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4711386/. Accessed December 6, 2021.26595227
14 National Advisory Committee on Rural Health and Human Services. Improving Oral Health Care Services in Rural America: Policy Brief and Recommendations. Washington, DC: U.S. Department of Health and Human Services; December 2018. https://www.hrsa.gov/sites/default/files/hrsa/advisory-committees/rural/publications/2018-Oral-Health-Policy-Brief.pdf. Accessed December 6, 2021.
15 Oral Health in Rural Communities. RHIhub. https://www.ruralhealthinfo.org/topics/oral-health. Accessed December 6, 2021.
16 Neuman P, Jacobson GA. Medicare Advantage checkup. N Engl J Med 2018 Nov 29;379(22):2163–72. Accessed December 6, 2021.30428276
17 Data Book: Beneficiaries Dually Eligible for Medicare and Medicaid. Washington, DC: Medicare Payment Advisory Commission and Medicaid and CHIP Payment and Access Commission; January 2018. https://www.macpac.gov/wp-content/uploads/2020/07/Data-Book-Beneficiaries-Dually-Eligible-for-Medicare-and-Medicaid-January-2018.pdf. Accessed December 6, 2021.
18 An AR, Kim K, Lee JH, Sung NJ, Lee SI, Hyun MK. Having a usual source of care and its associated factors in Korean adults: a cross-sectional study of the 2012 Korea Health Panel Survey. BMC Fam Pract. 2016 Dec;17(1):1–8. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5129206/. Accessed December 6, 2021.26739311
19 Blewett LA, Johnson PJ, Lee B, S, Scal PB. When a usual source of care and usual provider matter: adult prevention and screening services. J Gen Intern Med 2008 Sep; 23(9):1354–60. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2518015/. Accessed December 6, 2021.18506542
20 Institute of Medicine. Coverage Matters: Insurance and Health Care. Washington, DC: National Academy Press; 2001. https://www.nap.edu/catalog/10188/coverage-matters-insurance-andhealth-care. Accessed December 6, 2021.
21 Garfield R, Orgera K, Damico A. The Uninsured and the ACA: A Primer - Key Facts About Health Insurance and the Uninsured Amidst Changes to the Affordable Care Act. Washington, DC: KFF; January 2019. https://www.kff.org/report-section/the-uninsured-and-the-aca-a-primer-key-facts-about-health-insurance-and-the-uninsured-amidst-changes-to-the-affordable-care-act-how-does-lack-of-insurance-affect-access-to-care/. Accessed December 1, 2021.

### Quality in Healthcare

1 Chassin MR, Galvin RW. The urgent need to improve health care quality. Institute of Medicine National Roundtable on Health Care Quality. JAMA. 1998;280(11):1000–5. https://pubmed.ncbi.nlm.nih.gov/9749483/. Accessed December 9, 2021.9749483
2 Cancino RS, Su Z, Mesa R, Tomlinson GE, Wang J. The Impact of COVID-19 on Cancer Screening: Challenges and Opportunities. JMIR Cancer 2020;6(2):e21697. 10.2196/21697. Accessed December 20, 2021.33027039
3 Institute of Medicine Committee on Quality of Health Care in America. Crossing the Quality Chasm: A New Health System for the 21st Century. Washington, DC: National Academies Press; 2001. https://www.nap.edu/catalog/10027/crossing-the-quality-chasm-a-new-health-system-for-the. Accessed December 9, 2021.
4 Institute of Medicine Committee on the National Quality Report on Health Care Delivery. Envisioning the National Health Care Quality Report. Hurtado MP, Swift EK, Corrigan JM, eds. Washington, DC: National Academies Press; 2001. http://nap.edu/10073. Accessed December 9, 2021.
5 Ha JF, Longnecker N. Doctor-patient communication: a review. Ochsner J. 2010 Mar 20;10(1):38–43. http://www.ochsnerjournal.org/content/10/1/38.abstract. Accessed December 9, 2021.21603354
6 Doyle C, Lennox L, Bell D. A systematic review of evidence on the links between patient experience and clinical safety and effectiveness. BMJ Open. 2013 Jan 1;3(1):e001570. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3549241/. Accessed December 9, 2021.
7 Rocco N, Scher K, Basberg B, Yalamanchi S, Baker-Genaw K. Patient-centered plan-of-care tool for improving clinical outcomes. Qual Manag Healthc. 2011 Apr–Jun;20(2):89–97. 10.1097/qmh.0b013e318213e728. Accessed December 9, 2021.
8 Gethin G, Probst S, Stryja J, Christiansen N, Price P. Evidence for person-centered care in chronic wound care: a systematic review and recommendations for practice. J Wound Care. 2020 Sep 1;29(Sup9b):S1–22. 10.12968/jowc.2020.29.Sup9b.S1. Accessed December 9, 2021.
9 Holmes-Rovner M, Montgomery JS, Rovner DR, Scherer LD, Whitfield J, Kahn VC, Merkle EC, Ubel PA, Fagerlin A. Informed decision making: assessment of the quality of physician communication about prostate cancer diagnosis and treatment. Med Decis Mak. 2015;35(8):999–1009. 10.1177/0272989x15597226. Accessed December 9, 2021.
10 Weiner SJ, Schwartz A, Sharma G, Binns-Calvey A, Ashley N, Kelly B, Dayal A, Patel S, Weaver FM, Harris I. Patient-centered decision making and health care outcomes: an observational study. Ann Intern Med. 2013;158(8):573–9. 10.7326/0003-4819-158-8-201304160-00001. Accessed December 9, 2021.23588745
11 Okunrintemi V, Spatz ES, Di Capua P, Salami JA, Valero-Elizondo J, Warraich H, Virani SS, Blaha MJ, Blankstein R, Butt AA, Borden WB, Dharmarajan K, Ting H, Krumholz HM, Nasir K. Patient-provider communication and health outcomes among individuals with atherosclerotic cardiovascular disease in the United States: Medical Expenditure Panel Survey 2010 to 2013. Circ Cardiovasc Qual Outcomes. 2017;10(4):1–8. 10.1161/CIRCOUTCOMES.117.003635. Accessed December 9, 2021.
12 Committee on Diagnostic Error in Health Care; Board on Health Care Services; Institute of Medicine; National Academies of Sciences, Engineering, and Medicine. Improving Diagnosis in Health Care. Balogh EP, Miller BT, Ball JR, eds. Washington, DC: National Academies Press; December 2015. http://nap.edu/21794. Accessed December 9, 2021.
13 Chou C. Time to start using evidence-based approaches to patient engagement. NEJM Catalyst. 2018;4(2). https://catalyst.nejm.org/doi/full/10.1056/CAT.18.0220 (summary). Accessed December 9, 2021.
14 Øvretveit J. Do Changes to Patient-Provider Relationships Improve Quality and Save Money? A Review of the Evidence About Value Improvements Made by Changing Communication, Collaboration, and Support for Self-Care. London, UK: The Health Foundation; June 2012. http://www.health.org.uk/publications/do-changes-to-patient-provider-relationships-improve-quality-and-save-money. Accessed December 9, 2021.
15 Bertakis KD, Azari R. Patient-centered care is associated with decreased health care utilization. J Am Board Fam Med. 2011;24(3):229–39. https://www.jabfm.org/content/24/3/229.long. Accessed December 9, 2021.21551394
16 Slota C, Davis SA, Blalock SJ, Carpenter DM, Muir KW, Robin AL, Sleath B. Patient-physician communication on medication cost during glaucoma visits. Optom Vis Sci. 2017;94(12):1095–1101. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5726412/. Accessed December 9, 2021.29194229
17 Posner KL, Severson J, Domino KB. The role of informed consent in patient complaints: reducing hidden health system costs and improving patient engagement through shared decision making. J Healthc Risk Manag. 2015;35(2):38–45. 10.1002/jhrm.21200. Accessed December 9, 2021.26418139
18 Pain Management Best Practices Inter-Agency Task Force Report: Updates, Gaps, Inconsistencies, and Recommendations. Washington, DC: U.S. Department of Health and Human Services; May 2019. https://www.hhs.gov/sites/default/files/pmtf-final-report-2019-05-23.pdf. Accessed December 9, 2021.
19 Cagle J, Bunting M. Patient reluctance to discuss pain: understanding stoicism, stigma, and other contributing factors. J Soc Work End Life Palliat Care. 2017;13(1):27–43. https://pubmed.ncbi.nlm.nih.gov/28271970/. Accessed December 9, 2021.28271970
20 Dobscha SK, Corson K, Perrin NA, Hanson GC, Leibowitz RQ, Doak MN, , Dickinson KC, Sullivan MD, Gerrity MS. Collaborative care for chronic pain in primary care: a cluster randomized trial. JAMA. 2009;301(12):1242–52. https://pubmed.ncbi.nlm.nih.gov/19318652/. Accessed December 9, 2021.19318652
21 The Joint Commission. Pain Assessment and Management Standards for Home Health Services. R3 Report. 2018; issue 22. https://www.jointcommission.org/-/media/tjc/documents/standards/r3-reports/r3_22_pain_standards_hc_12_21_18_final.pdf. Accessed December 9, 2021.
22 Wilder HM, Parker Oliver D, Demiris G, Washington K. Informal hospice caregiving: the toll on quality of life. J Soc Work End Life Palliat Care. 2008;4(4):312–32. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2749275/. Accessed December 9, 2021.19779584
23 Williams AL, McCorkle R. Cancer family caregivers during the palliative, hospice, and bereavement phases: a review of the descriptive psychosocial literature. Palliat Support Care. 2011;9(3):315–25. https://pubmed.ncbi.nlm.nih.gov/21838952/. Accessed December 9, 2021.21838952
24 Centers for Disease Control and Prevention, National Center for Health Statistics. Therapeutic Drug Use. https://www.cdc.gov/nchs/fastats/drug-use-therapeutic.htm. Accessed December 9, 2021.
25 Branch J, Hiner D, Jackson V. The Impact of Communication on Medication Errors. Web M&M Case Studies 2021 Mar 15. https://psnet.ahrq.gov/web-mm/impact-communication-medication-errors. Accessed December 9, 2021.
26 Schneider J, Kaplan SH, Greenfield S, Li W, Wilson IB. Better physician-patient relationships are associated with higher reported adherence to antiretroviral therapy in patients with HIV infection. J Gen Intern Med. 2004;19(11):1096–103. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1494791/. Accessed December 9, 2021.15566438
27 Schoenthaler A, Chaplin WF, Allegrante JP, Fernandez S, Diaz-Gloster M, Tobin JN, Ogedegbe G. Provider communication effects medication adherence in hypertensive African Americans. Patient Educ Couns. 2009;75(2):185–91. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2698021/. Accessed December 9, 2021.19013740
28 Kohn LT, Corrigan JM, Donaldson MS, eds.; Committee on Quality of Health Care in America, Institute of Medicine. To Err Is Human: Building a Safer Health System. Washington, DC: National Academies Press; 2000. http://www.nap.edu/catalog/9728.html. Accessed December 9, 2021.
29 Hall WJ, Chapman MV, Lee KM, Merino YM, Thomas TW, Payne BK, Eng E, Day SH, Coyne-Beasley T. Implicit racial/ethnic bias among health care professionals and its influence on health care outcomes: a systematic review. Am J Public Health. 2015;105(12):e60–e76. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4638275/. Accessed December 9, 2021.
30 Sunshine JE, Meo N, Kassebaum NJ, Collison ML, Mokdad AH, Naghavi M. Association of adverse effects of medical treatment with mortality in the United States: a secondary analysis of the Global Burden of Diseases, Injuries, and Risk Factors Study. JAMA Netw Open 2019;2(1):e187041. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6484545/. Accessed December 9, 2021.30657530
31 AHRQ National Scorecard on Hospital-Acquired Conditions: Final Results for 2014 Through 2017. https://www.ahrq.gov/sites/default/files/wysiwyg/professionals/quality-patient-safety/pfp/Updated-hacreportFInal2017data.pdf. Accessed December 9, 2021.
32 Bailey MK, Weiss AJ, Barrett ML, Jiang HJ. Characteristics of 30-day readmissions, 2010–2016. HCUP Statistical Brief #248. Rockville, MD: Agency for Healthcare Research and Quality; February 2019. https://hcup-us.ahrq.gov/reports/statbriefs/sb248-Hospital-Readmissions-2010-2016.jsp. Accessed December 9, 2021.
33 Genao L, Buhr GT. Urinary tract infections in older adults residing in long-term care facilities. Ann Longterm Care. 2012 Apr;20(4):33–8. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3573848/. Accessed December 9, 2021.23418402
34 Mervis JS, Phillips TJ. Pressure ulcers: pathophysiology, epidemiology, risk factors, and presentation. J Am Acad Dermatol. 2019 Oct;81(4):881–90. https://pubmed.ncbi.nlm.nih.gov/30664905/ Accessed December 9, 2021.30664905
35 Mervis JS, Phillips TJ. Pressure ulcers: prevention and management. J Am Acad Dermatol. 2019 Oct;81(4):893–902. https://pubmed.ncbi.nlm.nih.gov/30664906/. Accessed December 9, 2021.30664906
36 Gajic-Veljanoski O, Phua CW, Shah PS, Cheung AM. Effects of long-term low-molecular-weight heparin on fractures and bone density in non-pregnant adults: a systematic review with meta-analysis. J Gen Intern Med 2016 Aug;31(8):947–57. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4945546/. Accessed December 9, 2021.26895998
37 Ellenbecker CH, Samia L, Cushman MJ, Alster K. Patient Safety and Quality in Home Health Care. In: Hughes RG, ed. Patient Safety and Quality: An Evidence-Based Handbook for Nurses. Rockville, MD: Agency for Healthcare Research and Quality; April 2008. Chapter 13. https://www.ncbi.nlm.nih.gov/books/NBK2631/. Accessed December 9, 2021.
38 Bodenheimer T. Coordinating care—a perilous journey through the health care system. N Engl J Med. 2008 Mar 6;358(10):1064–71. 10.1056/NEJMhpr0706165. Accessed December 9, 2021.18322289
39 McDonald KM, Sundaram V, Bravata DM, Lewis R, Lin N, Kraft SA, McKinnon M, Paguntalan H, Owens DK. Closing the Quality Gap: A Critical Analysis of Quality Improvement Strategies—Volume 7: Care Coordination. Rockville, MD: Agency for Healthcare Research and Quality; 2007. https://www.ncbi.nlm.nih.gov/books/NBK44015/. Accessed December 9, 2021.
40 Powell-Davies G, Williams AM, Larsen K, Perkins D, Roland M, Harris MF. Coordinating primary health care: an analysis of the outcomes of a systematic review. Med J Aust. 2008 Apr 21;188(8 Suppl):S65–8. https://www.ncbi.nlm.nih.gov/pubmed/18429740. Accessed December 9, 2021.18429740
41 Agency for Healthcare Research and Quality. Care Coordination. Content last reviewed August 2018. https://www.ahrq.gov/ncepcr/care/coordination.html. Accessed December 9, 2021.
42 Report to the Congress: Medicare Payment Policy. Chapter 9: Home Health Care Services. Washington, DC: Medicare Payment Advisory Commission; March 2019. https://www.medpac.gov/wp-content/uploads/import_data/scrape_files/docs/default-source/reports/mar20_medpac_ch9_sec.pdf. Accessed December 9, 2021.
43 Jencks SF, Williams MV, Coleman EA. Rehospitalizations among patients in the Medicare Fee for Service Program. N Engl J Med. 2009;360:1418–28. 10.1056/NEJMsa0803563. Accessed December 9, 2021.19339721
44 Coleman EA, Parry C, Chalmers S, Min SJ. The care transitions intervention: results of a randomized controlled trial. Arch Intern Med 2006 Sep 25;166(17):18228. https://www.ncbi.nlm.nih.gov/pubmed/17000937. Accessed December 9, 2021.
45 Centers for Disease Control. Most Recent National Asthma Data. Last reviewed March 2021. https://www.cdc.gov/asthma/most_recent_national_asthma_data.htm. Accessed December 9, 2021.
46 Asthma and Allergy Foundation and National Pharmaceutical Council. Ethnic Disparities in the Burden and Treatment of Asthma. January 2005. https://www.aafa.org/media/1633/ethnic-disparities-burden-treatment-asthma-report.pdf. Accessed December 9, 2021.
47 Kullgren JT, McLaughlin CG, Mitra N, Armstrong K. Nonfinancial barriers and access to care for U.S. adults. Health Serv Res. 2012;47(1 Pt 2):462–85. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3393009/. Accessed December 9, 2021.22092449
48 Wilper AP, Woolhandler S, Lasser KE, McCormick D, Bor DH, Himmelstein DU. Health insurance and mortality in U.S. adults. Am J Public Health. 2009;99(12):2289–95. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2775760/. Accessed December 9, 2021.19762659
49 Institute of Medicine; Committee on the Consequences of Uninsurance. Care Without Coverage: Too Little, Too Late. Washington, DC: National Academies Press; 2002. https://www.nap.edu/catalog/10367/care-without-coverage-too-little-too-late. Accessed December 9, 2021.
50 Tolbert J, Orgera K, Damico A. Key Facts About the Uninsured Population. San Francisco: KFF; December 2018 (updated November 2020). https://www.kff.org/uninsured/fact-sheet/key-facts-about-the-uninsured-population/. Accessed December 9, 2021.
51 Khullar D, Chokshi DA. Health, Income, & Poverty: Where We Are & What Could Help. Health Affairs Health Policy Brief 2018 Oct 4. https://www.healthaffairs.org/do/10.1377/hpb20180817.901935/full/. Accessed December 9, 2021.
52 Centers for Disease Control and Prevention, National Center for Chronic Disease Prevention and Health Promotion. Chronic Diseases in America. Last reviewed January 2021. https://www.cdc.gov/chronicdisease/resources/infographic/chronic-diseases.htm. Accessed December 9, 2021.
53 Raghupathi W, Raghupathi V. An empirical study of chronic diseases in the United States: a visual analytics approach. Int J Environ Res Public Health. 2018 Mar;15(3):431. 10.3390/ijerph15030431. Accessed December 9, 2021.
54 Heron M. Deaths: Leading Causes for 2019. Natl Vital Stat Rep. 2021 Jul;70(9):1–114. https://www.cdc.gov/nchs/data/nvsr/nvsr70/nvsr70-09-508.pdf. Accessed December 9, 2021.
55 Kenealy T, Arroll B. Antibiotics for the common cold and acute purulent rhinitis. Cochrane Database Syst Rev. 2013 Jun 4;(6):CD000247. https://www.ncbi.nlm.nih.gov/pubmed/23733381. Accessed December 9, 2021.23733381
56 Vogel JD, Eskicioglu C, Weiser MR, Feingold DL, Steele SR. The American Society of Colon and Rectal Surgeons Clinical Practice Guidelines for the Treatment of Colon Cancer. Dis Colon Rectum. 2017 Oct;60(10):999–1017. 10.1097/DCR.0000000000000926. Accessed December 9, 2021.28891842
57 Chang GJ, Rodriguez-Bigas MA, Skibber JM, Moyer VA. Lymph node evaluation and survival after curative resection of colon cancer: systematic review. J Natl Cancer Inst. 2007 Mar 21;99(6):433–41. 10.1093/jnci/djk092. Accessed December 9, 2021.17374833
58 Wong SL. Lymph node counts and survival rates after resection for colon and rectal cancer. Gastrointest Cancer Res. 2009;3(2 Suppl):S33–S35. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2684729/. Accessed December 9, 2021.19461921
59 Centers for Disease Control and Prevention. HIV Surveillance Report, 2018 (Updated); vol. 31. http://www.cdc.gov/hiv/library/reports/hiv-surveillance.html. Published May 2020. Accessed December 9, 2021.
60 Marcus JL, Leyden WA, Alexeeff SE, Anderson AN, Hechter RC, Hu H, Lam JO, Towner WJ, Yuan Q, Horberg MA, Silverberg MJ. Comparison of overall and comorbidity-free life expectancy between insured adults with and without HIV infection, 2000–2016. JAMA Netw Open. 2020 Jun 1;3(6):e207954. 10.1001/jamanetworkopen.2020.7954. Accessed December 9, 2021.32539152
61 Centers for Disease Control and Prevention. HIV: Basic Statistics. Last reviewed October 2021. https://www.cdc.gov/hiv/basics/statistics.html. Accessed December 9, 2021.
62 Office of the Secretary, Department of Health and Human Services. Determination That a Public Health Emergency Exists. Issued October 26, 2017. https://www.hhs.gov/sites/default/files/opioid%20PHE%20Declaration-no-sig.pdf. Accessed December 9, 2021.
63 Centers for Disease Control and Prevention. Drug Overdose Deaths. Last reviewed March 2021. https://www.cdc.gov/drugoverdose/deaths/index.html. Accessed December 9, 2021.
64 Florence C, Luo F, Rice K. The economic burden of opioid use disorder and fatal opioid overdose in the United States, 2017. Drug Alcohol Depend. 2021 Jan 1;218:108350. 10.1016/j.drugalcdep.2020.108350. Accessed December 9, 2021.33121867
65 Luo F, Li M, Florence C. State-level economic costs of opioid use disorder and fatal opioid overdose — United States, 2017. MMWR Morb Mortal Wkly Rep 2021;70:541–6. https://www.cdc.gov/mmwr/volumes/70/wr/mm7015a1.htm?s_cid=mm7015a1_w. Accessed December 9, 2021.33857070
66 National Center for Health Statistics. Opioid Basics: Understanding the Epidemic. https://www.cdc.gov/opioids/basics/epidemic.html. Accessed December 9, 2021.
67 Hedegaard H, Miniño AM, Warner M. Drug Overdose Deaths in the United States, 1999–2019. NCHS Data Brief, No. 394. Hyattsville, MD: National Center for Health Statistics; 2020. https://www.cdc.gov/nchs/products/databriefs/db394.htm. Accessed December 9, 2021.
68 Wilson N, Kariisa M, Seth P, Smith H 4th, Davis NL. Drug and Opioid-Involved Overdose Deaths - United States, 2017–2018. MMWR Morb Mortal Wkly Rep. 2020 Mar 20;69(11):290–7. https://www.cdc.gov/mmwr/volumes/69/wr/mm6911a4.htm?s_cid=mm6911a4_w. Accessed December 9, 2021.32191688
69 Ahmad FB, Rossen LM, Sutton P. Provisional drug overdose death counts. Hyattsville, MD: National Center for Health Statistics; 2021. https://www.cdc.gov/nchs/nvss/vsrr/drug-overdose-data.htm. Accessed December 9, 2021.
70 Centers for Disease Control and Prevention. Facts About Suicide. Last reviewed August 2021. https://www.cdc.gov/suicide/facts/index.html. Accessed December 9, 2021.
71 Centers for Disease Control and Prevention, National Center for Injury Prevention and Control. Web-based Injury Statistics Query and Reporting System (https://www.cdc.gov/injury/wisqars) (WISQARS) Cost of Injury Data. 2020. https://www.cdc.gov/injury/wisqars/cost/. Accessed December 9, 2021.
72 Stone DM, Jones CM, Mack KA. Changes in suicide rates - United States, 2018–2019. MMWR Morb Mortal Wkly Rep. 2021 Feb 26;70(8):261–8. https://www.cdc.gov/mmwr/volumes/70/wr/mm7008a1.htm?s_cid=mm7008a1_w. Accessed December 9, 2021.33630824
73 D’Anci KE, Uhl S. Treatments for the prevention and management of suicide. Ann Intern Med. 2020 Jan 21;172(2):168. 10.7326/L19-0707. Accessed December 9, 2021.31958831
74 Office of the Surgeon General. National Action Alliance for Suicide Prevention. 2012 National Strategy for Suicide Prevention: Goals and Objectives for Action: A Report of the U.S. Surgeon General and of the National Action Alliance for Suicide Prevention. Washington, DC: U.S. Department of Health and Human Services; September 2012. https://www.hhs.gov/surgeongeneral/reports-and-publications/suicide-prevention/index.html. Accessed December 9, 2021.
75 Department of Veterans Affairs and Department of Defense. Assessment and Management of Patients at Risk for Suicide. (2019). https://www.healthquality.va.gov/guidelines/MH/srb/. Accessed December 9, 2021.
76 Ostchega Y, Fryar CD, Nwankwo T, Nguyen DT. Hypertension prevalence among adults aged 18 and over: United States, 2017–2018. NCHS Data Brief, No. 364. Hyattsville, MD: National Center for Health Statistics; 2020. https://www.cdc.gov/nchs/data/databriefs/db364-h.pdf. Accessed December 9, 2021.
77 U.S. Department of Health and Human Services. The Surgeon General’s Call to Action to Control Hypertension. Washington, DC: U.S. Department of Health and Human Services, Office of the Surgeon General; 2020. https://www.hhs.gov/sites/default/files/call-to-action-to-control-hypertension.pdf. Accessed December 9, 2021.
78 Nordio M, Limido A, Maggiore U, Nichelatti M, Postorino M, Quintaliani G; Italian Dialysis and Transplantation Registry. Survival in patients treated by long-term dialysis compared with the general population. Am J Kidney Dis. 2012 Jun;59(6):819–28. 10.1053/j.ajkd.2011.12.023. Accessed December 9, 2021.22361043
79 Tonelli M, Wiebe N, Knoll G, Bello A, Browne S, Jadhav D, Klarenbach S, Gill J. Systematic review: kidney transplantation compared with dialysis in clinically relevant outcomes. Am J Transplant. 2011 Oct;11(10):2093–109. 10.1111/j.1600-6143.2011.03686.x. Accessed December 9, 2021.21883901
80 United States Renal Data System. 2020 USRDS Annual Data Report: Chapter 1: Incidence, Prevalence, Patient Characteristics, and Treatment Modalities. Bethesda, MD: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases; 2020. https://adr.usrds.org/2020/end-stage-renal-disease/1-incidence-prevalence-patient-characteristics-and-treatment-modalities. Accessed December 9, 2021.
81 Kidney Disease Improving Global Outcomes Anemia Work Group. KDIGO Clinical Practice Guideline for Anemia in Chronic Kidney Disease. Kidney Int Suppl. 2012;2(4):279–335. https://kdigo.org/wp-content/uploads/2016/10/KDIGO-2012-Anemia-Guideline-English.pdf. Accessed December 8, 2021.]
82 Centers for Disease Control and Prevention. National Diabetes Statistics Report, 2020. Atlanta, GA: Centers for Disease Control and Prevention, U.S. Department of Health and Human Services; 2020. https://www.cdc.gov/diabetes/library/features/diabetes-stat-report.html. Accessed December 9, 2021.
83 Vijan S. Type 2 diabetes. Ann Intern Med. 2019 Nov 5;171(9):ITC65–ITC80. 10.7326/AITC201911050. Erratum in: Ann Intern Med. 2020 May 19;172(10):708. Erratum in: Ann Intern Med. 2021 May;174(5):735. Accessed December 9, 2021.31683294
84 Diabetes Prevention Program (DPP) Research Group. The Diabetes Prevention Program (DPP): description of lifestyle intervention. Diabetes Care. 2002 Dec;25(12):2165–71. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1282458/. Accessed December 9, 2021.12453955
85 Diabetes Prevention Program Research Group, Knowler WC, Fowler SE, Hamman RF, Christophi CA, Hoffman HJ, Brenneman AT, Brown-Friday JO, Goldberg R, Venditti E, Nathan DM. 10-year follow-up of diabetes incidence and weight loss in the Diabetes Prevention Program Outcomes Study. Lancet. 2009 Nov 14;374(9702):1677–86. Erratum in: Lancet. 2009 Dec 19;374(9707):2054. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3135022/. Accessed December 9, 2021.19878986
86 Diabetes Prevention Program Research Group. Long-term effects of lifestyle intervention or metformin on diabetes development and microvascular complications over 15-year follow-up: the Diabetes Prevention Program Outcomes Study. Lancet Diabetes Endocrinol. 2015 Nov;3(11):866–75. 10.1016/S2213-8587(15)00291-0. Accessed December 9, 2021.26377054
87 Centers for Disease Control and Prevention. HIV Surveillance Report, 2019; vol. 32. http://www.cdc.gov/hiv/library/reports/hiv-surveillance.html. Published May 2021. Accessed December 9, 2021.
88 Centers for Disease Control and Prevention. Arthritis-Related Statistics. https://www.cdc.gov/arthritis/data_statistics/arthritis-related-stats.htm. Accessed December 9, 2021.
89 Centers for Disease Control and Prevention. Pregnancy Mortality Surveillance System. Last reviewed November 2020. https://www.cdc.gov/reproductivehealth/maternalinfanthealth/pregnancy-mortality-surveillance-system.htm. Accessed December 9, 2021.
90 Building U.S. Capacity To Review and Prevent Maternal Deaths. Report From Nine Maternal Mortality Review Committees. 2018. https://www.cdcfoundation.org/building-us-capacity-review-and-prevent-maternal-deaths. Accessed December 9, 2021.
91 Geller SE, Rosenberg D, Cox SM, Brown ML, Simonson L, Driscoll CA, Kilpatrick SJ. The continuum of maternal morbidity and mortality: factors associated with severity. Am J Obstetr Gynecol. 2004;191(3):939–44. https://www.ncbi.nlm.nih.gov/pubmed/15467568. Accessed December 9, 2021.
92 Howell EA, Zeitlin J. Quality of care and disparities in obstetrics. Obstetr Gynecol Clin. 2017;44(1):13–25. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5300700/. Accessed December 9, 2021.
93 Office of the Surgeon General. The Surgeon General’s Call to Action To Improve Maternal Health. Washington, DC: U.S. Department of Health and Human Services; 2020. https://www.hhs.gov/sites/default/files/call-to-action-maternal-health.pdf. Accessed December 9, 2021.
94 Zhou F, Santoli J, Messonnier ML, Yusuf HR, Shefer A, Chu SY, Rodewald L, Harpaz R. Economic evaluation of the 7-vaccine routine childhood immunization schedule in the United States, 2001. Arch Pediatr Adolesc Med. 2005 Dec;159(12):1136–44. https://www.ncbi.nlm.nih.gov/pubmed/16330737. Accessed December 9, 2021.16330737
95 Centers for Disease Control and Prevention. Seasonal Influenza Vaccination Information for Health Care Workers. Influenza Facts. Last reviewed September 2021. https://www.cdc.gov/flu/professionals/vaccination/index.htm. Accessed December 9, 2021.
96 Luo H, Lin M, Castle N. Physical restraint use and falls in nursing homes: a comparison between residents with and without dementia. Am J Alzheimer Dis Other Demen. 2011 Feb;26(1) 44–50. https://pubmed.ncbi.nlm.nih.gov/21282277/. Accessed December 9, 2021.
97 Kamiya H, Cho BH, Messonnier ML, Clark TA, Clark TA, Liang JL. Impact and cost-effectiveness of a second tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) vaccine dose to prevent pertussis in the United States. Vaccine. 2016 Apr 4;34(15):1832–8. https://pubmed.ncbi.nlm.nih.gov/26899377/. Accessed December 9, 2021.26899377
98 Nace DA, Archbald-Pannone LR, Ashraf MS, Drinka PJ, Frentzel E, Gaur S, Mahajan D, Mehr DR, Mercer WC, Sloane PD, Jump RL; Infection Advisory Committee for AMDA—The Society of Post-Acute and Long-Term Care Medicine. Pneumococcal vaccination guidance for post-acute and long-term care settings: recommendations from AMDA’s Infection Advisory Committee. J Am Med Dir Assoc. 2017;18(2):99–104. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5308482/. Accessed December 9, 2021.28126142
99 Centers for Disease Control and Prevention. Defining Childhood Weight Status. Last reviewed June 2021. https://www.cdc.gov/obesity/childhood/defining.html. Accessed December 9, 2021.
100 Abbasi A, Juszczyk D, van Jaarsveld CHM, Gulliford MC. Body mass index and incident type 1 and type 2 diabetes in children and young adults: a retrospective cohort study. J Endocr Soc. 2017 Apr 25;1(5):524–37. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5686575/. Accessed December 9, 2021.29264507
101 Narang I, Mathew JL. Childhood obesity and obstructive sleep apnea. J Nutr Metab. 2012;2012:134202. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3432382/. Accessed December 9, 2021.22957216
102 Falkner B, Gidding SS, Ramirez-Garnica G, Wiltrout SA, West D, Rappaport EB. The relationship of body mass index and blood pressure in primary care pediatric patients. J Pediatr. 2006 Feb;148(2):195–200. https://pubmed.ncbi.nlm.nih.gov/16492428/. Accessed December 9, 2021.16492428
103 Centers for Disease Control and Prevention. Childhood Obesity Causes & Consequences. Last reviewed March 2021. https://www.cdc.gov/obesity/childhood/causes.html. Accessed December 9, 2021.

### Disparities in Healthcare

1 Office of Disease Prevention and Health Promotion, U.S. Department of Health and Human Services. Healthy People 2020. https://www.healthypeople.gov/. Accessed December 3, 2021.
2 Orgera K, Artiga S. Issue Brief. Disparities in health and health care: 5 key questions and answers. Washington, DC: Henry J. Kaiser Family Foundation; August 2018. https://www.kff.org/disparities-policy/issue-brief/disparities-in-health-and-health-care-five-key-questions-and-answers/. Accessed December 3, 2021.
3 Institute of Medicine. Unequal Treatment: Confronting Racial and Ethnic Disparities in Health Care. Washington, DC: National Academies Press; 2003. 10.17226/12875. Accessed December 3, 2021.
4 Fichtenberg CM, Alley DE, Mistry KB. Improving social needs intervention research: key questions for advancing the field. Am J Prev Med 2019 Dec;57(6 Suppl 1):S47–S54. https://pubmed.ncbi.nlm.nih.gov/31753279/. Accessed December 3, 2021.31753279
5 Marmot M. The Status Syndrome: How Social Standing Affects Our Health and Longevity. New York, NY: Henry Holt; 2004.
6 U.S. Department of Health and Human Services. Report of the Secretary’s Task Force on Black and Minority Health. Washington, DC: Government Printing Office; 1985. https://minorityhealth.hhs.gov/heckler30/. Accessed December 3, 2021.
7 Centers for Disease Control and Prevention. CDC Health Disparities and Inequalities Report — United States, 2013. MMWR 2013;62(Suppl 3):1–187. https://www.cdc.gov/minorityhealth/CHDIReport.html. Accessed December 3, 2021.
8 Office of Disease Prevention and Health Promotion, U.S. Department of Health and Human Services. Healthy People Foundation Health Measures. Disparities. https://www.healthypeople.gov/2020/about/foundation-health-measures/Disparities. Accessed December 3, 2021.
9 New Study Identifies Racial and Ethnic Disparities in Severe Flu Outcomes. Atlanta, GA: Centers for Disease Control and Prevention; August 24, 2021. https://www.cdc.gov/flu/spotlights/2020-2021/racial-ethnic-disparities-severe-flu-outcomes.htm. Accessed December 1, 2021.
10 Mulpuru S, Li L, Ye L, Hatchette T, Andrew MK, Ambrose A, Boivin G, Bowie W, Chit A, Dos Santos G, ElSherif M, Green K, Haguinet F, Halperin SA, Ibarguchi B, Johnstone J, Katz K, Langley JM, LeBlanc J, Loeb M, MacKinnon-Cameron D, McCarthy A, McElhaney JE, McGeer A, Powis J, Richardson D, Semret M, Shinde V, Smyth D, Trottier S, Valiquette L, Webster D, McNeil SA; Serious Outcomes Surveillance (SOS) Network of the Canadian Immunization Research Network (CIRN). Effectiveness of influenza vaccination on hospitalizations and risk factors for severe outcomes in hospitalized patients with COPD. Chest. 2019 Jan;155(1):69–78. https://journal.chestnet.org/article/S0012-3692(18)32725-9/fulltext. Accessed December 1, 2021.30616737
11 Colorectal Cancer, United States—2007–2016. U.S. Cancer Statistics Data Briefs, No. 16. Atlanta: Centers for Disease Control and Prevention; March 2020. https://www.cdc.gov/cancer/uscs/about/data-briefs/no16-colorectal-cancer-2007-2016.htm. Accessed December 1, 2021.
12 Colorectal Cancer: Screening. U.S. Preventive Services Task Force; May 18, 2021. https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/colorectal-cancer-screening. Accessed December 1, 2021.
13 American Cancer Society Updates Colorectal Cancer Screening Guideline. May 30, 2018. http://pressroom.cancer.org/releases?item=770. Accessed December 1, 2021.
14 2019 National HIV Surveillance System Reports. Atlanta: Centers for Disease Control and Prevention; May 27, 2021. https://www.cdc.gov/nchhstp/newsroom/2021/2019-national-hiv-surveillance-system-reports.html. Accessed December 1, 2021.
15 HIV and American Indian/Alaska Native People. https://www.cdc.gov/hiv/group/racialethnic/aian/index.html. Accessed December 1, 2021.
16 National Institute of Diabetes and Digestive and Kidney Diseases. Diabetic Kidney Disease. https://www.niddk.nih.gov/health-information/diabetes/overview/preventing-problems/diabetic-kidney-disease. Accessed December 1, 2021.
17 Burrows NR, Zhang Y, Hora I, Pavkov ME, Sheff K, Imperatore G, Bullock AK, Albright AL. Sustained lower incidence of diabetes-related end-stage kidney disease among American Indians and Alaska Natives, Blacks, and Hispanics in the U.S., 2000–2016. Diabetes Care 2020 Sep;43(9):2090–7. https://pubmed.ncbi.nlm.nih.gov/32616609/. Accessed December 1, 2021.32616609
18 Ngo-Metzger Q, Legedza AT, Phillips RS. Asian Americans’ reports of their health care experiences. Results of a national survey. J Gen Intern Med 2004 Feb;19(2):111–9. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1492145/. Accessed December 3, 2020.15009790
19 Ponce NA, Hays RD, Cunningham WE. Linguistic disparities in health care access and health status among older adults. J Gen Intern Med 2006 Jul;21(7):786–91. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1924691/. Accessed December 3, 2020.16808783
20 Zong J, Batalova J. Language diversity and English proficiency in the United States. Migration Information Source 2016 Nov 11. https://www.migrationpolicy.org/article/language-diversity-and-english-proficiency-united-states-2015. Accessed August 20, 2021.
21 Institute of Medicine Subcommittee on Standardized Collection of Race/Ethnicity Data for Healthcare Quality Improvement Board on Health Care Services; Ulmer C, McFadden B, Nerenz DR, eds. Race, Ethnicity, and Language Data: Standardization for Health Care Quality Improvement. Washington, DC: National Academies Press; 2009. https://www.ahrq.gov/research/findings/final-reports/iomracereport/index.html. Accessed December 15, 2021.
22 Instutute of Medicine Subcommittee on Standardized Collection of Race/Ethnicity Data for Healthcare Quality Improvement Board on Health Care Services; Ulmer C, McFadden B, Nerenz DR, eds. Race, Ethnicity, and Language Data: Standardization for Health Care Quality Improvement. 4. Defining language need and categories for collection. https://www.ahrq.gov/research/findings/final-reports/iomracereport/reldata4.html. Accessed December 15, 2021.
23 Limited English Proficiency: A Federal Interagency Website. Commonly Asked Questions. https://www.lep.gov/commonly-asked-questions. Accessed December 20, 2021.
24 TeamSTEPPS^®^ Enhancing Safety for Patients With Limited English Proficiency Module. Rockville, MD: Agency for Healthcare Research and Quality; 2012. https://www.ahrq.gov/teamstepps/lep/index.html. Accessed December 20, 2021.
25 Agency for Healthcare Research and Quality. Examples of Home Health Care Quality Measures for Consumers. Last updated November 2018. https://www.ahrq.gov/talkingquality/measures/setting/long-term-care/home-health/examples.html. Accessed December 20, 2021.
26 Hoover MA, Green HD Jr, Bogart LM, et al. Do people know I’m poz?: factors associated with knowledge of serostatus among HIV-positive African Americans’ social network members. AIDS Behav 2016 Jan;20(1):137–46. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4618789/. Accessed December 20, 2021.25903505
27 Wolitski R, Fecik N. Knowledge of HIV status is on the rise. Washington, DC: U.S. Department of Health and Human Services; August 2017. https://www.hiv.gov/blog/knowledge-hiv-status-rise. Accessed December 20, 2021.
28 Centers for Disease Control and Prevention. HIV and African American People. https://www.cdc.gov/hiv/group/racialethnic/africanamericans/index.html. Accessed December 1, 2021.
29 Office of Minority Health, U.S. Department of Health and Human Services. HIV/AIDS and African Americans. https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=4&lvlid=21. Accessed December 1, 2021.
30 Azar A. Ending the HIV Epidemic: A Plan for America. Washington, DC: U.S. Department of Health and Human Services; February 2019. https://www.hiv.gov/blog/ending-hiv-epidemic-plan-america. Accessed December 1, 2021.
31 Centers for Disease Control and Prevention. WISQARS Leading Causes of Death Reports, 1981 – 2019. https://wisqars.cdc.gov/fatal-leading. Accessed December 1, 2021.
32 U.S. Department of Health and Human Services. HIV Care and Treatment Activities. Last updated May 2017. https://www.hiv.gov/federal-response/federal-activities-agencies/hiv-care-and-treatment-activities. Accessed December 1, 2021.
33 Health Resources and Services Administration. Ryan White HIV/AIDS Program by the Numbers. https://hab.hrsa.gov/sites/default/files/hab/Publications/infographics/generalaudiencegraphic.pdf. Accessed December 1, 2021.
34 High-Impact Prevention At-a-Glance. https://www.cdc.gov/nchhstp/highimpactprevention/docs/HIP-at-a-glance-P.pdf. Accessed December 1, 2021.
35 Muntner P, Carey RM, Gidding S, Jones DW, Taler SJ, Wright JT, Whelton PK. Potential U.S. population impact of the 2017 American College of Cardiology/American Heart Association High Blood Pressure Guideline. Circulation. 2018;137:109–18. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5873602/. Accessed December 20, 2021.29133599
36 Whelton PK, Carey RM, Aronow WS, Casey DE, Collins KJ, Dennison Himmelfarb C, DePalma SM, Gidding S, Jamerson KA, Jones DW, MacLaughlin EJ, Muntner P, Ovbiagele B, Smith SC, Spencer CC, Stafford RS, Taler SJ, Thomas RJ, Williams KA, Williamson JD, Wright JT. ACC/AHA/AAPA/ABC/ACPM/AGS/APhA/ASH/ASPC/NMA/PCNA Guideline for the Prevention, Detection, Evaluation, and Management of High Blood Pressure in Adults: A Report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. Hypertension. 2018;71:1269–24. 10.1161/HYP.0000000000000065. Accessed December 20, 2021.29133354
37 Thomas SJ, Booth JN III, Dai C, Li X, Allen N, Calhoun D, Carson AP, Gidding S, Lewis CE, Shikany JM, Shimbo D, Sidney S, Muntner P. Cumulative incidence of hypertension by 55 years of age in Blacks and Whites: The CARDIA Study. J Am Heart Assoc. 2018;7:e007988. 10.1161/JAHA.117.007988. Accessed December 1, 2021.29997132
38 U.S. Department of Health and Human Services, Office of Minority Health. Diabetes and African Americans. Last modified December 19, 2019. https://www.minorityhealth.hhs.gov/omh/browse.aspx?lvl=4&lvlid=18. Accessed December 1, 2021.
39 Office of Minority Health. Profile: Hispanic/Latino Americans. Last modified October 2021. https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=3&lvlid=64. Accessed December 3, 2021.
40 HIV.gov. U.S. Statistics. https://www.hiv.gov/hiv-basics/overview/data-and-trends/statistics. Accessed December 3, 2021.
41 Grohskopf LA, Sokolow LZ, Broder KR, Walter EB, Fry AM, Jernigan DB. Prevention and control of seasonal influenza with vaccines: recommendations of the Advisory Committee on Immunization Practices-United States, 2018–19 influenza season. MMWR Recomm Rep 2018 Aug 24;67(3):1–20. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6107316/. Accessed December 3, 2021.
42 Office of Disease Prevention and Health Promotion. HealthyPeople.gov. Access to Primary Care. https://www.healthypeople.gov/2020/topics-objectives/topic/social-determinants-health/interventions-resources/access-to-primary. Accessed December 3, 2021.
43 National Institute of Diabetes and Digestive and Kidney Diseases. Diabetic Kidney Disease. https://www.niddk.nih.gov/health-information/diabetes/overview/preventing-problems/diabetic-kidney-disease. Accessed December 3, 2021.
44 HIV.gov. What Is the Impact of HIV on Racial and Ethnic Minorities in the U.S.? https://www.hiv.gov/hiv-basics/overview/data-and-trends/impact-on-racial-and-ethnic-minorities. Accessed December 3, 2021.
45 Medicare.gov. What’s Home Health Care? https://www.medicare.gov/what-medicare-covers/whats-home-health-care. Accessed December 3, 2021.
46 Smith JM, Lin H, Thomas-Hawkins C, Tsui J, Jarrín OF. Timing of home health care initiation and 30-day rehospitalizations among Medicare beneficiaries with diabetes by race and ethnicity. Int J Environ Res Public Health. 2021;18(11): 5623. 10.3390/ijerph18115623. Accessed December 3, 2021.34070282
47 Centers for Disease Control and Prevention. Vital Signs: HIV Testing. Last reviewed November 2017. https://www.cdc.gov/vitalsigns/hiv-testing/. Accessed December 3, 2021.
48 Centers for Disease Control and Prevention. Factors That Increase HIV Risk. Last reviewed April 2021. https://www.cdc.gov/hiv/basics/hiv-transmission/increase-hiv-risk.html. Accessed December 3, 2021.
49 Khullar D, Chokshi DA. Health Policy Brief. Health, Income, & Poverty: Where We Are & What Could Help. Health Affairs 2018 Oct 4. https://www.healthaffairs.org/do/10.1377/hpb20180817.901935/full/. Accessed December 3, 2021.
50 Larrimore J. Does a higher income have positive health effects? Using the earned income tax credit to explore the income-health gradient. Milbank Q 2011 Dec;89(4):694–727. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3250638/. Accessed December 3, 2021.22188352
51 Shaw KM, Theis KA, Self-Brown S, Roblin DW, Barker L. Chronic disease disparities by county economic status and metropolitan classification, Behavioral Risk Factor Surveillance System, 2013. Prev Chronic Dis 2016 Sep 1;13:E119. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5008860/. Accessed December 3, 2021.27584875
52 Bor J, Cohen GH, Galea S. Population health in an era of rising income inequality: USA, 1980–2015. Lancet 2017 Apr 8;389(10077):1475–90. 10.1016/S0140-6736(17)30571-8. Accessed December 3, 2021.28402829
53 Office of the Assistant Secretary for Planning and Evaluation, U.S. Department of Health and Human Services. U.S. Federal Poverty Guidelines Used To Determine Financial Eligibility for Certain Federal Programs. https://aspe.hhs.gov/poverty-guidelines. Accessed December 3, 2021.
54 Centers for Disease Control and Prevention. Children’s Oral Health. Last reviewed April 2021. https://www.cdc.gov/oralhealth/basics/childrens-oral-health/index.html. Accessed December 3, 2021.
55 Henry J. Kaiser Family Foundation. Key Facts About the Uninsured Population. December 2018. https://www.kff.org/uninsured/fact-sheet/key-facts-about-the-uninsured-population/. Accessed December 3, 2021.
56 Centers for Disease Control and Prevention. Measles (Rubeola). https://www.cdc.gov/measles/hcp/index.html. Accessed December 3, 2021.
57 Centers for Disease Control and Prevention. Complications of Mumps. https://www.cdc.gov/mumps/about/complications.html. Accessed December 3, 2021.
58 Centers for Disease Control and Prevention. Rubella in the U.S. https://www.cdc.gov/rubella/about/in-the-us.html. Accessed December 3, 2021.
59 Centers for Disease Control and Prevention. National Diabetes Statistics Report 2020: Estimates of Diabetes and Its Burden in the United States. https://www.cdc.gov/diabetes/pdfs/data/statistics/national-diabetes-statistics-report.pdf. Accessed December 3, 2021.
60 Organisation for Economic Cooperation and Development. Health at a Glance 2019: OECD Indicators. Diabetes Care. Figure 6.12. Diabetes hospital admission in adults, 2012 and 2017 (or nearest year). https://www.oecd-ilibrary.org/sites/402e2e10-en/index.html?itemId=/content/component/402e2e10-en. Accessed December 3, 2021.
61 Centers for Disease Control and Prevention. Meningococcal Disease. Last reviewed January 2020. https://www.cdc.gov/meningococcal/. Accessed December 3, 2021.
62 Centers for Disease Control and Prevention. Vaccines and Preventable Diseases. Meningococcal Vaccination. Last reviewed October 2021. https://www.cdc.gov/vaccines/vpd/mening/index.html. Accessed December 3, 2021.
63 Scholl L, Seth P, Kariisa M, Wilson N, Baldwin G. Drug and opioid-involved overdose deaths - United States, 2013–2017. MMWR Morb Mortal Wkly Rep. 2018 Jan 4;67(5152):1419–27. 10.15585/mmwr.mm675152e1. Accessed December 3, 2021.30605448
64 U.S. Department of Health and Human Services. What Is the U.S. Opioid Epidemic? Last reviewed October 2021. https://www.hhs.gov/opioids/about-the-epidemic/index.html. Accessed December 3, 2021.
65 Center for Behavioral Health Statistics and Quality. Results From the 2020 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration; 2021. https://www.samhsa.gov/data/report/2020-nsduh-detailed-tables. Accessed December 3, 2021.
66 Sommers BD, Gawande AA, Baicker K. Health insurance coverage and health - what the recent evidence tells us. N Engl J Med. 2017 Aug 10;377(6):586–93. 10.1056/NEJMsb1706645. Accessed December 2, 2021.28636831
67 Allen H, Baicker K, Finkelstein A, Taubman S, Wright BJ; Oregon Health Study Group. What the Oregon Health Study can tell us about expanding Medicaid. Health Aff (Millwood). 2010 Aug;29(8):1498–506. 10.1377/hlthaff.2010.0191. Accessed December 2, 2021.20679654
68 Institute of Medicine Committee on the Consequences of Uninsurance. 4. The Difference Coverage Could Make to the Health of Uninsured Adults. In: Care Without Coverage: Too Little, Too Late. Washington, DC: National Academies Press; 2002. https://www.ncbi.nlm.nih.gov/books/NBK220633/. Accessed December 2, 2021.
69 Kaiser Family Foundation. State Health Facts. Medicaid Expansion Enrollment (Dec 2020). https://www.kff.org/health-reform/state-indicator/medicaid-expansion-enrollment/?currentTimeframe=0&sortModel=%7B%22colId%22:%22Location%22,%22sort%22:%22asc%22%7D. Accessed December 2, 2021.
70 Centers for Medicare & Medicaid Services. CMS Fast Facts. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/CMS-Fast-Facts. Accessed December 2, 2021.
71 Woolhandler S, Himmelstein DU. The relationship of health insurance and mortality: is lack of insurance deadly? Ann Intern Med. 2017 Sep 19;167(6):424–31. 10.7326/M17-1403. Accessed December 2, 2021.28655034
72 Office of Disease Prevention and Health Promotion. Access to Health Services. Last updated October 2021. https://www.healthypeople.gov/2020/leading-health-indicators/2020-lhi-topics/Access-to-Health-Services. Accessed December 2, 2021.
73 de Boniface J, Szulkin R, Johansson ALV. Survival after breast conservation vs mastectomy adjusted for comorbidity and socioeconomic status: a Swedish national 6-year follow-up of 48 986 women. JAMA Surg. 2021 Jul 1;156(7):628–37. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC8100916/. Accessed December 2, 2021.33950173
74 Early Breast Cancer Trialists’ Collaborative Group (EBCTCG), Darby S, McGale P, Correa C, Taylor C, Arriagada R, Clarke M, Cutter D, Davies C, Ewertz M, Godwin J, Gray R, Pierce L, Whelan T, Wang Y, Peto R. Effect of radiotherapy after breast-conserving surgery on 10-year recurrence and 15-year breast cancer death: meta-analysis of individual patient data for 10,801 women in 17 randomised trials. Lancet. 2011 Nov 12;378(9804):1707–16. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3254252/. Accessed December 2, 2021.22019144
75 Committee on Diagnostic Error in Health Care; Board on Health Care Services; Institute of Medicine; The National Academies of Sciences, Engineering, and Medicine. Improving Diagnosis in Health Care. Balogh EP, Miller BT, Ball JR, eds. Washington, DC: National Academies Press; December 2015. https://www.ncbi.nlm.nih.gov/books/NBK338596/. Accessed December 2, 2021.
76 Weiner SJ, Schwartz A, Sharma G, Binns-Calvey A, Ashley N, Kelly B, Dayal A, Patel S, Weaver FM, Harris I. Patient-centered decision making and health care outcomes: an observational study. Ann Intern Med. 2013 Apr 16;158(8):573–9. 10.7326/0003-4819-158-8-201304160-00001. Accessed December 2, 2021.23588745
77 Cohen RA, Cha AE, Terlizzi EP, Martinez ME. Demographic Variation in Health Insurance Coverage: United States, 2019. National Health Statistics Reports, No. 159. Hyattsville, MD: National Center for Health Statistics; 2021. 10.15620/cdc:106462
78 Hagan JF, Shaw JS, Duncan PM, eds. Bright Futures: Guidelines for Health Supervision of Infants, Children, and Adolescents. 4th ed. Elk Grove Village, IL: American Academy of Pediatrics; 2017.
79 Whelton PK, Carey RM, Aronow WS, Casey DE Jr, Collins KJ, Dennison Himmelfarb C, DePalma SM, Gidding S, Jamerson KA, Jones DW, MacLaughlin EJ, Muntner P, Ovbiagele B, Smith SC Jr, Spencer CC, Stafford RS, Taler SJ, Thomas RJ, Williams KA Sr, Williamson JD, Wright JT Jr. 2017 ACC/AHA/AAPA/ABC/ACPM/AGS/APhA/ASH/ASPC/NMA/PCNA Guideline for the Prevention, Detection, Evaluation, and Management of High Blood Pressure in Adults: Executive Summary: A Report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. Circulation. 2018 Oct 23;138(17):e426–e483. 10.1161/CIR.0000000000000597. Accessed December 2, 2021.30354655
80 Centers for Disease Control and Prevention. Flu & People With Diabetes. Last reviewed August 2021. https://www.cdc.gov/flu/diabetes/index.htm. Accessed December 2, 2021.
81 Horvitz-Lennon M, Volya R, Garfield R, Donohue JM, Lave JR, Normand SL. Where you live matters: quality and racial/ethnic disparities in schizophrenia care in four state Medicaid programs. Health Serv Res. 2015 Oct;50(5):1710–29. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4600368/. Accessed December 2, 2021.25759240
82 Lin YH, McLain AC, Probst JC, Bennett KJ, Qureshi ZP, Eberth JM. Health-related quality of life among adults 65 years and older in the United States, 2011–2012: a multilevel small area estimation approach. Ann Epidemiol. 2017 Jan;27(1):52–58. https://www.ncbi.nlm.nih.gov/pubmed/27814940. Accessed December 2, 2021.27814940
83 Trivedi T, Liu J, Probst JC, Merchant A, Jones S, Martin AB. Obesity and obesity-related behaviors among rural and urban adults in the USA. Rural Remote Health. 2015;15:3267. https://www.rrh.org.au/journal/article/3267. Accessed December 2, 2021.26458564
84 Andrilla CHA, Patterson DG, Garberson LA, Coulthard C, Larson EH. Geographic variation in the supply of selected behavioral health providers. Am J Prev Med 2018 Jun;54(6S3):S199–S207. https://www.ncbi.nlm.nih.gov/pubmed/29779543. Accessed December 2, 2021.29779543
85 Skinner AC, Slifkin RT. Rural/urban differences in barriers to and burden of care for children with special health care needs. J Rural Health. 2007 Spring;23(2):150–7. https://www.ncbi.nlm.nih.gov/pubmed/17397371. Accessed December 2, 2021.17397371
86 Hale N, Probst J, Robertson A. Rural area deprivation and hospitalizations among children for ambulatory care sensitive conditions. J Community Health 2016 Jun;41(3):451–60. https://www.ncbi.nlm.nih.gov/pubmed/26516019. Accessed December 2, 2021.26516019
87 Meit M, Knudson A, Gilbert T, Tzy-Chyi Yu A, Tanenbaum E, Ormson E, TenBroeck S, Bayne A, Popat S. The 2014 Update of the Rural-Urban Chartbook. Bethesda, MD: Rural Health Reform Policy Research Center; October 2014. https://ruralhealth.und.edu/projects/health-reform-policy-research-center/pdf/2014-rural-urban-chartbook-update.pdf. Accessed December 2, 2021.
88 Galea S, Vlahov D. Urban health: evidence, challenges, and directions. Annu Rev Public Health. 2005;26:341–65. 10.1146/annurev.publhealth.26.021304.144708. Accessed December 2, 2021.15760293
89 Heady HR. MSJAMA. A delicate balance: the economics of rural health care delivery. JAMA. 2002 Jan 2;287(1):110. PMID: 11754720.11754720
90 Henning-Smith C. Meeting the social needs of older adults in rural areas. JAMA Health Forum. 2020;1(11):e201411–e.
91 Ingram DD, Franco SJ. 2013 NCHS Urban–Rural Classification Scheme for Counties. National Center for Health Statistics. Vital Health Stat 2(166). 2014. https://www.cdc.gov/nchs/data/series/sr_02/sr02_166.pdf. Accessed December 2, 2021.
92 Centers for Disease Control and Prevention. NCHS Urban-Rural Classification Scheme for Counties. Last reviewed June 2017. https://www.cdc.gov/nchs/data_access/urban_rural.htm. Accessed December 2, 2021.
93 Agency for Healthcare Research and Quality. National Healthcare Quality and Disparities Report State View. https://datatools.ahrq.gov/nhqdr. Accessed December 2, 2021.
94 Centers for Disease Control and Prevention. HIV Surveillance Report, 2019; vol. 32. Published May 2021. http://www.cdc.gov/hiv/library/reports/hiv-surveillance.html. Accessed December 2, 2021.
95 U.S. Department of Health and Human Services. What Is Ending the HIV Epidemic in the U.S.? Last updated June 2021. https://www.hiv.gov/federal-response/ending-the-hiv-epidemic/overview. Accessed December 2, 2021.
96 U.S. Department of Health and Human Services. HIV Prevention Activities: Reducing New HIV Infections. https://www.hiv.gov/federal-response/federal-activities-agencies/hiv-prevention-activities. Accessed December 2, 2021.
97 Zahran HS, Bailey CM, Damon SA, Garbe PL, Breysse PN. Vital Signs: Asthma in children — United States, 2001–2016. MMWR Morb Mortal Wkly Rep 2018;67:149–155. https://www.cdc.gov/mmwr/volumes/67/wr/mm6705e1.htm. Accessed December 2, 2021.29420459
98 National Heart, Lung, and Blood Institute. Guidelines for the Diagnosis and Management of Asthma 2007 (EPR-3). https://www.nhlbi.nih.gov/health-topics/guidelines-for-diagnosis-management-of-asthma. Accessed December 2, 2021.
99 National Heart, Lung, and Blood Institute. Asthma Management Guidelines: Focused Updates 2020. https://www.nhlbi.nih.gov/health-topics/asthma-management-guidelines-2020-updates. Accessed December 2, 2021.
100 Coller RJ, Kelly MM, Ehlenbach ML, Goyette E, Warner G, Chung PJ. Hospitalizations for ambulatory care-sensitive conditions among children with chronic and complex diseases. J Pediatr. 2018 Mar;194:218–24. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5826824/. Accessed December 2, 2021.29198530
101 Mack KA, Jones CM, Ballesteros MF. Illicit Drug Use, Illicit Drug Use Disorders, and Drug Overdose Deaths in Metropolitan and Nonmetropolitan Areas — United States. MMWR Surveill Summ. 2017;66(No. SS-19):1–12. https://www.cdc.gov/mmwr/volumes/66/ss/ss6619a1.htm?s_cid=ss6619a1_w#. Accessed December 2, 2021.
102 Centers for Disease Control and Prevention. Opioids: Understanding the Epidemic. https://www.cdc.gov/opioids/basics/epidemic.html Accessed December 2, 2021.
103 Hedegaard H, Spencer MR. Urban–Rural Differences in Drug Overdose Death Rates, 1999–2019. NCHS Data Brief, No. 403. Hyattsville, MD: National Center for Health Statistics. 2021. https://www.cdc.gov/nchs/data/databriefs/db403-H.pdf. Accessed December 2, 2021.
104 Diabetes Canada Clinical Practice Guidelines Expert Committee, Wherrett DK, Ho J, Huot C, Legault L, Nakhla M, Rosolowsky E. Type 1 diabetes in children and adolescents. Can J Diabetes. 2018 Apr;42 Suppl 1:S234–S246. 10.1016/j.jcjd.2017.10.036. Accessed December 2, 2021..29650103
105 American Diabetes Association. 12. Children and Adolescents: Standards of Medical Care in Diabetes—2018 Diabetes Care. 2018 Jan;41(Suppl 1):S126–S136. https://care.diabetesjournals.org/content/41/Supplement_1/S126.long. Accessed December 2, 2021.29222383
106 Grundy SM, Stone NJ; Guideline Writing Committee for the 2018 Cholesterol Guidelines. 2018 Cholesterol Clinical Practice Guidelines: Synopsis of the 2018 American Heart Association/American College of Cardiology/Multisociety Cholesterol Guideline. Ann Intern Med. 2019 Jun 4;170(11):779–83. 10.7326/M19-0365. Accessed December 2, 2021.31132793
107 U.S. Preventive Services Task Force, Bibbins-Domingo K, Grossman DC, Curry SJ, Davidson KW, Epling JW Jr, García FAR, Gillman MW, Kemper AR, Krist AH, Kurth AE, Landefeld CS, LeFevre ML, Mangione CM, Phillips WR, Owens DK, Phipps MG, Pignone MP. Statin Use for the Primary Prevention of Cardiovascular Disease in Adults: U.S. Preventive Services Task Force Recommendation Statement. JAMA. 2016 Nov 15;316(19):1997–2007. doi: 10.1001/jama.2016.15450. Erratum in: JAMA. 2020 Feb 18;323(7):669. Erratum in: JAMA. 2020 Feb 18;323(7):669–70. https://pubmed.ncbi.nlm.nih.gov/27838723/. Accessed December 2, 2021.27838723
108 Centers for Disease Control and Prevention. Infant Mortality. https://www.cdc.gov/reproductivehealth/maternalinfanthealth/infantmortality.htm. Accessed December 2, 2021.
109 Committee on Practice and Ambulatory Medicine, Section on Ophthalmology. American Association of Certified Orthoptists; American Association for Pediatric Ophthalmology and Strabismus; American Academy of Ophthalmology. Eye examination in infants, children, and young adults by pediatricians. Pediatrics. 2003 Apr;111(4 Pt 1):902–7. https://pubmed.ncbi.nlm.nih.gov/12671132/. Accessed December 2, 2021.12671132
110 Loh AR, Chiang MF. Pediatric vision screening. Pediatr Rev. 2018 May;39(5):225–34. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6317790/. Accessed December 2, 2021.29716965
111 Virani SS, Alonso A, Benjamin EJ, Bittencourt MS, Callaway CW, Carson AP, Chamberlain AM, Chang AR, Cheng S, Delling FN, Djousse L, Elkind MSV, Ferguson JF, Fornage M, Khan SS, Kissela BM, Knutson KL, Kwan TW, Lackland DT, Lewis TT, Lichtman JH, Longenecker CT, Loop MS, Lutsey PL, Martin SS, Matsushita K, Moran AE, Mussolino ME, Perak AM, Rosamond WD, Roth GA, Sampson UKA, Satou GM, Schroeder EB, Shah SH, Shay CM, Spartano NL, Stokes A, Tirschwell DL, VanWagner LB, Tsao CW; American Heart Association Council on Epidemiology and Prevention Statistics Committee and Stroke Statistics Subcommittee. Heart Disease and Stroke Statistics—2020 Update: A Report From the American Heart Association. Circulation. 2020 Mar 3;141(9):e139–e596. 10.1161/CIR.0000000000000757. Accessed December 2, 2021.31992061
112 McDermott KW, Jiang HJ. Characteristics and Costs of Potentially Preventable Inpatient Stays, 2017. HCUP Statistical Brief #259. Rockville, MD: Agency for Healthcare Research and Quality; June 2020. https://hcup-us.ahrq.gov/reports/statbriefs/sb259-Potentially-Preventable-Hospitalizations-2017.jsp. Accessed December 2, 2021.
113 Oliveira GH, Al-Kindi SG, Pronovost PJ. Dose titration of ambulatory care for heart failure: a new paradigm to keep patients healthy at home rather than healing in hospital. Circ Cardiovasc Qual Outcomes. 2019 Dec;12(12):e005952. 10.1161/CIRCOUTCOMES.119.005952. Accessed December 2, 2021.32522025
114 U.S. Department of Health and Human Services. Oral Health in America: A Report of the Surgeon General. Rockville, MD: U.S. Department of Health and Human Services, National Institute of Dental and Craniofacial Research, National Institutes of Health; 2000. https://www.nidcr.nih.gov/sites/default/files/2017-10/hck1ocv.%40www.surgeon.fullrpt.pdf. Accessed December 2, 2021.
115 Patel NA, Yun JK, Afshar S. Relieving emergency department burden during COVID-19: Section 1135 waivers for dental case diversion. J Oral Maxillofac Surg. 2020 Dec;78(12):2110–1. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7364142/. Accessed December 2, 2021..32777246
116 Musher DM, Thorner AR. Community-acquired pneumonia. N Engl J Med. 2014 Oct 23;371(17):1619–28. 10.1056/NEJMra1312885. Accessed December 2, 2021.25337751
117 McDermott KW, Roemer M. Most Frequent Principal Diagnoses for Inpatient Stays in U.S. Hospitals, 2018. HCUP Statistical Brief #277. Rockville, MD: Agency for Healthcare Research and Quality;July 2021. https://hcup-us.ahrq.gov/reports/statbriefs/sb277-Top-Reasons-Hospital-Stays-2018.jsp. Accessed December 2, 2021.
118 Centers for Disease Control and Prevention. Underlying Cause of Death, 1999–2019. CDC WONDER, released 2020. https://wonder.cdc.gov/controller/saved/D76/D99F514, Accessed December 2, 2021.
119 Office of the Secretary. Determination That a Public Health Emergency Exists. Washington, DC: U.S. Department of Health and Human Services; 2017. https://www.hhs.gov/sites/default/files/opioid%20PHE%20Declaration-no-sig.pdf. Accessed December 2, 2021.
120 Centers for Disease Control and Prevention. Drug Overdose Deaths. https://www.cdc.gov/drugoverdose/deaths/index.html. Accessed December 2, 2021.

### Looking Forward

1 Centers for Disease Control and Prevention. Science Brief: Evidence Used To Update the List of Underlying Medical Conditions Associated With Higher Risk for Severe COVID-19. Last reviewed October 14, 2021. https://www.cdc.gov/coronavirus/2019-ncov/science/science-briefs/underlying-evidence-table.html. Accessed December 8, 2021.
2 Webb Hooper M, Nápoles AM, Pérez-Stable EJ. COVID-19 and racial/ethnic disparities. JAMA 2020;323(24):2466–7. 10.1001/jama.2020.8598.32391864
3 U.S. Department of Health and Human Services. What Is the U.S. Opioid Epidemic? https://www.hhs.gov/opioids/about-the-epidemic/index.html. Accessed December 8, 2021.
4 U.S. Department of Health and Human Services. Overdose Prevention Strategy. https://www.hhs.gov/overdose-prevention/. Accessed December 8, 2021.