# LOOKING FORWARD

The 2021 NHQDR has examined data from more than 25 federal data sources to describe trends and disparities in access measures and quality measures across the following six domains:

- Person-Centered Care.
- Patient Safety.
- Care Coordination.
- Affordable Care.
- Effective Treatment.
- Healthy Living.

The report offers a comprehensive assessment of the best and worst performing quality and access measures over the past year. While the limited availability of trend data partially constrains this year’s analysis, it is clear that disparities by race, ethnicity, sex, age, income, insurance status, residence location, and other factors persist, and they lead to unacceptable consequences that affect the health of the nation.

## Emerging Opportunities for Measurement

The NHQDR measure set is assessed annually to explore how new clinical areas can be included to provide a more complete representation of healthcare quality and disparities in the United States. Recently, the reports have included data on patient safety events reported by Patient Safety Organizations (PSOs). The NHQDR measure set will continue to be assessed as part of the ongoing development of future reports in order to maintain its relevance to evolving healthcare quality measurement and improvement needs.

## Notable Examples of Collaboration To Improve Healthcare Quality

HHS agencies work in collaboration with federal and nonfederal partners to enhance and protect the health and well-being of all Americans, and the following examples intend to support improvements that would, in turn, influence the measures and results included in future reports.

### Report on Strategies To Improve Patient Safety

The report on Strategies To Improve Patient Safety reviews some of the principles and concepts underlying effective patient safety improvement. In addition, it describes how the effectiveness of a given patient safety improvement strategy or practice must continually be assessed over time as it is implemented and experience is gained in keeping patients safe in various healthcare settings.

Several approaches could accelerate progress in improving patient safety and encouraging the use of effective improvement strategies:

- Patient safety research, measurement, and practice improvement should encompass analytic approaches that support learning about how and why care is delivered safely as planned in healthcare and how to monitor risk while addressing specific adverse events and harms.
- More research is needed to develop the patient safety evidence base because safety is an important aspect of care for every patient in all healthcare disciplines, specialties, settings, and modes of healthcare delivery.
- Translating evidence-based practices into real-world settings requires the development of clinically useful tools and infrastructure and often foundational changes in organizational culture, leadership and patient engagement, teamwork, and communication.
- Encouraging the development of learning health systems that integrate continuous learning and improvement in day-to-day operations can speed the application of the most promising evidence to improve care.
- Safer Together: A National Action Plan to Advance Patient Safety (https://www.ahrq.gov/patient-safety/reports/safer-together.html), put forth by the National Steering Committee for Patient Safety, has the potential to advance and align efforts to encourage the use of effective patient safety strategies.

### Maternal Morbidity

Addressing disparities in maternal health and birth outcomes is a national priority. Various collaborations across federal agencies and stakeholders are designed to help mothers and babies. These include The Surgeon General’s Call to Action To Improve Maternal Health (https://www.hhs.gov/sites/default/files/call-to-action-maternal-health.pdf) and the 2020 U.S. Department of Health and Human Services (HHS) Healthy Women, Healthy Pregnancies, Healthy Futures: Action Plan To Improve Maternal Health (https://aspe.hhs.gov/system/files/aspe-files/264076/healthy-women-healthy-pregnancies-healthy-future-action-plan_0.pdf). Both of these efforts are based on the life-course approach.

The Call to Action engages and equips individuals, organizations, agencies, and entire communities with evidence-based actions that will improve women’s health before, during, and after pregnancy. The HHS Action Plan summarizes the Department’s work to ensure the United States is one of the safest countries in the world in which to give birth, realizing that the scope of this vision extends beyond the federal government.

Supplemental measures in the NHQDR related to maternal morbidity and mortality include:

- Morbidity measures:
  ■ Venous thromboembolism or pulmonary embolism per 1,000 delivery discharges.
  ■ Hypertensive disorders in pregnancy per 1,000 delivery hospitalizations.
  ■ Severe postpartum hemorrhage per 1,000 delivery hospitalizations.
  ■ Severe maternal morbidity per 1,000 delivery hospitalizations.
  ■ Cesarean deliveries among low-risk first births.
- Mortality measures:
  ■ In-hospital deaths per 100,000 delivery hospitalizations.

These data are available through the online query tool at https://datatools.ahrq.gov/nhqdr, and further analysis and discussion are featured in the latest NHQDR Chartbook on Patient Safety (https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/patientsafety/index.html).

## Top Priorities and Tasks at HHS

HHS has refocused efforts on several priorities and tasks. These efforts work to advance scientific research and improve health services for affected populations. In support of these aims, the NHQDR team will continue to explore opportunities to include additional data in future reports that are relevant to these topics. This section elaborates on how the NHQDR’s team’s activities remain relevant to the many ongoing HHS priorities.

### COVID-19

While the data in this report predate the COVID-19 pandemic, COVID-19 is significantly affecting several aspects of healthcare and the lives of those it serves. The ultimate influence of COVID-19 on healthcare quality and disparities is uncertain, but the effects to date in addition to the potential influences are many. For example, people with underlying conditions and older adults are at increased risk for severe illness due to COVID-19 and may experience additional burdens from associated healthcare safety and quality concerns.^1^ Similarly, initial data show a disproportionate impact of the pandemic on racial and ethnic groups.^2^ Future versions of the report will track the long-term effects of the COVID-19 pandemic on healthcare quality and disparities when data covering 2021 are available.

### Opioids

In 2017, HHS declared a public health emergency, announced a strategy to combat the opioid crisis,^3^ and outlined a five-point strategy to combat the epidemic. The Overdose Prevention Strategy^4^ later expanded the scope of the crisis response beyond opioids to include other substances often involved in overdoses, including stimulants such as methamphetamine and cocaine. This new strategy promotes groundbreaking research and evidence-informed methods to improve the health and safety of our communities. The strategy is guided by four principles—equity; data and evidence; coordination, collaboration, and integration; and reduction of stigma.

Strategic priorities are:

- Primary Prevention: focuses on root causes and key predictors of substance use and substance use disorder and how to safely and effectively manage pain.
- Harm Reduction: focuses on reducing risks associated with substance use, including overdose and infectious disease transmission.
- Evidence-Based Treatment: focuses on providing the most effective, evidence-based treatments without delay, stigma, or other barriers.
- Recovery Support: focuses on funding, reimbursement, workforce training, development of protocols related to peer support, employment, and housing.

In June 2018, the Substance Abuse and Mental Health Services Administration (SAMHSA) published the Opioid Overdose Prevention Toolkit in English (https://store.samhsa.gov/product/Opioid-Overdose-Prevention-Toolkit/SMA18-4742) and Spanish (https://store.samhsa.gov/product/Opioid-Overdose-Prevention-Toolkit-Spanish-/SMA18-4742SPANISH). The toolkit offers strategies to healthcare providers, communities, and local governments for developing practices and policies to help prevent opioid-related overdoses and deaths.

The NHQDR continues to track data for eight opioid-related measures and will add new measures that offer additional insight about the epidemic as they become available:

- Hospital inpatient stays related to opioid use per 100,000 population.
- Emergency department visits involving opioid-related diagnoses per 100,000 population.
- Percentage and population estimates of past-year opioid (either prescription opioid or heroin) use disorder among people age 12 and over.
- Rate per 100,000 population of deaths from drug overdoses involving opioids.
- Rate per 100,000 population of deaths from drug overdoses involving natural and semisynthetic opioids (e.g., oxycodone, hydrocodone, or morphine).
- Rate per 100,000 population of deaths from drug overdoses involving synthetic opioids other than methadone (e.g., prescription and illicit fentanyl, tramadol).
- Adults who filled an outpatient opioid prescription in the calendar year.
- Adults who filled four or more outpatient opioid prescriptions in the calendar year.

The NHQDR team and SAMHSA (https://www.samhsa.gov/) produced a data spotlight in 2020 to examine disparities in opioid-related deaths. The data spotlight (https://www.ahrq.gov/sites/default/files/wysiwyg/research/findings/nhqrdr/dataspotlight-opioid.pdf) and infographic (https://www.ahrq.gov/data/infographics/qdr-opioids.html) show that Black people are experiencing fast-rising rates of overdose deaths involving synthetic opioids other than methadone.

SAMHSA is further exploring how the opioid crisis is disproportionately affecting vulnerable racial and ethnic populations, including Hispanic and Black people. In April 2020, SAMHSA published The Opioid Crisis and the Black/African American Population: An Urgent Issue (https://store.samhsa.gov/product/The-Opioid-Crisis-and-the-Black-African-American-Population-An-Urgent-Issue/PEP20-05-02-001). In July and October 2020, SAMHSA published The Opioid Crisis and the Hispanic/Latino Population: An Urgent Issue in English (https://store.samhsa.gov/product/The-Opioid-Crisis-and-the-Hispanic-Latino-Population-An-Urgent-Issue/PEP20-05-02-002) and Spanish (https://store.samhsa.gov/product/the-opioid-crisis-and-the-hispanic-latino-population-an-urgent-issue-spanish-version/PEP20-05-02-003). Both documents detail additional resources to combat the opioid crisis.

SAMHSA has also published a Behavioral Health Treatment Services Locator. This tool is a confidential and anonymous source of information for people seeking treatment facilities in the United States or U.S. territories for substance use, addiction, or mental health issues. The locator is available online at https://findtreatment.samhsa.gov/.

### Equitable Access to High-Quality and Affordable Healthcare

HHS works to protect and strengthen equitable access to high-quality and affordable healthcare. Increasing choice, affordability, and enrollment in high-quality healthcare coverage is a focus of the Department’s efforts in addition to reducing costs, improving quality of healthcare services, and ensuring access to safe medical devices and drugs. HHS also works to expand equitable access to comprehensive, community-based, innovative, and culturally competent healthcare services while addressing social determinants of health.

The Department is driving the integration of behavioral health into the healthcare system to strengthen and expand access to mental health and substance use disorder treatment and recovery services for individuals and families. HHS also bolsters the healthcare workforce to ensure delivery of quality services and care.

The NHQDR currently tracks 14 Access to Care measures: 5 measures related to insurance, 4 measures related to patient perception of need, 3 measures of ability to get care, and 2 measures related to usual source of care.

The Access to Care measures in the NHQDR include:

- People under a ge 65 with health insurance.
- People under age 65 with any private health insurance.
- Adults age 65 and over with any private health insurance.
- People under age 65 who were uninsured all year.
- People under age 65 with any period of uninsurance during the year.
- People with a usual source of care, excluding hospital emergency rooms, who has office hours at night or on weekends.
- People with a usual source of care who is somewhat to very difficult to contact during regular business hours over the telephone.
- Adults who tried to make an appointment to see a specialist in the last 12 months who sometimes or never found it easy to get the appointment.
- Children who needed to see a specialist in the last 12 months who sometimes or never found it easy to see a specialist.
- Adults who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed.
- Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed.
- Adults who needed care right away for an illness, injury, or condition in the last 12 months who sometimes or never got care as soon as needed.
- People with a specific source of ongoing care.
- People in fair or poor health with a specific source of ongoing care.

The NHQDR also includes one measure of the financial burden of healthcare:

- People under age 65 whose family’s health insurance premiums and out-of-pocket medical expenditures were more than 10%oftotal family income.

Among these measures, this report has already highlighted the widening and narrowing disparities experienced by various racial and ethnic groups. These data are available through the online query tool at https://datatools.ahrq.gov/nhqdr. Moving forward, the NHQDR team will continue to track these measures with our data partners to understand how differences in quality measurement, disparities, and mortality are occurring over time.

## Future Research and Work

Readers can use this report and related NHQDR products including Chartbooks (https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/index.html) and Data Spotlights (https://www.ahrq.gov/research/findings/nhqrdr/data-spotlights/index.html) to learn more about the nation’s progress in improving healthcare and to explore emerging topics. The report helps identify opportunities to improve quality and reduce disparities. Ongoing disparities in care by race, ethnicity, income, residence location, and other socioeconomic factors underscore that while we have made important strides in the quality and accessibility of healthcare, these outcomes are not equitably experienced across the United States, and much work remains.

The 2021 NHQDR presents data through 2019 and can serve as a snapshot of both healthcare quality and disparities in healthcare across the United States as the country entered the COVID-19 pandemic. The report can help answer questions such as which aspects of our healthcare system exhibited the highest and lowest levels of quality and which were improving or worsening at the fastest rates before the pandemic began.

As more recent data continue to be collected and analyzed, further consideration in the context of prepandemic status may offer additional insight into questions such as:

- How did various examples of lower quality of care (overall and for specific vulnerable populations) magnify the health threats that the COVID-19 pandemic has imposed?
- Which groups experienced lower quality care?
- How should the healthcare system address specific safety and quality concerns?
- How can the work to improve safety and quality help prepare communities and the nation for the next healthcare crisis?