# QUALITY IN HEALTHCARE

The foundation of quality healthcare is doing the right thing at the right time in the right way for the right person and having the best results possible. Quality healthcare often means striking the right balance when providing healthcare services by avoiding overuse (e.g., unnecessary tests), underuse (e.g., missed blood pressure screening), or misuse (e.g., prescribing of drugs with harmful interactions).^1^

The COVID-19 pandemic has affected almost all aspects of the way people live and work, especially with regard to healthcare and quality of healthcare people have received during the pandemic. More data are needed to fully understand how healthcare quality has been affected but one area with evidence of a decrease in quality of care is preventive healthcare. For instance, cancer screening is integral to cancer control and prevention. Due to the COVID-19 outbreak, many screenings have either been canceled or postponed, leaving a vast number of patients without access to recommended healthcare services. This disruption to cancer screening services may have a significant impact on patients, healthcare practitioners, and health systems.^2^

The quality of healthcare can be measured, monitored, and improved over time. By specifying clearly, based on current science, which services should be provided to patients who have or are at risk for certain conditions and finding out whether those services are being correctly provided at the right time, we can track the performance of our medical care system. Experts in a field can propose a measure of performance, then test, adopt, and implement it.

Measures of healthcare quality tracked in the National Healthcare Quality and Disparities Report (NHQDR) encompass a broad array of services (prevention, acute treatment, and chronic disease management) and settings (doctors’ offices, emergency departments [EDs], dialysis centers, hospitals, nursing homes, hospices, and home health). Most NHQDR quality measures quantify processes that make up high-quality healthcare or outcomes related to receipt of high-quality healthcare. A few structural measures are included, such as the availability of health information technologies and workforce diversity.

Data used to generate NHQDR measures include results from more than three dozen datasets that provide estimates for various population subgroups and data years. Sources used to assess healthcare quality in the report include:

- Surveys of patients, patients’ families, caregivers, and providers;
- Administrative data from healthcare facilities;
- Abstracts of clinical charts;
- Registry data; and
- Vital statistics.

Most data are reported annually and are generally available through 2016, 2017, or 2018.

As defined by the landmark Institute of Medicine report Crossing the Quality Chasm: A New Health System for the 21st Century, “equity” in health caregiving is based on the idea that “all individuals rightly expect to be treated fairly by social institutions, including health care organizations.” In addition, applying an “equity” approach ensures that quality care is available to all and that the quality of care provided does not differ by race, ethnicity, or other personal characteristics unrelated to a patient’s reason for seeking care.^3^

Due in part to unfair policies, practices, and conditions, the quality of healthcare has varied based on race, ethnicity, socioeconomic status, age, sex, disability status, sexual orientation, and residence location. As specified in the Healthcare Research and Quality Act, this report focuses on disparities related to race, ethnicity, socioeconomic status, and geographic location. Through the examination of disparities in care, policymakers, researchers, providers, and public health practitioners can better understand the relationship between quality and equity in care.

## TRENDS IN QUALITY

Major updates made to three data sources since 2018—specifically the Medical Expenditure Panel Survey (MEPS), Healthcare Cost and Utilization Project (HCUP), and National Health Interview Survey (NHIS)—have had an outsized impact on the information available for presentation as part of the 2021 NHQDR. Trend data are currently not available for almost half of the core measures. Therefore, the 2021 NHQDR does not include a summary figure showing all trend measures or all changes in disparities. The report does include summary trend and change in disparities figures for some populations and results for individual measures.

## Trends in Person-Centered Care

The National Academy of Medicine, formerly Institute of Medicine (IOM), identifies patient centeredness as a core component of quality healthcare.^3^ Patient centeredness is defined as:

[H]ealth care that establishes a partnership among practitioners, patients, and their families (when appropriate) to ensure that decisions respect patients’ wants, needs, and preferences and that patients have the education and support they need to make decisions and participate in their own care.^4^

Patient centeredness “encompasses qualities of compassion, empathy, and responsiveness to the needs, values, and expressed preferences of the individual patient.”^Error! Bookmark not defined.^ In addition, translation and interpretation services, as well as auxiliary aids and services, facilitate communication between individuals and providers and are often a legal requirement.^xii^ The patient- or person-centered approach includes viewing the individual as a unique person, rather than focusing strictly on the diagnosis or chronic condition, and building a therapeutic alliance based on the person’s and provider’s perspectives.

Person-centered care is supported by good communication between individuals and providers so that individuals’ needs and wants are understood and addressed and individuals understand and participate in their own care. This approach to care has been shown to improve health and healthcare.^5,^ ^6,^ ^7,^ ^8^ Examples of person-centered care are ensuring that individuals’ feedback on their preferences, desired outcomes, and experiences of care is integrated into care delivery and enabling people to effectively manage their own care and services.

Unfortunately, many barriers exist to good communication. Providers differ in communication proficiency, including varied listening skills and different views from their patients and caregivers of symptoms and treatment plans.^9^ Additional factors influencing person-centeredness and communication include:

- Language barriers.
- Racial and ethnic concordance between individuals and providers.
- Effects of disabilities on individuals’ healthcare experiences.
- Providers’ cultural competency.
- Accommodations for low health literacy.

### Importance of Person-Centered Care

#### Morbidity and Mortality

- Person-centered decision making (when physicians consider the needs and circumstances of an individual) for planning an individual’s care has been shown to improve healthcare outcomes.^10^
- Person-centered approaches to care have been shown to improve individuals’ health status. These approaches rely on building a relationship between the individual and the provider, improving communication, fostering a positive atmosphere, and encouraging individuals to actively participate in interactions with their provider.^11^
- Person-centered care can reduce the chance of misdiagnosis due to poor communication.^12^

Person-centered care and successful communication help lead to increased individual and provider satisfaction, trust in the provider, and functional and psychological well-being. Effective communication also leads to improved outcomes, including:

- A small but significant absolute risk reduction of mortality from coronary artery disease,
- Improved control of diabetes and hyperlipidemia,
- Better adherence to antihypertensive medication,
- Bereavement adjustment in caregivers of cancer patients, and
- Higher self-efficacy of adherence to HIV medications.^13^

#### Cost

In addition to improved outcomes, research indicates that effective person-centered care may result in decreased healthcare costs:

- Poor communication, lack of collaboration, and lack of support for self-care are associated with suffering and waste in healthcare.^14^
- Person-centeredness has been shown to reduce overuse of medical care.^15^
- Improved communication methods can lower barriers to discussion about medication costs with individuals.^16^
- Improved communication between individuals and providers during medical decision making can reduce costs.^17^

### Findings on Person-Centered Care

The Person-Centered Care priority area includes measures^xiii^ of:

- Patient Experience of Care.
- Hospital Communication.
- Home Health Care Communication.
- Hospice Care.

Data for these measures can be found at https://datatools.ahrq.gov/nhqdr.

Of the 26 Person-Centered Care measures included, 14 measures (54%) improved over time and no measures worsened. Three Person-Centered Care measures of communication between individuals and providers that showed significant improvement include:

- Adults who reported that home health care providers talked about pain in the last 2 months of care.
- Family caregivers who received the right amount of emotional and spiritual support from the hospice care team.
- Adult hospital patients who sometimes or never had good communication about medications they received in the hospital.

More than half of the Person-Centered Care measures showed significant improvement, with measures of communication between individuals and providers showing the greatest improvement.

#### Improving Trend: Discussions About Pain for Individuals in Home Health Care

More than 50 million adults in the United States have chronic daily pain. Best practices for pain management emphasize person-centered care in the diagnosis and treatment of pain.^18^ However, individuals can be reluctant to discuss pain with their providers.^19^ It is imperative for providers to openly discuss, actively monitor, and accurately assess pain with those in their care, as collaborative and effective interventions can improve individuals’ pain.^20^ Pain assessment and pain management are also requirements for accrediting home health organizations.^21^

Figure 1 Adults who reported that home health care providers talk ed about pain in the last 2 months of care, 2012–2019

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Medicare & Medicaid Services, Home Health Care Consumer Assessment of Healthcare Providers and Systems Survey, 2012–2019.

- From 2012 to 2019, overall, the percentage of adults who reported that home health care providers talked about pain in the last 2 months of care increased from 87.5% to 90.0% (Figure 1).
- The 2015 achievable benchmark was 91.3%. At the current rate of increase, overall, the benchmark could be achieved in 3 years.
- The top 10% of states that contributed to the achievable benchmark were Alabama, Missouri, New Mexico, North Dakota, Oklahoma, West Virginia, and Wisconsin. One territory, Guam, was not included in the benchmark but was in the benchmark range.

#### Improving Trend: Emotional and Spiritual Support for Family Caregivers

Hospice care increasingly relies on unpaid caregivers in home and other community settings, a difficult role for people who may not be formally trained, as “responsibilities must be managed while simultaneously witnessing and coping with the impending death of a loved one.”^22^ However, quality of care can decline as caregivers’ anxiety and depression increase.^23^ Addressing the emotional and spiritual well-being of family caregivers is therefore an essential part of effective hospice care for both the caregiver and the patient.

Figure 2 Family caregivers who received the right amount of emotional and spiritual support from the hospice care team, 2015–2019

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage: 2015, 88.8 2016, 89.0 2017, 89.0 2018, 89.6 2019, 90.0 achievable benchmark: 90.9%

Source: Centers for Medicare & Medicaid Services, Hospice Consumer Assessment of Healthcare Providers and Systems Survey, 2015–2019.

- From 2015 to 2019, overall, the percentage of family caregivers who received the right amount of emotional and spiritual support from the hospice care team increased from 88.8% to 90.0% (Figure 2).
- The 2015 achievable benchmark was 90.9%. At the current rate of increase, overall, the benchmark could be achieved in 3 years.
- The top 10% of states that contributed to the achievable benchmark were Arkansas, Idaho, Kentucky, North Carolina, and West Virginia.

#### Improving Trend: Communication About Medication for Inpatients

Inpatients often receive medications during their hospital stay. For example, 80% of ED visits involve drug therapy.^24^ Good communication between the individual and the healthcare provider decreases the risk of medication-related adverse events^25^ and has also been shown to increase adherence to prescription medications.^26,^ ^27^ Therefore, effectively discussing medications is a key component of communication between individuals and providers.

Figure 3 Adult hospital patients who sometimes or never had good communication about medications they received in the hospital, 2009–2019 (lower rates are better)

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems Survey, 2009–2019.

- From 2009 to 2019, overall, the percentage of adult hospital patients who sometimes or never had good communication about medications they received in the hospital decreased from 12.7% to 10.8% (Figure 3).
- The 2015 achievable benchmark was 7.8%. At the current rate of increase, overall, the benchmark could not be achieved for 15 years.
- The top 10% of states that contributed to the achievable benchmark were Alabama, Alaska, Colorado, Kansas, Mississippi, South Dakota, Utah, and Wyoming. One territory, the Virgin Islands, was not included in the benchmark but its percentage was in the benchmark range.

##### Resources

Efforts to promote person-centered care are underway within the Department of Health and Human Services (HHS) and other government agencies. For example:

- Through its Consumer Assessment of Healthcare Providers and Systems (CAHPS^®^) (https://www.ahrq.gov/cahps/surveys-guidance/index.html) program, the Agency for Healthcare Research and Quality (AHRQ) has been dedicated to advancing scientific knowledge, measurement, and improvement of person-centered care since 1995. The CAHPS surveys assess healthcare quality by asking patients to report on
- their experiences with care. Survey findings are used to monitor and drive improvements in experience with care and better inform consumers about healthcare providers in their area. Users of CAHPS surveys include the Centers for Medicare & Medicaid Services (CMS), National Committee for Quality Assurance, Department of Veterans Affairs, and Department of Defense.
- The HHS Office of Minority Health has developed Think Cultural Health (https://thinkculturalhealth.hhs.gov/), a website featuring information, resources, and continuing education opportunities related to culturally and linguistically appropriate services (CLAS) and the National CLAS Standards for healthcare professionals.
- The HHS Office for Civil Rights (OCR) Medical School Curriculum Initiative educates future healthcare practitioners about OCR’s civil rights authorities to prevent and address racial and ethnic health disparities. Since 2009, OCR has presented the medical school curriculum to approximately 8,500 medical school, nursing, and allied health students, including professional school and undergraduate students. As part of this initiative, OCR takes part in the Association of American Medical Colleges’ Summer Health Professionals Education Program (SHPEP). Through the SHPEP, OCR has provided training to nearly 1,000 premedical and predental college students at a dozen universities every summer since 2014.
  Currently, SHPEP trainings consist of two modules. The first module, launched in 2014, addresses compliance with Title VI of the Civil Rights Act of 1964, which prohibits recipients from discriminating on the basis of race, color, or national origin. It also covers Title IX of the Education Amendments of 1972 and Section 1557 of the Affordable Care Act (Section 1557), which prohibit harassment and discrimination on the basis of sex (including pregnancy, sexual orientation, and gender identity) in education and health programs or activities funded by HHS. In 2020, OCR added a second module on effective communication requirements for individuals who are deaf or hard of hearing, pursuant to Section 1557, Section 504 of the Rehabilitation Act of 1973, and the Americans With Disabilities Act.
- The Administration for Community Living (ACL) and CMS administer the National Center on Advancing Person-Centered Practices and Systems (NCAPPS) (https://ncapps.acl.gov/) to help states, tribes, and territories apply person-centered thinking, planning, and practice. NCAPPS provides technical assistance, learning collaboratives, public monthly webinars, and a resource clearinghouse dedicated to improving education about and implementation of person-centered principles.
- The Veterans Health Administration (VHA) Office of Patient Centered Care & Cultural Transformation is transforming from the traditional model of healthcare to a personalized, proactive, patient-driven model through the Whole Health program (https://www.va.gov/wholehealth/).

An individual’s experience is also affected by health literacy levels. AHRQ has produced a toolkit called the SHARE approach (https://www.ahrq.gov/health-literacy/curriculum-tools/shareddecisionmaking/index.html), which involves a five-step process for shared decision making and tools to help individuals and providers ensure clear understanding and communication with one another.

#### Examining Person-Centered Care Quality Measures by Setting of Care

Figure 4 Number and percentage of all person-centered care measures improving, not changing, or worsening from 2002 to 2019, by setting of care

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percent change is 1% or greater in the desirable direction, and p <0.10.
- Not changing: The average annual percent change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percent change is 1% or greater in the undesirable direction, and p <0.10.

Stacked bar chart showing number of measures in each category: Total (n=26), 14 improving, 12 not changing Hospital (n=1), 1 improving, 0 not changing, 0 worsening. Ambulatory (n=8, 6 improving, 2 not changing, 0 worsening. Home Health (n=9), 4 improving, 5 not changing, 0 worsening. Hospice Care (n=8), 3 improving, 5 not changing, 0 worsening.

Core measures listed below are noted as improving (green) or not changing (yellow). More information on how this analysis is conducted is available in the NHQDR Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html). More details about the measures shown here are available at the NHQDR website (https://datatools.ahrq.gov/nhqdr).

Table 1 Hospital Measures

Among the core Person-Centered Care measures, only one speaks to inpatient quality of care. The inpatient quality of care measure improved.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Communication | Adult hospital patients who sometimes or never had good communication about medications they received in the hospital (Hospital Consumer Assessment of Healthcare Providers and Systems [HCAHPS]) | 12.7% in 2009 | 10.8% in 2019

Table 2 Ambulatory Measures

Among eight measures related to ambulatory care, six were improving over time and two were not changing. These measures include experience of care measures that examine communication between individuals and providers over the course of a year.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Health Literacy | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always gave them easy-to-understand instructions about what to do for a specific illness or health condition (Medical Expenditure Panel Survey [MEPS]) | 64.1% in 2011 | 73.0% in 2017
Health Literacy | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand (MEPS) | 9.0% in 2002 | 7.4% in 2017
Respect | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never spent enough time with them (MEPS) | 15.3% in 2002 | 11.0% in 2017
Respect | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say (MEPS) | 8.8% in 2002 | 6.9% in 2017
Respect | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never listened carefully to them (MEPS) | 10.3% in 2002 | 8.2% in 2017
Healthcare Experience | Adults who rated their healthcare received in the last 12 months as poor (0–6) on a scale of 0–10 (where 0 is the worst and 10 is the best) (MEPS) | 14.4% in 2002 | 12.8% in 2017
Not Changing
Health Literacy | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always asked them to describe how they would follow the instructions (MEPS) | 24.4% in 2011 | 26.6% in 2017
Health Literacy | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always offered help in filling out forms (MEPS) | 14.8% in 2011 | 15.4% in 2017

Table 3 Home Health Care Measures

Among nine home health care measures, four improved over time. Five measures showed no statistically significant change.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Pain | Adults who reported that home health care providers talked about pain in the last 2 months of care (Home Health Care Consumer Assessment of Healthcare Providers and Systems [HHCAHPS]) | 87.5% in 2012 | 90.0% in 2019
Caregiving | Adults who reported being told what care and services they would get when they first started getting home health care (HHCAHPS) | 88.2% in 2012 | 89.3% in 2019
Health Literacy | Adults who reported that home health care providers always explained things in a way that was easy to understand in the last 2 months of care (HHCAHPS) | 82.3% in 2012 | 83.8% in 2019
Respect | Adults who reported that home health care providers always treated them with courtesy and respect in the last 2 months of care (HHCAHPS) | 93.2% in 2012 | 93.7% in 2019
Not Changing
Respect | Adults who reported that home health care providers always listened carefully to them in the last 2 months of care (HHCAHPS) | 83.9% in 2012 | 84.7% in 2019
Caregiving | Adults who reported that home health care providers always kept them informed about when they would arrive at their home in the last 2 months of care (HHCAHPS) | 78.8% in 2012 | 79.8% in 2019
Pain | Adults who reported that home health care providers always treated them as gently as possible in the last 2 months of care (HHCAHPS) | 90.0% in 2012 | 90.3% in 2019
Caregiving | Adults who did not have any problem with the care they received from their home health care providers in the last 2 months of care (HHCAHPS) | 92.6% in 2012 | 92.6% in 2019
Shared Decision Making | Adults who reported getting the help or advice they needed when they contacted their home health care provider in the last 2 months of care (HHCAHPS) | 28.2% in 2012 | 23.8% in 2019

Table 4 Hospice Care Measures

Among eight hospice care outcome measures, three improved over time. Five measures showed no statistically significant change.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Caregiving | Family caregivers who received the right amount of emotional and spiritual support from the hospice care team (Hospice CAHPS) | 88.8% in 2015 | 90.0% in 2019
Caregiving | Family caregivers who rated the hospice care for their family member best (9–10) on a scale of 0–10 (where 0 is the worst and 10 is the best) (Hospice CAHPS) | 79.9% in 2015 | 81.0% in 2019
Caregiving | Hospice patients whose hospice care team always communicated well with their family caregivers about taking care of them (Hospice CAHPS) | 79.4% in 2015 | 80.3% in 2019
Not Changing
Caregiving | Hospice patients whose hospice care team always treated them with dignity and respect, and really cared about them (Hospice CAHPS) | 89.5% in 2015 | 89.9% in 2019
Caregiving | Family members who definitely received training about taking care of their family member from the hospice care team (Hospice CAHPS) | 72.6% in 2015 | 73.3% in 2019
Caregiving | Hospice patients who always received enough help for pain, sadness, breathing, or constipation from the hospice care team (Hospice CAHPS) | 74.7% in 2015 | 75.0% in 2019
Caregiving | Family caregivers who would definitely recommend this hospice to their friends and family (Hospice CAHPS) | 84.6% in 2015 | 84.8% in 2019
Caregiving | Hospice patients and family caregivers who always got help as soon as they needed from the hospice care team (Hospice CAHPS) | 77.4% in 2015 | 77.5% in 2019

## Trends in Patient Safety

The Institute of Medicine (IOM)^xiv^ defines patient safety as “freedom from accidental injury due to medical care or medical errors.”^28^ In 1999, the IOM published their landmark report, To Err Is Human: Building a Safer Health System,^28^ which called for a national effort to reduce medical errors and improve patient safety. Since then, AHRQ has been the federal lead for patient safety research.^xv^

The IOM report was the impetus for the Patient Safety and Quality Improvement Act of 2005. The Act outlined a patient safety reporting system to provide anonymous and aggregated data about patient safety events, including the creation of AHRQ’s Network of Patient Safety Databases (NPSD) and certification of listed Patient Safety Organizations (PSOs).

In 2015, the National Academy of Medicine built on its initial report on patient safety by publishing Improving Diagnosis in Health Care, which identifies eight major goals for effecting progress on diagnostic error and improving patient safety outcomes.^12^ Although improving diagnostic safety and quality was not fully addressed in To Err is Human, the patient safety field has now established consensus that more attention needs to be placed on reducing diagnostic error.

In 2020, AHRQ published an updated synthesis of the scientific evidence for various patient safety practices, Making Healthcare Safer III (https://www.ahrq.gov/research/findings/making-healthcare-safer/mhs3/index.html). This compendium summarizes the evidence for 47 different patient safety practices that address 17 different harm areas, such as healthcare-associated infections, medication management, and diagnostic safety.

More recently, AHRQ released Strategies to Improve Patient Safety: Draft Report to Congress for Public Comment and Review by the National Academy of Medicine (https://pso.ahrq.gov/sites/default/files/wysiwyg/strategies-to-improve-patient-safety_draft-report.pdf) for public comments in December 2020. This draft report provides an overview of the Patient Safety and Quality Improvement Act of 2005, strategies for reducing medical errors and increasing patient safety, and recommendations for encouraging the use of patient safety strategies.

In addition to providing reports and materials, AHRQ has identified three long-term goals related to improving patient safety. These are:

- Reducing preventable hospital admissions and readmissions,
- Reducing the incidence of adverse healthcare-associated conditions (HACs), and
- Reducing harm from inappropriate or unnecessary care.

To meet these goals, AHRQ supports research and quality improvement programs to reduce healthcare-associated infections (HAIs) and HACs, adverse drug events, and other preventable adverse events. In particular, a common cause of adverse events is gaps in communication either between providers or with patients, their family members, or caregivers.

Communication gaps may occur unintentionally and may result from implicit biases among healthcare providers.^29^ Thus, researchers, providers, and policymakers are considering patient safety and person-centered care together to better understand breakdowns in care so that patients experience safer care and better health outcomes.

### Importance of Patient Safety

#### Mortality

Number of deaths in U.S. hospitals due to medical error each year (1999) | 44,000–98,000^28^
Age-standardized mortality rate due to adverse effects of medical treatment (2016) | 1.15 per 100,000 population^30^

#### Prevalence

Number of hospital-acquired conditions in U.S. hospitals (2017) | 2,550,000^31^
All-payer 30-day readmission rate (2016) | 13.9% of admissions^32^

#### Cost

Additional hospital inpatient cost due to hospital-acquired conditions (2014)^30^:

Central line-associated bloodstream infection (CLABSI) | $48,108
Ventilator-associated pneumonia | $47,238
Surgical site infection (SSI) | $28,219
Venous thromboembolism | $17,367

### Findings on Patient Safety

The Patient Safety priority area includes measures of:

- Healthcare-Associated Infections.
- Surgical Care.
- Other Complications of Hospital Care.
- Complications of Medication.
- Birth-Related Complications.
- Maternal Morbidity and Mortality.
- Inappropriate Treatment.
- Supportive and Palliative Care.
- Home Health Care Communication.

Data for these measures can be found at https://datatools.ahrq.gov/nhqdr. More information on maternal morbidity and mortality measures, including measures related to postpartum hemorrhage, eclampsia/preeclampsia, and cesarean delivery, can be found in the NHQDR Chartbook on Patient Safety (https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/patientsafety/index.html).

Measures related to urinary tract infections and pressure ulcers in nursing home residents were better than the benchmark.

Of the 26 Patient Safety measures included, 11 measures (42%) improved over time. The following three measures showed the most improvement:

- Long-stay nursing home residents with a urinary tract infection.
- Short-stay nursing home patients with pressure ulcers that are new or worsened.
- Adverse drug event with IV heparin in adult hospital patients who received an anticoagulant.

One measure worsened:

- Adults who reported a home health care provider asking to see all the prescription and over-the-counter medicines they were taking, when they first started getting home health care.

#### Improving Trend: Urinary Tract Infections Among Nursing Home Residents

Urinary tract infections are one of the most frequent types of infections among nursing home residents. These residents typically have other comorbidities and may not receive timely diagnoses, “leading to increased rates of adverse drug effects and more recurrent infections with drug-resistant bacteria.”^33^

Figure 5 Long-stay nursing home residents with a urinary tract infection, 2013–2018 (lower rates are better)

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage: 2013, 4.9 2014, 4.4 2015, 3.7 2016, 3.0 2017, 2.2 2018, 2.0 2015 achievable benchmark: 2.8%

Source: Centers for Medicare & Medicaid Services, Minimum Data Set, 2013–2018.

- From 2013 to 2018, overall, the percentage of long-stay nursing home residents with a urinary tract infection decreased from 4.9% to 2.0% (Figure 5).
- The 2015 achievable benchmark was 2.8%. The national rate in 2018 was better than the benchmark percentage.
- The top 10% of states that contributed to the achievable benchmark were California, Connecticut, Hawaii, New Jersey, and New Mexico.

#### Improving Trend: New or Worsening Pressure Ulcers Among Nursing Home Patients

Pressure ulcers, also known as bedsores, are injuries to the skin typically caused by pressure against the skin in people with limited mobility. The earlier pressure ulcers are identified, the easier they are to treat. Chronic pressure ulcers are often more difficult to treat and recur after healing. Severe pressure ulcers may require surgery. Although they are typically preventable, pressure ulcers affect more than 3 million people each year.^34,^ ^35^

Figure 6 Short-stay nursing home patients with pressure ulcers that are new or worsened, 2013–2018 (lower rates are better)

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is in Introductions and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage: 2013, 0.68 2014, 0.56 2015, 0.52 2016, 0.47 2017, 0.42 2018, 0.23 2015 achievable benchmark: 0.31%

Source: Centers for Medicare & Medicaid Services, Minimum Data Set, 2013–2018.

- From 2013 to 2018, overall, the percentage of short-stay nursing home patients with pressure ulcers that are new or worsened decreased from 0.68% to 0.23% (Figure 6).
- The 2015 achievable benchmark was 0.31%. The national rate in 2018 was better than the benchmark percentage.
- The top 10% of states that contributed to the achievable benchmark were Arizona, Hawaii, Nevada, Utah, and Vermont.

#### Improving Trend: Adverse Drug Events With Heparin and Factor Xa

Adverse drug events (ADEs) include medication errors and adverse drug reactions, representing a major source of harm among hospitalized patients. Anticoagulant drugs are some of the most implicated medications causing ADEs in hospitalized patients and many of their associated ADEs may be preventable.^36^

Anticoagulant drugs include warfarin, unfractionated heparin (UFH), and low-molecular-weight heparin (LMWH). UFH and LMWH are used to prevent venous thromboembolic disease on acute or elective admission to the hospital and to treat deep vein thrombosis and pulmonary embolism. Factor Xa is used to reverse the effects of certain anticoagulant drugs when bleeding becomes uncontrolled.

Figure 7 Adverse drug event with IV heparin in adult hospital patients who received an anticoagulant, 2014–2019 (lower rates are better)

Note: Data were pooled for 2018 and 2019.

Line graph showing percentage: 2014, 11.1 2015, 10.8 2016, 7.2 2017, 6.1 2018–2019, 5.8

Source: Agency for Healthcare Research and Quality and Centers for Medicare & Medicaid Services, Medicare Patient Safety Monitoring System, 2014–2019.

- From 2014 to 2019, overall, the percentage of inpatient adults who received an anticoagulant and experienced an ADE associated with IV heparin decreased from 11.1% to 5.8% (Figure 7).

#### Worsening Trend: Home Health Care Provider Checking Medication

Home health care providers’ asking to see all prescribed and over-the-counter medications is a preliminary step in ensuring that patients take only medications appropriate to their condition and understand why, when, and how much of each medication to take. This step may be especially important in protecting against medication errors and adverse events after transitions from facility-based institutional care to care in the community.^37^

This measure focuses on patients’ recollection of their experience with the home health care agency. It is important to note that the skill sets and required background training of home health care workers vary substantially across states. While home health care workers in some states may be trained to assist providers in medication reconciliation, workers in other states may not. Medication reconciliation is a key part of ambulatory care.

Figure 8 Adults who reported a home health care provider asking to see all the prescription and over-the-counter medicines they were taking when they first started getting home health care, 2012–2019

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is in Introductions and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage: 2015 Achievable Benchmark: 85.5% 2012, 78.8 2013, 78.9 2014, 78.3 2015, 77.8 2016, 77.6 2017, 77.1 2018, 76.5 2019, 76.3

Source: Centers for Medicare & Medicaid Services, Home Health Care Consumer Assessment of Healthcare Providers and Systems, 2012–2019.

- From 2012 to 2019, overall, the percentage of adults who reported a home health care provider asking to see all the prescription and over-the-counter medicines they were taking when they first started getting home health care decreased from 78.8% to 76.3% (Figure 8).
- The 2015 achievable benchmark was 85.5%. There is no evidence of progress toward the benchmark.
- The top 10% of states that contributed to the achievable benchmark were Alabama, Arkansas, Louisiana, Mississippi, Texas, and West Virginia. Four territories, Guam, Northern Mariana Islands, Puerto Rico, and Virgin Islands, while not included in the benchmark, had percentages within the benchmark range.

One home health care measure showed widening disparities over time between Asian people and White people: Oral medication management among home health care patients (see Disparities section, Racial and Ethnic Disparities).

#### Resources

Efforts to promote patient safety are underway within HHS. The following are examples of resources available related to patient safety background, education and training, toolkits, data, and surveys. Additional resources can be found on AHRQ’s Patient Safety site (https://www.ahrq.gov/patient-safety/index.html).

##### Background

- The National Steering Committee for Patient Safety is cochaired by AHRQ and the Institute for Healthcare Improvement with members from the healthcare, policy, regulatory, and advocacy communities. The committee is charged with creating a national action plan to guide patient safety efforts (https://www.ahrq.gov/patient-safety/reports/safer-together.html) across the country in a cohesive and coordinated fashion.
- Recognizing the role ADE prevention plays in improving patient safety, the Office of Disease Prevention and Health Promotion developed the National Action Plan for Adverse Drug Event Prevention (https://health.gov/hcq/ade-action-plan.asp). The initial targets of the Action Plan are bleeding related to use of anticoagulants; hypoglycemia related to use of diabetes medications; and accidental overdose, oversedation, and respiratory depression related to use of opioids. The plan suggests a four-pronged approach of surveillance, prevention, incentives and oversight, and research.
- AHRQ implements the Patient Safety and Quality Improvement Act (https://pso.ahrq.gov/legislation) of 2005 except for the confidentiality and related enforcement provisions delegated to the Office for Civil Rights. The goal of the Act is to improve patient safety, in part by creating federally listed PSOs to collect and analyze aggregated, privileged, and confidential data on patient safety events.
- AHRQ maintains PSNet (https://psnet.ahrq.gov/), a web-based tool with more than 15,000 resources, providing the latest literature, news, and commentary on patient safety. PSNet includes weekly literature updates, news, tools, and meetings; patient safety primers; and annotated links to important research and other information on patient safety.
- Morbidity and Mortality Rounds on the Web (Web M&M (https://psnet.ahrq.gov/webmm)) is a peer-reviewed online journal and forum on patient safety and healthcare quality. It provides case reports, safety perspectives, and expert analysis.

##### Education and Training

- AHRQ sponsors the Comprehensive Unit-based Safety Program (https://www.ahrq.gov/hai/cusp/index.html) (CUSP). This patient safety method combines improvement in safety culture, teamwork, and communication with a set or checklist of evidence-based practices known to be effective in preventing HAI or other harms. It builds the capacity to address safety issues by combining clinical best practices and the science of safety. The core CUSP principles can be applied to reduce and eliminate HAIs and perinatal safety events. AHRQ has sponsored 10 related programs (https://www.ahrq.gov/hai/cusp/index.html) to date. CUSP also provides a 23-minute video, Understand the Science of Safety (https://www.ahrq.gov/professionals/education/curriculum-tools/cusptoolkit/videos/04a_scisafety/index.html).
- AHRQ, with the Department of Defense, sponsored the development of Team Strategies and Tools to Enhance Performance and Patient Safety (TeamSTEPPS^®^ (https://www.ahrq.gov/teamstepps)). TeamSTEPPS is an evidence-based set of teamwork tools aimed at optimizing patient outcomes by improving communication and teamwork skills among healthcare professionals. The TeamSTEPPS curriculum is available online and can be used to train inpatient, nursing home, and medical office providers.
- AHRQ developed the SHARE Approach (https://www.ahrq.gov/health-literacy/professional-training/shared-decision/index.html) and workshop curriculum to provide a comprehensive resource to healthcare staff, with materials supporting shared decision making between providers, patients, and patients’ caregivers.
- AHRQ’s Health Literacy microsite (http://www.ahrq.gov/health-literacy) includes improvement tools, such as the AHRQ Health Literacy Universal Precautions Toolkit (https://www.ahrq.gov/health-literacy/improve/precautions/index.html), to promote better understanding by all patients. It also provides education and trainings to increase health literacy and publications related to health literacy. The microsite includes the AHRQ Pharmacy Health Literacy Center (https://www.ahrq.gov/health-literacy/improve/pharmacy/index.html).

##### Toolkits

- Communication and Optimal Resolution (CANDOR) is a process healthcare institutions and practitioners can use to respond in a timely, thorough, and just way when unexpected events cause patient harm. AHRQ has pilot tested and produced the CANDOR Toolkit (https://www.ahrq.gov/patient-safety/capacity/candor/modules.html) for hospitals and healthcare systems to implement as a process for responding to harm events and initiating improvements in safety outcomes.
- AHRQ created the On-Time Pressure Ulcer Prevention Toolkit (https://www.ahrq.gov/patient-safety/settings/long-term-care/resource/ontime/pruprev/index.html) to help nursing homes with electronic medical records reduce the occurrence of in-house pressure ulcers.
- AHRQ developed the Safety Program for Perinatal Care (SPPC) to improve the patient safety culture of labor and delivery units and decrease maternal and neonatal adverse events resulting from poor communication and system failures. The SPPC developed the Toolkit for Improving Perinatal Safety (https://www.ahrq.gov/hai/tools/perinatal-care/index.html) around three program pillars: teamwork and communication skills, perinatal safety strategies, and in situ simulation training.
- To improve consistency between a patient’s current medication regimen and physicians’ orders, AHRQ funded the development of the Medications at Transitions and Clinical Handoffs (MATCH) Toolkit (http://www.ahrq.gov/patient-safety/resources/match/index.html) for medication reconciliation.
- AHRQ provides toolkits to reduce specific HAIs, including Toolkit for Reduction of Clostridium difficile Infections Through Antimicrobial Stewardship (https://www.ahrq.gov/hai/patient-safety-resources/cdiff-toolkit/index.html), Toolkit for Reducing Catheter-Associated Urinary Tract Infections (CAUTIs) in Hospitals (https://www.ahrq.gov/hai/tools/cauti-hospitals/index.html), and Toolkit for Reducing Central Line-Associated Blood Stream Infections (CLABSIs) (https://www.ahrq.gov/hai/clabsi-tools/index.html).
- Recognizing that medical errors can occur during transitions in care due, in part, to a lack of effective communication, AHRQ funded the Toolkit to Engage High-Risk Patients in Safe Transitions Across Ambulatory Settings (https://www.ahrq.gov/hai/tools/ambulatory-care/safe-transitions.html). The goal is to help providers actively engage patients and their care partners to prevent errors during transitions of care from one ambulatory setting to another.
- AHRQ provides the Toolkit to Promote Safe Surgery (https://www.ahrq.gov/hai/tools/surgery/index.html) to reduce patient safety events in hospitals and the Toolkit to Improve Safety in Ambulatory Surgery Centers (https://www.ahrq.gov/hai/tools/ambulatory-surgery/index.html) to improve patient safety in ambulatory settings.

##### Data

- AHRQ’s Network of Patient Safety Databases (https://www.ahrq.gov/npsd/index.html) consists of patient safety data submitted by providers through PSOs that can be used for national learning to improve patient safety. The NPSD represents the first attempt to collect this type of comprehensive data on a national scale, and its data reporting tools include annually updated dashboards and chartbooks. Findings based on the 2020 NPSD Dashboards (https://www.ahrq.gov/npsd/data/dashboard/index.html) are presented below.
- The AHRQ National Scorecard on Hospital-Acquired Conditions (https://www.ahrq.gov/hai/pfp/index.html) provides longitudinal data and reports related to trends across hospital-acquired conditions overall and for specific conditions, such as ADEs, HAIs, and falls. The scorecard also provides data visualization tools.

##### Surveys

- The Centers for Disease Control and Prevention (CDC) HAI and Antibiotic Use Prevalence Survey (https://www.cdc.gov/hai/eip/antibiotic-use.html) assesses the prevalence and types of HAIs, types of antimicrobial medications (e.g., antibiotics), and ways antimicrobial medications are used in hospitals and nursing homes. Especially with the rise in antibiotic-resistant strains of germs such as bacteria and fungi, the survey is critical in tracking HAIs and the medications used to treat them.
- AHRQ funded the development of the Surveys on Patient Safety Culture (SOPS^®^) (https://www.ahrq.gov/sops/index.html) to give healthcare staff resources to assess the patient safety and healthcare quality in their facility. The surveys are tailored to the healthcare setting and are available for hospitals, medical offices, nursing homes, community pharmacies, and ambulatory surgery centers.
- AHRQ oversees and funds the Consumer Assessment of Healthcare Providers and Systems (CAHPS) (https://www.ahrq.gov/cahps/index.html) surveys. The surveys assess patient experiences with their providers, healthcare facilities, and health plans. CAHPS databases provide aggregated data from select CAHPS surveys.
- CDC’s National Ambulatory Medical Care Survey (NAMCS) and National Hospital Ambulatory Medical Care Survey (NHAMCS) (https://www.cdc.gov/nchs/ahcd/index.htm) may be used to assess various procedures and screenings (or lack thereof) when certain diagnoses are present, in relation to some guideline or best practice. In addition, NHAMCS collects data from ED visits related to injuries and falls.

##### Additional Resources

- AHRQ funds the Nursing Home COVID-19 Action Network (https://www.ahrq.gov/nursing-home/index.html) to support the implementation of patient safety and quality best practices in nursing homes to reduce the spread of COVID-19.
- CDC’s Antibiotic Prescribing and Use in the U.S. Stewardship Reports (https://www.cdc.gov/antibiotic-use/stewardship-report/index.html) provide:
  ■ Information about outpatient antibiotic prescribing rates and implementation of hospital antibiotic stewardship programs by state;
  ■ National Healthcare Safety Network Antimicrobial Use Option updates and success stories;
  ■ Recent literature highlighting progress made and opportunities for improvement;
  ■ New and updated resources for health departments, facilities, and healthcare professionals to implement antibiotic stewardship; and
  ■ Examples of key contributions to improve antibiotic prescribing practices.
- CDC’s 2020 National and State Healthcare HAI Progress Report (https://www.cdc.gov/hai/data/portal/progress-report.html):
  ■ Presents information on select HAIs across four healthcare settings: acute care hospitals, critical access hospitals, inpatient rehabilitation facilities, and long-term acute care hospitals.
  ■ Provides national- and state-level data about HAI incidence during 2020, primarily focusing on the following HAIs: CLABSIs, CAUTIs, ventilator-associated events (VAEs), surgical site infections (SSIs), methicillin-resistant Staphylococcus aureus (MRSA) bloodstream events, and Clostridioides difficile (C. difficile) events.
  ■ Assesses the impact of the COVID-19 pandemic on HAI incidence.

#### Examining Patient Safety Quality Measures by Setting of Care

Figure 9 Number and percentage of all patient safety measures improving, not changing, or worsening from 2002 to 2019, by setting of care

Key: n = number of measures.

Note: Patient safety measures include measures related to nursing home resident safety. For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percent change is 1% or greater in the desirable direction, and p <0.10.
- Not changing: The average annual percent change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percent change is 1% or greater in the undesirable direction, and p <0.10.

Stacked bar chart showing number of measures in each category: Total (n=26), 11 improving, 14 not changing, 1 worsening. Hospital (n=11), 2 improving, 9 not changing, 0 worsening. Ambulatory (n=2), 2 improving, 0 not changing, 0 worsening. Home Health (n=8), 3 improving, 4 not changing, 1 worsening. Hospice Care (n=5), 4 improving, 1 not changing, 0 worsening.

Core measures listed below are noted as improving (green), not changing (yellow), or worsening (red) over time. More information on how this analysis is conducted is available in the NHQDR Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html). More details about the measures shown here are available at the NHQDR website (https://datatools.ahrq.gov/nhqdr).

Table 5 Hospital Measures

Among 11 Patient Safety measures for inpatients, 2 measures were improving and 9 were not changing. The improving measures were related to medication safety and HAIs.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Medication Safety | Adverse drug event with IV heparin in adult hospital patients who received an anticoagulant (Medicare Patient Safety Monitoring System [MPSMS]) | 11.1% in 2014 | 5.8% in 2018–2019
Healthcare-Associated Infections | Adult surgery patients with catheter-associated urinary tract infection (MPSMS) | 2.6% in 2014 | 1.9% in 2018–2019
Not Changing
Medication Safety | Hospital patients with an anticoagulant-related adverse drug event to low-molecular-weight heparin (LMWH) and factor Xa (MPSMS) | 3.5% in 2014 | 2.2% in 2018–2019
Surgical Safety | Inpatient adverse events in adults receiving hip joint replacement due to degenerative conditions (MPSMS) | 2.9% in 2014 | 1.9% in 2018–2019
Medication Safety | Hospital patients who received a hypoglycemic agent who had an adverse drug event with a hypoglycemic agent (MPSMS) | 8.8% in 2014 | 7.2% in 2018–2019
Healthcare-Associated Infections | Adult surgery patients with postoperative pneumonia events (MPSMS) | 1.8% in 2014 | 1.4% in 2018–2019
Surgical Safety | Inpatient adverse events in adults receiving hip joint replacement due to fracture (MPSMS) | 9.8% in 2014 | 8.9% in 2018–2019
Medication Safety | Hospital patients with an anticoagulant-related adverse drug event to warfarin (MPSMS) | 4.8% in 2014 | 4.9% in 2018–2019
Procedural Event | Mechanical adverse events in adult patients receiving central venous catheter placement (MPSMS) | 3.3% in 2014 | 3.3% in 2018–2019
Surgical Safety | Inpatient adverse events in adults receiving knee replacement (MPSMS) | 2.6% in 2014 | 2.6% in 2018–2019
Venous Thromboembolism | Adult surgery patients with postoperative venous thromboembolic events (MPSMS) | 0.45% in 2014 | 0.51% in 2018–2019

Table 6 Ambulatory Measures

Both of the two ambulatory care Patient Safety measures were improving over time. Both were process measures pertaining to prescription medications.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Medication Safety | Adults age 65 and over who received in the calendar year at least 1 of 11 prescription medications that should be avoided in older adults (MEPS) | 3.3% in 2002 | 1.3% in 2018
Medication Safety | Adults age 65 and over who received in the calendar year at least 1 of 33 potentially inappropriate prescription medications for older adults (MEPS) | 19.3% in 2002 | 10.2% in 2018

Table 7 Home Health Care Measures

Among eight home health care measures, three measures were improving over time, one of which examines a healthcare outcome by looking at oral medication management. One measure was worsening over time, home health care provider assessment of patient medications.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Medication Safety | Home health care patients whose management of oral medications improved (Outcome and Assessment Information System [OASIS]) | 51.9% in 2013 | 70.6% in 2018
Surgical Safety | Home health care patients whose surgical wound was improved (OASIS) | 89.3% in 2013 | 91.6% in 2018
Falls | Adults who reported a home health care provider talking with them about how to set up their home so they could move around safely when they first started getting home health care (HHCAHPS) | 74.2% in 2012 | 77.0% in 2019
Not Changing
Medication Safety | Adults who reported a home health care provider talking with them about all the prescription and over-the-counter medicines they were taking when they first started getting home health care (HHCAHPS) | 83.8% in 2012 | 84.0% in 2019
Medication Safety | Adult who reported that home health care providers talked with them about the side effects of medicines in the last 2 months of care (HHCAHPS) | 26.4% in 2012 | 23.8% in 2019
Medication Safety | Adults who reported that home health care providers talked with them about the purpose for taking their new or changed prescription medicines in the last 2 months of care (HHCAHPS) | 33.1% in 2012 | 30.7% in 2019
Medication Safety | Adults who reported that home health care providers talked with them about when to take medicines in the last 2 months of care (HHCAHPS) | 30.7% in 2012 | 28.0% in 2019
Worsening
Medication Safety | Adults who reported a home health care provider asking to see all the prescription and over-the-counter medicines they were taking when they first started getting home health care (HHCAHPS) | 78.8% in 2012 | 76.3% in 2019

Table 8 Nursing Home Care Measures

Among five nursing home care measures, four were improving over time. The one measure that was not changing over time examines long-stay (e.g., 100+ days) nursing home patients who experience injuries after falls.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Procedural Event | Long-stay nursing home residents with a urinary tract infection (Minimum Data Set [MDS]) | 4.9% in 2013 | 2.0% in 2018
Pressure Ulcers | Short-stay nursing home patients with pressure ulcers that are new or worsened (MDS) | 0.68% in 2013 | 0.23% in 2018
Healthcare-Associated Infections | Low-risk, long-stay nursing home residents with a catheter inserted and left in the bladder (MDS) | 3.4% in 2013 | 2.7% in 2018
Pressure Ulcers | High-risk, long-stay nursing home patients with pressure ulcer (MDS) | 5.3% in 2013 | 4.8% in 2018
Not Changing
Falls | Long-stay nursing home patients experiencing one or more falls with major injury (MDS) | 0.60% in 2013 | 0.59% in 2018

#### Examining Patient Safety Data Reported to the Network of Patient Safety Databases by AHRQ-Listed Patient Safety Organizations

The NPSD provides an interactive, evidence-based resource for providers, PSOs, and others with the capacity to accept, aggregate, and analyze nonidentifiable patient safety work product submitted by PSOs from across the country. The NPSD is a unique source of data that supports national learning into how and why patient safety events occur by providing insight into areas such as contributing factors.

The NPSD strives to make data publicly available at a level of detail that is useful for learning about patient safety, but it must do so without compromising the confidentiality of patients, providers, and reporters. The NPSD does not contain a representative sample of patient safety concerns and cannot be used to calculate the actual incidence or prevalence of patient safety concerns.

The data presented in this section are based on the NPSD Dashboards (https://www.ahrq.gov/npsd/data/dashboard/index.html), visualization products based on more than 1.7 million records reported by healthcare providers to approximately 15% of AHRQ-listed PSOs (https://pso.ahrq.gov/listed). Providers and PSOs that contribute data play an essential role in growing the NPSD into a more robust national resource for patient safety and quality improvement. The voluntarily submitted patient safety data include information about patient safety concern (event types), report type, extent of harm, and event type-specific details.

The data below are a subset of figures available on the NPSD Dashboards. Figures 10–12 present data across multiple patient safety concerns (event types) from the NPSD Generic Dashboard. Figures 13–16 provide information on four of the patient safety concern-specific dashboards (Blood and Blood Product Dashboard; Device or Medical/Surgical Supply, Including HIT, Dashboard; Falls Dashboard; and Medication or Other Substance Dashboard).

Figure 10 Distribution of Patient Safety Concerns (Event Types) Reported to the Network of Patient Safety Databases by AHRQ-Listed Patient Safety Organizations, 2009–2019

Note: Patient safety concerns (event types) also include healthcare-associated infection and venous thromboembolism, for which percentages were suppressed to meet nonidentification requirements. Other indicates an event type other than the types listed.

Columns showing percentage: Other, 50.6% Medication or Other Substance, 22.6% Fall, 10.7% Surgery or Anesthesia, 5.3% Pressure Ulcer, 5.1% Device or Medical/Surgical Supply, 2.6% Perinatal, 1.8% Blood or Blood Product, 1.3%

Source: Agency for Healthcare Research and Quality, National Patient Safety Database, 2009–2019.

- In 2009–2019, most reported patient safety concerns were categorized as an “other” event type (50.6%) (Figure 10). Medication or other substance (22.6%) and fall (10.7%) were the next most common types of reported patient safety concerns.

Figure 11 Distribution of Report Type by Patient Safety Concerns (Event Types) Reported to the Network of Patient Safety Databases by AHRQ-Listed Patient Safety Organization, 2009–2019

Note: Patient safety concerns (event types) also include healthcare-associated infection and venous thromboembolism, for which percentages were suppressed to meet nonidentification requirements. Other indicates an event type other than the types listed. Incident is defined as a patient safety event that reached the patient, whether or not the patient was harmed; near-miss (often called a close call) is defined as a patient safety event that transpired but did not reach the patient; and unsafe condition is defined as any circumstance that increases the probability that a patient safety event may occur.

Bar charts showing percentage of incidents, near-misses, and unsafe conditions for each event type. Key findings are in the text below the chart.

Source: Agency for Healthcare Research and Quality, National Patient Safety Database, 2009–2019.

- In 2009–2019, 100% of reported fall, perinatal, and pressure ulcer patient safety concerns were incidents (Figure 11). The percentage of near-miss reports was highest for device or medical/surgical supply (28.4%) and medication or other substance (27.3%). The percentage of reported unsafe conditions was highest for other event types (9.6%) and device or medical/surgical supply (9.0%).

Figure 12 Distribution of Extent of Harm by Patient Safety Concerns (Event Types) Reported to the Network of Patient Safety Databases by AHRQ-Listed Patient Safety Organizations, 2009–2019

Note: Patient safety concerns (event types) also include healthcare-associated infection and venous thromboembolism, for which percentages were suppressed to meet nonidentification requirements. Other indicates an event type other than the types listed. No harm is defined as an event that reached the patient, but no harm was evident; mild harm is defined as bodily or psychological injury resulting in minimal symptoms or loss of function, or injury limited to additional treatment, monitoring, and/or increased length of stay; moderate harm is defined as bodily or psychological injury adversely affecting functional ability or quality of life, but not at the level of severe harm; and severe harm is defined as bodily or psychological injury (including pain or disfigurement) that interferes substantially with functional ability or quality of life. Given the large percentage of unknown harm responses for some patient safety concerns (event types), the true extent of harm percentages may vary from what is presented in the figure.

Bar chart showing percentage of no harm, mild harm, moderate harm, severe harm, death, and unknown harm for each event type. Key findings are in the text below the chart.

Source: Agency for Healthcare Research and Quality, National Patient Safety Database, 2009–2019.

- In 2009–2019, blood or blood product patient safety concerns had the highest percentage of no harm reported (64.6%), and pressure ulcer had the highest percentage of mild harm reported (70.1%) (Figure 12). Surgery or anesthesia had the highest percentage of moderate harm (6.3%), severe harm (1.0%), and death reported (1.0%).

Figure 13 Distribution of Process Stage When Blood or Blood Product Event Originated Reported to the Network of Patient Safety Databases by AHRQ-Listed Patient Safety Organizations, 2009–2019

Note: The percentages for sample receipt and unknown categories were suppressed to meet nonidentification requirements.

Bar showing percentage: Product Manipulation, 1.6% Product Selection, 1.8% Product Check-In, 2.3% Product Storage, 2.7% Sample Testing, 2.9% Sample Handling, 3.2%, Available for Issue, 4.6% Request for Pickup, 5.4% Product Administration, 6.0% Product Issue, 7.2% Product Test or Request, 8.6% Sample Collection, 12.0% Other Process, 12.8% Posttransfusion or Administration, 15.8%

Source: Agency for Healthcare Research and Quality, National Patient Safety Database, 2009–2019.

- In 2009–2019, posttransfusion or administration (15.8%), other process (12.8%), and sample collection (12.0%) were the three most commonly reported process stages for blood or blood product patient safety concerns (Figure 13).

Figure 14 Distribution of Device Type for Device or Medical/Surgical Supply Patient Safety Concern Reported to the Network of Patient Safety Databases by AHRQ-Listed Patient Safety Organizations, 2009–2019

Note: Patient safety concerns related to device or supply event or unsafe condition involve defect, failure, or incorrect use of devices.

Bars showing percentage: Implantable Device (i.e., device intended to be inserted into, and remain permanently in, tissue), 4.9% Health Information Technology (HIT) Device, 5.5% Medical/Surgical Supply, Including Disposable Product (e.g., incontinence supply), 11.8% Medical Equipment (e.g., walker, hearing aid), 77.8%

Source: Agency for Healthcare Research and Quality, National Patient Safety Database, 2009–2019.

- In 2009–2019, medical equipment (77.8%) was the most commonly reported device type for patient safety concerns related to device or medical/surgical supply. Implantable device (4.9%) was the least commonly reported device type (Figure 14).

Figure 15 Distribution of Injury Type Experienced by Patient With Fall Resulting in Injury Reported to the Network of Patient Safety Databases by AHRQ-Listed Patient Safety Organizations, 2009–2019

Note: The patient outcomes for fall include no injury, not shown here.

Bars showing percentage: Dislocation, 0.6% Intracranial Injury, 2.6% Laceration Requiring Sutures, 6.1% Fracture, 11.3% Other Injury, 39.7% Skin Tear, Avulsion, Hematoma, or Significant Bruising, 39.8%

Source: Agency for Healthcare Research and Quality, National Patient Safety Database, 2009–2019.

- In 2009–2019, the most commonly reported fall-related injuries were a skin tear, avulsion, hematoma, or significant bruising (39.8%) and “other injury” not specified on the form (39.7%) (Figure 15).

Figure 16 Distribution of Incorrect Actions for Medication or Other Substance Patient Safety Concern Reported to the Network of Patient Safety Databases by AHRQ-Listed Patient Safety Organizations, 2009–2019

Note: Incorrect dosage form refers to incorrect drug characteristics (e.g., enteric coating, sustained release, capsule, tablet). Incorrect preparation refers to drug delivery methods (e.g., inappropriate cutting of tablets or error in compounding or mixing). Medication or substance that is known allergen to patient also includes items to which a patient is sensitive. Medication or substance contraindicated for patient refers to a reason other than patient allergy or sensitivity. The percentage for patient not known to be allergic or sensitive to medication or substance was suppressed to meet nonidentification requirements.

Bars showing percentage. Key findings are in the text below the chart.

Source: Agency for Healthcare Research and Quality, National Patient Safety Database, 2009–2019.

- In 2009–2019, other incorrect action (32.8%), incorrect dose (25.5%), and incorrect medication or substance (11.5%) were the three most commonly reported types of incorrect action for medication or other substance patient safety concerns (Figure 16).

## Trends in Care Coordination

Healthcare delivery in the United States can be fragmented. Clinical services are frequently organized around small groups of providers who function autonomously and specialize in specific symptoms or organ systems. Therefore, many patients receive attention only for individual health conditions rather than receiving coordinated care. For example, the typical Medicare beneficiary sees a median of two primary care providers and five specialists working in four different practices each year.^38^ Communication of important information among providers and between providers and patients and caregivers may entail delays or inaccuracies or may fail to occur.

Care coordination is a conscious effort to ensure that all key information needed to make care decisions is available to patients and providers. It is defined as the deliberate organization of patient care activities between two or more participants involved in a patient’s care to facilitate appropriate delivery of healthcare services.^39^ Care coordination is multidimensional and essential to preventing adverse events, ensuring efficiency, and making care person centered.^40^

Patients in greatest need of care coordination include those with:

- Multiple chronic medical conditions,
- Concurrent care from several health professionals across care settings,
- Many medications,
- Extensive diagnostic workups, and
- Transitions from one care setting to another.

Effective care coordination requires well-defined multidisciplinary teamwork based on the principle that all who interact with a person must work together to ensure the delivery of safe, high-quality care in every setting.

The goal of care coordination is to enable healthcare providers, patients, and caregivers to all work together to understand and make sure that “patient’s needs and preferences are known and communicated at the right time to the right people and that this information is used to guide the delivery of safe, appropriate, and effective care.”^41^ While measurement of care coordination is at an early stage of development, key goals include coordinating transitions of care, reducing hospital readmissions, communicating medication information, and reducing preventable ED visits.

### Importance of Care Coordination

#### Morbidity and Mortality

Care coordination interventions have been shown to:

- Reduce mortality among patients with heart failure;
- Reduce mortality and dependency among patients with stroke;
- Reduce symptoms among patients with depression and at the end of life; and
- Improve glycemic control among patients with diabetes.^39^

#### Cost

Care coordination interventions have been shown to:

- Reduce hospitalizations among patients with heart failure;
- Reduce readmissions among patients with mental health conditions; and
- Be cost-effective when applied to treatment of depression.^39^

### Findings on Care Coordination

The Care Coordination priority area includes measures of:

- Medication Information.
- Preventable Emergency Department Visits.
- Preventable Hospitalizations Among Home Health Patients.
- Supportive and Palliative Care.
- Transitions of Care.

Other areas represented in the supplemental dataset include:

- Preventable Hospitalizations.
- Potentially Harmful Services Without Benefit.
- Potentially Avoidable Admissions.

Data for these measures can be found at https://datatools.ahrq.gov/nhqdr.

Progress in Care Coordination in certain settings has been slow, with little improvement and three measures getting worse.

The three measures of Care Coordination that showed the greatest improvement are:

- Home health care patients who had timely initiation of care.
- Home health care patients who had to be admitted to the hospital.
- Adult hospital patients who did not receive good communication about discharge information.

In contrast, the three Care Coordination measures that worsened over time are:

- Emergency department visits for asthma per 10,000 population, ages 2–19.
- Home health care patients who had an emergency department visit without a hospitalization.
- Adult hospital patients who strongly disagree or disagree that staff took their preferences and those of their family and caregiver into account when deciding what the patient’s discharge healthcare would be.

#### Improving Trend: Initiation of Home Health Care

The demand for home health care services is increasing due to the growing older population, rising rates of chronic conditions, personal preferences, and advances in the provision of health-related services in patients’ homes. In 2017, 11,844 home health agencies served 3.4 million Medicare beneficiaries at a cost of $17.7 billion.^42^

Figure 17 Home health care patients who had timely initiation of care, 2013–2018

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage: 2015 achievable benchmark: 94.9% 2013, 90.4 2014, 90.5 2015, 91.4 2016, 92.8 2017, 93.6 2018, 94.0

Source: Centers for Medicare & Medicaid Services, Outcome and Assessment Information Set, 2013–2018.

- From 2013 to 2018, overall, the percentage of home health care patients who had timely initiation of care increased from 90.4% to 94.0% (Figure 17).
- The 2015 achievable benchmark was 94.9%. At the current rate of increase, overall, the benchmark could be achieved in 1 year.
- The top 10% of states that contributed to the achievable benchmark were Louisiana, Nebraska, North Dakota, South Dakota, and West Virginia.

#### Improving Trend: Hospitalization of Home Health Care Patients

Nearly 20% of all Medicare beneficiaries discharged from hospitals are rehospitalized within 30 days and 34% are rehospitalized within 90 days.^43^ Reducing the rate of acute care hospitalization for Medicare beneficiaries receiving home health benefits can improve quality and reduce healthcare costs.

Figure 18 Home health care patients who had to be admitted to the hospital, 2013–2018 (lower rates are better)

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage: 2015 achievable benchmark: 10.5% 2013, 15.0 2014, 15.2 2015, 15.1 2016, 14.8 2017, 14.3 2018, 11.5

Source: Centers for Medicare & Medicaid Services, Outcome and Assessment Information Set, 2013–2018.

- From 2013 to 2018, overall, the percentage of home health care patients who had to be admitted to the hospital decreased from 15.0% to 11.5% (Figure 18).
- The 2015 achievable benchmark was 10.5%. There is no evidence of progress toward the benchmark.
- The top 10% of states that contributed to the achievable benchmark were Colorado, Delaware, Montana, South Dakota, and Utah.

#### Improving Trend: Communication About Discharge Information

Effective care coordination begins with ensuring that accurate clinical information is available to support medical decisions by patients and providers. A common transition of care is discharge from the hospital. Giving patients and caregivers self-management support after discharge has been shown to reduce readmissions to the hospital and lower costs.^44^

Figure 19 Adult hospital patients who did not receive good communication about discharge information, 2009–2019 (lower rates are better)

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems, 2009–2019.

- From 2009 to 2019, overall, the percentage of adult hospital patients who did not receive good communication about discharge information decreased from 15.8% to 10.7% (Figure 19).
- The 2015 achievable benchmark was 7.7%. At the current rate of decrease, overall, the benchmark could be achieved in 6 years.
- The top 10% of states that contributed to the achievable benchmark were Colorado, Nebraska, New Hampshire, South Dakota, and Utah.

#### Worsening Trend: Emergency Department Visits for Asthma Among Children

In 2019, 20 million adults and 5.1 million children in the United States had asthma.^45^ Access to care is hampered by socioeconomic disparities, shortages of primary care physicians in minority communities, and language and literacy barriers.^46^

Figure 20 Emergency department visits for asthma per 10,000 population, ages 2–19, 2006–2017 (lower rates are better)

Line graph showing rate per 10,000 population. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2006–2017.

- From 2006 to 2017, overall, the rate of ED visits for asthma among people ages 2–19 years increased from 82.5 to 91.2 per 10,000 population (Figure 20).

#### Worsening Trend: Emergency Department Visits of Home Health Care Patients

Home health care patients can often manage their care with a home health care provider’s support and coordination. When a patient’s need exceeds the resources available to a home health care provider, the provider may refer the patient to an ED.

An ED visit for an urgent need or assessment without a hospitalization is a positive outcome; however, without care coordination, patients may experience similar or related emergencies and return to the ED. Such recurrences can lead to increased costs to the patient and poor health outcomes.

Figure 21 Home health care patients who had an emergency department visit without a hospitalization, 2013–2018 (lower rates are better)

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage: 2015 achievable benchmark: 2.8% 2013, 3.5 2014, 3.6 2015, 3.8 2016, 3.8 2017, 3.9 2018, 3.9

Source: Centers for Medicare & Medicaid Services, Outcome and Assessment Information Set, 2013–2018.

- From 2013 to 2018, overall, the percentage of home health care patients who had an ED visit without a hospitalization increased from 3.5% to 3.9% (Figure 21).
- The 2015 achievable benchmark was 2.8%. There is no evidence of progress toward the benchmark.
- The top 10% of states that contributed to the achievable benchmark were Alabama, District of Columbia, Florida, New Jersey, and Texas. Puerto Rico was not included in the benchmark calculation but its percentage was in the benchmark range.

#### Worsening Trend: Staff Consideration of Patient Preferences on Discharge

Effective care coordination begins with ensuring that accurate clinical information is available to support medical decisions by patients and providers. A common transition of care is discharge from the hospital. Giving patients and caregivers self-management support after discharge has been shown to reduce readmissions to the hospital and lower costs.^40^

Figure 22 Adult hospital patients who strongly disagree or disagree that staff took their preferences and those of their family and caregiver into account when deciding what the patient’s discharge healthcare would be, 2014–2019 (lower rates are better)

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage: 2015 achievable benchmark: 3.2% 2014, 5.4 2015, 5.4 2016, 5.4 2017, 5.5 2018, 5.8 2019, 5.9

Source: Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems, 2014–2019.

- From 2014 to 2019, overall, the percentage of adult hospital patients who strongly disagree or disagree that staff took their preferences and those of their family and caregiver into account when deciding what the patient’s discharge healthcare would be increased from 5.4% to 5.9% (Figure 22).
- The 2015 achievable benchmark was 3.2%. There is no evidence of progress toward the benchmark.
- The top 10% of states that contributed to the achievable benchmark were Iowa, Minnesota, Nebraska, South Dakota, and Utah.

##### Resources

Efforts to promote care coordination are underway within HHS. AHRQ has produced several resources and reports to support improved care coordination in healthcare delivery, including:

- The Care Coordination Measures Atlas Update (https://www.ahrq.gov/professionals/prevention-chronic-care/improve/coordination/atlas2014/index.html) (published in 2014) expands on the atlas first published by AHRQ in 2011. The updated compendium of care coordination measures offers new measures with a focus on those that reflect coordination efforts within the primary care setting. It also includes a section on emerging trends in care coordination measurement.
- The CAHPS Home Health Care Survey (https://www.ahrq.gov/cahps/surveys-guidance/home/index.html) asks patients who receive home health care services about their experiences with home health care agencies, providers, and staff. This instrument focuses on patients who receive skilled home health care services from Medicare-certified home health agencies. Skilled services refer to healthcare services provided by nurses and therapists, including physical, occupational, and speech-language therapists.
- The Clinical-Community Relationships Measures Atlas (https://www.ahrq.gov/professionals/prevention-chronic-care/resources/clinical-community-relationships-measures-atlas/index.html) was published in 2013 to identify ways to further define, measure, and evaluate programs based on clinical-community relationships for the delivery of clinical preventive services. This atlas provides a measurement framework and lists existing measures of clinical-community relationships and is intended to support research and evaluation in the field.

#### Examining Care Coordination Quality Measures by Topic Areas

Figure 23 Number and percentage of all care coordination measures improving, not changing, or worsening from 2002 to 2019, by sub-area

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percent change is 1% or greater in the desirable direction, and p <0.10.
- Not changing: The average annual percent change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percent change is 1% or greater in the undesirable direction, and p <0.10.

Stacked bar chart showing number of measures: Medication Information (n=1), 1 Improving, 0 Not Changing, 0 Worsening. Preventable Eme0gency Department Visits (n=1), 0 Improving, 0 Not Changing, 1 Worsening. Preventable Hospitalizations Among Home Health and Nursing Home Patients (n=1), 0 Improving, 1 Not Changing, 0 Worsening. Supportive and Palliative Care (n=4), 3 Improving, 0 Not Changing, 1 Worsening. Transitions of Care (n=2), 1 Improving, 0 Not Changing, 1 Worsening.

Core measures listed below are noted as improving (green), not changing (yellow), or worsening (red) over time. More information on how this analysis was conducted is available in the NHQDR Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html). More details about the measures shown here are available at the NHQDR website (https://datatools.ahrq.gov/nhqdr).

Table 9 Medication Information Measures

One medication information measure improved over time.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Prescription Medications and Treatment | People with a usual source of care who usually asks about prescription medications and treatments from other doctors (MEPS) | 75.1% in 2002 | 80.0% in 2018

Table 10 Preventable Emergency Department Visit Measures

One measure pertaining to ED visits for asthma worsened over time.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Asthma | Emergency department visits for asthma per 10,000 population, ages 2–19 (National Hospital Ambulatory Medical Care Survey [NHAMCS]) | 82.5 per 10,000 in 2006–2008 | 91.2 per 10,000 in 2015–2017

Table 11 Preventable Hospitalizations Among Home Health and Nursing Home Patient Measures

One measure pertaining to preventable ED visits did not change over time.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Emergency Department Visits | Home health care patients who had an emergency department visit and were then hospitalized (OASIS) | 11.0% in 2013 | 10.4% in 2018

Table 12 Supportive and Palliative Care Measures

Four measures under supportive and palliative care examine the experiences of home health care patients. Patient reporting of home health care provider awareness of the past treatment plan showed improvement whereas number of patients who had an ED visit without a hospitalization worsened over time.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Patient-Provider Communication | Adults who reported that home health providers always seemed informed and up to date about all the care or treatments they got at home in the last 2 months of care (HHCAHPS) | 62.2% in 2012 | 64.9% in 2019
Initiation of Care | Home health care patients who had timely initiation of care (OASIS) | 90.4% in 2013 | 94.0% in 2018
Hospital Admissions | Home health care patients who had to be admitted to the hospital (OASIS) | 15.0% in 2013 | 11.5% in 2018
Worsening
Emergency Department Visits | Home health care patients who had an emergency department visit without a hospitalization (OASIS) | 3.5% in 2013 | 3.9% in 2018

Table 13 Transitions of Care Measures

One measure pertaining to communication about discharge information improved over time and another examining patient experience of providers who considered their preferences worsened over time.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Patient Discharge | Adult hospital patients who did not receive good communication about discharge information (HCAHPS) | 15.8% in 2009 | 10.7% in 2019
Patient Discharge | Adult hospital patients who strongly disagree or disagree that staff took their preferences and those of their family and caregiver into account when deciding what the patient’s discharge healthcare would be (HCAHPS) | 5.4% in 2014 | 5.9% in 2019

## Trends in Affordable Care

The goal of the Affordable Care Act was to establish quality, affordable healthcare for Americans. The law also created a platform to test new healthcare payment and delivery models through the Centers for Medicare & Medicaid Services. Tracking this quality domain helps healthcare professionals, researchers, and policymakers better understand the status of affordable care.

Reducing the cost of healthcare will support two related goals under this quality domain. The first includes ensuring affordable and accessible high-quality healthcare for people, families, caregivers, employers, and governments. The second is supporting and enabling communities to ensure accessible, high-quality care while reducing waste and fraud.

### Importance of Affordable Care

#### Morbidity and Mortality

Affordability of care remains a central barrier to access to care for many individuals and families and caregivers. Several financial and nonfinancial barriers contribute to the inaccessibility of care. Financial barriers include high premiums and copays, lack of insurance, and underinsurance. Nonfinancial barriers include transportation challenges, negative interactions with care teams, delayed access to a healthcare provider, and inability to access care due to competing demands (e.g., childcare, work schedules).^47^ Past research continues to show that lack of insurance and inaccessible care are linked to patient mortality.^48,^ ^49^

#### Cost

Cost of affordable care includes insurance, usual source of care, and personal medical expenditures.

### Findings on Affordable Care

The Affordable Care priority area includes measures of:

- Financial Burden of Healthcare.
- Usual Source of Care.

Data for these measures can be found at https://datatools.ahrq.gov/nhqdr.

Two measures examining financial burden of healthcare and usual source of care showed improvement for people with public health insurance:

- People under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income.
- People without a usual source of care who indicated a financial or insurance reason for not having a source of care.

#### Improving Trend: High Family Medical Expenditures

The most prominent barriers to healthcare coverage include affordability, eligibility for public coverage in a person’s state, immigration status, and lack of familiarity with signup procedures.^50^ Poor health may require a family to spend more on healthcare, resulting in less income. Costs will vary based on each person or family’s needs and may inhibit a family’s ability to reach other goals.^51^

Figure 24 People under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income by insurance status, 2002–2018 (lower rates are better)

Line graph showing percentage. Key findings are in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, for public health insurance, the percentage of people under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income decreased from 17.7% to 12.7% (Figure 24).

#### Improving Trend: Difficulty Accessing a Usual Source of Care

People with lower incomes may experience difficulty accessing affordable care and are less likely to have a usual source of care that is readily accessible.^51^ People who are unwell and have low incomes are also more likely to experience poverty.^48^

Figure 25 People without a usual source of care who indicated a financial or insurance reason for not having a source of care, by insurance status, 2002–2018 (lower rates are better)

Line graph showing percentage. Key findings are in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, for public health insurance, the percentage of people without a usual source of care who indicated a financial or insurance reason for not having a source of care decreased from 18.5% to 17.9% (Figure 25).

##### Resources

Efforts to promote affordable care are underway within the Department of Health and Human Services (HHS). For example:

- The Department is working to transform the U.S. system from one that pays for procedures and sickness (volume-based care) to one that pays for outcomes and health (value-based care, or VBC). CMS operates multiple VBC programs (https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/Value-Based-Programs/Value-Based-Programs), which span different settings of care (e.g., inpatient, home health) and conditions (e.g., end stage renal disease and hospital-acquired conditions). In January 2017, CMS implemented the Quality Payment Program (https://qpp.cms.gov/about/qpp-overview) for clinicians, which consists of two tracks: the Merit-based Incentive Payment Systems (MIPS); and participation in Advanced Alternative Payment Models. Both tracks commit clinicians to practicing VBC.
- The Health Resources and Services Administration (HRSA)-sponsored Federally Qualified Health Centers (https://www.hrsa.gov/opa/eligibility-and-registration/health-centers/fqhc/index.html) function as part of the nation’s safety net. These providers receive funds from the HRSA Health Center Program (https://bphc.hrsa.gov/about/index.html) to provide primary care services in underserved areas.
- The Consumer Assistance Program (https://www.cms.gov/CCIIO/Resources/Consumer-Assistance-Grants) originated as a state-based federal grant program. State programs offer direct assistance by phone, direct mail, email, or walk-in locations to help consumers learn how to obtain or use their insurance effectively.
- CMS produces Coverage to Care (C2C) (https://www.cms.gov/About-CMS/Agency-Information/OMH/equity-initiatives/from-coverage-to-care), which offers healthcare coverage information in multiple languages for providers and consumers.

#### Examining Affordable Care Quality Measures by Sub-Areas

Figure 26 Number and percentage of all affordable care measures improving, not changing, or worsening from 2002 to 2018, by sub-area

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percent change is 1% or greater in the desirable direction, and p <0.10.
- Not changing: The average annual percent change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percent change is 1% or greater in the undesirable direction, and p <0.10.

Bar chart showing that one measure of usual source of care and one measure of financial burden were not changing.

Core measures listed below are noted as improving (green), not changing (yellow), or worsening (red) over time. More information on how this analysis was conducted is available in the NHQDR Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html). More details about the measures shown here are available at the NHQDR website (https://datatools.ahrq.gov/nhqdr).

Table 14 Financial Burden of Healthcare Measures

The core set of measures includes only one measure that specifically examines the financial burden of healthcare. This measure did not show statistically significant change over time.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Medical Care | People under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income (MEPS) | 14.3% in 2002 | 17.5% in 2018

Table 15 Usual Source of Care Measures

Among all Affordable Care core measures, one usual source of care measure did not show statistically significant change over time.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Primary Care | People without a usual source of care who indicated a financial or insurance reason for not having a source of care (MEPS) | 15.6% in 2002 | 15.8% in 2018

## Trends in Effective Treatment

As better understanding of health has led to superior ways of preventing, diagnosing, and treating diseases, the health of most Americans has improved dramatically; however, more than half of all Americans are managing one chronic disease and do not receive the full benefits of high-quality care.^52,^ ^53^

The Effective Treatment quality domain focuses on effective ways to prevent and treat the leading causes of mortality. The NHQDR focuses on leading causes of mortality because these conditions are important and have more robust data available. For organizational purposes, musculoskeletal disease, which is not a leading cause of death, is included in this section because it is a leading cause of functional limitation in the United States. Measures of tobacco cessation counseling and obesity care, which are also effective ways to reduce morbidity and mortality, are reported in the Healthy Living section.

### Importance of Effective Treatment

Effective treatment interventions have been shown to reduce mortality and morbidity among people with chronic diseases. The following are some of the leading causes of death in the United States and number of deaths from those causes in 2019^54^:

- Heart disease: 659,041.
- Cancer: 599,601.
- Chronic lower respiratory diseases: 156,979.
- Stroke (cerebrovascular diseases): 150,005.
- Alzheimer’s disease: 121,499.
- Diabetes: 87,647.
- Nephritis, nephrotic syndrome, and nephrosis (kidney disorders): 51,565.
- Intentional self-harm (suicide): 47,511.

Effective primary and preventive care can help reduce the prevalence and mortality of these conditions.

### Findings on Effective Treatment

The Effective Treatment priority area includes measures of the following concerns:

- Cancer
  ■ Management of Breast Cancer
  ■ Deaths From Breast Cancer
  ■ Management of Colorectal Cancer
  ■ Deaths From Colorectal Cancer
  ■ Deaths From Lung Cancer
- Cardiovascular Disease
  ■ Control of High Blood Pressure
- End Stage Renal Disease
  ■ Management of Dialysis for End Stage Renal Disease
  ■ Kidney Transplantation for End Stage Renal Disease
- Diabetes
  ■ Management of Diabetes
  ■ Prevention of Diabetes-Related Complications
- HIV Infection
  ■ Prevention of HIV Infection
  ■ Management of HIV Infection
  ■ Deaths From HIV Infection
- Mental Health and Substance Use
  ■ Management of Depression
  ■ Deaths From Suicide
  ■ Management of Substance Use
  ■ Healthcare Utilization for Opioid-Related Illness
- Musculoskeletal Disease
  ■ Management of Joint Pain
- Respiratory Diseases
  ■ Management of Viral Upper Respiratory Infections
  ■ Management of Tuberculosis Infections

Measures cover preventive care, treatment of illness, chronic disease management, and outcomes of care. Data for these measures can be found at https://datatools.ahrq.gov/nhqdr.

The three Effective Treatment measures that worsened most overall are related to substance use or mental illness. Recent data point to important developments in the years since 2018 for both conditions.

The three measures of Effective Treatment that showed the greatest improvement were related to the management of different health conditions:

- Doctor’s office and ED visits where antibiotics were prescribed for a diagnosis of common cold per 10,000 population.
- Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined.
- HIV infection deaths per 100,000 population.

In contrast, the three Effective Treatment measures that worsened over time all relate to mental illness and substance use:

- Emergency department visits involving opioid-related diagnoses per 100,000 population.
- Hospital inpatient stays involving opioid-related diagnoses per 100,000 population.
- Suicide deaths among people age 12 and over per 100,000 population.

#### Improving Trend: Antibiotics for Common Cold

Most people around the world will have one or more common cold episodes each year. However, common colds are caused by viruses, which do not respond to antibiotics, and antibiotics can cause side effects, such as adverse drug reactions and diarrhea. Overuse of antibiotics also leads to bacteria becoming resistant to antibiotics.^55^

Figure 27 Doctor’s office, emergency department, and outpatient department visits where antibiotics were prescribed for a diagnosis of common cold per 10,000 population, 2010–2011 to 2016–2017 (lower rates are better)

Line graph showing rate per 10,000 population: 2010–2011, 108.8 2011–2012, 106 2012–2013, 72.4 2013–2014, 72.1 2014–2015, 62.3 2015–2016, 42.9 2016–2017, 42

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Ambulatory Medical Care Survey and National Hospital Ambulatory Medical Care Survey, 2010–2011 to 2016–2017.

- From 2010–2011 to 2016–2017, overall, the rate of doctor’s office and ED visits where antibiotics were prescribed for a diagnosis of common cold per 10,000 population decreased from 108.8 to 42.0 per 10,000 population (Figure 27).

#### Improving Trend: Colon Cancer Treatment

Surgical removal is a potentially curative treatment for localized, early stage colon cancers.^56^ Clinical practice guidelines recommend removal and examination of lymph nodes during surgical resection. Lymph node examination can identify otherwise undetected spread of cancer, inform prognosis, and guide postoperative management decisions, such as whether to also administer chemotherapy. Oncology research has shown that examination and removal of lymph nodes during surgical treatment of colon cancer are linked with better patient outcomes and survival.^57,^ ^58^

Figure 28 Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined, 2005–2017

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage. Key information is in the text below the chart.

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005–2017.

- From 2005 to 2017, overall, the percentage of patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined increased from 59.9% to 92.9% (Figure 28).
- The 2015 achievable benchmark was 95.4%. At the current rate of increase, overall, the benchmark could be achieved in 1 year.
- The top 10% of states that contributed to the achievable benchmark were District of Columbia, Maine, Massachusetts, Rhode Island, and Vermont.

#### Improving Trend: Deaths From HIV infection

HIV mortality rates are a function of the nation’s effectiveness in preventing new HIV infection and extending the lives of those already infected. In 2018, 37,881 new cases of HIV infection were diagnosed in the United States and its territories.^59^ This 7% decrease in overall incidence between 2014 and 2018 can be attributed to public health prevention efforts, such as routine screening for HIV, use of pre- and postexposure prophylaxis, and educational campaigns.

Mortality for people with HIV infection has also decreased due to early linkage to specialty care, improved quality of care, and widespread use of anti-retroviral therapy (ART). It is now estimated that life expectancy of a patient with HIV infection who receives ART can approach that of a person without HIV infection.^60^

Barriers to effective HIV treatment include lack of awareness of HIV status, difficulty accessing care for HIV, and difficulty remaining in care and treatment. In 2018, an estimated 1 in 7 people with HIV infection in the United States were unaware of their infection.^61^

Figure 29 HIV infection deaths per 100,000 population, 2005–2018 (lower rates are better)

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing deaths per 100,000 population. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 2005–2018.

- From 2005 to 2018, the overall rate of HIV infection deaths per 100,000 population improved from 4.2 to 1.5 (Figure 29).
- The 2015 achievable benchmark was 0.75 per 100,000 population. At the current rate of increase, overall, the benchmark could be achieved in 3 years.
- The top 10% of states that contributed to the achievable benchmark were Kansas, Kentucky, Minnesota, Missouri, Ohio, and Washington.

#### Worsening Trend: Emergency Department Visits Involving Opioids

Opioid-related illness and deaths constitute a continuing public health emergency.^62^ Drug overdose deaths quadrupled between 1999 and 2019, and opioid-related deaths accounted for the largest share of deaths during this period, with more than 70% of overdose deaths in 2019 involving an opioid.^63^

In addition to the human toll, economic analyses published in 2017 estimate the opioid epidemic’s total cost to the nation to be $1.02 trillion, factoring in loss of life, reduced quality of life, healthcare utilization, criminal justice, and lost productivity.^64^ Other analyses describe the unequal distribution of this burden, with per capita costs to states ranging between $1,204 (Hawaii) and $7,247 (West Virginia).^65^

Figure 30 Emergency department visits involving opioid-related diagnoses per 100,000 population, 2005–2018 (lower rates are better)

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing rate per 100,000 population. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample and Nationwide Emergency Department Sample, 2005–2018.

- From 2005 to 2018, overall, the rate of ED visits related to opioid use increased from 89.1 to 238.0 per 100,000 population. The rate peaked at 249.1 emergency visits per 100,000 population in 2017 (Figure 30).
- The 2015 achievable benchmark was 65.3 emergency visits per 100,000 population. There has been no progress toward the benchmark.
- The top 10% of states that contributed to the achievable benchmark were Iowa, Kansas, Nebraska, and South Dakota.

#### Worsening Trend: Hospital Stays Involving Opioids

Figure 31 Hospital inpatient stays involving opioid-related diagnoses per 100,000 population, 2005–2018 (lower rates are better)

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing rate per 100,000 population. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample and Nationwide Emergency Department Sample, 2005–2018.

- From 2005 to 2018, overall, the rate of hospital inpatient stays related to opioid use increased from 136.8 to 286.1 per 100,000 population. The rate peaked at 299.7 hospitalizations per 100,000 population in 2017 (Figure 31).
- The 2015 achievable benchmark was 102.9 hospitalizations per 100,000 population. There has been no progress toward the benchmark.
- The top 10% of states that contributed to the achievable benchmark were Georgia, Iowa, Nebraska, Texas, and Wyoming.

The flattening curve shown in Figures 30 and 31 should be interpreted with care. The opioid epidemic has evolved through multiple waves since the 1990s, with the first, second, and third waves characterized by overdose deaths due to prescription opioids, heroin, and synthetic opioids such as illicitly manufactured fentanyl, respectively.^66^ These data may represent a snapshot that captures a brief reprieve between one wave’s retreat and another’s arrival.

Prescription opioids and heroin accounted for most opioid-related ED visits, hospitalizations, and overdose deaths between 1999 and 2016. Thus, a decline in overdoses due to these substance between 2017 and 2018 may account for the plateauing ED visit and hospitalization rates shown here.^67^ However, during the same period, rates of overdose due to synthetic opioids were rising rapidly, even as a “fourth wave” of overdose deaths related to polysubstance use, specifically the co-use of opioids and psychostimulants such as methamphetamine and cocaine, emerged.^68^

Leading indicators point to synthetic opioids and co-occurring use of opioids and psychostimulants replacing earlier substances as primary drivers, and even accelerators, of the opioid epidemic. Provisional drug overdose counts from CDC show the overdose death rate falling by 4% from 2017 to 2018, but rapidly increasing by 4.8% from 2018 to 2019 and by 30% from 2019 to 2020.^69^ The continuing rapid rise in opioid-related deaths and their association with different, more potent substances suggest important changes in the opioid crisis, which these figures may obscure.

#### Worsening Trend: Suicide Mortality

Suicide rates, which increased 33% between 1999 and 2018, represent a crisis occurring in parallel with the opioid epidemic. Suicide currently is the 10^th^ leading cause of death in the United States, accounting for more than 47,500 deaths annually.^70^ Studies estimate that for every suicide death, as many as 30 additional suicide attempts, or 1.4 million individuals, are made each year. Based on 2010 data, the estimated cost of suicides and suicide attempts was more than $55 billion per year in lifetime medical and work-loss costs (or nearly $70 billion after adjusting for inflation).^71^

Figure 32 Suicide deaths among people age 12 and over, per 100,000 population, 2008–2018

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing rate per 100,000 population. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Vital Statistics System-Mortality, 2008–2018.

- From 2008 to 2018, overall, the rate of suicide deaths among people age 12 and over increased from 14.0 to 17.2 per 100,000 population (Figure 32), which is nearly double the achievable benchmark rate.
- The 2015 achievable benchmark was 9.4 suicide deaths per 100,000 population.
- The top 10% of states that contributed to the achievable benchmark were District of Columbia, Maryland, Massachusetts, New Jersey, and New York.

As with the trends in opioid-related conditions, the data shown in Figure 32 may have captured a moment just before an inflection point occurred in the suicide epidemic.

Earlier this year, CDC reported that the national suicide rate among people age 10 years and over decreased by 2.1% from a rate of 14.2 deaths per 100,000 population to 16.9 deaths per 100,000 population between 2018 and 2019, interrupting the multiyear trend shown above.^72^ This overall improvement was attributable to fewer suicides in White (−2.2% relative change) and Hispanic (−1.4% relative change) populations, while suicide rates either remained stable or continued to rise in Asian (no change), American Indian/Alaska Native (+0.9% relative change), Black (+2.7% relative change), and Native Hawaiian/Pacific Islander (+21.0% relative change) populations.

While promising, the recent CDC report should be interpreted cautiously. A single-year change might occur due to statistical variability or to the way data are collected and reported in a given year and thus should not be interpreted as a trend. Nonetheless, the CDC’s findings offer evidence that national suicide prevention efforts, including those outlined in the National Suicide Prevention Strategy,^73,^ ^74^ are working They also signal an urgent need to both build on current suicide prevention efforts and develop targeted strategies for populations in which suicide rates continue to rise.

##### Resources

Efforts to promote effective screening for and treatment of substance use and depression are underway within HHS. These efforts include medications for opioid use disorder (MOUD) (previously called medication-assisted treatment),^xvi^ which improve the likelihood of successfully stopping opioid use and reduce the risk of overdose among people with opioid use disorder. Thus, it is a cornerstone of many treatment programs.

HHS efforts in this area include the following.

###### Resources for Addressing Substance Use

- HHS has established the Behavioral Health Coordinating Council to coordinate the Department’s behavioral health efforts. The Council is cochaired by the Assistant Secretary for Substance Abuse and Mental Health, Dr. Miriam Delphin-Rittmon, and the Assistant Secretary for Health, Dr. Rachel L Levine.
- HHS has also released a national Overdose Prevention Strategy (https://aspe.hhs.gov/sites/default/files/documents/101936da95b69acb8446a4bad9179cc0/overdose-prevention-strategy.pdf), which includes resources to address four priority areas (https://www.hhs.gov/opioids/): primary prevention, harm reduction, evidence-based treatment, and recovery support.
- AHRQ has published an evidence review, a rapid review, and several statistical briefs on opioid use. In 2020, the U.S. Preventive Services Task Force published recommendation statements on Screening for Unhealthy Drug Use (https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/drug-use-illicit-screening) in adolescents, adults, and seniors; and on interventions to prevent illicit drug use in adolescents and children (https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/drug-use-illicit-primary-care-interventions-for-children-and-adolescents).
- AHRQ has also sponsored the development of tools and grant programs for managing patients with opioid use disorder, such as:
  ■ Six Building Blocks: A Team-Based Approach to Improving Opioid Management in Primary Care (https://www.ahrq.gov/professionals/prevention-chronic-care/improve/six-building-blocks.html). An AHRQ grantee developed a structured systems-based approach for primary care providers and their staff members to improve management of patients on chronic opioid therapy.
  ■ The Academy: Integrating Behavioral Health and Primary Care (https://integrationacademy.ahrq.gov/). AHRQ has previously sponsored the Academy, which works to expand the integration of behavioral healthcare and primary care. It also supports those who are implementing MOUD/MAT in primary care settings.
- CDC, in addition to providing a collection of information and data (https://www.cdc.gov/opioids/index.html) on the opioid epidemic, offers several practical resources for frontline clinicians and health systems. These include a Guideline for Prescribing Opioids for Chronic Pain (https://www.cdc.gov/opioids/providers/prescribing/guideline.html) and a Handbook for Healthcare Executives (https://www.cdc.gov/opioids/healthcare-admins/executive-handbook.html) who want to implement best practices for opioid prescribing.
- The Substance Abuse and Mental Health Services Administration (SAMHSA) has developed a Treatment Improvement Protocol on Medications for Opioid Use Disorder (https://store.samhsa.gov/sites/default/files/SAMHSA_Digital_Download/PEP21-02-01-002.pdf), Clinical Guidance for Treating Pregnant and Parenting Women With Opioid Use Disorder and Their Infants (https://store.samhsa.gov/sites/default/files/d7/priv/sma18-5054.pdf), and tip sheets to inform people with substance use disorders and family members about using naloxone (https://store.samhsa.gov/sites/default/files/d7/priv/sma17-5053-13.pdf) to rescue people from overdose and to help them find high-quality treatment (https://store.samhsa.gov/sites/default/files/d7/priv/pep18-treatment-loc.pdf).
- The Food and Drug Administration offers a Remove the Risk outreach toolkit (https://www.fda.gov/drugs/safe-disposal-medicines/safe-opioid-disposal-remove-risk-outreach-toolkit), which provides fact sheets and multiple-format public service announcements and tools to raise awareness about risks related to storing opioid pain medications in the home, as well as providing guidance for safely disposing of them.
- The Health Resources and Services Administration funds several efforts intended to expand capacity for providing substance use and mental health services (https://www.hrsa.gov/opioids) in rural, frontier, and other underserved communities. These include programs that provide training, technical assistance, and access to substance use and mental health expertise to disseminate resources and share best practices for treating substance use disorders and mental health concerns.
  Other HRSA efforts focus on expanding capacity in underserved communities, such as programs that build telehealth infrastructure to deliver substance use and mental health services to rural communities, and programs that encourage National Health Services Corp clinicians to offer MOUD/MAT.
- The Centers for Medicare & Medicaid Services (CMS) provides an online data visualization tool (https://data.cms.gov/summary-statistics-on-use-and-payments/medicare-medicaid-opioid-prescribing-rates/medicaid-opioid-prescribing-rates-by-geography) that maps state-level opioid prescribing rates.
- The National Institutes of Health has established the Helping to End Addiction Long-term^®^ (HEAL) (https://heal.nih.gov/) initiative. HEAL is an aggressive, transagency effort to accelerate research to improve treatment of opioid misuse and addiction and to advance the science of managing chronic pain.
- The National Institute on Drug Abuse (NIDA) is a scientific institute under the National Institutes of Health, which supports scientific research on drug use and its consequences and applies that knowledge to improve individual and public health. Through NIDAMED (https://www.drugabuse.gov/nidamed-medical-health-professionals), it compiles several resources for healthcare professionals, including educational opportunities, resources for screening for and treating substance use disorders, and tools to help clinicians discuss drug use and addiction prevention with patients.
- Federal initiatives outside HHS include:
  ■ The U.S. Department of Agriculture (USDA) offers a Rural Community Toolbox (https://www.ruralcommunitytoolbox.org/assets/3664-15201/federal-rural-resource-guide.pdf), which provides communities with tools and access to funding opportunities to address opioid misuse in rural communities. USDA also funded the development of an interactive map (https://opioidmisusetool.norc.org/) that visually displays county-level drug overdose deaths in the United States and can be stratified by social and economic factors, such as age, race/ethnicity, unemployment rate, and availability of substance use and mental health services.

###### Resources for Addressing Risk for Suicide

- The Surgeon General has issued a Call to Action To Implement the National Strategy for Suicide Prevention (https://www.hhs.gov/sites/default/files/sprc-call-to-action.pdf), which follows up on the Surgeon General’s National Action Strategy and 2012 report.
- HHS and the SAMHSA Center for Mental Health Services jointly fund the Suicide Prevention Resource Center (https://www.hhs.gov/sites/default/files/sprc-call-to-action.pdf), which builds capacity to implement the National Strategy for Suicide Prevention by linking states, tribal communities, colleges and universities, EDs, primary care, and other settings to resources, training, and consultation services.
- SAMHSA also implemented the National Suicide Prevention Lifeline (https://suicidepreventionlifeline.org/), a national network of more than 180 local crisis centers, combining custom local care and resources with national standards and best practices. Accessed through a single toll-free phone number, the Lifeline provides free and confidential emotional support 24 hours a day, 7 days a week to people in suicidal crisis or emotional distress. Other suicide prevention resources include tools focused on American Indian and Alaska Native communities (https://www.samhsa.gov/tribal-ttac/resources/suicide-prevention) and high school-age students (https://store.samhsa.gov/product/Preventing-Suicide-A-Toolkit-for-High-Schools/SMA12-4669), as well as videos.
- CDC has published Preventing Suicide: A Technical Package of Policy, Programs, and Practices (https://www.cdc.gov/violenceprevention/pdf/suicidetechnicalpackage.pdf), a select group of strategies based on the best available evidence to help communities and states sharpen their focus on activities with the greatest potential to prevent suicide. These strategies include strengthening economic supports; strengthening access and delivery of suicide care; creating protective environments; promoting connectedness; teaching coping and problem-solving skills; identifying and supporting people at risk; and lessening harms and preventing future risk.
  A CDC Suicide Prevention website (https://www.cdc.gov/suicide/resources/index.html) offers links to other reports and resources, including links for the Suicide Prevention Lifeline (https://suicidepreventionlifeline.org/) and the Veterans Crisis Line. (https://www.veteranscrisisline.net/)
- Federal Initiatives outside HHS include:
  ■ The Department of Veterans Affairs and the Department of Defense have published clinical practice guidelines (https://www.healthquality.va.gov/guidelines/MH/srb)^75^ that provide evidence-based guidelines to support identification of individuals at risk for suicide, provider evaluation, and management of acute risk for suicide.

#### Examining Effective Treatment Measures by Sub-Areas

The core measures within the Effective Treatment priority area are summarized below. They are grouped by clinical condition sub-areas and displayed as improving (green), not changing (yellow), or worsening (red) over time. More information on how this analysis is conducted is available in the NHQDR Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).

Figure 33 Number and percentage of all effective treatment measures improving, not changing, or worsening from 2000 to 2018 by disease category

Key: n = number of measures.

Stacked bar chart showing number of measures in each category: Cancer (n=6), 5 improving, 1 not changing, 0 worsening. Cardiovascular Disease (n=1), 0 improving, 1 not changing, 0 worsening. Chronic Kidney Disease (n=5), 2 improving, 2 not changing, 1 worsening. Diabetes (n=6), 1 improving, 5 not changing, 0 worsening. HIV Infection (n=5), 4 improving, 1 not changing, 0 worsening. Mental Health and Substance Use (n=9), 1 improving, 5 not changing, 3 worsening. Musculoskeletal Disease (n=1), 0 improving, 1 not changing, 0 worsening. Respiratory Diseases (n=2), 2 improving, 0 not changing, 0 worsening.

The tables that follow provide details about the Effective Treatment core measures in each clinical condition sub-area.

Table 16 Cancer Measures

Among the six core measures of cancer care, five have improved over time. These include measures related to management of patients with the most common forms of cancer: breast, colorectal, and lung cancer. The sixth measure, women with clinical Stage I–IIb breast cancer who received axillary node dissection or sentinel lymph node biopsy at time of surgery, shows no statistically significant change.

Earlier editions of the NHQDR had reported the measure of women with clinical Stage I–IIb breast cancer who received axillary node dissection or sentinel lymph node biopsy at time of surgery as improving over time. The difference may relate to changes in the measure specifications, which were made in response to National Quality Forum recommendations. The recommendations were to include only women with Stage I/II cancer in the denominator and exclude those with Stage III disease during lymph node surgery (based on four or more positive nodes) if their stage prior to surgery (i.e., clinical stage) was not recorded. The changes may have artificially lowered the rates for this measure.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Breast Cancer | Women under age 70 treated for breast cancer with breast-conserving surgery who received radiation therapy to the breast within 1 year of diagnosis (National Cancer Data Base [NCDB]) | 84.2% in 2005 | 89.0% in 2017
Breast Cancer | Breast cancer deaths per 100,000 female population per year (National Vital Statistics System-Mortality [NVSS-M]) | 26.8 per 100,000 population in 2000 | 19.7 per 100,000 population in 2018
Colorectal Cancer | Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined (NCDB) | 55.1% in 2004 | 92.9% in 2017
Colorectal Cancer | Colorectal cancer deaths per 100,000 population per year (NVSS-M) | 20.8 per 100,000 population in 2000 | 13.4 per 100,000 population in 2018
Lung Cancer | Lung cancer deaths per 100,000 population per year (NVSS-M) | 56.1 per 100,000 population in 2000 | 34.8 per 100,000 population in 2018
Not Changing
Breast Cancer | Women with clinical Stage I–IIb breast cancer who received axillary node dissection or sentinel lymph node biopsy (SLNB) at the time of surgery (lumpectomy or mastectomy) (NCDB) | 82.0% in 2005 | 82.0% in 2017

Table 17 Cardiovascular Disease Measures

The core set of cardiovascular disease care measures includes one measure assessing blood pressure control. High blood pressure, also known as hypertension, is a chronic condition in which blood vessel walls are damaged by excessive force placed on them. An estimated 148.5 million, or 45.4%, of U.S. adults had high blood pressure in 2018.^76^ It is a leading precursor to stroke, heart attacks, heart failure, and end-stage renal disease. Scientific investments have identified a range of effective, inexpensive treatments, including lifestyle behaviors and medications, that lower blood pressure, yet blood pressure control rates remain unchanged.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Prevention of Heart Disease | Adults with hypertension with blood pressure less than 140/90 mm Hg (National Health and Nutrition Examination Survey [NHANES])^xvii^ | 29.4% in 1999–2002 | 39.9% in 2015–2018

Efforts within HHS to increase blood pressure control are underway:

- The Surgeon General has issued a Call to Action To Control Hypertension,^77^ which describes a multisector approach to increase blood pressure control and reduce cardiovascular risk.
- In collaboration with a wide range of partners, the Centers for Disease Control and Prevention have organized Million Hearts 2022 (https://millionhearts.hhs.gov/index.html) with the aim of preventing 1 million heart attacks and strokes within 5 years.
- The Million Hearts initiative (https://millionhearts.hhs.gov/index.html) includes information and tools for health systems, providers, and patients that support effective hypertension management, as well as cholesterol management, smoking cessation, and strategies to prevent heart attacks after one has occurred.

Table 18 End Stage Renal Disease Measures

In 2018, an estimated 785,883 people in the United States had end stage renal disease (ESRD). Approximately 70% of people with ESRD are treated with hemodialysis or peritoneal dialysis, while just under 30% receive kidney transplantation. While hemodialysis is lifesaving, it does not substitute for a person’s kidneys. Five-year survival for people on dialysis is 13% to 60% lower than for similarly aged people in the general population. Compared with those treated with dialysis, people who undergo kidney transplant experience better quality of life, fewer cardiovascular complications, and lower mortality.^78,^ ^79^

Of five measures related to ESRD care, two related to quality of dialysis care were improving, and one related to quality of dialysis care was worsening. The dialysis measure is examined further below. Two measures examining care leading to kidney transplantation were not changing.^80^

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Chronic Care of ESRD | Adult end stage renal disease patients who saw a nephrologist at least 12 months prior to initiation of renal replacement therapy (U.S. Renal Disease System [USRDS]) | 25.7% in 2005 | 38.1% in 2018
Chronic Care of ESRD | Adult hemodialysis patients who use arteriovenous fistulas as the primary mode of vascular access (USRDS) | 62.1% in 2012 | 65.7% in 2018
Not Changing
Chronic Care of ESRD | Dialysis patients who were registered on a waiting list for transplantation (USRDS) | 15.2% in 2000 | 15.2% in 2017
Chronic Care of ESRD | Patients with treated chronic kidney failure who received a transplant within 3 years of date of renal failure (USRDS) | 19.1% in 2000 | 12.5% in 2015
Worsening
Chronic Care of ESRD | Hemodialysis patients whose hemoglobin level was less than 10 g/dL (University of Michigan Kidney Epidemiology and Cost Center [UMKECC]) | 20.7% in 2015 | 22.3% in 2019

Anemia (i.e., low hemoglobin) is common among people with chronic kidney disease, including those with end-stage renal disease. Screening for and treating anemia is recommended for routine hemodialysis care, as it is associated with increased risk for hospitalization and higher morbidity and mortality if left untreated.^81^

Figure 34 Hemodialysis patients whose hemoglobin level is less than 10 g/dL, 2015–2019 (lower rates are better)

Key: AI/AN = American Indian/Alaska Native.

Line graph showing percentage. Key findings are noted in the text below the chart.

Source: University of Michigan Kidney Epidemiology and Cost Center, Dialysis Facility Reports, 2015–2019.

- Overall, the percentage of hemodialysis patients with a hemoglobin level less than 10 g/dL increased from 2015 to 2019 (Figure 34).
- From 2015 to 2019, the percentage of hemodialysis patients with a hemoglobin level less than 10 g/dL increased for American Indian and Alaska Native, Black, and White populations. Further examination of these data may point to targeted ways to reverse this worsening trend and the persistent health disparity between Black people and White people (the Disparities section of this report provides more information on measures with disparities).

Table 19 Diabetes Measures

An estimated 34.1 million adults age 18 years and over, or 13% of all U.S. adults, had diabetes in 2018.^82^ Type 2 diabetesis a chronic illness that often can be prevented through physical activity, healthy diet, and weight loss. Left untreated, diabetes damages blood vessels, nerves, and the immune system, leading to complications such as vision loss, high blood pressure, heart attacks, strokes, kidney failure, increased susceptibility to infections, and shortened life expectancy.^83^

The core set of measures includes one assessing diagnosis of diabetes, four examining quality of care delivered to people with diabetes, and one assessing complications that result from poorly controlled diabetes. Detection of diabetes improved between 2002 and 2018. No measure related to quality of diabetes management or to complications resulting from diabetes changed overtime.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Diabetes – Management | Adults age 40 and over with diabetes whose condition was diagnosed (NHANES) | 67.1% in 1999–2002 | 78.0% in 2015–2018
Not Changing
Diabetes – Management | Adults age 40 and over with diagnosed diabetes who received at least two hemoglobin A1c measurements in the calendar year (MEPS) | 80.7% in 2002 | 74.3% in 2018
Diabetes – Management | Adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year (MEPS) | 58.2% in 2008 | 62.8% in 2018
Diabetes – Management | Adults age 40 and over with diagnosed diabetes who received a dilated eye examination in the calendar year (MEPS) | 62.1% in 2002 | 61.9% in 2018
Diabetes – Management | Adults age 40 and over with diagnosed diabetes with blood pressure less than 130/80 mm Hg (NHANES) | 40.4% in 1999–2002 | 48.0% in 2015–2018
Diabetes – Complications | Adjusted incident rates of end stage renal disease due to diabetes per million population (USRDS) | 177.8 per million in 2001 | 179.5 per million in 2018

The Centers for Disease Control and Prevention has organized the National Diabetes Prevention Program (https://www.cdc.gov/diabetes/prevention/index.html) (National DPP), which Congress authorized in 2010 to prevent or delay type 2 diabetes mellitus through partnerships with public and private organizations. The National DPP builds on findings from clinical research funded by the National Institutes of Health,^84^ which showed that a lifestyle change program focused on reducing calories and increasing physical activity to at least 2.5 hours per week or treatment with metformin reduced the risk of type 2 diabetes by 58% among adults at high risk. In addition, patients continued to benefit 10 and 15 years later.^85,^ ^86^

Working with a range of organizations, such as state and local health departments, businesses with a focus on wellness, employers, healthcare providers, and others, CDC provides training and support (https://coveragetoolkit.org/about-national-dpp/) to help people with diabetes. The goals are to ensure Americans have access to high-quality lifestyle change programs, ensure that programs adhere to scientifically proven standards, facilitate referrals to the programs, and help increase insurance coverage for program services. Information about the National DPP is available through the National DPP website (https://www.cdc.gov/diabetes/prevention/index.html).

Table 20 HIV Infection Measures

An estimated 1,061,482 adults and adolescents were living with HIV infection in 2019, compared with 1,038,812 people with HIV in 2018.^87^ The core set of measures includes five measures that examine HIV management. One assesses prevention of new infections, three examine quality of care provided to those infected with HIV, and one examines HIV infection mortality. Four measures were improving over time. One measure that assesses whether patients receive laboratory testing to monitor their infection at recommended intervals showed no statistically significant change.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
HIV Infection – Management | New HIV cases per 100,000 population age 13 and over (HIV/AIDS Surveillance System [HIVAIDSSS]) | 18.8 per 100,000 population in 2008 | 12.9 per 100,000 population in 2019
HIV Infection – Management | People age 13 and over living with HIV who know their HIV status (HIVAIDSSS) | 82.3% in 2010 | 86.7% in 2019
HIV Infection – Management | People age 13 and over living with diagnosed HIV whose most recent viral load in the last 12 months was under 200 copies/mL (HIVAIDSSS) | 57.9% in 2014 | 64.7% in 2018
HIV Infection – Management | HIV infection deaths per 100,000 population (NVSS-M) | 5.2 per 100,000 population in 2000 | 1.5 per 100,000 population in 2018
Not Changing
HIV Infection – Management | People age 13 and over living with diagnosed HIV who had at least two CD4 or viral load tests performed at least 3 months apart during the last year, among reporting jurisdictions (HIVAIDSSS) | 56.9% in 2014 | 57.9% in 2018

Table 21 Mental Health and Substance Use Measures

The core set of measures includes measures that assess the care delivered to people with depression and people with substance use disorders. One measure, examining prevention of depression symptoms among nursing home residents, was improving. Five measures examining access to treatment for depression or substance use disorders^xviii^ were not changing. One measure assessing suicide deaths and two measures tracking healthcare utilization for opioid-related illness were worsening.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Depression Treatment | Long-stay nursing home residents with depression symptoms (MDS) | 6.1% in 2013 | 4.4% in 2018
Not Changing
Depression Treatment | Children ages 12–17 with a major depressive episode in the last 12 months who received treatment for depression in the last 12 months (National Survey on Drug Use and Health [NSDUH]) | 37.7% in 2008 | 43.3% in 2019
Depression Treatment | Adults age 18 and over with a major depressive episode in the last 12 months who received treatment for depression in the last 12 months (NSDUH) | 68.3% in 2008 | 66.3% in 2019
Substance Use Treatment | People age 12 and over who needed treatment for an alcohol problem who received such treatment at a specialty facility in the last 12 months (NSDUH) | 8.2% in 2015 | 9.5% in 2019
Substance Use Treatment | People age 12 and over who needed treatment for illicit drug use and who received such treatment at a specialty facility in the last 12 months (NSDUH) | 18.3% in 2015 | 17.8% in 2019
Substance Use Treatment | People age 12 and over treated for substance use who completed treatment course (Treatment Episode Data Set [TEDS]) | 41.3% in 2005 | 42.1% in 2018
Worsening
Depression Treatment | Suicide deaths among people age 12 and over per 100,000 population (NVSS-M) | 14.0 per 100,000 population in 2008 | 17.2 per 100,000 population in 2018
Substance Use Treatment | Emergency department visits involving opioid-related diagnoses per 100,000 population (Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample [HCUP, NEDS]) | 89.1 per 100,000 population in 2005 | 238.0 per 100,000 population in 2018
Substance Use Treatment | Hospital inpatient stays involving opioid-related diagnoses per 100,000 population (HCUP) | 136.8 per 100,000 population in 2005 | 286.1 per 100,000 population in 2018

Table 22 Musculoskeletal Disease Measures

From 2013 to 2015, an estimated 54.4 million people had doctor-diagnosed arthritis.^88^ Among these individuals, approximately 44% had symptoms severe enough to limit activities. Chronic joint pain is a leading cause of work disability among U.S. adults. The core set of measures includes one measure examining access to medical care for chronic joint disease. This measure was not changing over time.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Musculoskeletal Disease | Adults with chronic joint symptoms who have ever seen a doctor or other health professional for joint symptoms (National Health Interview Survey [NHIS]) | 70.5% in 2009 | 74.0% in 2018

Table 23 Respiratory Disease Measures

Two core measures pertaining to respiratory treatment were improving over time. One examines appropriate use of antibiotics among patients with viral respiratory illness. The other assesses quality of care delivered to people with tuberculosis.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Treatment of Respiratory Infections | Doctor’s office and emergency department visits where antibiotics were prescribed for a diagnosis of common cold per 10,000 population (National Ambulatory Medical Care Survey [NAMCS]/NHAMCS) | 108.8 per 10,000 population in 2011 | 42.0 per 10,000 population in 2017
Treatment of Respiratory Infections | Patients with tuberculosis who completed a curative course of treatment within 1 year of initiation of treatment (National Tuberculosis Surveillance System [TBSS]) | 82.3% in 2004 | 90.0% in 2017

## Trends in Healthy Living

The percentage of home health care patients who had influenza vaccination during flu season has increased consistently since 2015 and has surpassed the achievable benchmark.

Many illnesses associated with chronic conditions are related to unhealthy behaviors, environmental hazards, and poor social supports. These illnesses can be prevented by increasing access to effective clinical preventive services and promoting community interventions that advance public and population health. Working with communities is critical to ensure that immunizations and early detection and prevention services reach everyone who needs them and to build healthy neighborhoods and support networks.

Promoting healthy lifestyles that prevent disease and disability is better for people and more efficient than treating conditions after organ damage has occurred.

### Importance of Healthy Living

#### Morbidity and Mortality

Healthy living is supported through preventive care strategies that cross all age groups and the care continuum. Among the most impactful preventive strategies are vaccinations for children and prenatal care.

Advances in medical science protect children against more diseases than ever before. Some diseases that once injured or killed thousands of children have been eradicated completely and others are close to eradication, primarily due to safe and effective vaccines. Polio is one example of the great impact vaccines have had in the United States. Polio was once America’s most feared disease, causing death and paralysis across the country, but today, thanks to vaccination, there are no reports of polio in the United States.

Effective and continuous prenatal care can also improve birth and health outcomes for mothers and children. Currently, the NHQDR tracks one preventive health measure related to maternal health (i.e., women who completed a pregnancy in the last 12 months who received early and adequate prenatal care).

Research has shown that most cases of maternal mortality and severe maternal morbidity are preventable, and prevention strategies can directly reduce morbidity and mortality.^89,^ ^90,^ ^91^ Recognition is growing of the need to develop, monitor, and improve performance on quality measures in obstetrics care, particularly around disparities.^92^ Addressing disparities in maternal health and birth outcomes is a national priority, covered in The Surgeon General’s Call to Action To Improve Maternal Health (https://www.hhs.gov/sites/default/files/call-to-action-maternal-health.pdf).^93^

#### Cost

A strong body of research shows the cost-effectiveness of immunization; however, opportunities still exist for providers, patients, and systems to optimize immunization participation. It is less expensive to prevent a disease using immunization than to treat it. In a 2005 study on the economic impact of routine childhood immunization in the United States, researchers estimated that for every dollar spent, the vaccination program saved more than $5 in direct costs and approximately $11 in additional costs to society.^94^

### Findings on Healthy Living

The Healthy Living priority area includes measures of:

- Maternal and Child Health.
- Lifestyle Modification.
- Functional Status Preservation and Rehabilitation.
- Supportive and Palliative Care.
- Clinical Preventive Services.

Data for these measures can be found at https://datatools.ahrq.gov/nhqdr.

The top Healthy Living measures that showed improvement over time included two vaccination measures and one measure of use of restraints in nursing homes:

- Home health care patients who had influenza vaccination during flu season.
- Long-stay nursing home residents with physical restraints.
- Adolescents ages 16–17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of 10 years.

Two Healthy Living measures for which updated data were available worsened over time, including one that examined care for nursing home residents and one on childhood obesity:

- Long-stay nursing home residents who were assessed for pneumococcal vaccination.
- Children ages 2–19 with obesity.

These measures are also discussed in the Disparities section to show narrowing and widening disparities (see Disparities section, Race, Income).

#### Improving Trend: Influenza Vaccinations in Home Health Patients

Influenza vaccination is a proven preventive strategy for reducing the incidence of influenza. All people age 6 months and over are recommended to receive the vaccination, and vulnerable populations, including home health care patients, are especially encouraged to do so.^95^

Figure 35 Home health care patients who had influenza vaccination during flu season, 2015–2018

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage: 2015 achievable benchmark: 94.1% 2015, 87.3 2016, 93 2017, 95 2018, 95.2

Source: Centers for Medicare & Medicaid Services, Outcome and Assessment Information Set, 2015–2018.

- From 2015 to 2018, overall, the percentage of home health care patients who had influenza vaccinations during flu season increased from 87.3% to 95.2% (Figure 35).
- The 2015 achievable benchmark was 94.1%. The benchmark was achieved in 2017 and again in 2018.
- The top 10% of states that contributed to the achievable benchmark were Montana, Nebraska, North Dakota, South Dakota, Vermont, and Wisconsin.

#### Improving Trend: Physical Restraint Use in Nursing Home Residents

Long-stay residents typically enter a nursing facility because they can no longer care for themselves at home. They tend to remain in the facility for several months or years. Most residents want to care for themselves, and the ability to perform daily activities is important to their quality of life. While some functional decline among residents cannot be avoided, high-quality nursing home care should minimize the rate of decline and the number of patients experiencing decline.

Adverse outcomes associated with physical restraint of nursing home residents include decreases in cognitive function and performance of activities of daily living, falls, pressure ulcers, and incontinence.^96^

Figure 36 Long-stay nursing home residents with physical restraints, 2013–2018 (lower rates are better)

Note: The benchmark calculation takes the average of the top10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage: 2015 achievable benchmark: 0.27% 2013, 1.33 2014, 1.05 2015, 0.78 2016, 0.51 2017, 0.38 2018, 0.25

Source: Centers for Medicare & Medicaid Services, Minimum Data Set, 2013–2018.

- From 2013 to 2018, overall, the percentage of long-stay nursing home patients with physical restraints decreased from 1.3% to 0.25% (Figure 36).
- The 2015 achievable benchmark was 0.27%. In 2018, the benchmark was achieved.
- The top 10% of states that contributed to the achievable benchmark were Arizona, Kansas, Minnesota, Nebraska, and New Hampshire.

#### Improving Trend: Adolescent Tdap Vaccination

CDC’s Advisory Committee on Immunization Practices (ACIP) recommends routine vaccination for tetanus, diphtheria, and pertussis. Infants and young children are recommended to receive a 5-dose series of diphtheria and tetanus toxoids and acellular pertussis vaccines, with one adolescent booster dose of Tdap vaccine. One study noted that the cost per quality-adjusted life-year saved from immunization would be approximately $163,361 (booster at 16 years) and $204,556 (booster at 21 years).^97^

Figure 37 Adolescents ages 16–17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of 10 years, 2008–2018

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Immunization and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008–2018.

- From 2008 to 2018, overall, the percentage of adolescents ages 16–17 years who received 1 or more doses of Tdap vaccine increased from 31.9% to 90% (Figure 37).
- The 2015 achievable benchmark was 95.9%. At the current rate of increase, overall, the benchmark could be achieved in 1 year.
- The top 10% of states that contributed to the achievable benchmark were Alabama, Georgia, Missouri, Rhode Island, and Vermont.

#### Worsening Trend: Pneumococcal Vaccinations in Nursing Home Residents

ACIP recommends that all adults over 65 years of age and those with risk factors such as chronic disease receive pneumococcal vaccinations.^98^

Figure 38 Long-stay nursing home residents who were assessed for pneumococcal vaccination, 2013–2018

Note: The benchmark calculation takes the average of the top 10% of states with statistically reliable data. U.S. territories are not included in the calculations. Some benchmarks were calculated with more than five states’ data due to ties. (More information is available in Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html).)

Line graph showing percentage: 2015 achievable benchmark: 97% 2013, 93.8 2014, 93.3 2015, 92.9 2016, 92.7 2017, 92.5 2018, 92.1

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Residence Assessment Files, Minimum Data Set 3.0, 2013–2018.

- From 2013 to 2018, overall, the percentage of long-stay nursing home residents who were assessed for pneumococcal vaccination decreased from 93.8% to 92.1% (Figure 38).
- The 2015 achievable benchmark was 97.0%. There is no evidence of progress toward the benchmark.
- The top 10% of states that contributed to the achievable benchmark were Delaware, Mississippi, New Hampshire, North Dakota, Utah, and Wisconsin.

#### Worsening Trend: Childhood Obesity

In children, sex-specific body mass index (BMI)-for-age percentile cutoffs from the CDC growth charts are used to define a level above which a child is more likely to have or be at risk of developing obesity-associated adverse health outcomes or diseases. BMI between the 85th and 94th percentiles is in the overweight range, whereas BMI ≥95th percentile for age and gender is in the obese range.^99^

Children with obesity are four times as likely to develop type 2 diabetes compared with children with a normal BMI.^100^ As many as 60% of children and adolescents with obesity have obstructive sleep apnea or some sort of disrupted breathing during sleep.^101^ The greatest risk factor for pediatric hypertension is elevated BMI.^102^

Obesity during childhood can harm the body in a variety of ways. Children who have obesity are more likely to have:

- High blood pressure and high cholesterol, which are risk factors for cardiovascular disease;
- Increased risk of impaired glucose tolerance, insulin resistance, and type 2 diabetes;
- Breathing problems, such as asthma and sleep apnea;
- Joint problems and musculoskeletal discomfort; and
- Fatty liver disease, gallstones, and gastroesophageal reflux.^103^

Figure 39 Children ages 2–19 with obesity, 1999–2018

Line graph showing percentage: 1999–2002, 14.8 2003–2006, 16.3 2007–2010, 16.8 2011–2014, 17 2015–2018, 18.9

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2002 to 2015–2018.

- From 1999–2002 to 2015–2018, overall, the percentage of children with obesity increased from 14.8% to 18.9% (Figure 39).

#### Resources

Efforts to promote healthy living are underway within HHS. For example:

- CDC’s School Health Guidelines to Promote Healthy Eating and Physical Activity (https://www.cdc.gov/healthyschools/npao/pdf/MMWR-School-Health-Guidelines.pdf). CDC synthesized research and best practices related to promoting healthy eating and physical activity in schools, culminating in nine guidelines. The guidelines serve as the foundation for developing, implementing, and evaluating school-based healthy eating and physical activity policies and practices for students. Each guideline is accompanied by a set of implementation strategies to help schools work toward achieving healthy eating and physical activity goals.
- CDC’s Guidance for Influenza Outbreak Management in Long-Term Care and Post-Acute Care Facilities (https://www.cdc.gov/flu/professionals/infectioncontrol/ltc-facility-guidance.htm) outlines how to prevent the introduction and spread of influenza viruses using a multifaceted approach of influenza vaccination, testing, prevention and control measures, and treatment. The guideline notes that, if possible, all residents should receive inactivated influenza vaccine annually before influenza season.
- Childhood Obesity Research Demonstration (CORD) 3.0 (https://www.cdc.gov/obesity/strategies/healthcare/cord3.html) focuses on adapting, testing, and packaging effective programs to reduce obesity among children from lower income families. In addition, CORD 3.0 projects work toward programs that are sustainable and cost-effective in multiple settings.

#### Summary of Healthy Living Measures by Topic Areas

The core Healthy Living measures in the 2021 NHQDR are summarized in Figure 40 by topic area. The topic areas are clinical preventive services, functional status preservation and rehabilitation, supportive and palliative care, lifestyle modification, and maternal and child health.

Figure 40 Number and percentage of all healthy living measures improving, not changing, or worsening from 2000 to 2019, by topic area

Key: n = number of measures.

Note: National Health Interview Survey measures that have been included in previous years were unavailable for this report.

Stacked bar chart showing number of measures improving, not changing, and worsening: Clinical Preventive Services (n=38), 22 improving, 15 not changing, 1 worsening. Functional Status Preservation and Rehabilitation (n=6), 5 improving, 1 not changing, 0 worsening. Supportive and Palliative Care (n=10), 9 improving, 0 not changing, 1 worsening. Lifestyle Modification (n=8), 3 improving, 2 not changing, 1 worsening. Maternal and Child Health (n=3), 1 improving, 2 not changing, 0 worsening.

- From 2000 to 2019, 90% of supportive and palliative care, 83% of functional status and rehabilitation, 58% of clinical preventive services, 50% of lifestyle modification, and 33% of maternal and child health measures showed improvement.

The Clinical Preventive Services measures (n=38) in the Healthy Living section are further broken out by sub-areas to show the variation of measures (Figure 41). These sub-areas include adult preventive care, childhood immunization, other childhood preventive care, and overall preventive care.

Figure 41 Number and percentage of all clinical preventive services measures improving, not changing, or worsening from 2000 to 2019, by sub-area

Key: n = number of measures.

Note: National Health Interview Survey measures that have been included in previous years were unavailable for this report. For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percent change is 1% or greater in the desirable direction, and p <0.10.
- Not changing: The average annual percent change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percent change is 1% or greater in the undesirable direction, and p <0.10.

Stacked bar chart showing number of measures improving, not changing, and worsening: Adult Preventive Care (n=10), 6 improving, 4 not changing, 0 worsening. Childhood Immunization (n=14), 11 improving, 3 not changing, 0 worsening. Other Childhood Preventive Care (n=8), 3 improving, 5 not changing, 0 worsening. Overall Preventive Care (n=6), 2 improving, 3 not changing, 1 worsening.

Core measures listed below are noted as improving (green), not changing (yellow), or worsening (red) over time. More information on how this analysis was conducted is available in the NHQDR Introduction and Methods (https://www.ahrq.gov/research/findings/nhqrdr/nhqdr21/index.html). More details about the measures shown here are available at the NHQDR website (https://datatools.ahrq.gov/nhqdr).

More information about the average annual percent change and the statistical significance for these measures is also available at https://datatools.ahrq.gov/nhqdr.

Table 24 Clinical Preventive Measures: Adult Preventive Care

The core set of measures includes six measures that were improving. Improving measures included four measures examining vaccinations and two measures of diagnosis of cancer at an advanced stage. Four measures were not changing over time.

Only two measures, cancers diagnosed at an advanced stage, were improving and included updated data.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Colorectal Cancer Diagnosis | Colorectal cancer diagnosed at advanced stage (tumors diagnosed at regional or distant stage) per 100,000 population age 50 and over (National Program of Cancer Registries – U.S. Cancer Statistics [NPCR-USCS]) | 101.5 per 100,000 population in 2000 | 63.8 per 100,000 population in 2017
Cervical Cancer Diagnosis | Cervical cancer diagnosed at advanced stage (all invasive tumors) per 100,000 women age 20 and over (NPSC-USCS) | 13.4 per 100,000 women in 2000 | 10.5 per 100,000 women in 2017
Not Changing
Breast Cancer Diagnosis | Breast cancer diagnosed at advanced stage (regional, distant stage, or local stage with tumor greater than 2 cm) per 100,000 women age 40 and over (NPCR-USCS) | 95.6 per 100,000 women in 2000 | 84.5 per 100,000 women in 2017
Adult Preventive Dental Service | Adults who received a preventive dental service in the calendar year (MEPS) | 33.6% in 2002 | 35.4% in 2018
Adult Dental Visit | Adults with a dental visit in the calendar year (MEPS) | 43.2% in 2002 | 44.0% in 2018
Adult Pneumonia Vaccination | Adults ages 18–64 at high risk (e.g., COPD) who ever received pneumococcal vaccination (NHIS) | 15.4% in 2000 | 23.3% in 2018

Figure 42 Colorectal cancer diagnosed at advanced stage per 100,000 population age 50 and over, 2000–2017 (lower rates are better)

Note: Rates are age-adjusted to the 2000 U.S. standard population (19 age groups - Census P25-1130). Includes NPCR and SEER registries meeting United States Cancer Statistics publication criteria by year. The period 2003–2017 covers 100% of the U.S. population; 2001–2002 covers 99.0% of the U.S. population (MS excluded); and 2000 covers 97.8% of the total U.S. population (AR, MS, SD excluded).

Line graph showing rate per 100,000 population. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Program of Cancer Registries (NPCR), and National Cancer Institute, Surveillance, Epidemiology, and End Results Program (SEER), United States Cancer Statistics, 2000–2017.

- From 2000 to 2017, overall, the rate of colorectal cancer diagnosed at advanced stage decreased from 101.5 per 100,000 population to 63.8 per 100,000 population (Figure 42).

Figure 43 Cervical cancer diagnosed at advanced stage per 100,000 women age 20 and over, 2000–2017 (lower rates are better)

Note: Includes NPCR and SEER registries meeting United States Cancer Statistics publication criteria by year. The period 2003–2017 covers 100% of the U.S. population; 2001–2002 covers 99.0% of the U.S. population (MS excluded); and 2000 covers 97.8% of the total U.S. population (AR, MS, SD excluded).

Line graph showing rate per 100,000 women. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Program of Cancer Registries (NPCR), and National Cancer Institute, Surveillance, Epidemiology, and End Results Program (SEER), United States Cancer Statistics, 2000–2017.

- From 2000 to 2017, overall, the rate of cervical cancer diagnosed at advanced stage decreased from 13.4 per 100,000 women to 10.5 per 100,000 women (Figure 43).

Figure 44 Breast cancer diagnosed at advanced stage, 2000–2017 (lower rates are better)

Note: Includes NPCR and SEER registries meeting United States Cancer Statistics publication criteria by year. The period 2003–2017 covers 100% of the U.S. population; 2001–2002 covers 99.0% of the U.S. population (MS excluded); and 2000 covers 97.8% of the total U.S. population (AR, MS, SD excluded).

Line graph showing rate per 100,000 women. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Program of Cancer Registries (NPCR), and National Cancer Institute, Surveillance, Epidemiology, and End Results Program (SEER), United States Cancer Statistics, 2000–2017.

- From 2000 to 2017, overall, the rate of breast cancer diagnosed at advanced stage did not have any statistically significant changes, decreasing from 95.6 per 100,000 women to 84.5 per 100,000 women (Figure 44).

Figure 45 Adults age 18 and over who had a dental visit in the calendar year, 2002–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, overall, the percentage of adults age 18 and over who had a dental visit in the calendar year did not have any statistically significant changes, increasing slightly from 43.2% to 44.0% (Figure 45).

Figure 46 Adults age 18 and over who received any preventive dental service in the calendar year, 2002–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, overall, the percentage of adults age 18 and over who received any preventive dental service in the calendar year did not have any statistically significant changes, increasing slightly from 33.6% to 35.4% (Figure 46).

Table 25 Clinical Preventive Measures: Childhood Immunization

The core set of childhood immunization measures includes 11 measures that were improving, 3 measures that showed no statistically significant changes over time, and none that were worsening.

The three measures that showed the fastest improvement were tetanus-diphtheria-acellular pertussis (Tdap) vaccine, ages 16–17 years; meningococcal conjugate vaccine; and tetanus-diphtheria-acellular pertussis (Tdap) vaccine, ages 13–15 years.

The three measures that were not changing over time all cover vaccination for children ages 19–35 months, diphtheria-tetanus-pertussis (DTP), hepatitis B, and measles-mumps-rubella (MMR).

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Adolescent – Tdap | Adolescents ages 16–17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis since the age of 10 years (National Immunization Survey-Teen [NIS-TEEN]) | 31.9% in 2008 | 90.0% in 2018
Adolescent – Meningitis | Adolescents ages 16–17 who received 1 or more doses of meningococcal conjugate vaccine (NIS-TEEN) | 38.6% in 2008 | 87.2% in 2018
Adolescent – Tdap | Adolescents ages 13–15 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis since the age of 10 years (NIS-TEEN) | 46.7% in 2008 | 88.2% in 2018
Adolescent – Meningitis | Adolescents ages 13–15 who received 1 or more doses of meningococcal conjugate vaccine (NIS-TEEN) | 43.9% in 2008 | 86.2% in 2018
Adolescent – HPV | Adolescent males ages 16–17 who received 3 or more doses of human papillomavirus vaccine (NIS-TEEN) | 6.6% in 2012 | 40.6% in 2018
Adolescent – HPV | Adolescent females ages 16–17 who received 3 or more doses of human papillomavirus vaccine (NIS-TEEN) | 19.8% in 2008 | 53.7% in 2018
Pediatric – Varicella | Children ages 19–35 months who received 1 or more doses of varicella vaccine (NIS) | 76.3% in 2001 | 92.0% in 2018
Adolescent – HPV | Adolescent males ages 13–15 who received 3 or more doses of human papillomavirus vaccine (NIS-TEEN) | 6.9% in 2012 | 26.1% in 2018
Adolescent – HPV | Adolescent females ages 13–15 who received 3 or more doses of human papillomavirus vaccine (NIS-TEEN) | 16.6% in 2008 | 28.4% in 2018
Pediatric – Influenza | Children ages 6 months to 17 years who received influenza vaccination in the last flu season (NHIS) | 42.1% in 2010 | 53.3% in 2018
Pediatric – Polio | Children ages 19–35 months who received 3 or more doses of polio vaccine (NIS) | 89.4% in 2001 | 93.6% in 2018
Not Changing
Pediatric – Hepatitis B | Children ages 19–35 months who received 3 or more doses of hepatitis B vaccine (NIS) | 88.9% in 2001 | 92.1% in 2018
Pediatric–DTP | Children ages 19–35 months who received 4 or more doses of diphtheria-tetanus-pertussis vaccine (NIS) | 82.1% in 2001 | 83.8% in 2018
Pediatric – MMR | Children ages 19–35 months who received 1 or more doses of measles-mumps-rubella vaccine (NIS) | 91.4% in 2001 | 92.1% in 2018

Figure 47 Adolescents ages 16–17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of 10 years, 2008–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey - Teen, 2008–2018.

- From 2008 to 2018, overall, the percentage of adolescents ages 16–17 years who received 1 or more doses of tetanus-diphtheria-acellular pertussis (Tdap) vaccine increased from 31.9% to 90.0% (Figure 47).

Figure 48 Adolescents ages 16–17 years who received 1 or more doses of meningococcal conjugate vaccine, 2008–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008–2018.

- From 2008 to 2018, overall, the percentage of adolescents ages 16–17 years who received 1 or more doses of meningococcal conjugate vaccine increased from 38.6%to 87.2% (Figure 48).

Figure 49 Adolescents ages 13–15 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of 10 years, 2008–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008–2018.

- From 2008 to 2018, overall, the percentage of adolescents ages 13–15 years who received 1 or more doses of tetanus-diphtheria-acellular pertussis (Tdap) vaccine increased from 46.7% to 88.2% (Figure 49).

Figure 50 Children ages 19–35 months who received 3 or more doses of hepatitis B vaccine, 2001–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey, 2001–2018.

- From 2001 to 2018, overall, the percentage of children ages 19–35 months who received 3 or more doses of hepatitis B vaccine showed no statistically significant change (88.9% to 92.1%) (Figure 50).

Figure 51 Children ages 19–35 months who received 4 or more doses of diphtheria-tetanus-pertussis vaccine, 2001–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey, 2001–2018.

- From 2001 to 2018, overall, the percentage of children ages 19–35 months who received 4 or more doses of diphtheria-tetanus-pertussis vaccine showed no statistically significant change (82.1% to 83.8%) (Figure 51).

Figure 52 Children ages 19–35 months who received 1 or more doses of measles-mumps-rubella vaccine, 2001–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey, 2001–2018.

- From 2001 to 2018, overall, the percentage of children ages 19–35 months who received 1 or more doses of measles-mumps-rubella vaccine showed no statistically significant change (91.4% to 92.1%) (Figure 52).

Table 26 Clinical Preventive Measures: Other Childhood Preventive Care

Three improving measures pertain to multiple sub-areas, including height/weight measurement, vision screening, and counseling about car seat safety. Five measures were not changing over time, including dental care, counseling about secondhand smoke, and counseling for bicycle use safety.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Pediatric Height and Weight | Children who had their height and weight measured by a health provider within the past 2 years (MEPS) | 86.7% in 2002 | 89.9% in 2018
Pediatric Vision Screening | Children ages 3–5 who ever had their vision checked by a health provider (MEPS) | 54.5% in 2002 | 70.7% in 2018
Counseling – Travel Safety | Children 41–80 lb for whom a health provider gave advice within the past 2 years about using a booster seat when riding in the car (MEPS) | 26.8% in 2002 | 38.0% in 2018
Not Changing
Pediatric Preventive Dental Service | Children ages 2–17 who received a preventive dental service in the calendar year (MEPS) | 40.0% in 2002 | 48.5% in 2018
Counseling – Secondhand Smoke | Children for whom a health provider gave advice within the past 2 years about how smoking in the house can be bad for a child (MEPS) | 38.8% in 2002 | 40.9% in 2018
Counseling – Travel Safety | Children ages 2–17 for whom a health provider gave advice within the past 2 years about using a helmet when riding a bicycle or motorcycle (MEPS) | 31.2% in 2002 | 34.4% in 2018
Pediatric Dental Caries | Children ages 5–17 with untreated dental caries (NHANES) | 23.1% in 2001–2004 | 13.1% in 2015–2018
Pediatric Dental Visit | Children ages 2–17 who had a dental visit in the calendar year (MEPS) | 49.1% in 2002 | 56.7% in 2018

Figure 53 Children who had their height and weight measured by a health provider within the past 2 years, 2002–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, overall, the percentage of children who had their height and weight measured by a health provider within the past 2 years increased from 86.7% to 89.9% (Figure 53).

Figure 54 Children ages 3–5 who ever had their vision checked by a health provider, 2002–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, overall, the percentage of children who had their vision checked by a health provider within the past 2 years increased from 54.5% to 70.7% (Figure 54).

Figure 55 Children 41–80 lb for whom a health provider gave advice within the past 2 years about using a booster seat when riding in the car, 2002–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, overall, the percentage of children 41–80 lb for whom a health provider gave advice within the past 2 years about using a booster seat when riding in the car increased from 26.8% to 38.0% (Figure 55).

Figure 56 Children ages 2–17 who received a preventive dental service in the calendar year, 2002–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, overall, the percentage of children ages 2–17 who received any preventive dental service in the calendar year showed no statistically significant change (40.0% to 48.5%) (Figure 56).

Figure 57 Children for whom a health provider gave advice within the past 2 years about how smoking in the house can be bad for a child, 2002–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, overall, the percentage of children for whom a health provider gave advice within the past 2 years about how smoking in the house can be bad for a child showed no statistically significant change (38.8% to 40.9%) (Figure 57).

Figure 58 Children ages 2–17 for whom a health provider gave advice within the past 2 years about using a helmet when riding a bicycle or motorcycle, 2002–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, overall, the percentage of children ages 2–17 for whom a health provider gave ad vice within the past 2 years about using a helmet when riding a bicycle or motorcycle showed no statistically significant change (31.2% to 34.4%) (Figure 58).

Table 27 Clinical Preventive Measures: Overall Preventive Care

The core set of measures includes two measures improving over time that look at influenza vaccination in home health care and nursing home care. Two nursing home and one home health care measure did not change over time and one measure examining pneumococcal vaccination in long-stay nursing home residents worsened.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Home Health | Home health care patients who had influenza vaccination during flu season (OASIS) | 87.3% in 2015 | 95.2% in 2018
Nursing Home | Long-stay nursing home patients who were assessed and appropriately given the seasonal influenza vaccine (MDS) | 90.0% in 2013 | 91.7% in 2018
Not Changing
Nursing Home | Short-stay nursing home patients who had flu vaccination appropriately given (MDS) | 86.8% in 2013 | 86.8% in 2018
Nursing Home | Short-stay nursing home residents who were assessed for pneumococcal vaccination (MDS) | 85.6% in 2013 | 85.6% in 2018
Home Health | Home health care patients who had pneumococcal polysaccharide vaccination (OASIS) | 84.0% in 2015 | 82.2% in 2018
Worsening
Nursing Home | Long-stay nursing home residents who were assessed for pneumococcal vaccination (MDS) | 93.8% in 2013 | 92.1% in 2018

Figure 59 Home health care patients who had influenza vaccination during flu season, 2015–2018

Line graph showing percentage: 2015, 87.3 2016, 93 2017, 95 2018, 95.2

Source: Centers for Medicare & Medicaid Services, Home Health Quality Initiative, Chronic Condition Data Warehouse, Outcome and Assessment Information Set, 2015–2018.

- From 2015 to 2018, overall, the percentage of home health patients who had influenza vaccination during flu season increased from 87.3% to 95.2% (Figure 59).

Figure 60 Long-stay nursing home patients who were assessed and appropriately given the seasonal influenza vaccine, 2013–2018

Line graph showing percentage: 2013, 90 2014, 90 2015, 90.5 2016, 90.9 2017, 91.2 2018, 91.7

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Residence Assessment Files, Minimum Data Set 3.0, 2013–2018.

- From 2013 to 2018, overall, the percentage of long-stay nursing home patients who were assessed and appropriately given the seasonal influenza vaccine increased from 90.0% to 91.7% (Figure 60).

Figure 61 Short-stay nursing home residents who had flu vaccination appropriately given, 2013–2018

Line graph showing percentage: 2013, 86.8 2014, 86.4 2015, 86.2 2016, 86.7 2017, 86.7 2018, 86.8

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Residence Assessment Files, Minimum Data Set 3.0, 2013–2018.

- From 2013 to 2018, overall, the percentage of short-stay nursing home patients who had flu vaccination appropriately given showed no statistically significant change (86.8% to 86.8%) (Figure 61).

Figure 62 Short-stay nursing home residents who were assessed and appropriately given the pneumococcal vaccination, 2013–2018

Line graph showing percentage: 2013, 85.6 2014, 85.3 2015, 84.7 2016, 84.9 2017, 85.7 2018, 85.6

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Residence Assessment Files, Minimum Data Set 3.0, 2013–2018.

- From 2013 to 2018, overall, the percentage of short-stay nursing home residents who were assessed for pneumococcal vaccination showed no statistically significant change (85.6% to 85.6%) (Figure 62).

Figure 63 Home health care patients who had pneumococcal polysaccharide vaccination, 2015–2018

Line graph showing percentage: 2015, 84 2016, 85.4 2017, 81.6 2018, 82.2

Source: Centers for Medicare & Medicaid Services, Home Health Quality Initiative, Chronic Condition Data Warehouse, Outcome and Assessment Information Set, 2015–2018.

- From 2015 to 2018, overall, the percentage of home health care patients who had pneumococcal polysaccharide vaccination showed no statistically significant change (84.0% to 82.2%) (Figure 63).

Figure 64 Long-stay nursing home residents who were assessed for pneumococcal vaccination, 2013–2018

Line graph showing percentage: 2013, 93.8 2014, 93.3 2015, 92.9 2016, 92.7 2017, 92.5 2018, 92.1

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Residence Assessment Files, Minimum Data Set 3.0, 2013–2018.

- From 2013 to 2018, overall, the percentage of long-stay nursing home residents who were assessed for pneumococcal vaccination decreased from 93.8% to 92.1% (Figure 64).

Table 28 Functional Status Preservation and Rehabilitation Measures

The core set of measures includes four home health care measures and one nursing home measure that were improving over time. One measure was not changing over time.

Home health care measures of ability to get in and out of bed, ambulation, and bathing were the fastest improving measures.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Home Health | Home health care patients whose ability to get in and out of bed improved (OASIS) | 57.9% in 2013 | 78.6% in 2018
Home Health | Home health care patients whose ability to walk or move around improved (OASIS) | 62.2% in 2013 | 78.4% in 2018
Home Health | Home health care patients whose bathing improved (OASIS) | 68.3% in 2013 | 80.3% in 2018
Home Health | Home health care patients who had improvement in toileting (OASIS) | 69.1% in 2013 | 75.2% in 2018
Nursing Home | Long-stay nursing home residents whose need for help with daily activities increased (MDS) | 22.8% in 2013 | 20.5% in 2018
Not Changing
Nursing Home | Long-stay nursing home residents whose ability to move independently worsened (MDS) | 24.5% in 2013 | 23.9% in 2018

Figure 65 Home health care patients whose ability to get in and out of bed improved, 2013–2018

Line graph showing percentage: 2013, 57.9 2014, 59.6 2015, 63.8 2016, 69.4 2017, 75.6 2018, 78.6

Source: Centers for Medicare & Medicaid Services, Home Health Quality Initiative, Chronic Condition Data Warehouse, Outcome and Assessment Information Set, 2013–2018.

- From 2013 to 2018, overall, the percentage of home health care patients whose ability to get in and out of bed improved increased from 57.9% to 78.6% (Figure 65).

Figure 66 Home health care patients whose ability to walk or move around improved, 2013–2018

Line graph showing percentage: 2013, 62.2 2014, 64.1 2015, 67.7 2016, 72.3 2017, 76.4 2018, 78.4

Source: Centers for Medicare & Medicaid Services, Home Health Quality Initiative, Chronic Condition Data Warehouse, Outcome and Assessment Information Set, 2013–2018.

- From 2013 to 2018, overall, the percentage of home health care patients whose ability to walk or move around improved increased from 62.2% to 78.4% (Figure 66).

Figure 67 Home health care patients whose bathing improved, 2013–2018

Line graph showing percentage: 2013, 68.3 2014, 69.1 2015, 71.5 2016, 75.2 2017, 78.7 2018, 80.3

Source: Centers for Medicare & Medicaid Services, Home Health Quality Initiative, Chronic Condition Data Warehouse, Outcome and Assessment Information Set, 2013–2018.

- From 2013 to 2018, overall, the percentage of home health care patients whose bathing improved increased from 68.3% to 80.3% (Figure 67).

Figure 68 Long-stay nursing home residents with worsening ability to move independently, 2013–2018 (lower rates are better)

Line graph showing percentage: 2013, 24.5 2014, 24.9 2015, 24.7 2016, 22.8 2017, 23.9 2018, 23.9

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Residence Assessment Files, Minimum Data Set 3.0, 2013–2018.

- From 2013 to 2018, overall, the percentage of long-stay nursing home residents with worsening ability to move independently showed no statistically significant changes (24.5% to 23.9%) (Figure 68).

Table 29 Supportive and Palliative Care Measures

Nine measures pertaining to nursing home care and home health care improved over time. The three fastest improving measures were measures of the use of physical restraints, shortness of breath, and pain.

One nursing home measure examining bowel and bladder control among residents worsened over time.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Nursing Home | Long-stay nursing home residents with physical restraints (MDS) | 1.3% in 2013 | 0.25% in 2018
Home Health | Home health care patients whose shortness of breath decreased (OASIS) | 65.2% in 2013 | 80.3% in 2018
Nursing Home | Short-stay nursing home residents with moderate to severe pain (MDS) | 17.7% in 2013 | 11.3% in 2017
Home Health | Home health care patients whose pain when moving around decreased (OASIS) | 68.1% in 2013 | 80.8% in 2018
Nursing Home | Long-stay nursing home residents with moderate to severe pain (MDS) | 9.2% in 2013 | 6.2% in 2017
Home Health | Home health care patients who had improvement in upper body dressing (OASIS) | 70.8% in 2013 | 79.2% in 2018
Home Health | Home health care patients who stayed at home after an episode of home health care (OASIS) | 81.3% in 2013 | 85.0% in 2018
Home Health | Home health care patients who had improvement in confusion frequency (OASIS) | 44.5% in 2013 | 51.8% in 2018
Nursing Home | Long-stay nursing home residents with too much weight loss (MDS) | 5.6% in 2013 | 5.2% in 2018
Worsening
Nursing Home | Low-risk, long-stay nursing home residents with loss of control of bowels or bladder (MDS) | 64.2% in 2013 | 74.3% in 2017

Figure 69 Long-stay nursing home residents with physical restraints, 2013–2018 (lower rates are better)

Note: Data reflect care for the latest episode in the calendar year.

Line graph showing percentage: 2013, 1.33 2014, 1.05 2015, 0.78 2016, 0.51 2017, 0.38 2018, 0.25

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Residence Assessment Files, Minimum Data Set 3.0, 2013–2018.

- From 2013 to 2018, overall, the percentage of long-stay nursing home residents with physical restraints decreased from 1.3% to 0.25% (Figure 69).

Figure 70 Home health care patients with decreased shortness of breath, 2013–2018

Line graph showing percentage: 2013, 65.2 2014, 65.8 2015, 69.9 2016, 73.6 2017, 78 2018, 80.3

Source: Centers for Medicare & Medicaid Services, Home Health Quality Initiative, Chronic Condition Data Warehouse, Outcome and Assessment Information Set, 2013–2018.

- From 2013 to 2018, overall, the percentage of home health care patients with decreased shortness of breath (improved breathing) increased from 65.2% to 80.3% (Figure 70).

Figure 71 Short-stay nursing home residents with moderate to severe pain, 2013–2017 (lower rates are better)

Line graph showing percentage: 2013, 17.7 2014, 16.6 2015, 15.1 2016, 13 2017, 11.3

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Residence Assessment Files, Minimum Data Set 3.0, 2013–2017.

- From 2013 to 2017, overall, the percentage of short-stay nursing home residents with moderate to severe pain decreased from 17.7% to 11.3% (Figure 71).

Figure 72 Long-stay nursing home residents with loss of control of bowels or bladder, 2013–2017 (lower rates are better)

Line graph showing percentage: 2013, 64.2 2014, 71.8 2015, 72.5 2016, 73 2017, 74.3

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Residence Assessment Files, Minimum Data Set 3.0, 2013–2017.

- From 2013 to 2017, overall, the percentage of long-stay nursing home residents with loss of control of bowels or bladder increased from 64.2% to 74.3% (Figure72).

Table 30 Lifestyle Modification Measures

Three core measures improved over time. These measures examine related topics, including smoking in adults, children’s diet, and exercise and fitness in children. Two measures were not changing over time and include measures examining pediatric and adult obesity. One measure related to childhood obesity worsened over time.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Smoking in Adults | Adult current smokers who had a doctor’s office or clinic visit in the last 12 months who received advice from their providers to quit smoking (MEPS) | 65.2% in 2002 | 76.5% in 2017
Pediatric Diet and Obesity | Children ages 2–17 for whom a health provider gave advice within the past 2 years about healthy eating (MEPS) | 46.9% in 2002 | 52.0% in 2018
Pediatric Exercise and Fitness | Children ages 2–17 for whom a health provider gave advice within the past 2 years about the amount and kind of exercise, sports, or physically active hobbies they should have (MEPS) | 30.0% in 2002 | 38.4% in 2018
Not Changing
Pediatric Weight | Children with obesity 2–19 years of age who had been told by a doctor or health professional that they were overweight (NHANES) | 37.0% in 1999–2002 | 43.8% in 2015–2018
Adult Diet and Obesity | Adults with obesity age 20 and over who had been told by a doctor or health professional that they were overweight (NHANES) | 67.9% in 1999–2002 | 71.9% in 2015–2018
Worsening
Pediatric Diet and Obesity | Children ages 2–19 with obesity (NHANES) | 14.8% in 1999–2002 | 18.9% in 2015–2018

Figure 73 Adult current smokers with a doctor’s office or clinic visit in the last 12 months who received advice to quit smoking, 2002–2017

Note: Estimates are age-adjusted to the 2000 U.S. standard population using three age groups: 18–44, 45–64, and 65 and over.

Line graph showing percentage. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2017.

- From 2002 to 2017, overall, the percentage of adults who currently smoke and had a doctor’s office or clinic visit in the last 12 months who received advice to quit smoking increased from 65.2% to 76.5% (Figure 73).

Figure 74 Children ages 2–17 for whom a health provider gave advice within the past 2 years about healthy eating, 2002–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, overall, the percentage of children ages 2–17 for whom a health provider gave advice within the past 2 years about healthy eating increased from 46.9% to 52.0% (Figure 74).

Figure 75 Children ages 2–17 for whom a health provider gave advice within the past 2 years about the amount and kind of exercise, sports, or physically active hobbies they should have, 2002–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002–2018.

- From 2002 to 2018, overall, the percentage of children ages 2–17 for whom a health provider gave advice within the past 2 years about the amount and kind of exercise, sports, or physically active hobbies they should have increased from 30.0% to 38.4% (Figure 75).

The only lifestyle modification measure that showed no statistically significant change over time and had updated data was a measure related to provider communication about childhood obesity.

Figure 76 Children ages 2–19 with obesity who had been told by a doctor or health professional that they were overweight, 1999–2018

Line graph showing percentage: 1999–2002, 37 2003–2006, 39.4 2007–2010, 44.6 2011–2014, 48.5 2015–2018, 43.8

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2018.

- From 1999–2002 to 2015–2018, overall, the percentage of children ages 2–19 with obesity who had been told by a doctor or health professional that they were overweight showed no statistically significant changes (37.0% to 43.8%) (Figure 76).

Figure 77 Children ages 2–19 with obesity, 1999–2018 (lower rates are better)

Line graph showing percentage: 1999–2002, 14.8 2003–2006, 16.3 2007–2010, 16.8 2011–2014, 17 2015–2018, 18.9

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2002 to 2015–2018.

- From 1999–2002 to 2015–2018, overall, the percentage of children ages 2–19 with obesity increased from 14.8% to 18.9% (Figure 77).

Table 31 Maternal and Child Health Measures

The core set of measures includes only one measure that examines breastfeeding and this measure improved over time. Two measures examined infant mortality and low birth weight. These measures were not changing over time.

Sub-Area | Measure Title (Data Source) | Baseline Rate and Year | Current Rate and Year
Improving
Breastfeeding | Infants born in the calendar year who were breastfed exclusively through 3 months (NIS) | 35.9% in 2009 | 46.3% in 2018
Not Changing
Infant Mortality | Infant mortality per 1,000 live births, birth weight 2,500 grams or more (National Vital Statistics System-Linked Birth and Death File [NVSS-L]) | 2.4% in 2001 | 2.0% in 2017
Infant Birth Weight | Live-born infants with low birth weight (less than 2,500 g) (NVSS-L) | 8.2% in 2007 | 8.3% in 2019

Figure 78 Infants born in the calendar year who received breastfeeding exclusively through 3 months, 2009–2018

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey, 2009–2018.

- From 2009 to 2018, overall, the percentage of infants born in the calendar year who received breastfeeding exclusively through 3 months increased from 35.9% to 46.3% (Figure 78).

Figure 79 Infant mortality per 1,000 live births, birth weight 2,500 grams or more, 2001–2017 (lower rates are better)

Note: 2006 data not available.

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Linked Birth and Infant Death Data, 2001–2017.

- From 2001 to 2017, overall, the rate of infant mortality per 1,000 live births, birth weight 2,500 grams or more, showed no statistically significant changes (2.4% to 2.0%) (Figure 79).

Figure 80 Live-born infants with low birth weight (less than 2,500 grams), 2007–2019 (lower rates are better)

Line graph showing percentage. Key information is in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics system - Natality, 2007–2019.

- From 2007 to 2019, overall, the percentage of live-born infants with low birth weight (less than 2,500 grams) showed no statistically significant changes (8.2% to 8.3%) (Figure 80).

xii For example, Section 1557 of the Affordable Care Act (ACA), 42 U.S.C. 18116, and Title VI of the Civil Rights Act of 1964, 42 U.S.C. 2000d, require the practitioner or hospital to take reasonable steps to ensure meaningful access to individuals with limited English proficiency, such as providing language interpreters and translating vital documents. Section 1557 of the ACA and Section 504 of the Rehabilitation Act of 1973, 29 U.S.C. 794, require the practitioner or hospital to take appropriate steps to ensure effective communication with individuals with disabilities, such as by providing sign language interpreters, materials in Braille, and/or accessible electronic formats.

xiii Eight measures of patient experience of care in ambulatory settings included in this report were not updated this year because new data were not available. They will be updated in the 2022 report when new data become available.

xiv The Institute of Medicine formally changed its name to the National Academy of Medicine in 2015.

xv This report focuses on patient safety activities led by AHRQ. Other federal agencies, including the Centers for Disease Control and Prevention and CMS, also have large portfolios of patient safety work that are not fully captured in this report.

xvi HHS, in accordance with expert recommendation, has replaced the term “medication-assisted therapy” (MAT) with “medications for opioid use disorder” (MOUD) when referring to an evidence-based treatment approach that uses medications, such as methadone, buprenorphine, or naltrexone, to reduce cravings and withdrawal symptoms associated with stopping opioid use. More information is available in National Academies of Sciences, Engineering, and Medicine. 2019. Medications for Opioid Use Disorder Save Lives. Washington, DC: The National Academies Press. https://doi.org/10.17226/25310. As both terms remain in use, this report, when appropriate, describes tools as MOUD/MAT in recognition that some resources may still use the older term for this approach.

xvii The most recent hypertension guidelines published by the American College of Cardiology and American Heart Association recommend blood pressure control targets of less than 140/90 mm Hg for most people and less than 130/80 mm Hg for people with elevated cardiovascular risk. The NHQDR defines blood pressure control in this report as blood pressure less than 140/90 mmHg, which aligns with the blood pressure control threshold used by Healthy People 2030.

xviii SAMHSA defines substance use disorder as characterized by impairment caused by the recurrent use of alcohol, other drugs (including illicit drugs), or both, leading to health problems, disability, and failure to meet major responsibilities at work, school, or home.