# APPENDIX C MEASURES USED IN THE 2021 STATE MAPS

## Disparities Map

Measure Title | Data Source | Data Year
Sepsis diagnoses per 1,000 elective-surgery admissions of length 4 or more days, adults | HCUP | 2018
Reclosure of postoperative abdominal wound dehiscence per 1,000 abdominopelvic-surgery admissions of length 2 or more days, adults | HCUP | 2018
Home health care patients whose surgical wound was improved | OASIS | 2018
Hospital admissions with iatrogenic pneumothorax per 1,000 medical and surgical admissions, adults | HCUP | 2018
Deaths per 1,000 elective-surgery admissions having developed specified complications of care during hospitalization, adults ages 18–89 or obstetric admissions | HCUP | 2018
Deaths per 1,000 hospital admissions with expected low-mortality | HCUP | 2018
Home health care patients whose management of oral medications improved | OASIS | 2018
Birth trauma - injury to neonate per 1,000 selected live births | HCUP | 2018
High-risk, long-stay nursing home patients with pressure ulcer | MDS | 2018
Low-risk, long-stay nursing home residents with a catheter inserted and left in the bladder | MDS | 2018
Long-stay nursing home residents with a urinary tract infection | MDS | 2018
Long-stay nursing home patients experiencing one or more falls with major injury | MDS | 2018
Short-stay nursing home patients with pressure ulcers that are new or worsened | MDS | 2018
Adults who reported a home health care provider talking with them about how to set up their home so they can move around safely when they first started getting home health care | HHCAHPS | 2019
Adults who reported a home health care provider talking with them about all the prescription and over-the-counter medicines they were taking when they first started getting home health care | HHCAHPS | 2019
Adults who reported a home health care provider asking to see all the prescription and over-the-counter medicines they were taking, when they first started getting home health care | HHCAHPS | 2019
Adults who reported that home health care providers talked with them about the purpose for taking their new or changed prescription medicines in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers talked with them about when to take medicines in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers talked with them about the side effects of medicines in the last 2 months of care | HHCAHPS | 2019
Adult hospital patients who sometimes or never had good communication about medications they received in the hospital | HCAHPS | 2019
Adults who reported being told what care and services they would get when they first started getting home health care | HHCAHPS | 2019
Adults who reported that home health care providers talk about pain in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers always kept them informed about when they would arrive at their home in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers always treated them as gently as possible in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers always explained things in a way that was easy to understand in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers always listen carefully to them in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers always treated them with courtesy and respect in the last 2 months of care | HHCAHPS | 2019
Adults who reported getting the help or advice they needed when they contacted their home health care providers in the last 2 months of care | HHCAHPS | 2019
Adults who did not have any problem with the care they received from their home health care providers in the last 2 months of care | HHCAHPS | 2019
Adult hospital patients who did not receive good communication about discharge information | HCAHPS | 2019
Adult hospital patients who strongly disagree or disagree that staff took their preferences and those of their family and caregiver into account when deciding what the patients discharge health care would be | HCAHPS | 2019
Hospital admissions for uncontrolled diabetes without complications per 100,000 population, adults | HCUP | 2018
Hospital admissions for short-term complications of diabetes per 100,000 population, adults | HCUP | 2018
Hospital admissions for short-term complications of diabetes per 100,000 population, children ages 6–17 | HCUP | 2018
Hospital admissions for long-term complications of diabetes per 100,000 population, adults | HCUP | 2018
Hospital admissions for lower extremity amputations per 1,000 population, adults age 18 and over with diabetes | HCUP | 2018
Hospital admissions for asthma per 100,000 population, adults ages 18–39 | HCUP | 2018
Hospital admissions for asthma per 100,000 population, children ages 2–17 | HCUP | 2018
Home health care patients who had an emergency department visit and then hospitalized | OASIS | 2018
Home health care patients who had an emergency department visit without a hospitalization | OASIS | 2018
Home health care patients who had to be admitted to the hospital | OASIS | 2018
Home health care patients who had timely initiation of care | OASIS | 2018
Adults who reported that home health care providers always seem informed and up-to-date about all the cares or treatments they got at home in the last 2 months of care | HHCAHPS | 2019
Hospital admissions for hypertension per 100,000 population, adults age 18 and over | HCUP | 2018
Hospital admissions for chronic obstructive pulmonary disease or asthma per 100,000 population, adults age 40 and over | HCUP | 2018
Hospital admissions for community-acquired pneumonia per 100,000 population, adults age 18 and over | HCUP | 2018
Deaths per 1,000 adult hospital admissions with acute myocardial infarction (AMI) | HCUP | 2018
Hospital admissions for heart failure per 100,000 population | HCUP | 2018
Deaths per 1,000 adult hospital admissions with heart failure | HCUP | 2018
Deaths per 1,000 adult hospital admissions with abdominal aortic aneurysm (AAA) repair | HCUP | 2018
Deaths per 1,000 hospital admissions with coronary artery bypass surgery, adults age 40 and over | HCUP | 2018
Deaths per 1,000 hospital admissions with percutaneous coronary intervention (PCI), age 40 and over | HCUP | 2018
Adults age 40 and over with diagnosed diabetes who received at least two hemoglobin A1c measurements in the calendar year | BRFSS | 2019
Adults age 40 and over with diagnosed diabetes who received a dilated eye examination in the calendar year | BRFSS | 2019
Adults age 40 and over with diagnosed diabetes who had their feet checked for sores or irritation in the calendar year | BRFSS | 2019
Adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year | BRFSS | 2019
Long-stay nursing home residents have depressive symptoms | MDS | 2018
Deaths per 1,000 adult hospital admissions with pneumonia | HCUP | 2018
Home health care patients whose ability to walk or move around improved | OASIS | 2018
Home health care patients whose ability to get in and out of bed improved | OASIS | 2018
Home health care patients whose bathing improved | OASIS | 2018
Home health care patients who had improvement in toileting | OASIS | 2018
Long-stay nursing home residents whose need for help with daily activities increased | MDS | 2018
Long-stay nursing home residents whose ability to move independently worsened | MDS | 2018
Long-stay nursing home residents with too much weight loss | MDS | 2018
Low-risk, long-stay nursing home residents with loss of control of bowels or bladder | MDS | 2018
Long-stay nursing home residents with physical restraints | MDS | 2018
Home health care patients whose shortness of breath decreased | OASIS | 2018
Home health care patients who stayed at home after an episode of home health care | OASIS | 2018
Home health care patients who had improvement in upper body dressing | OASIS | 2018
Home health care patients who had improvement in confusion frequency | OASIS | 2018
Home health care patients whose pain when moving around decreased | OASIS | 2018
Women ages 50–74 who received a mammogram in the last 2 years | BRFSS | 2018
Women ages 21–65 who received a Pap smear in the last 3 years or human papillomavirus (HPV) vaccines in the last 5 years | BRFSS | 2018
Adults who received a blood cholesterol measurement in the last 5 years | BRFSS | 2019
Adults ages 18–64 at high risk (e.g., COPD) who received an influenza vaccination in the last flu season | BRFSS | 2019
Adults age 65 and over who received an influenza vaccination in the last flu season | BRFSS | 2019
Hospital admissions for immunization-preventable influenza per 100,000 population, adults age 65 and over | HCUP | 2018
Adults ages 18–64 at high risk (e.g., COPD) who ever received pneumococcal vaccination | BRFSS | 2019
Adults age 65 and over who ever received pneumococcal vaccination | BRFSS | 2019
Long-stay nursing home patients who were assessed and appropriately given the seasonal influenza vaccine | MDS | 2018
Long-stay nursing home residents who were assessed for pneumococcal vaccination | MDS | 2018
Short-stay nursing home patients who had flu vaccination appropriately given | MDS | 2018
Short-stay nursing home residents who were assessed for pneumococcal vaccination | MDS | 2018
Home health care patients who had influenza vaccination during flu season | OASIS | 2018
Home health care patients who had pneumococcal polysaccharide vaccination | OASIS | 2018
Adults who had an appointment for routine health care in the last 6 or 12 months who sometimes or never got an appointment for routine care as soon as wanted, Medicare managed care | NCBD | 2019
Adults who had an appointment for routine health care in the last 6 or 12 months who sometimes or never got an appointment for routine care as soon as wanted, Medicare fee-for-service | NCBD | 2019
Adults who needed care right away for an illness, injury, or condition in the last 6 or 12 months who sometimes or never got care as soon as wanted, Medicare managed care | NCBD | 2019
Adults who needed care right away for an illness, injury, or condition in the last 6 or 12 months who sometimes or never got care as soon as wanted, Medicare fee-for-service | NCBD | 2019
Adults who needed to see a specialist in the last 6 or 12 months who sometimes or never found it easy to see a specialist, Medicare managed care | NCBD | 2019
Adults who needed to see a specialist in the last 6 or 12 months who sometimes or never found it easy to see a specialist, Medicare fee-for-service | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, Medicare fee-for-service | NCBD | 2019
Composite measure: Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never listened carefully, explained things clearly, respected what they had to say, and spent enough time with them, Medicare managed care | NCBD | 2019
Composite measure: Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never listened carefully, explained things clearly, respected what they had to say, and spent enough time with them, Medicare-fee-for-service | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never listened carefully to them, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never listened carefully to them, Medicare fee-for-service | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never explained things in a way they could understand, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never explained things in a way they could understand, Medicare fee-for-service | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never showed respect for what they had to say, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never showed respect for what they had to say, Medicare fee-for-service | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never spent enough time with them, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never spent enough time with them, Medicare fee-for-service | NCBD | 2019
Rating of health care 0–6 on a scale from 0 (worst grade) to 10 (best grade) by adults who had a doctor’s office or clinic visit in the last 12 months, Medicare managed care | NCBD | 2019
Rating of health care 0–6 on a scale from 0 (worst grade) to 10 (best grade) by adults who had a doctor’s office or clinic visit in the last 12 months, Medicare fee-for-service | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months who sometimes or never got advice to quit smoking from provider, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months who sometimes or never got advice to quit smoking from provider, Medicare fee-for-service | NCBD | 2019

## QUALITY MAP

Measure Title | Data Source | Data Year
Home health care patients whose surgical wound was improved | OASIS | 2018
Home health care patients whose management of oral medications improved | OASIS | 2018
High-risk, long-stay nursing home patients with pressure ulcer | MDS | 2018
Low-risk, long-stay nursing home residents with a catheter inserted and left in the bladder | MDS | 2018
Long-stay nursing home residents with a urinary tract infection | MDS | 2018
Long-stay nursing home patients experiencing one or more falls with major injury | MDS | 2018
Short-stay nursing home patients with pressure ulcers that are new or worsened | MDS | 2018
Adults who reported a home health care provider talking with them about how to set up their home so they can move around safely when they first started getting home health care | HHCAHPS | 2019
Adults who reported a home health care provider talking with them about all the prescription and over-the-counter medicines they were taking when they first started getting home health care | HHCAHPS | 2019
Adults who reported a home health care provider asking to see all the prescription and over-the-counter medicines they were taking, when they first started getting home health care | HHCAHPS | 2019
Adults who reported that home health care providers talked with them about the purpose for taking their new or changed prescription medicines in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers talked with them about when to take medicines in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers talked with them about the side effects of medicines in the last 2 months of care | HHCAHPS | 2019
Adult hospital patients who sometimes or never had good communication about medications they received in the hospital | HCAHPS | 2019
Adults who reported being told what care and services they would get when they first started getting home health care | HHCAHPS | 2019
Adults who reported that home health care providers talk about pain in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers always kept them informed about when they would arrive at their home in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers always treated them as gently as possible in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers always explained things in a way that was easy to understand in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers always listen carefully to them in the last 2 months of care | HHCAHPS | 2019
Adults who reported that home health care providers always treated them with courtesy and respect in the last 2 months of care | HHCAHPS | 2019
Adults who reported getting the help or advice they needed when they contacted their home health care providers in the last 2 months of care | HHCAHPS | 2019
Adults who did not have any problem with the care they received from their home health care providers in the last 2 months of care | HHCAHPS | 2019
Hospice patients whose hospice care team always communicated well with their family caregivers about taking care them | HOSPICE CAHPS | 2019
Hospice patients and family caregivers who always got help as soon as they need from hospice care team | HOSPICE CAHPS | 2019
Hospice patients whose hospice care team always treated them with dignity and respect, and really cared about them | HOSPICE CAHPS | 2019
Hospice patients who always received enough helps for pain, sadness, breathing, or constipations from hospice care team | HOSPICE CAHPS | 2019
Family members who definitely received trainings about taking care their family member from hospice care team | HOSPICE CAHPS | 2019
Family caregivers who received right amount of emotional and spiritual supports from hospice care team | HOSPICE CAHPS | 2019
Family caregivers who rated the hospice care for their family member best (9–10) on a scale of 0–10 (where 0 is the worst and 10 is the best) | HOSPICE CAHPS | 2019
Family caregivers who would definitely recommend this hospice to their friends and family | HOSPICE CAHPS | 2019
Adult hospital patients who did not receive good communication about discharge information | HCAHPS | 2019
Adult hospital patients who strongly disagree or disagree that staff took their preferences and those of their family and caregiver into account when deciding what the patients discharge health care would be | HCAHPS | 2019
Home health care patients who had an emergency department visit and then hospitalized | OASIS | 2018
Home health care patients who had an emergency department visit without a hospitalization | OASIS | 2018
Home health care patients who had to be admitted to the hospital | OASIS | 2018
Home health care patients who had timely initiation of care | OASIS | 2018
Adults who reported that home health care providers always seem informed and up-to-date about all the cares or treatments they got at home in the last 2 months of care | HHCAHPS | 2019
Women with clinical Stage I–IIb breast cancer who received axillary node dissection or sentinel lymph node biopsy at the time of breast cancer surgery (lumpectomy or mastectomy) | NCDB | 2017
Women under age 70 treated for breast cancer with breast-conserving surgery who received radiation therapy to the breast within 1 year of diagnosis | NCDB | 2017
Breast cancer deaths per 100,000 female population per year | NVSS_M | 2018
Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined | NCDB | 2017
Colorectal cancer deaths per 100,000 population per year | NVSS_M | 2018
Lung cancer deaths per 100,000 population per year | NVSS_M | 2018
Adult end stage renal disease (ESRD) patients who saw a nephrologist at least 12 months prior to initiation of renal replacement therapy | USRDS | 2018
Ratio of observed deaths to expected deaths among Medicare hemodialysis patients | UMKECC | 2019
Dialysis patients who were registered on a waiting list for transplantation | USRDS | 2017
Patients with treated chronic kidney failure who received a transplant within 3 years of date of kidney failure | USRDS | 2015
Hemodialysis patients whose hemoglobin level is less than 10 g/dL | UMKECC | 2019
Adult hemodialysis patients who use arteriovenous fistulas as the primary mode of vascular access | USRDS | 2018
Adults age 40 and over with diagnosed diabetes who received at least two hemoglobin A1c measurements in the calendar year | BRFSS | 2019
Adults age 40 and over with diagnosed diabetes who received a dilated eye examination in the calendar year | BRFSS | 2019
Adults age 40 and over with diagnosed diabetes who had their feet checked for sores or irritation in the calendar year | BRFSS | 2019
Adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year | BRFSS | 2019
New HIV cases per 100,000 population age 13 and over | HIVAIDSSS | 2019
People age 13 and over living with HIV who know their serostatus | HIVAIDSSS | 2019
People age 13 and over living with diagnosed HIV who had at least two CD4 or viral load tests performed at least 3 months apart during the last year, among reporting jurisdictions | HIVAIDSSS | 2018
People age 13 and over living with diagnosed HIV whose most recent viral load in the last 12 months was under 200 copies/mL | HIVAIDSSS | 2018
HIV infection deaths per 100,000 population | NVSS_M | 2018
Adults with a major depressive episode in the last 12 months who received treatment for depression in the last 12 months | NSDUH | 2019
Children ages 12–17 with a major depressive episode in the last 12 months who received treatment for depression in the last 12 months | NSDUH | 2019
Suicide deaths among people age 12 and over per 100,000 population | NVSS_M | 2018
Long-stay nursing home residents have depressive symptoms | MDS | 2018
People age 12 and over who needed treatment for illicit drug use and who received such treatment at a specialty facility in the last 12 months | NSDUH | 2019
People age 12 and over who needed treatment for alcohol problem who received such treatment at a specialty facility in the last 12 months | NSDUH | 2019
People age 12 and over treated for substance abuse who completed treatment course | TEDSD | 2018
Patients with tuberculosis who completed a curative course of treatment within 1 year of initiation of treatment | NTBSS | 2017
Infants born in the calendar year who received breastfeeding exclusively through 3 months | NIS | 2018
Home health care patients whose ability to walk or move around improved | OASIS | 2018
Home health care patients whose ability to get in and out of bed improved | OASIS | 2018
Home health care patients whose bathing improved | OASIS | 2018
Home health care patients who had improvement in toileting | OASIS | 2018
Long-stay nursing home residents whose need for help with daily activities increased | MDS | 2018
Long-stay nursing home residents whose ability to move independently worsened | MDS | 2018
Long-stay nursing home residents with moderate to severe pain | MDS | 2017
Long-stay nursing home residents with too much weight loss | MDS | 2018
Low-risk, long-stay nursing home residents with loss of control of bowels or bladder | MDS | 2018
Long-stay nursing home residents with physical restraints | MDS | 2018
Short-stay nursing home residents with moderate to severe pain | MDS | 2017
Home health care patients whose shortness of breath decreased | OASIS | 2018
Home health care patients who stayed at home after an episode of home health care | OASIS | 2018
Home health care patients who had improvement in upper body dressing | OASIS | 2018
Home health care patients who had improvement in confusion frequency | OASIS | 2018
Home health care patients whose pain when moving around decreased | OASIS | 2018
Women ages 50–74 who received a mammogram in the last 2 years | BRFSS | 2018
Breast cancer diagnosed at advanced stage (regional, distant stage, or local stage with tumor greater than 2 cm) per 100,000 women age 40 and over | NPCR USCS | 2017
Women ages 21–65 who received a Pap smear in the last 3 years | BRFSS | 2018
Cervical cancer diagnosed at advanced stage (all invasive tumors) per 100,000 women age 20 and over | NPCR USCS | 2017
Colorectal cancer diagnosed at advanced stage (tumors diagnosed at regional or distant stage) per 100,000 population age 50 and over | NPCR USCS | 2017
Adults who received a blood cholesterol measurement in the last 5 years | BRFSS | 2019
Adults ages 18–64 at high risk (e.g., COPD) who received an influenza vaccination in the last flu season | BRFSS | 2019
Adults age 65 and over who received an influenza vaccination in the last flu season | BRFSS | 2019
Adults ages 18–64 at high risk (e.g., COPD) who ever received pneumococcal vaccination | BRFSS | 2019
Adults age 65 and over who ever received pneumococcal vaccination | BRFSS | 2019
Hospital patients who received influenza vaccination | HIQR | 2018
Children ages 19–35 months who received 4 or more doses of diphtheria-tetanus-pertussis vaccine | NIS | 2018
Children ages 19–35 months who received 3 or more doses of polio vaccine | NIS | 2018
Children ages 19–35 months who received 1 or more doses of measles-mumps-rubella vaccine | NIS | 2018
Children ages 19–35 months who received 3 or more doses of hepatitis B vaccine | NIS | 2018
Children ages 19–35 months who received 1 or more doses of varicella vaccine | NIS | 2018
Adolescents ages 13–15 who received 1 or more doses of meningococcal conjugate vaccine | NIS TEEN | 2018
Adolescents ages 16–17 who received 1 or more doses of meningococcal conjugate vaccine | NIS TEEN | 2018
Adolescents females ages 13–15 who received 3 or more doses human papillomavirus vaccine | NIS TEEN | 2018
Adolescents females ages 16–17 who received 3 or more doses human papillomavirus vaccine | NIS TEEN | 2018
Adolescent males ages 13–15 who received 3 or more doses of human papillomavirus (HPV) vaccine | NIS TEEN | 2018
Adolescent males ages 16–17 who received 3 or more doses of human papillomavirus (HPV) vaccine | NIS TEEN | 2018
Adolescents ages 13–15 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of ten years | NIS TEEN | 2018
Adolescents ages 16–17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of ten years | NIS TEEN | 2018
Long-stay nursing home patients who were assessed and appropriately given the seasonal influenza vaccine | MDS | 2018
Long-stay nursing home residents who were assessed for pneumococcal vaccination | MDS | 2018
Short-stay nursing home patients who had flu vaccination appropriately given | MDS | 2018
Short-stay nursing home residents who were assessed for pneumococcal vaccination | MDS | 2018
Home health care patients who had influenza vaccination during flu season | OASIS | 2018
Home health care patients who had pneumococcal polysaccharide vaccination | OASIS | 2018
Adults who had an appointment for routine health care in the last 6 months who sometimes or never got an appointment for routine care as soon as wanted, Medicaid | NCBD | 2020
Adults who had an appointment for routine health care in the last 6 or 12 months who sometimes or never got an appointment for routine care as soon as wanted, Medicare managed care | NCBD | 2019
Adults who had an appointment for routine health care in the last 6 or 12 months who sometimes or never got an appointment for routine care as soon as wanted, Medicare fee-for-service | NCBD | 2019
Children who had an appointment for routine health care in the last 6 months who sometimes or never got an appointment for routine care as soon as wanted, Medicaid | NCBD | 2020
Adults who needed care right away for an illness, injury, or condition in the last 6 months who sometimes or never got care as soon as wanted, Medicaid | NCBD | 2020
Adults who needed care right away for an illness, injury, or condition in the last 6 or 12 months who sometimes or never got care as soon as wanted, Medicare managed care | NCBD | 2019
Adults who needed care right away for an illness, injury, or condition in the last 6 or 12 months who sometimes or never got care as soon as wanted, Medicare fee-for-service | NCBD | 2019
Adults who needed to see a specialist in the last 6 or 12 months who sometimes or never found it easy to see a specialist, Medicare managed care | NCBD | 2019
Adults who needed to see a specialist in the last 6 or 12 months who sometimes or never found it easy to see a specialist, Medicare fee-for-service | NCBD | 2019
Adults who needed to see a specialist in the last 6 months who sometimes or never found it easy to see a specialist, Medicaid | NCBD | 2020
Children who needed to see a specialist in the last 6 months who sometimes or never found it easy to see a specialist, Medicaid | NCBD | 2020
Adults who had a doctor’s office or clinic visit in the last 6 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, Medicaid | NCBD | 2020
Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, Medicare fee-for-service | NCBD | 2019
Children who had a doctor’s office or clinic visit in the last 6 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, Medicaid | NCBD | 2020
Composite measure: Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never listened carefully, explained things clearly, respected what they had to say, and spent enough time with them, Medicare managed care | NCBD | 2019
Composite measure: Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never listened carefully, explained things clearly, respected what they had to say, and spent enough time with them, Medicare-fee-for-service | NCBD | 2019
Composite measure: Adults who had a doctor’s office or clinic visit in the last 6 months whose health providers sometimes or never listened carefully, explained things clearly, respected what they had to say, and spent enough time with them, Medicaid | NCBD | 2020
Composite measure: Children who had a doctor’s office or clinic visit in the last 6 months whose health providers always listened carefully, explained things clearly, respected what they or their parents had to say, and spent enough time with them, Medicaid | NCBD | 2020
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never listened carefully to them, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never listened carefully to them, Medicare fee-for-service | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 months whose health providers sometimes or never listened carefully to them, Medicaid | NCBD | 2020
Children who had a doctor’s office or clinic visit in the last 6 months whose health providers always listened carefully, Medicaid | NCBD | 2020
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never explained things in a way they could understand, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never explained things in a way they could understand, Medicare fee-for-service | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 months whose health providers sometimes or never explained things in a way they could understand, Medicaid | NCBD | 2020
Children who had a doctor’s office or clinic visit in the last 6 months whose health providers always explained things clearly to their parents, Medicaid | NCBD | 2020
Children who had a doctor’s office or clinic visit in the last 6 months whose health providers always explained things clearly to child, Medicaid | NCBD | 2020
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never showed respect for what they had to say, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never showed respect for what they had to say, Medicare fee-for-service | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 months whose health providers sometimes or never showed respect for what they had to say, Medicaid | NCBD | 2020
Children who had a doctor’s office or clinic visit in the last 6 months whose health providers always showed respect for what their parents had to say, Medicaid | NCBD | 2020
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never spent enough time with them, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months whose health providers sometimes or never spent enough time with them, Medicare fee-for-service | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 months whose health providers sometimes or never spent enough time with them, Medicaid | NCBD | 2020
Children who had a doctor’s office or clinic visit in the last 6 months whose health providers always spent enough time with them, Medicaid | NCBD | 2020
Rating of health care 0–6 on a scale from 0 (worst grade) to 10 (best grade) by adults who had a doctor’s office or clinic visit in the last 12 months, Medicare managed care | NCBD | 2019
Rating of health care 0–6 on a scale from 0 (worst grade) to 10 (best grade) by adults who had a doctor’s office or clinic visit in the last 12 months, Medicare fee-for-service | NCBD | 2019
Rating of health care 0–6 on a scale from 0 (worst grade) to 10 (best grade) by adults who had a doctor’s office or clinic visit in the last 12 months, Medicaid | NCBD | 2020
Adults who had a doctor’s office or clinic visit in the last 6 months who sometimes or never got advice to quit smoking from provider, Medicaid | NCBD | 2020
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months who sometimes or never got advice to quit smoking from provider, Medicare managed care | NCBD | 2019
Adults who had a doctor’s office or clinic visit in the last 6 or 12 months who sometimes or never got advice to quit smoking from provider, Medicare fee-for-service | NCBD | 2019