# APPENDIX B DEFINITIONS AND ABBREVIATIONS USED IN 2021 NHQDR

## Definitions

### Racial and Ethnic Groups

Racial and ethnic groups are defined according to Standards for the Classification of Federal Data on Race and Ethnicity, issued by the Office of Management and Budget (available at https://www.gpo.gov/fdsys/granule/FR-1997-10-30/97-28653).

The basic racial and ethnic categories for federal statistics and program administrative reporting are defined as follows:

1. American Indian or Alaska Native (AI/AN). A person having origins in any of the original peoples of North and South America (including Central America) and who maintains tribal affiliation or community attachment.
2. Asian. A person having origins in any of the original peoples of the Far East, Southeast Asia, or the Indian subcontinent, including, for example, Cambodia, China, India, Japan, Korea, Malaysia, Pakistan, the Philippine Islands, Thailand, and Vietnam.
3. Black or African American. A person having origins in any of the Black racial groups of Africa. Terms such as “Haitian” can be used in addition to “Black or African American.”
4. Hispanic or Latino. A person of Cuban, Mexican, Puerto Rican, Central or South American, or other Spanish culture or origin, regardless of race. The term “Spanish origin” can be used in addition to “Hispanic or Latino.”
5. Native Hawaiian/Pacific Islander (NHPI). A person having origins in any of the original peoples of Hawaii, Guam, Samoa, or other Pacific Islands.
6. White. A person having origins in any of the original peoples of Europe, the Middle East, or North Africa.

### Income

Income groups are based on the federal poverty level (FPL) for a family of four:

- Poor: Less than 100% of FPL
- Low income: 100% to less than 200% of FPL
- Middle income: 200% to less than 400% of FPL
- High income: 400% or more of FPL

The poverty guidelines are available at https://aspe.hhs.gov/poverty-guidelines.

### Urban-Rural Areas

Urban and rural areas are defined based on the National Center for Health Statistics 2013 Urban-Rural Classification Scheme.

Figure B-1 Map Showing 2013 NCHS Urban-Rural County Classifications in the United States

Map of United States showing urban and rural classifications, which are defined in the text below the map

- Metropolitan counties:
  ■ Large central metro counties in metropolitan statistical area (MSA) of 1 million or more population that: (1) contain the entire population of the largest principal city of the MSA, or (2) are completely contained within the largest principal city of the MSA, or (3) contain at least 250,000 residents of any principal city in the MSA
  ■ Large fringe metro counties in MSA of 1 million or more population that do not qualify as large central.
  ■ Medium metro counties in MSA of 250,000–999,999 population.
  ■ Small metro counties in MSAs of less than 250,000 population.
- Nonmetropolitan counties:
  ■ Micropolitan: Counties in a micropolitan statistical area.
  ■ Noncore: Nonmetropolitan counties that are not in a micropolitan statistical area.

More information is available at https://www.cdc.gov/nchs/data_access/urban_rural.htm.

### Disabilities

Disability status is defined by following the methodology of the American Community Survey, which is different from the Activity Limitation used in the 2007–2018 NHQDR.

- Adults age 18 and over are defined as with disability if one reported with serious difficulty in hearing, serious difficulty in vision, serious cognitive difficulty, serious difficulty in walking or climbing stairs, difficulty in dressing or bathing, and difficulty in doing errands.
- Children with special health care needs (CSHCN): Children ages 0–17 with activity limitations or need or use of more healthcare or other services than is usual for most children of the same age. Question sequences^ii^ are asked about the following five health consequences: the need or use of medicines prescribed by a doctor; the need or use of more medical care, mental health care, or education services than is usual for most children; limitations or inability to do things most children can do; the need or use of special therapy, such as physical, occupational, or speech therapy; and the need or use of treatment or counseling for emotional, developmental, or behavioral problems. Children with responses to at least one of the five health consequences were identified as having a special health care need.

## Abbreviations Used in the NHQDR

- AAA: abdominal aortic aneurysm
- ACIP: Advisory Committee on Immunization Practices
- ADE: adverse drug event
- AI/AN: American Indian or Alaska Native
- API: Asian and Pacific Islander
- BMI: body mass index
- BRFSS: Behavioral Risk Factor Surveillance System
- CAH: critical access hospital
- CAHPS: Consumer Assessment of Healthcare Providers and Systems
- CAP: community-acquired pneumonia
- CHIP: Children’s Health Insurance Program
- CLAS: culturally and linguistically appropriate services
- COPD: chronic obstructive pulmonary disease
- ED: emergency department
- EMT: emergency medical technician
- FFS: fee for service
- FPL: Federal Poverty Level
- HCUP: Healthcare Cost & Utilization Project
- HCAHPS: Hospital Consumer Assessment of Healthcare Providers and Systems
- HHCAHPS: Home Health Consumer Assessment of Healthcare Providers and Systems
- HHS: U.S. Department of Health and Human Services
- HIQR: Hospital Inpatient Quality Reporting program
- HIVAIDSSS: HIV/AIDS Surveillance System
- HPV: human papillomavirus
- ICD-9: International Classification of Diseases, Ninth Revision
- ICD-10: International Classification of Diseases, Tenth Revision
- IOM: Institute of Medicine
- LMWH: low-molecular-weight heparin
- MA: Medicare Advantage
- MDS: Minimum Data Set
- MEPS: Medical Expenditure Panel Survey
- MPSMS: Medicare Patient Safety Monitoring System
- MSA: metropolitan statistical area
- NAMCS: National Ambulatory Medical Care Survey
- NCBD: National CAHPS Benchmarking Database
- NCAPPS: National Center on Advancing Person-Centered Practices and Systems
- NCDB: National Cancer Data Base
- NEDS: National Emergency Department Sample
- NHAMCS: National Hospital Ambulatory Medical Care Survey
- NHANES: National Health and Nutrition Examination Survey
- NHIS: National Health Interview Survey
- NHPI: Native Hawaiian/Pacific Islander
- NHQDR: National Healthcare Quality and Disparities Report
- NICU: neonatal intensive care unit
- NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases
- NIS: National Immunization Survey
- NPCR-USCS: National Program of Cancer Registries – U.S. Cancer Statistics
- NPSD: National Patient Safety Databases
- NSDUH: National Survey on Drug Use and Health
- NTBSS: National Tuberculosis Surveillance System
- NVSS-M: National Vital Statistics System - Mortality
- OASIS: Outcome and Assessment Information Set
- OCR: Office for Civil Rights
- PA: physician assistant
- PSO: Patient Safety Organization
- RWHAP: Ryan White HIV/AIDS Program
- SHPEP: Summer Health Professionals Education Program
- SID: State Inpatient Databases
- TEDS: Treatment Episode Data Set
- UM-KECC: University of Michigan Kidney Epidemiology and Cost Center
- USC: usual source of care
- USRDS: U.S. Renal Data System
- YPLL: years of potential life lost

## Agencies and Offices in the U.S. Department of Health and Human Services

- AHRQ: Agency for Healthcare Research and Quality
  ■ CFACT: Center for Financing, Access, and Cost Trends
  ■ CQuIPS: Center for Quality Improvement and Patient Safety
  ■ OC: Office of Communications
  ■ OEREP: Office of Extramural Research, Education, and Priority Populations
- ACL: Administration for Community Living
- ASPE: Office of the Assistant Secretary for Planning and Evaluation
- CDC: Centers for Disease Control and Prevention
  ■ NCHS: National Center for Health Statistics
  ■ NPCR: National Program of Cancer Registries
  ■ NCCDPHP-ONDIEH: National Center for Chronic Disease Prevention and Health Promotion, Office of Noncommunicable Diseases, Injury, and Environmental Health
- CMS: Centers for Medicare & Medicaid Services
- FDA: Food and Drug Administration
- HRSA: Health Resources and Services Administration
- IHS: Indian Health Service
- NIH: National Institutes of Health
  ■ NCI: National Cancer Institute
  ■ NIDA: National Institute on Drug Abuse
  ■ NIMHD: National Institute on Minority Health and Health Disparities
  ■ OD-ORWH: Office of the Director-Office of Research on Women’s Health
- OASH: Office of the Assistant Secretary for Health
- SAMHSA: Substance Abuse and Mental Health Services Administration

## Other Federal Agencies

- VHA: Veterans Health Administration

## Private Organizations

- ACS NSQIP: American College of Surgeons National Surgical Quality Improvement Program

ii A CSHCN Screener instrument was developed through a national collaborative process as part of the Child and Adolescent Health Measurement Initiative coordinated by the Foundation for Accountability. For more information, refer to Bethell CD, Read D, Stein REK, . Identifying children with special health care needs: development and evaluation of a short screening instrument. Ambul Pediatr 2002 Feb;2(1):38–48. https://www.ncbi.nlm.nih.gov/pubmed/11888437. Accessed May 23, 2019 11888437 .