# APPENDIX A DATA SOURCES USED FOR 2021 NHQDR

The National Healthcare Quality and Disparities Report (NHQDR) is a comprehensive national overview of quality of healthcare in the United States. The report also examines disparities in healthcare among priority populations, such as racial and ethnic minority groups. The report is compiled from multiple federal, state, and private data sources, including databases and surveys.

## Federal Sources of Data

### Agency for Healthcare Research and Quality

- Healthcare Cost and Utilization Project (HCUP) (see next page for details)
- Medical Expenditure Panel Survey (MEPS)
- National CAHPS® Benchmarking Database (NCBD) – Health Plan Survey Database
- National Patient Safety Database (NPSD)

### Centers for Disease Control and Prevention

- Behavioral Risk Factor Surveillance System (BRFSS)
- National Ambulatory Medical Care Survey (NAMCS)
- National Health and Nutrition Examination Survey (NHANES)
- National Health Interview Survey (NHIS)
- National HIV Surveillance System (NHSS)
- National Hospital Ambulatory Medical Care Survey (NHAMCS)
- National Immunization Survey (NIS)
- National Program of Cancer Registries (NPCR)
- National Tuberculosis Surveillance System (NTSS)
- National Vital Statistics System—Linked Birth and Infant Death Data (NVSS-L)
- National Vital Statistics System—Mortality (NVSS-M)
- National Vital Statistics System—Natality (NVSS-N)

### Centers for Medicare & Medicaid Services

- Hospital Inpatient Quality Reporting (HIQR) Program

### Health Resources and Services Administration

- Uniform Data System (UDS)
- HIV/AIDS Bureau - Ryan White HIV/AIDS Program

### Indian Health Service

- Indian Health Service National Data Warehouse (NDW)

### National Institutes of Health

- United States Renal Data System (USRDS)

### Substance Abuse and Mental Health Services Administration

- National Survey on Drug Use and Health (NSDUH)
- Substance Use Disorder Treatment Episode Data Set (TEDS)

## Multi-Agency Data Sources

### Centers for Medicare & Medicaid Services and Agency for Healthcare Research and Quality

- Home Health Consumer Assessment of Healthcare Providers and Systems (HHCAHPS)
- Hospital Consumer Assessment of Healthcare Providers and Systems (HCAHPS)
- Medicare Patient Safety Monitoring System (MPSMS)

## Academic Institutions

### University of Michigan

- University of Michigan Kidney Epidemiology and Cost Center (UMKECC)

## Professional Organizations and Associations

### Commission on Cancer and American Cancer Society

- National Cancer Data Base (NCDB)

## Additional Information on Agency for Healthcare Research and Quality HCUP Partners

The State Inpatient Databases (SID) disparities analysis file was created from SID data to provide national estimates for the NHQDR. It consists of weighted records from a sample of hospitals from the following 36 states participating in the Healthcare Cost and Utilization Project (HCUP) that have high-quality race/ethnicity data: AR, AZ, CA, CO, CT, DC,^i^ FL, GA, HI, IA, IL, IN, KS, KY, MD, MI, MO, NC, NJ, NM, NV, NY, OK, OR, PA, RI, SC, SD, TN, TX, VA, VT, WA, WI, WV, and WY.

In 2014, the 36 states accounted for 80% of U.S. discharges from community, nonrehabilitation hospitals (based on the American Hospital Association Annual Survey). A full list of HCUP partners appears below, including states that are not part of the disparities analysis file.

### Sources of HCUP Data

- Alaska Department of Health and Social Services
- Alaska State Hospital and Nursing Home Association
- Arizona Department of Health Services
- Arkansas Department of Health
- California Office of Statewide Health Planning and Development
- Colorado Hospital Association
- Connecticut Hospital Association
- District of Columbia Hospital Association
- Florida Agency for Health Care Administration
- Georgia Hospital Association
- Hawaii Health Information Corporation
- Illinois Department of Public Health
- Indiana Hospital Association
- Iowa Hospital Association
- Kansas Hospital Association
- Kentucky Cabinet for Health and Family Services
- Louisiana Department of Health
- Maine Health Data Organization
- Maryland Health Services Cost Review Commission
- Massachusetts Center for Health Information and Analysis
- Michigan Health and Hospital Association
- Minnesota Hospital Association
- Mississippi State Department of Health
- Missouri Hospital Industry Data Institute
- Montana Hospital Association
- Nebraska Hospital Association
- Nevada Department of Health and Human Services
- New Hampshire Department of Health and Human Services
- New Jersey Department of Health
- New Mexico Department of Health
- New York State Department of Health
- North Carolina Department of Health and Human Services
- North Dakota (data provided by the Minnesota Hospital Association)
- Ohio Hospital Association
- Oklahoma State Department of Health
- Oregon Association of Hospitals and Health Systems
- Oregon Office of Health Analytics
- Pennsylvania Health Care Cost Containment Council
- Rhode Island Department of Health
- South Carolina Revenue and Fiscal Affairs Office
- South Dakota Association of Healthcare Organizations
- Tennessee Hospital Association
- Texas Department of State Health Services
- Utah Department of Health
- Vermont Association of Hospitals and Health Systems
- Virginia Health Information
- Washington State Department of Health
- West Virginia Health Care Authority
- Wisconsin Department of Health Services
- Wyoming Hospital Association

i For purposes of the NHQDR, the District of Columbia is treated as a state.