# REFERENCES

### Overview

1 Gardner JW, Sanborn JS. Years of potential life lost (YPLL)-what does it measure? Epidemiology 1990;1:322–9. https://www.ncbi.nlm.nih.gov/pubmed/2083312 [abstract]. Accessed December 3, 2020.2083312
2 Zhang X, Lin D, Pforsich H, . Physician workforce in the United States of America: forecasting nationwide shortages. Hum Resour Health 2020;18(1):8. https://pubmed.ncbi.nlm.nih.gov/32029001/. Accessed December 3, 2020.32029001
3 Snyder CR, Frogner BK, Skillman SM. Facilitating racial and ethnic diversity in the health workforce. J Allied Health 2018;47(1):58–65. https://pubmed.ncbi.nlm.nih.gov/29504021/. Accessed December 3, 2020.29504021
4 Brown T, Liu JX, Scheffler RM. Does the under- or overrepresentation of minority physicians across geographical areas affect the location decisions of minority physicians? Health Serv Res 2009;44:1290–1308. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2739029/. Accessed December 3, 2020.19467025
5 Day JC, Christnacht C. Women hold 76% of all health care jobs, gaining in higher-paying occupations. Suitland, MD: U.S. Census Bureau; August 14, 2019. https://www.census.gov/library/stories/2019/08/your-health-care-in-womens-hands.html. Accessed December 3, 2020.
6 Greenwood BN, Carnahan S, Huang L. Patient–physician gender concordance and increased mortality among female heart attack patients. PNAS 2018 Aug 21;115(34):8569–74. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6112736/. Accessed December 3, 2020.30082406
7 Peabody MR, Eden AR, Douglas M, . Board certified family physician workforce: progress in racial and ethnic diversity. J Am Board Fam Med 2018 Nov;31(6):842–3. https://www.jabfm.org/content/31/6/842. Accessed December 3, 2020.30413540
8 Malhotra J, Rotter D, Tsui J, . Impact of patient-provider race, ethnicity, and gender concordance on cancer screening: findings from Medical Expenditure Panel Survey. Cancer Epidemiol Biomarkers Prev 2017;26(12):1804–11. https://cebp.aacrjournals.org/content/26/12/1804.long. Accessed December 3, 2020.29021217
9 Garcia RI, Blue Spruce G, Sinkford JC, . Workforce diversity in dentistry - current status and future challenges. J Public Health Dent 2017 Mar;77(2):99–104. Epub 2017 May 12. https://pubmed.ncbi.nlm.nih.gov/28497850/. Accessed December 3, 2020.28497850
10 Phillips JM, Malone B. Increasing racial/ethnic diversity in nursing to reduce health disparities and achieve health equity. Public Health Rep 2014;129 Suppl 2(Suppl 2):45–50. https://pubmed.ncbi.nlm.nih.gov/24385664/. Accessed December 3, 2020.24385664
11 Health Resources and Services Administration, National Center for Health Workforce Analysis. Sex, Race, and Ethnic Diversity of U.S. Health Occupations (2011-2015). Rockville, MD: U.S. Department of Health and Human Services; August 2017. https://bhw.hrsa.gov/sites/default/files/bhw/nchwa/diversityushealthoccupations.pdf. Accessed December 3, 2020.
12 Bush AA. A conceptual framework for exploring the experiences of underrepresented racial minorities in pharmacy school. Am J Pharm Educ 2020 Jan;84(1):7544. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7055416/. Accessed December 3, 2020.32292197
13 O’Neil E, Dower C. Primary care health workforce in the United States. Synth Proj Res Synth Rep 2011;(22):72579. https://pubmed.ncbi.nlm.nih.gov/22041996/. Accessed December 3, 2020.
14 Naylor MD, Kurtzman ET. The role of nurse practitioners in reinventing primary care. Health Aff (Millwood) 2010;29(5):893–9. https://www.healthaffairs.org/doi/full/10.1377/hlthaff.2010.0440?url_ver=Z39.88-2003&rfr_id=ori:rid:crossref.org&rfr_dat=cr_pub%20%200pubmed. Accessed December 3, 2020.20439877
15 Crowe RP, Krebs W, Cash RE, . Females and minority racial/ethnic groups remain underrepresented in emergency medical services: a ten-year assessment, 2008-2017. Prehosp Emerg Care 2020 Mar–Apr;24(2):180–7. Epub 2019 Jul 24. https://pubmed.ncbi.nlm.nih.gov/ (https://pubmed.ncbi.nlm.nih.gov/%2031225772/). Accessed December 3, 2020.31225772
16 Beck AJ, Manderscheid RW, Buerhaus P. The future of the behavioral health workforce: optimism and opportunity. Am J Prev Med 2018;54(6):S187–S189. https://www.ajpmonline.org/article/S0749-3797(18)31627-1/fulltext. Accessed December 3, 2020.29779540
17 Health Resources and Services Administration, National Center for Health Workforce Analysis; Substance Abuse and Mental Health Services Administration, Office of Policy, Planning, and Innovation. National Projections of Supply and Demand for Behavioral Health Practitioners: 2013-2015. Rockville, MD: U.S. Department of Health and Human Services; 2015. https://bhw.hrsa.gov/sites/default/files/bhw/health-workforce-analysis/research/projections/behavioral-health2013-2025.pdf. Accessed December 3, 2020.
18 Olfson M. Building the mental health workforce capacity needed to treat adults with serious mental illnesses. Health Aff (Millwood) 2016;35(6):983–90. https://www.healthaffairs.org/doi/pdf/10.1377/hlthaff.2015.1619. Accessed December 3, 2020.27269013
19 Substance Abuse and Mental Health Services Administration. National Survey on Drug Use and Health: 2018. https://www.samhsa.gov/data/sites/default/files/cbhsq-reports/Assistant-Secretary-nsduh2018_presentation.pdf. Accessed December 3, 2020.
20 Substance Abuse and Mental Health Services Administration. 2018 National Survey on Drug Use and Health: Asians/Native Hawaiian and Other Pacific Islanders (NHOPI). https://www.samhsa.gov/data/sites/default/files/reports/rpt23248/3_Asian_NHOPI_2020_01_14.pptx. Accessed December 3, 2020.
21 Substance Abuse and Mental Health Services Administration. 2018 National Survey on Drug Use and Health: African Americans. https://www.samhsa.gov/data/sites/default/files/reports/rpt23247/2_AfricanAmerican_2020_01_14.pptx. Accessed December 3, 2020.
22 Substance Abuse and Mental Health Services Administration. 2018 National Survey on Drug Use and Health: Hispanics, Latino or Spanish Origin or Descent. https://www.samhsa.gov/data/sites/default/files/reports/rpt23249/4_Hispanic_2020_01_14.pptx. Accessed December 3, 2020.
23 Eylem O, de Wit L, van Straten A, . Stigma for common mental disorders in racial minorities and majorities a systematic review and meta-analysis. BMC Public Health 2020;20(1):1–20. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7278062/. Accessed December 3, 2020.31898494
24 Substance Abuse and Mental Health Services Administration, Center for Mental Health Services; National Institute of Mental Health. Mental Health: Culture, Race, and Ethnicity: A Supplement to Mental Health: A Report of the Surgeon General. Washington, DC: Department of Health and Human Services, Public Health Service, Office of the Surgeon General; August 2001. https://www.ncbi.nlm.nih.gov/books/NBK44243/. Accessed December 3, 2020.
25 Wahowiak L. Addressing stigma, disparities in minority mental health: access to care among barriers. Nation’s Health 2015 Feb;45 (1):1–20. https://thenationshealth.aphapublications.org/content/45/1/1.3. Accessed December 3, 2020.
26 Santiago CD, Miranda J. Progress in improving mental health services for racial-ethnic minority groups: a ten-year perspective. Psychiatr Serv 2014;65(2):180–5. https://ps.psychiatryonline.org/doi/pdfplus/10.1176/appi.ps.201200517. Accessed December 3, 2020.24178249
27 Alegría M, Roter DL, Valentine A, . Patient-clinician ethnic concordance and communication in mental health intake visits. Patient Educ Couns 2013 Nov;93(2):188–96. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3800470/. Accessed December 15, 2020.23896127
28 U.S. Bureau of Labor Statistics. Occupational Outlook Handbook: Psychologists. Last modified September 1, 2020. https://www.bls.gov/ooh/life-physical-and-social-science/psychologists.htm. Accessed December 3, 2020.
29 Centers for Medicare & Medicaid Services. National Health Expenditures by Type of Service and Source of Funds, CY 1960-2017. Last modified December 17, 2019. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html. Accessed December 3, 2020.
30 Centers for Medicare & Medicaid Services. National Health Expenditure Accounts: Methodology Paper, 2018: Definitions, Sources, and Methods. https://www.cms.gov/files/document/definitions-sources-and-methods.pdf. Accessed December 3, 2020.

### Access to Healthcare and Disparities in Access

1 Institute of Medicine, Committee on Monitoring Access to Personal Health Care Services. Access to Health Care in America. Millman M, ed. Washington, DC: National Academies Press; 1993. https://www.ncbi.nlm.nih.gov/books/NBK235882/. Accessed December 3, 2020.
2 Office of Disease Prevention and Health Promotion. HealthyPeople.gov. Access to Health Services. https://www.healthypeople.gov/2020/topics-objectives/topic/Access-to-Health-Services. Accessed December 3, 2020.
3 National Academies of Science, Engineering, and Medicine. Communities in Action: Pathways to Health Equity. Washington, DC: National Academies Press; 2017. https://pubmed.ncbi.nlm.nih.gov/28418632/. Accessed December 3, 2020.
4 Sommers BD, Maylone B, Blendon RJ, . Three-year impacts of the Affordable Care Act: improved medical care and health among low-income adults. Health Aff 2017;36(6): 1119–28. https://pubmed.ncbi.nlm.nih.gov/28515140/. Accessed December 3, 2020.
5 Oral Health in America: A Report of the Surgeon General. Rockville, MD: National Institute of Dental and Craniofacial Research, National Institutes of Health; 2000. https://www.nidcr.nih.gov/research/data-statistics/surgeon-general. Accessed December 3, 2020.
6 Stephens MB, Wiedemer JP, Kushner GM. Dental problems in primary care. Am Fam Physician 2018;98(11):654–60. https://www.aafp.org/afp/2018/1201/p654.html. Accessed August 13, 2020.30485039
7 Fullerton CA, Witt WP, Chow CM, . Impact of a usual source of care on health care use, spending, and quality among adults with mental health conditions. Adm Policy Ment Health 2018 May;45(3):462–71. https://pubmed.ncbi.nlm.nih.gov/29189994/. Accessed December 3, 2020.29189994
8 Committee on Optimizing Scheduling in Health Care; Institute of Medicine. Kaplan K, Hamilton Lopez M, McGinnis JM, eds. Transforming Health Care Scheduling and Access: Getting to Now. Washington, DC: National Academies Press; 2015. https://www.ncbi.nlm.nih.gov/books/NBK316132/. Accessed December 3, 2020.
9 Brunner J, Rose DE, Chuang E, . The role of healthcare system hassles in delaying or forgoing care. Healthc (Amst) (https://www.ncbi.nlm.nih.gov/pubmed/32127306) 2020 Feb 29:100411. https://pubmed.ncbi.nlm.nih.gov/32127306/. Accessed December 3, 2020.
10 Sommers BD, Gawande AA, Baicker K. Health insurance coverage and health –what the recent evidence tells us. N Engl J Med 2017;377;6:586–93. https://pubmed.ncbi.nlm.nih.gov/28636831/. Accessed December 3, 2020.28636831
11 Chen J, Vargas-Bustamante A, Mortensen K, . Racial and ethnic disparities in health care access and utilization under the Affordable Care Act. Med Care 2016;54:140–6. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4711386/. Accessed December 3, 2020.26595227
12 Centers for Disease Control and Prevention. Oral Health Surveillance Report: Trends in Dental Caries and Sealants, Tooth Retention, and Edentulism, United States, 1999–2004 to 2011–2016. Atlanta, GA: U.S. Department of Health and Human Services; 2019. https://www.cdc.gov/oralhealth/publications/OHSR-2019-index.html. Accessed December 3, 2020.
13 Neuman P, Jacobson GA. Medicare Advantage checkup. N Engl J Med 2018 Nov 29;379(22):2163–72.30428276
14 Data Book: Beneficiaries Dually Eligible for Medicare and Medicaid. Washington, DC: Medicare Payment Advisory Commission and Medicaid and CHIP Payment and Access Commission; January 2018. https://www.macpac.gov/wp-content/uploads/2020/07/Data-Book-Beneficiaries-Dually-Eligible-for-Medicare-and-Medicaid-January-2018.pdf. Accessed December 3, 2020.
15 Arnett MJ, Thorpe RJ Jr, Gaskin DJ, . Race, medical mistrust, and segregation in primary care as usual source of care: findings from the Exploring Health Disparities in Integrated Communities Study. J Urban Health 2016 Jun;93(3):456–67. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4899337/. Accessed December 3, 2020.27193595
16 Blewett LA, Johnson PJ, Lee B, . When a usual source of care and usual provider matter: adult prevention and screening services. J Gen Intern Med 2008 Sep; 23(9):1354–60. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2518015/. Accessed December 3, 2020.18506542
17 Institute of Medicine. Coverage Matters: Insurance and Health Care. Washington, DC: National Academy Press; 2001. https://www.nap.edu/catalog/10188/coverage-matters-insurance-and-health-care. Accessed December 3, 2020.

### Quality in Healthcare

1 Chassin MR, Galvin RW. The urgent need to improve health care quality. Institute of Medicine National Roundtable on Health Care Quality. JAMA 1998;280(11):1000–5.9749483
2 Corrigan JM, Donaldson MS, Kohn LT, . Crossing the Quality Chasm: A New Health System for the 21st Century. Washington, DC: Institute of Medicine, National Academy of Sciences, National Academies Press; 2001. https://www.nap.edu/catalog/10027/crossing-the-quality-chasm-a-new-health-system-for-the. Accessed December 3, 2020.
3 Institute of Medicine. Envisioning the National Health Care Quality Report. Washington, DC: National Academy Press; 2001. https://www.nap.edu/catalog/10073/envisioning-the-national-health-care-quality-report. Accessed December 3, 2020.
4 DiMatteo MR. The role of the physician in the emerging health care environment. West J Med 1998;168(5):328–33. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1304975/. Accessed December 3, 2020.9614789
5 Stewart M, Brown JB, Donner A, . The impact of patient-centered care on outcomes. J Fam Pract 2000;49(9):796–804. https://www.ncbi.nlm.nih.gov/pubmed/11032203 [abstract]. Accessed December 3, 2020.11032203
6 Little P, Everitt H, Williamson I, . Observational study of effect of patient centredness and positive approach on outcomes of general practice consultations. BMJ 2001;323(7318):908–11. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC58543/. Accessed December 3, 2020.11668137
7 Anderson EB. Patient-centeredness: a new approach. Nephrol News Issues 2002;16(12):80–2. https://www.ncbi.nlm.nih.gov/pubmed/12452113 [abstract]. Accessed December 3, 2020.12452113
8 Beck RS, Daughtridge R, Sloane PD. Physician-patient communication in the primary care office: a systematic review. J Am Board Fam Pract 2002;15(1):25–38. https://www.jabfm.org/content/15/1/25.long. Accessed December 3, 2020.11841136
9 Rhoades DR, McFarland KF, Finch WH, . Speaking and interruptions during primary care office visits. Fam Med 2001;33(7):528–32. https://www.ncbi.nlm.nih.gov/pubmed/11456245[abstract]. Accessed December 3, 2020.11456245
10 Weiner SJ, Schwartz A, Sharma G, . Patient-centered decision making and health care outcomes. Ann Intern Med 2013;158(8):573–9. https://www.ncbi.nlm.nih.gov/pubmed/23588745. Accessed December 3, 2020.23588745
11 Okunrintemi V, Spatz ES, Di Capua P, . Patient-provider communication and health outcomes among individuals with atherosclerotic cardiovascular disease in the United States: Medical Expenditure Panel Survey 2010 to 2013. Circ Cardiovasc Qual Outcomes 2017 Apr;10(4). https://www.ahajournals.org/doi/full/10.1161/CIRCOUTCOMES.117.003635?url_ver=Z39.88-2003&rfr_id=ori%3Arid%3Acrossref.org&rfr_dat=cr_pub%3Dpubmed. Accessed December 3, 2020.
12 National Academies of Sciences, Engineering, and Medicine. Improving Diagnosis in Health Care. Washington, DC: The National Academies Press; 2015. https://www.nap.edu/catalog/21794/improving-diagnosis-in-health-care. Accessed December 3, 2020.
13 Chou C. Time to start using evidence-based approaches to patient engagement. NEJM Catalyst 2018 Mar 28. https://catalyst.nejm.org/evidence-based-patient-provider-communication/. Accessed December 3, 2020.
14 Øvretveit, J. Do Changes to Patient-Provider Relationships Improve Quality and Save Money? A Review of the Evidence About Value Improvements Made by Changing Communication, Collaboration, and Support for Self-Care. London, UK: The Health Foundation; 2012. https://www.bl.uk/collection-items/do-changes-to-patientprovider-relationships-improve-quality-and-save-money-a-review-of-evidence-about-value-improvements-made-by-changing-communication-collaboration-and-support-for-selfcare. Accessed December 3, 2020.
15 Bertakis KD, Azari R. Patient-centered care is associated with decreased health care utilization. J Am Board Fam Med 2011 May–Jun;24(3):229–39. https://www.jabfm.org/content/24/3/229.long. Accessed December 3, 2020.21551394
16 Epstein RM, Franks P, Shields CG, . Patient-centered communication and diagnostic testing. Ann Fam Med 2005;3(5):415–21. http://www.annfammed.org/content/3/5/415.long. Accessed December 3, 2020.16189057
17 Posner KL, Severson J, Domino KB. The role of informed consent in patient complaints: reducing hidden health system costs and improving patient engagement through shared decision making. J Healthc Risk Manag 2015 Sep;35(2):38–45. https://www.ncbi.nlm.nih.gov/pubmed/26418139. Accessed December 3, 2020.26418139
18 Ponce NA, Hays RD, Cunningham WE. Linguistic disparities in health care access and health status among older adults. J Gen Intern Med 2006 Jul;21(7):786–91. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1924691/. Accessed December 3, 2020.16808783
19 Zong J, Batalova J. Language diversity and English proficiency in the United States. Migration Information Source 2016 Nov 11. https://www.migrationpolicy.org/article/language-diversity-and-english-proficiency-united-states-2015. Accessed December 15, 2020.
20 Institute of Medicine. Race, Ethnicity, and Language Data: Standardization for Health Care Quality Improvement. Washington, DC: The National Academies Press; 2009. 4. Defining language need and categories for collection. .https://www.ahrq.gov/research/findings/final-reports/iomracereport/reldata4.html. Accessed December 3, 2020.
21 Limited English Proficiency: A Federal Interagency Website. Frequently Asked Questions. https://www.lep.gov/faqs/faqs.html. Accessed December 3, 2020.
22 Kutner M, Greenberg E, Jin Y, . The health literacy of America’s adults: results from the 2003 National Assessment of Adult Literacy. Washington, DC: U.S. Department of Education; 2006. Publication No. NCES 2006-483. https://nces.ed.gov/pubs2006/2006483_1.pdf. Accessed February 6, 2019. This survey is the only national assessment of health literacy to date.
23 Institute of Medicine. Health literacy: a prescription to end confusion. Washington, DC: National Academies Press; 2004. https://www.nap.edu/catalog/10883/health-literacy-a-prescription-toend-confusion. Accessed December 3, 2020.
24 Schillinger D, Piette J, Grumbach K, . Closing the loop: physician communication with diabetic patients who have low health literacy. Arch Intern Med 2003;163(1):83–90.12523921
25 Data Spotlights. AHRQ Publication No. 18(19)-0033-8-EF. Content last reviewed March 2019 Agency for Healthcare Research and Quality, Rockville, MD. https://www.ahrq.gov/research/findings/nhqrdr/data-spotlights/index.html.
26 Boulware LE, Cooper LA, Ratner LE, . Race and trust in the health care system. Public Health Rep 2003; 118: 358–65.12815085
27 Kohn LT, Corrigan JM, Donaldson MS, eds; Committee on Quality of Health Care in America, Institute of Medicine. To Err Is Human: Building a Safer Health System. Washington, DC: National Academy Press; 2000. http://www.nap.edu/catalog/9728.html. Accessed December 3, 2020.
28 Sunshine JE, Meo N, Kassebaum NJ, . Association of adverse effects of medical treatment with mortality in the United States: a secondary analysis of the Global Burden of Diseases, Injuries, and Risk Factors Study. JAMA Netw Open 2019;2(1):e187041. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6484545/. Accessed December 3, 2020.30657530
29 AHRQ National Scorecard on Hospital-Acquired Conditions: Updated Baseline Rates and Preliminary Results 2014-2017. https://www.ahrq.gov/sites/default/files/wysiwyg/professionals/quality-patient-safety/pfp/hacreport-2019.pdf. Accessed Jully 20, 2020.
30 Bailey MK, Weiss AJ, Barrett ML, . Characteristics of 30-day readmissions, 2010-2016. HCUP Statistical Brief #248. Rockville, MD: Agency for Healthcare Research and Quality; February 2019. www.hcup-us.ahrq.gov/reports/statbriefs/sb248-Hospital-Readmissions-2010-2016.pdf. Accessed December 3, 2020.
31 Gajic-Veljanoski O, Phua CW, Shah PS, . Effects of long-term low-molecular-weight heparin on fractures and bone density in non-pregnant adults: a systematic review with meta-analysis. J Gen Intern Med 2016 Aug;31(8):947–57. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4945546/. Accessed December 3, 2020.26895998
32 A Patient’s Guide to Taking Warfarin. American Heart Association. https://www.heart.org/en/health-topics/arrhythmia/prevention-treatment-of-arrhythmia/a-patients-guide-to-taking-warfarin. Accessed August. 7, 2020.
33 Genao L, Buhr GT. Urinary tract infections in older adults residing in long-term care facilities. Ann Longterm Care 2012 Apr;20(4):33–8. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3573848/. Accessed December 3, 2020.23418402
34 Bodenheimer T. Coordinating care—a perilous journey through the health care system. N Engl J Med 2008 Mar 6;358(10):1064–71. DOI:10.1056/NEJMhpr0706165. Accessed December 3, 2020.18322289
35 Shojania K, McDonald K, Wachter R, . Closing the Quality Gap: A Critical Analysis of Quality Improvement Strategies—Volume 7: Care Coordination. Rockville, MD: Agency for Healthcare Research and Quality; 2007. http://www.ahrq.gov/research/findings/evidence-based-reports/caregaptp.html. Accessed December 3, 2020.
36 Powell-Davies G, Williams AM, Larsen K, . Coordinating primary health care: an analysis of the outcomes of a systematic review. Med J Aust (https://www.ncbi.nlm.nih.gov/pubmed/18429740) 2008 Apr 21;188(8 Suppl):S65–8. https://www.ncbi.nlm.nih.gov/pubmed/18429740 [abstract]. Accessed December 3, 2020.
37 Care Coordination. Content last reviewed August 2018. Agency for Healthcare Research and Quality, Rockville, MD. https://www.ahrq.gov/ncepcr/care/coordination.html.
38 Coleman EA, Parry C,Chalmers S, . The care transitions intervention: results of a randomized controlled trial. Arch Intern Med 2006 Sep 25;166(17):1822–8. https://www.ncbi.nlm.nih.gov/pubmed/17000937. Accessed August 2, 2019.17000937
39 Whittington J, Cohen H. OSF Healthcare’s journey in patient safety. Qual Manag Health Care (https://www.ncbi.nlm.nih.gov/pubmed/?term=whittington+cohen+medication+reconciliation) 2004 Jan–Mar;13(1):53–9. https://www.ncbi.nlm.nih.gov/pubmed/14976907 [abstract]. Accessed December 3, 2020.14976907
40 Jencks SF, Williams MV, Coleman EA. Rehospitalizations among patients in the Medicare Fee-for-Service Program. N Engl J Med 2009;360:1418–28. https://www.nejm.org/doi/10.1056/NEJMsa0803563?url_ver=Z39.88-2003&rfr_id=ori:rid:crossref.org&rfr_dat=cr_pub%3dwww.ncbi.nlm.nih.gov. Accessed December 3, 2020.19339721
41 Centers for Disease Control and Prevention, National Center for Health Statistics. Asthma. Last reviewed February 20, 2020. https://www.cdc.gov/nchs/fastats/asthma.htm. Accessed December 3, 2020.
42 The Asthma and Allergy Foundation and the National Pharmaceutical Council. Ethnic Disparities in the Burden and Treatment of Asthma. January 2005. https://www.aafa.org/media/1633/ethnic-disparities-burden-treatment-asthma-report.pdf. Accessed December 3, 2020.
43 Kullgren JT, McLaughlin CG, Mitra N, . Nonfinancial barriers and access to care for U.S. adults. Health Serv Res. 2012;47(1 Pt 2):462–485. doi:10.1111/j.1475-6773.2011.01308.x.22092449
44 Wilper AP, Woolhandler S, Lasser KE, . Health insurance and mortality in US adults. Am J Public Health. 2009;99(12):2289–2295. doi:10.2105/AJPH.2008.157685.19762659
45 Institute of Medicine; Committee on the Consequences of Uninsurance. Care Without Coverage: Too Little, Too Late. Washington, DC National Academies Pr 2002.
46 National Academies of Sciences, Engineering, and Medicine; Health and Medicine Division; Board on Health Care Services; Nass SJ, Madhavan G, Augustine NR, ., eds. Making Medicines Affordable: A National Imperative. Washington (DC): National Academies Press (US); 2017.
47 Centers for Disease Control and Prevention, National Center for Chronic Disease Prevention and Health Promotion. Chronic Diseases in America. Last reviewed October 2019. https://www.cdc.gov/chronicdisease/resources/infographic/chronic-diseases.htm. Accessed December 3, 2020.
48 Raghupathi W, Raghupathi V. An Empirical Study of Chronic Diseases in the United States: A Visual Analytics Approach. Int J Environ Res Public Health. 2018;15(3):431. Published 2018 Mar 1. doi:10.3390/ijerph15030431.
49 Xu J, Murphy SL, Kochanek KD, . Mortality in the United States, 2018. NCHS Data Brief No. 355, Hyattsville, MD: National Center for Health Statistics; 2020.
50 Centers for Disease Control and Prevention. Chronic Kidney Disease in the United States, 2019. Atlanta, GA: US Department of Health and Human Services, Centers for Disease Control and Prevention; 2019.
51 Kenealy T, Arroll B. Antibiotics for the common cold and acute purulent rhinitis. Cochrane Database Syst Rev 2013 Jun 4;(6):CD000247. https://www.ncbi.nlm.nih.gov/pubmed/23733381. Accessed December 3, 2020.
52 American Cancer Society. Surgery for Colon Cancer. Last revised February 21, 2018. https://www.cancer.org/cancer/colon-rectal-cancer/treating/colon-surgery.html. Accessed December 3, 2020.
53 Chang GJ, Rodriguez-Bigas MA, Skibber JM, . Lymph node evaluation and survival after curative resection of colon cancer: systematic review. J Natl Cancer Inst 2007 Mar 21;99(6):433–41. https://pubmed.ncbi.nlm.nih.gov/17374833/. Accessed December 3, 2020.17374833
54 Wong SL. Lymph node counts and survival rates after resection for colon and rectal cancer. Gastrointest Cancer Res 2009;3(2 Suppl):S33–S35. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2684729/. Accessed December 3, 2020.19461921
55 Scholl L, Seth P, Kariisa M, . Drug and opioid-involved overdose deaths — United States, 2013-2017. MMWR Morb Mortal Wkly Rep 2019;67:1419–27. 10.15585/mmwr.mm675152e1. Accessed December 3, 2020.
56 U.S. Department of Health and Human Services. What Is the U.S. Opioid Epidemic? Last reviewed January 2019. https://www.hhs.gov/opioids/about-the-epidemic/index.html. Accessed December 3, 2020.
57 Center for Behavioral Health Statistics and Quality. Key Substance Use and Mental Health Indicators in the United States: Results From the 2017 National Survey on Drug Use and Health. Detailed Tables (Table 1.65A). https://www.samhsa.gov/data/release/2017-national-survey-drug-use-and-health-nsduh-releases. . Accessed December 3, 2020.
58 Lapierre S, Erlangsen A, Waern M, . A systematic review of elderly suicide prevention programs. Crisis 2011;32(2):88–98. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3728773/. Accessed December 3, 2020.21602163
59 Owens PL, Fingar KR, Heslin KC, . Emergency Department Visits Related to Suicidal Ideation, 2006–2013. HCUP Statistical Brief #220. Rockville, MD: Agency for Healthcare Research and Quality; January 2017. http://www.hcup-us.ahrq.gov/reports/statbriefs/sb220-Suicidal-Ideation-ED-Visits.pdf. Accessed December 3, 2020.
60 Centers for Disease Control and Prevention. Pregnancy Mortality Surveillance System. Last reviewed August 2018. https://www.cdc.gov/reproductivehealth/maternalinfanthealth/pregnancy-mortality-surveillance-system.htm. Accessed December 3, 2020.
61 Building U.S. Capacity To Review and Prevent Maternal Deaths. Report From Nine Maternal Mortality Review Committees. 2018. http://reviewtoaction.org/Report_from_Nine_MMRCs. Accessed December 3, 2020.
62 Geller SE, Rosenberg D, Cox SM, . The continuum of maternal morbidity and mortality: factors associated with severity. Am J Obstetr Gynecol 2004;191(3):939–44. https://www.ncbi.nlm.nih.gov/pubmed/15467568. Accessed December 3, 2020.
63 Howell EA, Zeitlin J. Quality of care and disparities in obstetrics. Obstetr Gynecol Clin 2017;44(1):13–25. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5300700/. Accessed December 3, 2020.
64 Office of the Surgeon General. The Surgeon General’s Call to Action To Improve Maternal Health. Washington, DC: U.S. Department of Health and Human Services; 2020. https://www.hhs.gov/sites/default/files/call-to-action-maternal-health.pdf. Accessed December 15, 2020.
65 Zhou F, Santoli J, Messonnier ML, . Economic evaluation of the 7-vaccine routine childhood immunization schedule in the United States, 2001. Arch Pediatr Adolesc Med (https://www.ncbi.nlm.nih.gov/pubmed/16330737) 2005 Dec;159(12):1136–44. https://www.ncbi.nlm.nih.gov/pubmed/16330737. Accessed December 3, 2020.16330737
66 Centers for Disease Control and Prevention. Influenza Vaccination Information for Health Care Workers. Influenza Facts. Last reviewed December 2019. https://www.cdc.gov/flu/professionals/healthcareworkers.htm#flu-facts. Accessed December 3, 2020.
67 Kamiya H, Cho BH, Messonnier ML, Clark TA, . Impact and cost-effectiveness of a second tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) vaccine dose to prevent pertussis in the United States. Vaccine 2016 Apr 4;34(15):1832–8. Epub 2016 Feb 17. https://pubmed.ncbi.nlm.nih.gov/26899377/. Accessed December 3, 2020.26899377
68 Nace DA, Archbald-Pannone LR, Ashraf MS, . Pneumococcal Vaccination Guidance for Post-Acute and Long-Term Care Settings: Recommendations From AMDA’s Infection Advisory Committee. J Am Med Dir Assoc. 2017;18(2):99–104. doi:10.1016/j.jamda.2016.11.010.28126142
69 Leung FW, Schnelle JF. Urinary and fecal incontinence in nursing home residents. Gastroenterol Clin North Am. 2008;37(3):697–x. doi:10.1016/j.gtc.2008.06.005.18794004
70 McDaniel C, Ratnani I, Fatima S, . Urinary incontinence in older adults takes collaborative nursing efforts to improve. Cureus. 2020 Jul 12;12(7):e9161. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC7419143/. Accessed September 9, 2020.32802599
71 Noone AM, Howlader N, Krapcho M, . SEER Cancer Statistics Review, 1975-2015. Bethesda, MD: National Cancer Institute; 2018. https://seer.cancer.gov/archive/csr/1975_2015/index.html. Accessed December 3, 2020.

### Disparities in Healthcare

1 Office of Disease Prevention and Health Promotion, U.S. Department of Health and Human Services. Healthy People 2020. https://www.healthypeople.gov/. Accessed December 3, 2020.
2 Orgera K, Artiga S. Issue Brief. Disparities in health and health care: five key questions and answers. Washington, DC: Henry J. Kaiser Family Foundation; August 2018. https://www.kff.org/disparities-policy/issue-brief/disparities-in-health-and-health-care-five-key-questions-and-answers/. Accessed December 3, 2020.
3 Institute of Medicine. Unequal Treatment: Confronting Racial and Ethnic Disparities in Health Care. Washington, DC: National Academies Press; 2003. 10.17226/12875. Accessed December 3, 2020.
4 Fichtenberg CM, Alley DE, Mistry KB. Improving social needs intervention research: key questions for advancing the field. Am J Prev Med 2019 Dec;57(6 Suppl 1):S47–S54. https://pubmed.ncbi.nlm.nih.gov/31753279/. Accessed December 3, 2020.31753279
5 Marmot M. The Status Syndrome: How Social Standing Affects Our Health and Longevity. New York, NY: Henry Holt; 2004.
6 U.S. Department of Health and Human Services. Report of the Secretary’s Task Force on Black and Minority Health. Washington, DC: Government Printing Office; 1985. https://minorityhealth.hhs.gov/heckler30/. Accessed December 3, 2020.
7 Centers for Disease Control and Prevention. CDC health disparities and inequalities report — United States, 2013. MMWR 2013;62(Suppl 3):1–187. https://www.cdc.gov/minorityhealth/CHDIReport.html. Accessed December 3, 2020.
8 Office of Disease Prevention and Health Promotion, U.S. Department of Health and Human Services. Healthy People Foundation Health Measures. Disparities. https://www.healthypeople.gov/2020/about/foundation-health-measures/Disparities. Accessed December 3, 2020.
9 Centers for Disease Control and Prevention. HIV and African Americans. https://www.cdc.gov/hiv/group/racialethnic/africanamericans/index.html. Accessed December 3, 2020.
10 Office of Minority Health, U.S. Department of Health and Human Services. HIV/AIDS and African Americans. https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=4&lvlid=21. Accessed December 3, 2020.
11 Azar A. Ending the HIV Epidemic: A Plan for America. Washington, DC: U.S. Department of Health and Human Services; February 2019. https://www.hhs.gov/blog/2019/02/05/ending-the-hiv-epidemic-a-plan-for-america.html. Accessed December 3, 2020.
12 Centers for Disease Control and Prevention, National Center for Injury Prevention and Control (https://www.cdc.gov/injury). Leading Cause of Death, 2017. https://webappa.cdc.gov/sasweb/ncipc/leadcause.html. Accessed December 3, 2020.
13 U.S. Department of Health and Human Services. HIV Care and Treatment Activities. Last updated May 2017. https://www.hiv.gov/federal-response/federal-activities-agencies/hiv-care-and-treatment-activities. Accessed December 3, 2020.
14 Health Resources and Services Administration. Ryan White HIV/AIDS Program by the Numbers. https://hab.hrsa.gov/sites/default/files/hab/Publications/infographics/generalaudiencegraphic.pdf. Accessed December 3, 2020.
15 High-Impact Prevention At-a-Glance. https://www.cdc.gov/nchhstp/highimpactprevention/docs/HIP-at-a-glance-P.pdf. Accessed December 3, 2020.
16 Asthma and Allergy Foundation of America. Asthma Facts and Figures. Medical review February 2018; updated June 2019. https://www.aafa.org/asthma-facts/. Accessed December 3, 2020.
17 Centers for Disease Control and Prevention. Most Recent National Asthma Data. Last reviewed October 2020. https://www.cdc.gov/asthma/most_recent_national_asthma_data.htm. Accessed December 3, 2020.
18 Centers for Disease Control and Prevention. Asthma. CCARE. Last reviewed October 2019. https://www.cdc.gov/asthma/ccare.htm. Accessed December 3, 2020.
19 Glied S, Herzog K, Frank R. Review: the net benefits of depression management in primary care. Med Care Res Rev 2010 Jun;67(3):251–74.20093400
20 U.S. Department of Health and Human Services, Office of Minority Health. Diabetes and African Americans. Last modified December 19, 2019. https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=4&lvlid=18. Accessed December 3, 2020.
21 Ngo-Metzger Q, Legedza AT, Phillips RS. Asian Americans’ reports of their health care experiences. Results of a national survey. J Gen Intern Med 2004 Feb;19(2):111–9. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1492145/. Accessed December 3, 2020.15009790
22 Ponce NA, Hays RD, Cunningham WE. Linguistic disparities in health care access and health status among older adults. J Gen Intern Med 2006 Jul;21(7):786–91. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1924691/. Accessed December 3, 2020.16808783
23 Zong J, Batalova J. Language diversity and English proficiency in the United States. Migration Information Source 2016 Nov 11. https://www.migrationpolicy.org/article/language-diversity-and-english-proficiency-united-states-2015. Accessed December 15, 2020.
24 Institute of Medicine. Race, Ethnicity, and Language Data: Standardization for Health Care Quality Improvement. Washington, DC: The National Academies Press; 2009. 4. Defining language need and categories for collection. .https://www.ahrq.gov/research/findings/final-reports/iomracereport/reldata4.html. Accessed December 3, 2020.
25 Limited English Proficiency: A Federal Interagency Website. Frequently Asked Questions. https://www.lep.gov/faqs/faqs.html. Accessed December 3, 2020.
26 TeamSTEPPS^®^ Enhancing Safety for Patients With Limited English Proficiency Module. Rockville, MD: Agency for Healthcare Research and Quality; 2012. https://www.ahrq.gov/teamstepps/lep/index.html. Accessed December 3, 2020.
27 Agency for Healthcare Research and Quality. Examples of Home Health Care Quality Measures for Consumers. Last updated November 2018. https://www.ahrq.gov/talkingquality/measures/setting/long-term-care/home-health/examples.html. Accessed December 3, 2020.
28 Hoover MA, Green HD Jr, Bogart LM, . Do people know I’m poz?: factors associated with knowledge of serostatus among HIV-positive African Americans’ social network members. AIDS Behav 2016 Jan;20(1):137–46. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4618789/. Accessed December 3, 2020.25903505
29 Wolitski R, Fecik N. Knowledge of HIV status is on the rise. Washington, DC: U.S. Department of Health and Human Services; August 2017. https://www.hiv.gov/blog/knowledge-hiv-status-rise. Accessed December 3, 2020.
30 Centers for Disease Control and Prevention. Influenza (Flu). Last reviewed May 2019. https://www.cdc.gov/flu/index.htm. Accessed December 3, 2020.
31 Black CL, Yue X, Ball SW, . Influenza vaccination coverage among health care personnel — United States, 2017-18 influenza season. MMWR Morb Mortal Wkly Rep 2018;67:1050–4. 10.15585/mmwr.mm6738a2.. Accessed November 24, 2020.30260944
32 Mulpuru S, Li L, Ye L, . Effectiveness of influenza vaccination on hospitalizations and risk factors for severe outcomes in hospitalized patients with COPD. Chest 2019 Jan;155(1):69078. https://journal.chestnet.org/article/S0012-3692(18)32725-9/fulltext. Accessed December 3, 2020.
33 March of Dimes. Low Birthweight. Last reviewed March 2018. https://www.marchofdimes.org/complications/low-birthweight.aspx. Accessed June 19, 2020.
34 Partridge S, Balayla J, Holcroft CA, . Inadequate prenatal care utilization and risks of infant mortality and poor birth outcome: a retrospective analysis of 28,729,765 U.S. deliveries over 8 years. Amer J Perinatol 2012;29:787–94. https://www.ncbi.nlm.nih.gov/pubmed/22836820. Accessed December 3, 2020.22836820
35 National Institute of Diabetes and Digestive and Kidney Diseases. Diabetic Kidney Disease. https://www.niddk.nih.gov/health-information/diabetes/overview/preventing-problems/diabetic-kidney-disease. Accessed December 3, 2020.
36 Burrows NR, Zhang Y, Hora I, . Sustained lower incidence of diabetes-related end-stage kidney disease among American Indians and Alaska Natives, Blacks, and Hispanics in the U.S., 2000-2016. Diabetes Care 2020 Sep;43(9):2090–7. Epub 2020 Jul 2. https://pubmed.ncbi.nlm.nih.gov/32616609/. Accessed December 3, 2020.32616609
37 Whelton PK, Carey RM, Aronow WS, . ACC/AHA/AAPA/ABC/ACPM/AGS/APhA/ASH/ASPC/ NMA/PCNA Guideline for the Prevention, Detection, Evaluation, and Management of High Blood Pressure in Adults: A Report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. Hypertension 2018 Jun;71(6):e13–e115. https://pubmed.ncbi.nlm.nih.gov/29133356/. Accessed December 3, 2020.29133356
38 Centers for Disease Control and Prevention. Prevention Strategies for Seasonal Influenza in Healthcare Settings. Last reviewed October 2018. https://www.cdc.gov/flu/professionals/infectioncontrol/healthcaresettings.htm. Accessed December 3, 2020.
39 Centers for Disease Control and Prevention. Vital Signs: HIV Testing. Last reviewed November 2017. https://www.cdc.gov/vitalsigns/hiv-testing/. Accessed December 3, 2020.
40 Centers for Disease Control and Prevention. HIV Surveillance Report, 2017. Vol. 29. Published November 2018. https://www.cdc.gov/hiv/pdf/library/reports/surveillance/cdc-hiv-surveillance-report-2017-vol-29.pdf. Accessed December 3, 2020.
41 Grohskopf LA, Sokolow LZ, Broder KR, . Prevention and control of seasonal influenza with vaccines: recommendations of the Advisory Committee on Immunization Practices-United States, 2018-19 influenza season. MMWR Recomm Rep 2018 Aug 24;67(3):1–20. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6107316/. Accessed December 3, 2020.
42 National Institute of Diabetes and Digestive and Kidney Diseases. Diabetic Kidney Disease. https://www.niddk.nih.gov/health-information/diabetes/overview/preventing-problems/diabetic-kidney-disease. Accessed December 3, 2020.
43 Institute of Medicine and National Research Council. Improving Access to Oral Health Care for Vulnerable and Underserved Populations. Washington, DC: National Academies Press; 2011. 10.17226/13116. Accessed December 3, 2020.
44 Centers for Disease Control and Prevention. Adult Obesity Facts. Last reviewed June 2020. https://www.cdc.gov/obesity/data/adult.html. Accessed December 3, 2020.
45 National Institute of Diabetes and Digestive and Kidney Diseases. Talking With Patients About Weight Loss: Tips for Primary Care Providers. https://www.niddk.nih.gov/health-information/weight-management/talking-adult-patients-tips-primary-care-clinicians. Accessed December 3, 2020.
46 Office of the Assistant Secretary for Planning and Evaluation, U.S. Department of Health and Human Services. U.S. Federal Poverty Guidelines Used To Determine Financial Eligibility for Certain Federal Programs. https://aspe.hhs.gov/poverty-guidelines. Accessed December 3, 2020.
47 Khullar D, Chokshi DA. Health Policy Brief. Health, Income, & Poverty: Where We Are & What Could Help. Health Affairs 2018 Oct 4. https://www.healthaffairs.org/do/10.1377/hpb20180817.901935/full/. Accessed December 3, 2020.
48 Larrimore J. Does a higher income have positive health effects? Using the earned income tax credit to explore the income-health gradient. Milbank Q 2011 Dec;89(4):694–727. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3250638/. Accessed December 3, 2020.22188352
49 Shaw KM, Theis KA, Self-Brown S, . Chronic disease disparities by county economic status and metropolitan classification, Behavioral Risk Factor Surveillance System, 2013. Prev Chronic Dis 2016 Sep 1;13:E119. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5008860/. Accessed December 3, 2020.27584875
50 Bor J, Cohen GH, Galea S. Population health in an era of rising income inequality: USA, 1980-2015. Lancet 2017 Apr 8;389(10077):1475–90. 10.1016/S0140-6736(17)30571-8. Accessed December 3, 2020.28402829
51 Shaw KM, Theis KA, Self-Brown S, . Chronic disease disparities by county economic status and metropolitan classification, Behavioral Risk Factor Surveillance System, 2013. Prev Chronic Dis 2016 Sep 1;13:E119. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5008860/. Accessed December 3, 2020.27584875
52 Henry J. Kaiser Family Foundation. Key Facts About the Uninsured Population. December 2018. https://www.kff.org/uninsured/fact-sheet/key-facts-about-the-uninsured-population/. Accessed December 3, 2020.
53 Centers for Disease Control and Prevention. Healthy Weight, Nutrition, and Physical Activity. About Child & Teen BMI. Last reviewed June 29, 2020. https://www.cdc.gov/healthyweight/assessing/bmi/childrens_bmi/about_childrens_bmi.html. Accessed December 3, 2020.
54 Centers for Disease Control and Prevention. Vaccines and Preventable Diseases. Polio Vaccination. Last reviewed May 4, 2018. https://www.cdc.gov/vaccines/vpd/polio/index.html. Accessed December 3, 2020.
55 Centers for Disease Control and Prevention. Vital Signs. Asthma in Children. Last reviewed May 10, 2018. https://www.cdc.gov/vitalsigns/childhood-asthma/index.html. Accessed December 3, 2020.
56 Centers for Disease Control and Prevention. National Diabetes Statistics Report 2020: Estimates of Diabetes and Its Burden in the United States. https://www.cdc.gov/diabetes/pdfs/data/statistics/national-diabetes-statistics-report.pdf. Accessed December 3, 2020.
57 Organisation for Economic Cooperation and Development. Health at a Glance 2019: OECD Indicators. Diabetes Care. Figure 6.12. Diabetes hospital admission in adults, 2012 and 2017 (or nearest year). https://www.oecd-ilibrary.org/sites/402e2e10-en/index.html?itemId=/content/component/402e2e10-en. Accessed December 3, 2020.
58 Zong J, Batalova J. Language diversity and English proficiency in the United States. Migration Information Source 2016 Nov 11. https://www.migrationpolicy.org/article/language-diversity-and-english-proficiency-united-states-2015. Accessed December 15, 2020.
59 The Joint Commission. Overcoming the Challenges of Providing Care to LEP Patients. Quick Safety Issue 13; May 2015. https://www.jointcommission.org/-/media/deprecated-unorganized/imported-assets/tjc/system-folders/joint-commission-online/quick_safety_issue_13_may_2015_embargoed_5_27_15pdf.pdf?db=web&hash=390D4DDA38EF28D1243CE53A9C274B1A. Accessed December 3, 2020.
60 Centers for Disease Control and Prevention. Meningococcal Disease. Last reviewed January 21, 2020. https://www.cdc.gov/meningococcal/. Accessed December 3, 2020.
61 Centers for Disease Control and Prevention. Vaccines and Preventable Diseases. Meningococcal Vaccination. Last reviewed: July 26, 2019. https://www.cdc.gov/vaccines/vpd/mening/index.html. Accessed December 3, 2020.
62 Lebrun-Harris LA, Canto MT, Vodick P. Preventive oral health care use and oral health status among US children: 2016 National Survey of Children’s Health. JADA 2019 Apr; 150(4):246–58. https://pubmed.ncbi.nlm.nih.gov/30922456/. Accessed December 3, 2020.30922456
63 MacDougall H. Dental disparities among low-income American adults: a social work perspective. Health Soc Work 2016 Aug;41(3):208–10. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4985883/. Accessed December 3, 2020.29206952
64 Institute of Medicine Committee on the Consequences of Uninsurance. Care Without Coverage: Too Little, Too Late. Washington, DC: National Academies Press; 2002. 4, The difference coverage could make to the health of uninsured adults. https://www.ncbi.nlm.nih.gov/books/NBK220633/. Accessed December 3, 2020.
65 Moore LJ, Moore FA, Todd SR, . Sepsis in general surgery: the 2005-2007 National Surgical Quality Improvement Program perspective. Arch Surg 2010 Jul;145(7):695–700. https://pubmed.ncbi.nlm.nih.gov/20644134/. Accessed December 3, 2020.20644134
66 National Heart, Lung, and Blood Institute. High Blood Pressure. Last updated May 2020. https://www.nhlbi.nih.gov/health-topics/high-blood-pressure. Accessed December 3, 2020.
67 Centers for Disease Control and Prevention. Influenza (Flu): Diabetes. Last reviewed February 2019. https://www.cdc.gov/flu/diabetes/index.htm. Accessed December 3, 2020.
68 Information Series for Adults: What You Need To Know About Diabetes and Adult Vaccines. Atlanta, GA: Centers for Disease Control and Prevention; August 2018. https://www.cdc.gov/vaccines/hcp/adults/downloads/fs-diabetes-vaccines.pdf. Accessed December 3, 2020.
69 Horvitz-Lennon M, Volya R, Garfield R, . Where you live matters: quality and racial/ethnic disparities in schizophrenia care in four state Medicaid programs. Health Serv Res 2015 Oct;50(5):1710–29. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4600368/. Accessed December 3, 2020.25759240
70 Lin YH, McLain AC, Probst JC, . Health-related quality of life among adults 65 years and older in the United States, 2011-2012: a multilevel small area estimation approach. Ann Epidemiol (https://www.ncbi.nlm.nih.gov/pubmed/27814940) 2017 Jan;27(1):52–58. https://www.ncbi.nlm.nih.gov/pubmed/27814940. Accessed December 3, 2020.27814940
71 Trivedi T, Liu J, Probst JC, . Obesity and obesity-related behaviors among rural and urban adults in the USA. Rural Remote Health 2015;15:3267. https://www.rrh.org.au/journal/article/3267. Accessed December 3, 2020.26458564
72 Andrilla CHA, Patterson DG, Garberson LA, . Geographic variation in the supply of selected behavioral health providers. Am J Prev Med 2018 Jun;54(6S3):S199–S207. https://www.ncbi.nlm.nih.gov/pubmed/29779543. Accessed December 3, 2020.29779543
73 Skinner AC, Slifkin RT. Rural/urban differences in barriers to and burden of care for children with special health care needs. J Rural Health (https://www.ncbi.nlm.nih.gov/pubmed/17397371) 2007 Spring;23(2):150–7. https://www.ncbi.nlm.nih.gov/pubmed/17397371. Accessed December 3, 2020.17397371
74 Hale N, Probst J, Robertson A. Rural area deprivation and hospitalizations among children for ambulatory care sensitive conditions. J Community Health (https://www.ncbi.nlm.nih.gov/pubmed/26516019) 2016 Jun;41(3):451–60. https://www.ncbi.nlm.nih.gov/pubmed/26516019. Accessed December 3, 2020.26516019
75 Centers for Disease Control and Prevention. NCHS Urban-Rural Classification Scheme for Counties. Last reviewed June 2017. https://www.cdc.gov/nchs/data_access/urban_rural.htm. Accessed December 3, 2020.
76 Agency for Healthcare Research and Quality. National Healthcare Quality and Disparities Report State View. https://nhqrnet.ahrq.gov/inhqrdr/state/select. Accessed December 3, 2020.
77 Johnson LH, Chambers P, Dexheimer JW. Asthma-related emergency department use: current perspectives. Open Access Emerg Med 2016;8:47–55. Published online 2016 Jul 13. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4950546/. Accessed December 3, 2020.27471415
78 Jang H, Ozkaynak M, Ayer T, . Factors associated with first medication time for children treated in the emergency department for asthma. Pediatr Emerg Care 2018 Oct 2. [Epub ahead of print] https://www.ncbi.nlm.nih.gov/pubmed/30281550. Accessed December 3, 2020.
79 Bekmezian A, Fee C, Bekmezian S, . Emergency department crowding and younger age are associated with delayed corticosteroid administration to children with acute asthma. Pediatr Emerg Care 2013 Oct;29(10):1075–81. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3809097/. Accessed December 3, 2020.24076611
80 Zahran HS, Bailey CM, Damon SA, . Vital Signs: Asthma in children — United States, 2001–2016. MMWR Morb Mortal Wkly Rep 2018;67:149–155. https://www.cdc.gov/mmwr/volumes/67/wr/mm6705e1.htm. Accessed December 3, 2020.29420459
81 Centers for Disease Control and Prevention. 2017 Archived National Asthma Data. Last reviewd March 2020. https://www.cdc.gov/asthma/archivedata/2017/2017_archived_national_data.html. Accessed December 3, 2020.
82 Wall T, Nasseh K, Vujicic M. Majority of dental-related emergency department visits lack urgency and can be diverted to dental offices. Health Policy Institute Research Brief. Chicago, IL: American Dental Association; August 2014. https://www.ada.org/~/media/ADA/Science%20and%20Research/HPI/Files/HPIBrief_0814_1.ashx (https://www.ada.org/%7E/media/ADA/Science%20and%20%20Research/HPI/Files/HPIBrief_0814_1.ashx). Accessed December 3, 2020.
83 Centers for Disease Control and Prevention, National Center for Health Statistics. Emergency Department Visits. Last reviewed January 2017. https://www.cdc.gov/nchs/fastats/emergency-department.htm. Accessed December 3, 2020.
84 Brown JD, Harnett J, Chambers R, . The relative burden of community-acquired pneumonia hospitalizations in older adults: a retrospective observational study in the United States. BMC Geriatr 2018 Apr 16;18(1):92. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5902892/. Accessed December 3, 2020.29661135
85 Rozenbaum MH, Mangen MJ, Huijts SM, . Incidence, direct costs, and duration of hospitalization of patients hospitalized with community acquired pneumonia: a nationwide retrospective claims database analysis. Vaccine 2015 Jun 22;33(28):3193–9. https://www.ncbi.nlm.nih.gov/pubmed/25981488. Accessed December 3, 2020.25981488
86 Centers for Disease Control and Prevention. Pneumococcal Vaccination: Summary of Who and When To Vaccinate. https://www.cdc.gov/vaccines/vpd/pneumo/hcp/who-when-to-vaccinate.html. Accessed December 3, 2020.
87 CDC. HIV Surveillance Report, Diagnoses of HIV Infection in the United States and Dependent Areas, 2017. Vol. 29; November 2018. https://www.cdc.gov/hiv/pdf/library/reports/surveillance/cdc-hiv-surveillance-report-2017-vol-29.pdf. Accessed December 3, 2020.
88 U.S. Department of Health and Human Services. What is ‘Ending the HIV Epidemic: A Plan for America’? Last updated May 2019. https://www.hiv.gov/federal-response/ending-the-hiv-epidemic/overview. Accessed December 3, 2020.
89 U.S. Department of Health and Human Services. HIV Prevention Activities. https://www.hiv.gov/federal-response/federal-activities-agencies/hiv-prevention-activities. Accessed December 3, 2020.
90 American Academy of Pediatrics. AAP Schedule of Well-Child Care Visits. Last updated October 2018. https://www.healthychildren.org/English/family-life/health-management/Pages/Well-Child-Care-A-Check-Up-for-Success.aspx. Accessed December 3, 2020.
91 Peterson-Kaiser Health System Tracker. 30-Day Mortality Following Certain Admissions. https://www.healthsystemtracker.org/indicator/quality/30-day-mortality-following-certain-admissions/. Accessed December 3, 2020.
92 Agency for Healthcare Research and Quality PSNet. Readmissions and Adverse Events After Discharge. https://psnet.ahrq.gov/primers/primer/11/Readmissions-and-Adverse-Events-After-Discharge. Accessed December 3, 2020.
93 Shanmugam VK, Fernandez SJ, Evans KK, . Postoperative wound dehiscence: predictors and associations. Wound Repair Regen 2015 Mar–Apr;23(2):184–90. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4587566/. Accessed December 3, 2020.25683272
94 Gachabayov M, You K, Sullivan R, . A retrospective cohort study to determine predictive factors for abdominal wound disruption following colorectal surgery. Ostomy Wound Manage (https://www.ncbi.nlm.nih.gov/pubmed/29718814) 2018 Apr;64(4):22–29. https://www.ncbi.nlm.nih.gov/pubmed/29718814. Accessed December 3, 2020.
95 Chou C. Time to start using evidence-based approaches to patient engagement. NEJM Catalyst 2018 Mar 28. https://catalyst.nejm.org/evidence-based-patient-provider-communication/. Accessed December 3, 2020.
96 Hsu DJ, McCarthy EP, Stevens JP, . Hospitalizations, costs, and outcomes associated with heroin and prescription opioid overdoses in the United States 2001-12. Addiction 2017 Sep;112(9):1558–64. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5544564/. Accessed December 3, 2020.28191702

### Looking Forward

1 Centers for Disease Control and Prevention. Older Adults. Last reviewed June 2020. https://www.cdc.gov/coronavirus/2019-ncov/need-extra-precautions/people-at-increased-risk.html. Accessed December 3, 2020.
2 Webb Hooper M, Nápoles AM, Pérez-Stable EJ. COVID-19 and racial/ethnic disparities. JAMA 2020;323(24):2466–7. doi:10.1001/jama.2020.8598.32391864
3 U.S. Department of Health and Human Services, Minority HIV/AIDS Fund. Federal Response. Last reviewed June 2020. https://www.hiv.gov/federal-response. Accessed December 3, 2020.
4 U.S. Department of Health and Human Services. The Health Consequences of Smoking: 50 Years of Progress. A Report of the Surgeon General. Atlanta, GA: Centers for Disease Control and Prevention, National Center for Chronic Disease Prevention and Health Promotion, Office on Smoking and Health; 2014. Printed with corrections, January 2014. https://www.cdc.gov/tobacco/data_statistics/sgr/50th-anniversary/index.htm. Accessed December 3, 2020.
5 U.S. Department of Health and Human Services. Secretary Priorities. Last reviewed July 2018. https://www.hhs.gov/about/leadership/secretary/priorities/index.html. Accessed December 3, 2020.
6 U.S. Department of Health and Human Services. 5-Point Strategy To Combat the Opioid Crisis. Last reviewed August 2018. https://www.hhs.gov/opioids/about-the-epidemic/hhsresponse/index.html. Accessed December 3, 2020. Secretary Priorities: Value-Based Care. Content last reviewed July 23, 2018. Assistant Secretary for Public Affairs, Washington, D.C. https://www.hhs.gov/about/leadership/secretary/priorities/index.html#value-based-healthcare. Accessed December 11, 2020.
7 Centers for Medicare & Medicaid Services. What Are the Value-Based Programs? Last reviewed January 6, 2020. https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/Value-Based-Programs/Value-Based-Programs. Accessed December 3, 2020.