# ACKNOWLEDGMENTS

The National Healthcare Quality and Disparities Report (NHQDR) is the product of collaboration among agencies from the U.S. Department of Health and Human Services (HHS), other federal departments, and the private sector. Many individuals guided and contributed to this effort. Without their magnanimous support, the report would not have been possible. Specifically, we thank:

Primary AHRQ Staff: Gopal Khanna, David Meyers, Virginia Mackay-Smith, Jeff Brady, Erin Grace, Karen Chaves, Darryl Gray, Barbara Barton, Doreen Bonnett, Irim Azam, and Cecilia Hahn.

HHS Interagency Workgroup (IWG) for the NHQDR: Girma Alemu (HRSA), Irim Azam (AHRQ), Andreea Balan-Cohen (IMPAQ), Barbara Barton (AHRQ), Doreen Bonnett (AHRQ), Deron Burton (CDC), Victoria Chau (SAMHSA), Karen Chaves (AHRQ), Xiuhua Chen (Atlas Research), Deborah Duran (NIH-NIMHD), Melissa Evans (CMS), Camille Fabiyi (AHRQ), Paul Gorrell (Atlas Research), Darryl Gray (AHRQ), Kirk Greenway (IHS), Sarah Heppner (HRSA), Ed Huff (CMS), DeLoris Hunter (NIH-NIMHD), Susan Jenkins (ACL), Christine Lee (FDA), Doris Lefkowitz (AHRQ), Jesse Lichstein (HRSA), Lan Liang (AHRQ), Shari Ling (CMS), Iris Mabry-Hernandez (AHRQ), Marlene Matosky (HRSA), Tracy Matthews (HRSA), Christine Merenda (FDA), Kamila Mistry (AHRQ), Ernest Moy (VHA), Samia Noursi (NIH-NIDA), Kathy O’Connor (CDC), Rajasri Roy (NIH-OD-ORWH), Dianne Rucinski (OASH), Asel Ryskulova (CDC), Adelle Simmons (ASPE), Robin Streeter (HRSA), Loida Tamayo (CMS), Caroline Taplin (ASPE), Emmanuel Taylor (NIH-NCI), Michelle Washko (HRSA), and Ying Zhang (IHS).

IWG Subgroup – Access to Care: Karen Chaves (Chair), Girma Alemu (HRSA), Robin Cohen (CDC), Kirk Greenway (IHS), Lan Liang (AHRQ), Pradip Muhuri (AHRQ), Barbara Barton (AHRQ).

NHQDR Team: Irim Azam (CQuIPS), Barbara Barton (CQuIPS), Doreen Bonnett (OC), Xiuhua Chen (Atlas Research), James Cleeman (CQuIPS), Noel Eldridge (CQuIPS), Camille Fabiyi (OEREP), Paul Gorrell (Atlas Research), Erin Grace (CQuIPS), Darryl Gray (CQuIPS), Lan Liang (CFACT), Kamila Mistry (OEREP), Margie Shofer (CQuIPS).

HHS Data Experts: Cuong Bui (HRSA), Lara Bull (CDC), Robin Cohen (CDC-NCHS), Joann Fitzell (CMS), Elizabeth Goldstein (CMS), Irene Hall (CDC-HIV), Norma Harris (CDC-HIV), Pradip Muhuri (AHRQ), Jessica King (NPCR), Amanda Lankford (CDC), Denys Lau (CDC-NCHS), Lan Liang (AHRQ), Sharon Liu (SAMHSA), Marlene Matosky (HRSA), Tracy Matthews (HRSA), Robert Morgan (CMS), Richard Moser (NIH-NCI), Kathy O’Connor (CDC-NCHS), Robert Pratt (CDC), Neil Russell (SAMHSA), Asel Ryskulova (CDC-NCHS), Alek Sripipatana (HRSA), Reda Wilson (CDC- NCCDPHP-ONDIEH), Emily Zammitti (CDC-NCHS), and Xiaohong (Julia) Zhu (HRSA).

Other Data Experts: Mark Cohen (ACS NSQIP), Ashley Eckard (University of Michigan), Sheila Eckenrode (MPSMS-Qualidigm), Clifford Ko (ACS NSQIP), Vivian Kurtz (University of Michigan), Leticia Nogueira (American Cancer Society), Robin Padilla (University of Michigan KECC), Yun Wang (MPSMS-Qualidigm), and Robin Yabroff (American Cancer Society).

Other AHRQ Contributors: Cindy Brach, Edwin Lomotan, Karen Migdail, Pamela Owens, Wendy Perry, Mary Rolston, Bruce Seeman, Randie Siegel, and Michele Valentine.

Data Support Contractors: Atlas Research, IMPAQ International.