# LOOKING FORWARD

The 2019 NHQDR has examined data across more than 25 federal data sources to describe trends and disparities in access measures and quality measures across six domains. The report offers a comprehensive assessment of the best and worst performing quality and access measures over the past year. While trend data are still limited in this year’s analysis, it is still clear that disparities exist by race, ethnicity, income, age, insurance status, residence location, and many other variables.

## Opportunities for Measurement

The NHQDR measure set is assessed annually to explore whether new clinical areas can be included to provide a more complete representation of clinical, quality, and disparity issues across the United States. Recently, more data on the healthcare workforce and access to healthcare have been added. The NHQDR measure set will continue to be assessed for future reports to maintain its relevance to current quality measurement and quality improvement issues.

## Notable Examples of Collaboration for Healthcare Quality

HHS agencies work in collaboration with federal and nonfederal partners to enhance and protect the health and well-being of all Americans, and the following examples intend to support improvements that would influence measures included in future reports.

### National Action Plan To Advance Patient Safety

The National Steering Committee for Patient Safety is co-chaired by the Agency for Healthcare Research and Quality and the Institute for Healthcare Improvement. The National Steering Committee for Patient Safety, with members from the healthcare, policy, regulatory, and advocacy communities, is charged with creating a national action plan to guide patient safety efforts across the country in a cohesive and coordinated fashion.

The National Action Plan To Advance Patient Safety (https://www.ahrq.gov/patient-safety/reports/safer-together.html) includes 17 recommendations to advance patient safety, with a focus on eliminating inequities at the point of care. Supplemented by both a Self-Assessment Tool and an Implementation Resource Guide, the Plan centers on four foundational and interdependent priority areas:

- Culture, Leadership, and Governance: to demonstrate and foster commitments to safety as a core value and promote the development of safety cultures.
- Patient and Family Engagement: to instill the practice of codesigning and coproducing care with patients, families, and care partners to ensure their meaningful partnership in all aspects of care design, delivery, and operations.
- Workforce Safety: to ensure the safety and resiliency of organizations and workforces as a precondition to advancing patient safety with a unified, total systems-based approach to eliminate harm to both patients and the workforce.
- Learning System: to foster networked and continuous learning within and across healthcare organizations at all levels to encourage widespread sharing, learning, and improvement.

For more information on patient safety measures included in the NHQDR, see the NHQDR Chartbook on Patient Safety (https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/patientsafety/index.html).

### Maternal Morbidity

Addressing disparities in maternal health and birth outcomes is a national priority. The Surgeon General’s Call to Action To Improve Maternal Health (https://www.hhs.gov/sites/default/files/call-to-action-maternal-health.pdf) and the 2020 U.S. Department of Health and Human Services (HHS) Healthy Women, Healthy Pregnancies, Healthy Futures: Action Plan To Improve Maternal Health (https://aspe.hhs.gov/system/files/aspe-files/264076/healthy-women-healthy-pregnancies-healthy-future-action-plan_0.pdf) are collaborations across federal agencies and stakeholders for mothers and babies. Both of these efforts are based on the life-course approach.

The Call to Action engages and equips individuals, organizations, agencies, and entire communities with evidence-based actions that will improve women’s health prior to, during, and after pregnancy. The HHS Action Plan summarizes the Department’s work to ensure the United States is one of the safest countries in the world in which to give birth, realizing this vision goes beyond the federal government.

The supplemental measures in the NHQDR related to maternal morbidity and mortality include:

- Morbidity measures:
  ■ Venous thromboembolism or pulmonary embolism per 1,000 delivery discharges.
  ■ Hypertensive disorders in pregnancy per 1,000 delivery hospitalizations.
  ■ Severe postpartum hemorrhage per 1,000 delivery hospitalizations.
  ■ Severe maternal morbidity per 1,000 delivery hospitalizations.
  ■ Cesarean deliveries among low-risk first births.
- Mortality measures:
  ■ In-hospital deaths per 100,000 delivery hospitalizations.

These data are available through the online query tool at https://nhqrnet.ahrq.gov/inhqrdr/data/query and further analysis and discussion is also featured in the latest NHQDR Chartbook on Patient Safety (https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/patientsafety/index.html).

## Top Priorities and Tasks at HHS

HHS has refocused efforts on several priorities and tasks. These efforts work to advance scientific research and improve health services for affected populations. In support of these aims, the NHQDR team will continue to explore opportunities to include additional data relevant to these topics in future reports. This section elaborates on how the NHQDR’s activities remain relevant to the many ongoing HHS priorities.

### COVID-19

While the data in this report predate the COVID-19 pandemic, COVID-19 is significantly affecting several aspects of healthcare. How COVID-19 will influence healthcare disparities and quality is uncertain, but the potential influences are many. For example, people with underlying conditions and older adults are at increased risk for severe illness due to COVID-19 and may experience additional burdens from associated healthcare safety and quality concerns.^1^ Similarly, initial data show a disproportionate impact of the pandemic on racial and ethnic groups.^2^ Future versions of the report will track the long-term effects of COVID-19 related to healthcare quality and disparities when data covering 2020 are available.

### HIV Research

In 2019, the Administration established an initiative to end the HIV epidemic in the United States, with a goal of reducing new infections by 75% in 5 years and by 90% in 10 years.^3^ Ending the HIV Epidemic: A Plan for America (https://www.hiv.gov/federal-response/ending-the-hiv-epidemic/overview) (EHE) aims to end the HIV epidemic in the United States by 2030. EHE is the operational plan developed by agencies across HHS to pursue that goal.

The EHE plan leverages critical scientific advances in HIV prevention, diagnosis, treatment, and outbreak response by coordinating the highly successful programs, resources, and infrastructure of many HHS agencies and offices. In its first phase, the initiative is focusing on areas where HIV transmission occurs most frequently, providing 57 geographic focus areas with a rapid infusion of additional resources, expertise, and technology to develop and implement locally tailored EHE plans.

The NHQDR currently tracks four unique HIV-related quality measures, one mortality measure, and five supplemental measures (not shown here).

The core measures in the NHQDR related to HIV include:

- New HIV cases per 100,000 population age 13 and over.
- People age 13 and over living with HIV who know their serostatus.
- People age 13 and over living with diagnosed HIV who had at least two CD4 or viral load tests performed at least 3 months apart during the last year, among reporting jurisdictions.
- People age 13 and over living with diagnosed HIV whose most recent viral load in the last 12 months was under 200 copies/mL.
- HIV infection deaths per 100,000 population.

Among these measures, this report has already highlighted the widening and narrowing disparities experienced by various racial and ethnic groups. These data are available through the online query tool at https://nhqrnet.ahrq.gov/inhqrdr/data/query. Moving forward, the NHQDR team will continue to track these measures with our data partners to understand how differences in quality measurement, disparities, and mortality are occurring over time.

### Smoking Cessation

Smoking is the leading preventable cause of disease and death in the United States. More than 16 million Americans are living with a disease caused by smoking. Tobacco use causes about 480,000 deaths per year in the United States.^4^

For nearly 60 years, the Office of the Surgeon General has been reporting on the health hazards of smoking. The 32nd Surgeon General’s report on smoking and health (https://www.ncbi.nlm.nih.gov/books/NBK179276/pdf/Bookshelf_NBK179276.pdf), published in 2014, highlights half a century of progress in controlling and preventing tobacco use in the United States.

The core measures in the NHQDR related to smoking cessation include:

- Adult current smokers who had a doctor’s office or clinic visit in the last 12 months who received advice from their providers to quit smoking.
- Children for whom a health provider gave advice within the past 2 years about how smoking in the house can be bad for a child.

### Physical Activity and Nutrition

Being physically active is one of the most important actions people can take to improve their health. Based on the latest scientific evidence, the second edition of the Physical Activity Guidelines for Americans (https://health.gov/sites/default/files/2019-09/Physical_Activity_Guidelines_2nd_edition.pdf) is a resource for health professionals, policymakers, and the general public that provides guidance on how individuals can improve their health through regular physical activity.

The core measures in the NHQDR related to physical activity and nutrition include:

- Physical Activity (Adult and Pediatric Measures):
  ■ Adults with obesity who ever received advice from a health professional to exercise more.
  ■ Children ages 2-17 for whom a health provider gave advice within the past 2 years about the amount and kind of exercise, sports, or physically active hobbies they should have.
- Nutrition – Pediatric Measures:
  ■ Children ages 2-19 years with obesity.
  ■ Children ages 2-19 years with obesity who had been told by a doctor or health professional that they were overweight.
  ■ Children ages 2-17 for whom a health provider gave advice within the past 2 years about healthy eating.
- Nutrition – Adult Measures:
  ■ Adults age 20 and over with obesity who had been told by a doctor or health professional that they were overweight.
  ■ Adults with obesity who ever received advice from a health professional about eating fewer high-fat or high-cholesterol foods.

Among these measures, the data show that obesity affects populations disparately. These data are available through the online query tool at https://nhqrnet.ahrq.gov/inhqrdr/data/query. Moving forward, the NHQDR team will continue to track these measures with our data partners to understand how differences in quality measurement and disparities are occurring over time.

### Opioids

In 2017, HHS identified the opioid epidemic as an urgent national priority5 and outlined a five-point strategy to combat the epidemic,^6^ including:

- Improving access to treatment and recovery services,
- Promoting use of overdose-reversing drugs,
- Strengthening our understanding of the epidemic through better public health surveillance,
- Providing support for cutting-edge research on pain and addiction, and
- Advancing better practices for pain management.

In June 2018, SAMHSA published the Opioid Overdose Prevention Toolkit in English (https://store.samhsa.gov/product/Opioid-Overdose-Prevention-Toolkit/SMA18-4742) and Spanish (https://store.samhsa.gov/product/Opioid-Overdose-Prevention-Toolkit-Spanish-/SMA18-4742SPANISH) that offers strategies to healthcare providers, communities, and local governments for developing practices and policies to help prevent opioid-related overdoses and deaths.

The NHQDR continues to track data for eight opioid-related measures and will add new measures as better data become available:

- Hospital inpatient stays related to opioid use per 100,000 population.
- Emergency department visits involving opioid-related diagnoses per 100,000 population.
- Percentage and population estimates of past-year opioid (either prescription opioid or heroin) use disorder among people age 12 and over.
- Rate per 100,000 population of deaths from drug overdoses involving opioids.
- Rate per 100,000 population of deaths from drug overdoses involving natural and semisynthetic opioids (e.g., oxycodone, hydrocodone, or morphine).
- Rate per 100,000 population of deaths from drug overdoses involving synthetic opioids other than methadone (e.g., prescription and illicit fentanyl, tramadol).
- Adults who filled an outpatient opioid prescription in the calendar year.
- Adults who filled four or more outpatient opioid prescriptions in the calendar year.

The NHQDR team with the Substance Abuse Mental Health Administration (SAMHSA) produced a data spotlight in 2020 to examine disparities in opioid mortality. The data spotlight (https://www.ahrq.gov/sites/default/files/wysiwyg/research/findings/nhqrdr/dataspotlight-opioid.pdf) and infographic (https://www.ahrq.gov/data/infographics/qdr-opioids.html) show that Blacks are experiencing fast-rising rates of overdose deaths involving synthetic opioids other than methadone.

SAMHSA is further exploring how the opioid crisis is disproportionately affecting vulnerable racial and ethnic populations, including Hispanics and Blacks. In April 2020, SAMHSA published an issue brief titled “The Opioid Crisis and the Black/African American Population: An Urgent Issue (https://store.samhsa.gov/product/The-Opioid-Crisis-and-the-Black-African-American-Population-An-Urgent-Issue/PEP20-05-02-001)” and in July and October 2020, SAMHSA published “The Opioid Crisis and the Hispanic/Latino Population: An Urgent Issue” in English (https://store.samhsa.gov/product/The-Opioid-Crisis-and-the-Hispanic-Latino-Population-An-Urgent-Issue/PEP20-05-02-002) and Spanish (https://store.samhsa.gov/product/the-opioid-crisis-and-the-hispanic-latino-population-an-urgent-issue-spanish-version/PEP20-05-02-003). Both documents detail additional resources to combat the opioid crisis.

SAMHSA has also published a Behavioral Health Treatment Services Locator. This tool is a confidential and anonymous source of information for people seeking treatment facilities in the United States or U.S. territories for substance use, addiction, or mental health issues. The locator is available online at https://findtreatment.samhsa.gov/.

### Value-Based Care

Americans deserve better quality, affordable healthcare. Value based care (VBC) rewards healthcare providers and organizations with incentive payments for delivering high-quality care and better patient health outcomes. HHS is working to transform our system from one that pays for procedures and sickness (volume-based care) to one that pays for outcomes and health (VBC). The Department seeks to do so by focusing on four areas:

- Maximizing the promise of health information technology, including by promoting interoperability.
- Boosting transparency around price and quality.
- Pioneering bold new models in Medicare and Medicaid.
- Removing government burdens and barriers, especially those impeding care coordination.^7^

The Centers for Medicare & Medicaid Services (CMS) operates multiple VBC programs. These programs are continually monitored and include:

- End-Stage Renal Disease Quality Incentive Program (ESRD QIP (https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/ESRDQIP)) (2012).
- Hospital Value-Based Purchasing (HVBP) (https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/Value-Based-Programs/HVBP/Hospital-Value-Based-Purchasing) Program (2012).
- Hospital Readmission Reduction Program (HRRP) (https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/Value-Based-Programs/HRRP/Hospital-Readmission-Reduction-Program) [underlined: (2012).]
- Hospital Acquired Conditions (HAC) (https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/Value-Based-Programs/HAC/Hospital-Acquired-Conditions) Reduction Program (2014).
- Home Health Value-Based Purchasing (HHVBP (https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/Value-Based-Programs/Other-VBPs/HHVBP)) Model (2016; implemented in nine states).
- Skilled Nursing Facility Value-Based Program (SNFVBP (https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/Value-Based-Programs/SNF-VBP/SNF-VBP-Page)) (2018).^8^

In January 2017, CMS implemented another VBC program, the Quality Payment Program. This program consists of two tracks: participation in Advanced Alternative Payment Models (Advanced APMs) and the Merit-based Incentive Payment Systems (MIPS) programs. Clinicians must select one of the two tracks to participate in based on their practice size, specialty, location, or patient population.

Both the Advanced APM track and the MIPS track commit clinicians to practice VBC. MIPS provides performance-based Medicare payment adjustments for care given to Medicare patients. The Advanced APM trackoffers a customized payment approach to providers delivering high-quality care. More information is available in the CMS Quality Payment Program Overview at https://qpp.cms.gov/about/qpp-overview.

## Future Research and Work

Readers can use this report and related NHQDR products including Chartbooks (https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/index.html) and Data Spotlights (https://www.ahrq.gov/research/findings/nhqrdr/data-spotlights/index.html) to learn more about the nation’s progress in improving healthcare and to explore emerging topics. The report helps identify opportunities to improve quality and reduce disparities. Ongoing disparities in care by race, ethnicity, income, residence location, and other socioeconomic factors underscore that while we have made important strides in quality and accessibility of healthcare, these outcomes are not equitably experienced across the United States and much work remains.