# DISPARITIES IN HEALTHCARE

Healthcare delivery is not experienced equitably by all populations. A healthcare disparity is a difference between population groups in the way they access, experience, and receive healthcare. Factors that influence healthcare disparities include social, economic, environmental, and other disadvantages,^1,2^ some of which are explored in this report.

Unfortunately, Americans too often do not receive care they need, or they receive care that causes harm. Care can be delivered too late or without full consideration of a patient’s preferences and values. Many times, our healthcare system distributes services inefficiently and unevenly across populations. Some Americans receive worse care than others. These disparities may occur for a variety of reasons, including differences in access to care, social determinants, provider biases, poor provider-patient communication, and poor health literacy.

## Research Framework for Health Disparities

The National Institutes of Health’s (NIH) National Institute on Minority Health and Health Disparities (NIMHD)-developed Research Framework (Exhibit 1) is based on an evolving conceptualization of factors relevant to the understanding and promotion of minority health and to the understanding and reduction of health disparities. The framework serves as a vehicle for encouraging NIH-supported research that addresses the complex and multifaceted nature of minority health and health disparities. This research needs to span different domains of influence (Biological, Behavioral, Physical/Built Environment, Sociocultural Environment, Healthcare System) and different levels of influence (Individual, Interpersonal, Community, Societal) within those domains.

The framework also provides a classification structure that facilitates analysis of the NIMHD of NIH minority health and health disparities research portfolios to assess progress, gaps, and opportunities. Examples of factors are provided within each cell of the framework (e.g., Family Microbiome within the Interpersonal-Biological cell). These factors are not intended to be exhaustive. Health disparity populations, as well as other features of this framework, may be adjusted over time.

Exhibit 1 NIMHD Research Framework

Matrix showing the intersection of levels of influence (individual, interpersonal, community, and societal) and domains of influence over the lifecourse (biological, behavioral, physical/built environment, sociocultural environment, health care system) Individual: Biological: biological vulnerability and mechanisms Behavioral: health behaviors, coping strategies Physical/built environment: personal environment Sociocultural environment: sociodemographics, limited English, cultural identity, response to discrimination Health care system: insurance coverage, health literacy, treatment preferences Interpersonal Biological: caregiver-child interaction, family microbiome Behavioral: family functioning, school/work functioning Physical/built environment: household environment, school/work environment Sociocultural environment: social networks, family/peer norms, interpersonal discrimination Health care system: patient-clinician relationship, medical decision making Community Biological: community illness exposure, herd immunity Behavioral: community functioning Physical/built environment: community environment, community resources Sociocultural environment: community norms, local structural discrimination Health care system: availability of services, safety net services Societal Biological: sanitation, immunization, pathogen exposure Behavioral: policies and laws Physical/built environment: societal structure Sociocultural environment: social norms, societal structural discrimination Health care system: quality of care, health care policies Health outcomes: individual health, family/organizational health, community health, population health

| | | Levels of Influence^*^
| | | Individual | Interpersonal | Community | Societal
Domains of Influence; (Over the Lifecourse) | | Biological | Biological Vulnerability and Mechanisms | Caregiver-Child Interaction Family Microbiome | Community Illness Exposure Herd Immunity | Sanitation Immunization Pathogen Exposure
Domains of Influence; (Over the Lifecourse) | | Behavioral | Health Behaviors Coping Strategies | Family Functioning School/Work Functioning | Community Functioning | Policies and Laws
Domains of Influence; (Over the Lifecourse) | | Physical/Built Environment | Personal Environment | Household Environment School/Work Environment | Community Environment Community Resources | Societal Structure
Domains of Influence; (Over the Lifecourse) | | Sociocultural Environment | Sociodemographics Limited English Cultural Identity Response to Discrimination | Social Networks Family/Peer Norms Interpersonal Discrimination | Community Norms Local Structural Discrimination | Social Norms Societal Structural Discrimination
Domains of Influence; (Over the Lifecourse) | | Health Care System | Insurance Coverage Health Literacy Treatment Preferences | Patient-Clinician Relationship Medical Decision-Making | Availability of Services Safety Net Services | Quality of Care Health Care Policies
Health Outcomes | | | [image] Individual Health | [image] Family/Organizational Health | [image] Community Health | [image] Population Health

* Health Disparity Populations: Race/ethnicity, low socioeconomic status, rural, sexual/gender minority. Other Fundamental Characteristics: Sex/gender, disability, geographic region.

Source: National Institute on Minority Health and Health Disparities, 2018.

## Role of Research Framework in the NHQDR

The NHQDR reports on progress and opportunities for improving healthcare quality and reducing healthcare disparities. The NIMHD Minority Health and Health Disparities Research Framework highlights factors ranging from individual biology and behavior to social structure that affect disparities. In order to successfully reduce disparities, all these factors have to be addressed.

All Americans should have equitable access to high-quality care. Instead, racial and ethnic minorities and poor people often face more barriers to care and receive poorer quality of care when they can get it.^3^ In this report, we analyze disparities by breaking down measures by disparities groups and by settings of care.

An increasing number of healthcare organizations and payers are experimenting with strategies to identify needs and connect patients to resources that address identified needs with the goal of improving health outcomes, reducing avoidable utilization of costly health services, and improving health equity.^4^

Inequitable health outcomes result from inequities in the distribution of or access to resources that promote good health outcomes; differences refer to outcomes that are the result of biological risk or other factors that are not a matter of policy or discrimination in access. A difference may become a disparity when some subgroups and not others are given access to resources to manage their differential risk from biology or other factors and the groups without access have poorer outcomes. Thus, differences and disparities may have different determinants requiring different forms of intervention.^5^

The Disparities in Healthcare section of the 2019 NHQDR examines the best and worst performing quality measures among the measures used in the report. These quality measures are analyzed in this section of the report by race and ethnicity, income, insurance status, and residence location. While these categories are broad, each section begins with key definitions to orient readers and includes analyses showing quality measure performance in the latest data year and analyses showing whether disparities were widening or narrowing over time.

To learn more about the measures included in this section of the report, go to the NHQDR Data Query Tool to access the data directly (https://nhqrnet.ahrq.gov/inhqrdr/data/query). The tool also allows readers to stratify NHQDR data by other variables such as education, sex, and age where available.

## Racial and Ethnic Disparities

Researchers, patients, providers, and policymakers have worked to identify, understand, and eliminate the disparities experienced by different racial and ethnic groups across the healthcare system. In 1985, the Department of Health and Human Services published the Report of the Secretary’s Task Force on Black and Minority Health (Heckler Report), which marked the first comprehensive study of racial and minority health by the U.S. government.^6^ Since then, the Department, along with other stakeholders, has continued this work, including throughout the NHQDR. The growing evidence base shows that patients of different racial and ethnic groups experience quality of care inequitably and disparately.^7,8^

Racial and ethnic groups are defined according to Standards for the Classification of Federal Data on Race and Ethnicity, issued by the Office of Management and Budget (available at https://www.gpo.gov/fdsys/granule/FR-1997-10-30/97-28653).

The basic racial and ethnic categories for federal statistics and program administrative reporting are defined as follows:

1. American Indian or Alaska Native (AI/AN). A person having origins in any of the original peoples of North and South America (including Central America) and who maintains tribal affiliation or community attachment.
2. Asian. A person having origins in any of the original peoples of the Far East, Southeast Asia, or the Indian subcontinent, including, for example, Cambodia, China, India, Japan, Korea, Malaysia, Pakistan, the Philippine Islands, Thailand, and Vietnam.
3. Black or African American. A person having origins in any of the black racial groups of Africa. Terms such as “Haitian” can be used in addition to “Black or African American.”
4. Hispanic or Latino. A person of Cuban, Mexican, Puerto Rican, Central or South American, or other Spanish culture or origin, regardless of race. The term “Spanish origin” can be used in addition to “Hispanic or Latino.”
5. Native Hawaiian/Pacific Islander (NHPI). A person having origins in any of the original peoples of Hawaii, Guam, Samoa, or other Pacific Islands.
6. White. A person having origins in any of the original peoples of Europe, the Middle East, or North Africa.

This section presents three types of findings related to disparities for each population:

1. Largest disparities for a single data year, focusing on the most recent data year.
2. Trends in quality of care (number of measures improving, not changing, and worsening) for the population group.
3. Comparison with the reference group, focusing on the change in the gap between the two groups (gap is narrowing, widening, and not changing).

For more details about the measures shown below, visit the NHQDR website at https:// https://nhqrnet.ahrq.gov/inhqrdr/.

## Overview of Racial and Ethnic Disparities

Figure 1 Number and percentage of quality measures for which members of selected groups experienced better, same, or worse quality of care compared with reference group (White) for the most recent data year, 2014, 2016, 2017, or 2018

Key: n = number of measures; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value <0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Agency for Healthcare Research and Quality Healthcare Cost and Utilization Project (AHRQ HCUP) is 2017.

Stacked bar chart showing number of quality measures Black (n=202), Better, 23, Same, 97, Worse, 82 Asian (n=185), Better, 56, Same, 77, Worse, 52 AI/AN (n=116), Better, 13, Same, 56, Worse, 47 NHPI (n=72), Better, 11, Same, 37, Worse, 24 Hispanic, All Races (n=177), Better, 38, Same, 78, Worse, 61

- Figure 1 features quality measures that show whether Black, Asian, American Indian and Alaska Native (AI/AN), Native Hawaiian/Pacific Islander (NHPI), and Hispanic populations were performing better, same, or worse than White populations in the latest data year.
- Blacks and AI/ANs received worse care than Whites for about 40% of quality measures.
- Hispanics received worse care than non-Hispanic Whites for about 35% of quality measures.
- Asians and NHPIs received worse care than Whites for about 30% of quality measures but Asians also received better care for about 30% of quality measures.

Figure 2 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time,

Key: n = number of measures; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Different data sources have different data years. For example, the most recent data year available for trending from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems (CMS HCAHPS) is 2018.

Stacked bar chart showing number of quality measures Black (n=58), Improving, 3, Not Changing, 55, Worsening, 0 Asian (n=37), Improving, 1, Not Changing, 35, Worsening, 1 AI/AN (n=34), Improving, 2, Not Changing, 32, Worsening, 0 NHPI (n=16), Improving, 1, Not Changing, 15, Worsening, 0 Hispanic, All Races (n=53), Improving, 5, Not Changing, 48, Worsening, 0

Quality measures with disparities at baseline were analyzed to see if disparities related to race and ethnicity were narrowing (improving), widening (worsening), or not changing^i^:

- In this year’s analyses, for all racial and ethnic groups, over 90% of measures showed no change in disparities (Figure 2).
- Five measures showed improvement in disparities between Hispanics and non-Hispanic Whites.
- Three measures showed improvement in disparities between Blacks and Whites, and two measures showed improvement for AI/ANs.
- One measure for Asians and NHPIs showed improvement in disparities.
- One measure for Asians showed a worsening of disparities, home health care patients whose management of oral medications improved. There were no worsening disparities over time observed for Blacks, AI/ANs, and NHPIs in this year’s analysis.
- Fewer quality measures are available for select subpopulations overall. The percentage of quality measures with disparities at baseline that improved over time was 9% for Hispanics, 6% for AI/ANs, and NHPIs, 5% for Blacks, and 3% for Asians.

## Disparities for Blacks

In 2017, non-Hispanic Black children ages 2-17 were more than five times as likely as non-Hispanic Whites to be admitted to the hospital for asthma.

Figure 3 Number and percentage of quality measures for which Blacks experienced better, same, or worse quality of care compared with reference group (White) for the most recent data year, 2014, 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value <0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Agency for Healthcare Research and Quality Healthcare Cost and Utilization Project (AHRQ HCUP) is 2017.

Stacked bar chart showing number of quality measures Total (n=202), Better, 23, Same, 97, Worse, 82 Person-Centered Care (n=27), Better, 3, Same, 16, Worse, 8 Patient Safety (n=33), Better, 7, Same, 16, Worse, 10 Healthy Living (n=72), Better, 6, Same, 36, Worse, 30 Effective Treatment (n=44), Better, 6, Same, 21, Worse, 17 Care Coordination (n=21), Better, 1, Same, 6, Worse, 14 Affordable Care (n=5), Better, 0, Same, 2, Worse, 3

- Data for the most recent year show that quality was better for Blacks than for Whites on only 11% of all quality measures and that quality was better for Whites than for Blacks on 41% of all quality measures (Figure 3).
- For Patient Safety, quality was better for Blacks than for Whites for 21% of Patient Safety measures and better for Whites than for Blacks on 30% of Patient Safety measures.

### Largest Disparities

The measures with the largest disparities for Blacks include:

- New HIV cases per 100,000 population age 13 and over.
- HIV infection deaths per 100,000 population.
- Hospital admissions for asthma per 100,000 population, children ages 2-17.

#### New HIV Cases

According to CDC research, in 2017, Blacks accounted for 13% of the nation’s population but represented 43% of all new HIV cases. Most of these cases affect Black male adolescents and adults.^9^ The Office of Minority Health reports that in 2016, for every one White male, an estimated 7.8 African American males received a new HIV diagnosis.^10^

Figure 4 New HIV cases per 100,000 population age 13 and over, 2016

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population 2015 achievable benchmark: 4.2 per 100,000 population Total, 14.6 Non-Hispanic Black, 52 Non-Hispanic White, 5.9

Source: Centers for Disease Control and Prevention, National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, HIV AIDS Surveillance System, 2016.

- In 2016, non-Hispanic Blacks reported 52.0 new HIV cases per 100,000 population for people age 13 and over compared with 5.9 per 100,000 cases for non-Hispanic Whites (Figure 4).
- The 2015 achievable benchmark was 4.2 per 100,000 population. At the current rate of improvement (trends data not shown), non-Hispanic Blacks could achieve the benchmark in 18 years and non-Hispanic Whites could achieve the benchmark in 9 years.
- The top 10% of states and territories that reached the benchmark are Idaho, Iowa, Maine, West Virginia, and Wisconsin.

#### Resources

- In 2019, the administration announced a Presidential initiative to end the HIV epidemic in the United States. The Department of Health and Human Services has committed to “reducing new infections by 75 percent in the next five years and by 90 percent in the next ten years.”^11^ The Department’s website www.hiv.gov also outlines key resources for patients, provides data, and details programs supporting a federal response to the epidemic.

#### HIV Infection Deaths

HIV mortality disproportionately affects some racial and ethnic groups more than others. According to CDC data, in 2017, HIV was the sixth leading cause of death for Black men ages 25-34 and fifth for Black women ages 35-44.12

Figure 5 HIV infection deaths per 100,000 population, 2017

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population 2016 achievable benchmark: 0.75 per 100,000 population Total, 1.8 Non-Hispanic Black, 6.6 Non-Hispanic White, 0.9

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System-Mortality, 2017.

- In 2017, Blacks had 6.6 HIV infection deaths per 100,000 population compared with 0.9 per 100,000 cases for Whites (Figure 5). These cases represent mortality for which HIV was the primary cause of death.
- The 2016 achievable benchmark was 0.75 per 100,000 population. There is no evidence of progress toward the benchmark (trend data shown in Figure 10).
- The top 10% of states and territories that reached the benchmark are Kansas, Kentucky, Minnesota, Missouri, Ohio, and Washington (more than 5 states reached the benchmark due to ties).

#### Resources

- Federal efforts to reduce mortality include promotion of treatment therapies, such as antiretroviral therapy, pre-exposure prophylaxis, and postexposure prophylaxis.^13^ Several HHS agencies provide a federal response to the HIV epidemic, including the Health Resources and Services Administration (HRSA) HIV/AIDS Bureau, which administers the Ryan White HIV/AIDS Program (RWHAP). This is the largest federal program focused exclusively on providing HIV care and treatment to patients with inadequate or no insurance. Through RWHAP’s partnerships, more than 512,000 people receive care annually.^14^
- Federal efforts to prevent HIV infections include the High-Impact Prevention (HIP) program. HIP is a public health approach to disease prevention in which cost-effective, proven, and scalable interventions are targeted to specific populations based on disease burden. It provides a strategy for using data to maximize the impact of available resources and interventions. The primary goals of HIP are to prevent the largest number of new infections, save life-years, and reduce disparities among populations. In this approach to disease prevention, resources are aligned with disease burden in geographic areas and within populations.^15^

#### Hospital Admissions for Asthma

Asthma is the most common chronic lung condition among children under 17 years in the United States. Asthma has no cure and without treatment, patients can die.^16^ CDC research shows that from 2001 to 2016, 8% fewer children experienced one or more asthma attacks. Nonetheless, in 2018, about 1 in 13 children ages 0-17 had asthma and among them, asthma disproportionately affected males, non-Hispanic Black children, and children from low-income households. Data from 2016 to 2018 show that asthma affected 14.2% of non-Hispanic Black children and 13.6% of Puerto Rican children, compared with 6.8% of non-Hispanic White children. These are longstanding trends, noting the disproportionate impact on Puerto Rican and Black children.^17^

Figure 6 Hospital admissions for asthma per 100,000 population, children ages 2-17, 2017

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population Total, 81.8 Non-Hispanic Black, 216.5 Non-Hispanic White, 41.9

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2017.

- In 2017, the rate of hospital admissions for asthma was 216.5 per 100,000 population for non-Hispanic Black children compared with 41.9 per 100,000 cases for non-Hispanic White children (Figure 6).

##### Resources

- CDC’s current effort to reduce prevalence and improve control is the Controlling Childhood Asthma and Reducing Emergencies (CCARE) program (https://www.cdc.gov/asthma/ccare.htm).^18^ To help achieve CCARE’s objectives, CDC’s National Asthma Control Program developed EXHALE, a set of six evidence-based strategies that each contribute to better asthma control (https://www.cdc.gov/asthma/exhale/index.htm).
- In 1989, the National Heart, Lung, and Blood Institute of the National Institutes of Health established the National Asthma Education and Prevention Program (https://www.nhlbi.nih.gov/science/national-asthma-education-and-prevention-program-naepp) (NAEPP). NAEPP oversees the development of asthma guidelines, creates tools and materials to put guidelines into practice, coordinates federal asthma-related activities, and builds partnerships. The NAEPP has a federal advisory committee, the National Asthma Education and Prevention Program Coordinating Committee (https://www.nhlbi.nih.gov/advisory-and-peer-review-committees/national-asthma-education-and-prevention-program-coordinating).

### Trends in Quality of Care for Blacks

Figure 7 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, 2000 through 2014, 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percent change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing: The average annual percent change is ≤1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percent change is 1% or greater in the undesirable direction, and p <0.10.

Different data sources have different data years. For example, the most recent data year available for trending from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems (CMS HCAHPS) is 2018.

Stacked bar chart showing number of quality measures Total (n=162), Improving, 78, Not Changing, 74, Worsening, 10 Person-Centered Care (n=27), Improving, 10, Not Changing, 17, Worsening, 0 Patient Safety (n=19), Improving, 9, Not Changing, 8, Worsening, 2 Healthy Living (n=69), Improving, 39, Not Changing, 28, Worsening, 2 Effective Treatment (n=34), Improving, 16, Not Changing, 15, Worsening, 3 Care Coordination (n=8), Improving, 3, Not Changing, 2, Worsening, 3 Affordable Care (n=5), Improving, 1, Not Changing, 4, Worsening, 0

- Across the 162 measures of healthcare quality tracked in the report for Blacks, 48% showed improvement, 46% remained unchanged, and 6% were getting worse from 2000 to 2018 (Figure 7).^ii^
- Healthy Living (57% of measures), Effective Treatment (47% of measures), and Patient Safety (47% of measures) showed the most improvement.

### Changes in Disparities for Blacks

Figure 8 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time, total and by priority area, 2000 through 2014, 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: Different data sources have different data years. For example, the most recent data year available for trending from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems (CMS HCAHPS) is 2018.

Stacked bar chart showing number of quality measures improving and not changing; no measures were worsening Total (n=58), Improving, 2, Not Changing, 55 Person-Centered Care (n=6), Improving, 0, Not Changing, 6 Patient Safety (n=3), Improving, 0, Not Changing, 3 Healthy Living (n=29), Improving, 0, Not Changing, 29 Effective Treatment (n=14), Improving, 3, Not Changing, 11 Care Coordination (n=5), Improving, 0, Not Changing, 5 Affordable Care (n=1), Improving, 0, Not Changing, 1

- From 2000 to 2018, only 5% measures with disparities in quality of care experienced by Blacks were narrowing (Figure 8). Of 58 quality measures for which a disparity existed at baseline, only 3 showed a narrowing disparity:
  ■ Adults with a major depressive episode in the last 12 months who received treatment for depression in the last 12 months.
  ■ New HIV cases per 100,000 population age 13 and over.
  ■ Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population.
- Disparities were not changing for 95% of measures, and none were widening.

#### Treatment for Depression

Treatment for depression can reduce symptoms and associated illnesses and improve functioning and quality of life. Cost-benefit analyses showed that compared with usual care, strategies for treating depression in primary care settings, such as the collaborative care model, have produced positive net social benefits.^19^

Barriers to high-quality mental health care include:

- Cost of care,
- Lack of sufficient insurance or lack of insurance parity for mental health services,
- Discrimination, stigma, and other negative attitudes toward mental health problems,
- Lack of culturally and linguistically competent providers,
- Fragmented organization of services, and
- Mistrust of providers.

Figure 9 Adults with major depressive episode in the last 12 months who received treatment for depression in the last 12 months, 2008-2018

Line graph showing percentage who received treatment for depression Total White Black 2008 68.3 70.4 56 2009 64.4 66.1 53.1 2010 68.2 70.8 55.7 2011 68.1 70.9 54.9 2012 68 69.3 61 2013 68.6 70.2 62.3 2014 68.7 70.6 58 2015 67.2 69.3 58.9 2016 65.3 67.5 59.7 2017 66.8 68.5 63.7 2018 64.8 66.2 61.6

Source: Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality, National Survey on Drug Use and Health, 2008-2018.

- Data from 2008 to 2018 show that the disparity between Blacks and Whites is narrowing. The percentage of Blacks who needed and received treatment for depression increased from 56.0% in 2008 to 61.6% in 2018. There were no statistically significant changes in the percentages for Whites (Figure 9).

#### New HIV Cases

Figure 10 New HIV cases per 100,000 population age 13 and over, 2008-2016

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population of new HIV cases going from 73.9 for Blacks and 7.5 for Whites in 2008 to 52 for Blacks and 5.9 for Whites in 2016; total went from 19 in 2008 to 14.6 in 2016 2015 achievable benchmark: 4.2 per 100,000 population

Source: Centers for Disease Control and Prevention, National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, HIV-AIDS Surveillance System, 2008-2016.

- Data from 2008 to 2016 show that the disparity between non-Hispanic Blacks and non-Hispanic Whites is narrowing, but non-Hispanic Blacks are still experiencing a much higher rate of new HIV cases (52.0 per 100,000 population in 2016) compared with non-Hispanic Whites (5.9 per 100,000 population in 2016; Figure 10).
- The 2015 achievable benchmark was 4.2 per 100,000 population. At the current rate of increase, overall, the benchmark could be achieved by non-Hispanic Blacks in 18 years and non-Hispanic Whites in 9 years.
- The top 10% of states and territories that reached the benchmark are Idaho, Iowa, Maine, West Virginia, and Wisconsin.

#### End Stage Renal Disease Due to Diabetes

According to the Office of Minority Health, African American adults are 60 percent more likely than non-Hispanic White adults to have been diagnosed with diabetes by a physician and 3.5 times more likely to be diagnosed with end stage renal disease (ESRD) compared with non-Hispanic Whites. During 2017, there were 124,500 newly reported cases of ESRD and diabetes was listed as the primary cause for nearly 50% (58,371).^20^

Figure 11 Adjusted incident rates of end stage renal disease due to diabetes per million population, 2001-2017

Note: For this measure, lower rates are better.

Line graph showing rate per million population of end stage renal disease due to diabetes Total Black White 2001 177.8 525.7 133.3 2002 174.9 519.7 131.9 2003 174.2 511.3 132.3 2004 174 496.1 134.3 2005 173.7 496.5 135 2006 177.3 501.7 139.6 2007 171.4 477.8 136.2 2008 168.7 473.2 133.9 2009 169.3 470.8 135 2010 166.6 455.7 134.3 2011 159.7 435.6 129.2 2012 157.6 411 129.7 2013 158.8 400.4 132.5 2014 158.9 391.6 133.6 2015 164.1 393.5 139.8 2016 169 391.3 144.9 2017 165.7 366.2 138.4

Source: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases, U.S. Renal Data System, 2001-2017.

- Data from 2001 to 2017 show that the disparity between Blacks and Whites is narrowing, but Blacks are still experiencing a higher rate of ESRD due to diabetes (Figure 11).
- Disparities have been persistent, with Blacks having a higher incident rate of ESRD due to diabetes than Whites in all years.

## Disparities for Asians

In 2017, Asians with limited English proficiency and a usual source of care (USC) were less likely than Whites to report that their USC had language assistance.

Figure 12 Number and percentage of quality measures for which Asians experienced better, same, or worse quality of care compared with reference group (White) for the most recent data year, 2014, 2016, 2017, or 2018

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value <0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Agency for Healthcare Research and Quality Healthcare Cost and Utilization Project (AHRQ HCUP) is 2017.

Stacked bar chart showing number of quality measures Total (n=185), Better, 56, Same, 77, Worse, 52 Person-Centered Care (n=29), Better, 1, Same, 10, Worse, 18 Patient Safety (n=31), Better, 11, Same, 14, Worse, 6 Healthy Living (n=63), Better, 17, Same, 29, Worse, 17 Effective Treatment (n=40), Better, 10, Same, 22, Worse, 8 Care Coordination (n=20), Better, 15, Same, 2, Worse, 3 Affordable Care (n=2), Better, 2, Same, 0, Worse, 0

- Data for the most recent year show that quality was better for Asians than for Whites on almost a third of all quality measures, the same for 42%, and worse for 28% (Figure 12).

### Largest Disparities

The measures with the largest disparities across all quality domains for Asians include:

- Adults with limited English proficiency and a usual source of care (USC) whose USC had language assistance.
- Adults who reported that home health providers always treated them with courtesy and respect in the last 2 months of care.
- Adults who reported that home health providers always treated them as gently as possible in the last 2 months of care.

#### Providers With Language Assistance

Current research shows that Asians continue to experience health disparities in several quality areas, including patient-centered care and satisfaction.^21^ Adults who have limited English proficiency may experience disparities in their care and gaps in communication with their healthcare team.^22^

According to the Migration Policy Institute, in 2015, an estimated 25.9 million individuals living in the United States reported having limited English proficiency.^23^ “More than one in four people aged 5 and over with LEP are born in the U.S.”^24^ Language assistance such as access to translation services, health education materials written in a known language, and other resources are required by law, but not all patients have access to these services at their usual source of care.^25^

Figure 13 Adults with limited English proficiency and a usual source of care (USC) whose USC had language assistance, 2017

Columns showing percentage Total, 91.2, Asian, 78.9, White, 94.8

Source: Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, Asians with limited English proficiency and a usual source were less likely than Whites to have a USC with language assistance (78.9% compared with 94.8%; Figure 13).

The Limited English Proficiency website25 offers a repository of resources collated by the Department of Justice to support improved communication with patients. AHRQ has also established a Limited English Proficiency module as part of its TeamSTEPPS® training that shows the importance of language assistance services in keeping patients safe and avoiding adverse events.^26^

#### Treatment by Home Health Providers

Home health providers are committed to delivering high-quality and compassionate care and services to patients in a respectful manner that supports each patient’s dignity. Home health performance is examined through several types of quality measures that look at areas such as efficiency, patient safety, and patient-centered care. Evaluation of patient experience of care is conducted with the Consumer Assessment of Healthcare Providers and Systems Home Health Care Survey.^27^

Figure 14 Adults who reported that home health providers always treated them with courtesy and respect in the last 2 months of care, 2018

Columns showing percentage Total, 93.6, Asian, 85.2, White, 94.3 2015 achievable benchmark: 95%

Source: Agency for Healthcare Research and Quality, Home Health Consumer Assessment of Healthcare Providers and Systems, 2018.

- In 2018, the percentage of adults who reported that home health providers always treated them with courtesy and respect in the last 2 months was lower for Asians (85.2%) compared with Whites (94.3%; Figure 14).
- The 2015 achievable benchmark was 95%. There is no evidence of progress toward the benchmark (trend data not shown).
- The top 10% of states and territories that reached the benchmark are Alabama, Kentucky, Louisiana, Mississippi, South Carolina, and West Virginia (more than 5 states reached to the benchmark due to ties).

Figure 15 Adults who reported that home health providers always treated them as gently as possible in the last 2 months of care, 2018

Columns showing percentage Total, 90.2, Asian, 80.6, White, 91 2015 achievable benchmark: 92%

Source: Centers for Medicare & Medicaid Services, Home Health Consumer Assessment of Healthcare Providers and Systems, 2018.

- In 2018, 80.6% of Asian adults reported that home health providers always treated them as gently as possible compared with 91.0% of White adults (Figure 15).
- The 2015 achievable benchmark was 92%. There is no evidence of progress toward the benchmark (trend data not shown).
- The top 10% of states and territories that reached the benchmark are Alabama, Louisiana, Mississippi, Rhode Island, and West Virginia.

### Trends in Quality of Care for Asians

Figure 16 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2000 through 2011, 2014, 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percent change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing: The average annual percent change is ≤1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percent change is 1% or greater in the undesirable direction, and p <0.10.

Different data sources have different data years. For example, the most recent data year available for trending from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems (CMS HCAHPS) is 2018.

Stacked bar chart showing number of quality measures Total (n=137), Improving, 74, Not Changing, 56, Worsening, 7 Person-Centered Care (n=29), Improving, 17, Not Changing, 11, Worsening, 1 Patient Safety (n=14), Improving, 7, Not Changing, 6, Worsening, 1 Healthy Living (n=60), Improving, 37, Not Changing, 21, Worsening, 2 Effective Treatment (n=24), Improving, 11, Not Changing, 12, Worsening, 1 Care Coordination (n=7), Improving, 2, Not Changing, 3, Worsening, 2 Affordable Care (n=3), Improving, 0, Not Changing, 3, Worsening, 0

- Across the 137 measures of healthcare quality tracked in the report for Asians, 54% were improving, 41% were not changing, and 5% were getting worse from 2000 to 2018 (Figure 16).^iii^
- Affordable Care (no measures) and Care Coordination (29% of measures) showed the least improvement.
- Healthy Living (62%) and Person-Centered Care (59%) showed the most improvement.

### Changes in Disparities for Asians

Figure 17 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time, total and by priority area, 2000 through 2014, 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: Different data sources have different data years. For example, the most recent data year available for trending from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems (CMS HCAHPS) is 2018.

Stacked bar chart showing number of quality measures Total (n=37), Improving, 1, Not Changing, 35, Worsening, 1 Person-Centered Care (n=13), Improving, 0, Not Changing, 13, Worsening, 0 Patient Safety (n=1), Improving, 0, Not Changing, 0, Worsening, 1 Healthy Living (n=17), Improving, 0, Not Changing, 17, Worsening, 0 Effective Treatment (n=3), Improving, 1, Not Changing, 2, Worsening, 0 Care Coordination (n=3), Improving, 0, Not Changing, 3, Worsening, 0 Affordable Care (n=0)

- From 2000 through 2018, disparities in quality of care between Asians and Whites remained the same for most measures. Of 37 quality measures with a disparity at baseline, disparities were not changing for 35 (95%) (Figure 17).
- One measure showed narrowing disparities: People age 13 and over living with HIV who know their serostatus.
- One measure showed a widening disparity: Home health patients whose management of oral medications improved.
- No affordable care measures with data for Asians were available.

#### Knowledge of HIV Serostatus

Stigmatization of HIV hinders patients from getting tested, which may delay treatment and affect a patient’s health and quality of life.^28^ According to CDC, people ages 13-24 are less likely to know their HIV serostatus.^29^ Accurate estimates of new HIV infection rates are crucial for preventing the spread of the disease.

Figure 18 People age 13 and over living with HIV who know their serostatus, 2010-2016

Line graph showing percentage 2015 achievable benchmark: 91.9% 2010, Asian, 70.5, White, 86.4 2011, Asian, 72.0, White, 86.8 2012, Asian, 73.8, White, 87.1 2013, Asian, 75.4, White, 87.5 2014, Asian, 77.8, White, 87.9 2015, Asian, 80.4, White, 88.1 2016, Asian, 80.9, White, 88.5

Source: Centers for Disease Control and Prevention, National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, HIV-AIDS Surveillance System, 2010-2016.

- Data from 2000 to 2016 show that the disparity between Asians and Whites is narrowing as the percentage of Asians (70.5% to 80.9%) who know their serostatus increased at a faster rate compared with Whites (86.4% to 88.5%) (Figure 18).
- The 2015 achievable benchmark was 91.9%. At the current rate of increase, overall, the benchmark could be achieved in 6 years.
- The top 10% of states and territories that reached the benchmark are Idaho, New Jersey, Pennsylvania, South Dakota, and Vermont.

#### Oral Medication Management

The ability to perform daily activities, such as taking medications correctly, is important to the health status and quality of life of people living in the community. Taking too much or too little can keep the drugs from working properly and may cause unintended harm, including death. The home health team can help teach patients ways to organize medications and to take them properly. If patients get better at taking medications correctly, it means the home health team is doing a good job teaching patients how to take their drugs and about the possible harm if they do not follow these instructions.

Specific items that should be discussed include all the prescriptions and other medications the patient takes, allergic or other adverse reactions to drugs experienced in the past, and actions to take if a medication is not working. This measure shows how often the home health team helped patients get better at taking their prescription and other medications correctly (including prescription medications, over-the-counter medications, vitamins, and herbal supplements). Only medications the patient takes by mouth are considered.

Figure 19 Home health care patients whose management of oral medications improved, 2013-2017

Line graph showing percentage 2015 achievable benchmark: 66.2% Asian White 2013 47.3 53.3 2014 48.1 54.8 2015 50.2 58.5 2016 52.8 63.4 2017 58.1 68.9

Source: Centers for Medicare & Medicaid Services, Home Health Quality Initiative, Chronic Condition Data Warehouse, Outcome and Assessment Information Set, 2013-2017.

- From 2013 to 2017, the percentage of home health care patients whose management of oral medications improved increased for both Asians and Whites. Whites, however, improved faster than Asians, so the disparity between the groups has increased (Figure 19).
- The 2015 achievable benchmark was 66.2%. At the current rate of increase, the benchmark could be achieved by Asians in 3 years; Whites have already achieved the benchmark.
- The top 10% of states and territories that reached the benchmark are Delaware, Mississippi, New Jersey, North Dakota, and South Carolina.

## Disparities for American Indians and Alaska Natives

American Indians and Alaska Natives performed worse on two-thirds of Person-Centered Care quality measures.

Figure 20 Number and percentage of quality measures for which American Indians and Alaska Natives experienced better, same, or worse quality of care compared with reference group (White) for the most recent data year, 2014, 2016, 2017, or 2018

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value <0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Agency for Healthcare Research and Quality Healthcare Cost and Utilization Project (AHRQ HCUP) is 2017.

Stacked bar chart showing number of quality measures Total (n=116), Better, 13, Same, 56, Worse, 47 Person-Centered Care (n=21), Better, 1, Same, 6, Worse, 14 Patient Safety (n=13), Better, 1, Same, 10, Worse, 2 Healthy Living (n=49), Better, 3, Same, 28, Worse, 18 Effective Treatment (n=25), Better, 7, Same, 10, Worse, 8 Care Coordination (n=7), Better, 1, Same, 1, Worse, 5 Affordable Care (n=1), Better, 0, Same, 1, Worse, 0

- Data for the most recent year show that quality was worse for American Indians and Alaska Natives (AI/ANs) than for Whites for 41% of all quality measures and that quality was better for AI/ANs than for Whites for 11% of all quality measures (Figure 20).

Measures with the largest disparities for the most recent year where data were available include:

- Hospital patients who received influenza vaccination.
- Infant mortality per 1,000 live births, birth weight 2,500 grams or more.
- New HIV cases per 100,000 population age 13 and over.

### Influenza Vaccination

The Centers for Disease Control and Prevention (CDC) estimates that there were 21,500 to 35,500 flu-related deaths from October 1, 2018, through March 9, 2019.30 In 2017, approximately 92% of hospital employees reported receiving an influenza vaccination in the 2017-2018 season according to CDC.^31^

While long-debated as an issue of personal choice, influenza vaccination among healthcare providers can efficiently limit the spread of disease. Moreover, current research shows that influenza vaccination provided to hospital patients also limits the spread of the flu and is even effective in patients with chronic obstructive pulmonary disease (COPD).^32^

Current clinical guidelines show that people who are 6 months or older should receive an annual flu vaccine, but not all patients can access vaccines or treatment if they become ill. CDC details preventive strategies (https://www.cdc.gov/flu/prevent/index.html) to protect against the flu.

Figure 21 Hospital patients who received influenza vaccination, 2017

Key: AI/AN = American Indian or Alaska Native.

Columns showing percentage Total, 93.2, AI/AN, 83.3, White, 93.8

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse for Hospital Inpatient Quality Reporting Program, 2017.

- In 2017, 83.3% of AI/AN hospital patients received influenza vaccinations compared with 93.8% of Whites (Figure 21).

### Infant Mortality

Low birth weight can be a predictor of developmental delays and mortality among infants.^33^ Infant mortality and low birth weight can decline when pregnant women receive adequate prenatal care.^34^

Figure 22 Infant mortality per 1,000 live births, birth weight 2,500 grams or more, 2017

Key: AI/AN = American Indian or Alaska Native.

Columns showing rate per 1,000 live births Total, 2, AI/AN, 3.9, White, 1.8

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Linked Birth and Infant Death Data, 2017.

- In 2017, infant mortality per 1,000 live births, birth weight 2,500 grams or more, was twice as high for AI/ANs (3.9 per 1,000 births) compared with Whites (1.8 per 1,000 births; Figure 22).

#### Resources

- Federal resources to improve the rate of infant mortality include the CDC Perinatal Quality Collaborative and the HRSA Healthy Start Initiative.
- CDC provides support to perinatal quality collaboratives (PQCs) (https://www.cdc.gov/reproductivehealth/maternalinfanthealth/pqc.htm), which are state or multistate networks of teams working to improve health outcomes for mothers and babies. Funding supports building PQC capacity to improve the quality of perinatal care in their states, including efforts to reduce preterm births (https://www.cdc.gov/reproductivehealth/maternalinfanthealth/pretermbirth.htm) and improve prematurity outcomes. CDC works with experts to develop resources PQCs can use to further their development, including a how-to guide (https://www.cdc.gov/reproductivehealth/maternalinfanthealth/pdf/Best-Practices-for-Developing-and-Sustaining-Perinatal-Quality-Collaboratives_tagged508.pdf) [PDF, 567 KB] and a webinar series (https://www.cdc.gov/reproductivehealth/maternalinfanthealth/pqc_webinars.html).
- The HRSA Healthy Start program targets communities with infant mortality rates that are at least one and a half times the U.S. national average. It aims to reduce other negative birth outcomes such as maternal mortality (https://www.hrsa.gov/maternal-mortality/index.html), a growing and serious problem in our nation, as well as poverty, education, access to care, and other socioeconomic factors.

Perinatal Quality Collaboratives Logo

The program delivers standardized interventions, including risk assessment, health education, and medical and psychosocial supports and referrals, by a competent workforce; and support for ongoing evaluation at local and national levels.

### New HIV Infections

Since 2006, CDC has recommended universal screening for HIV infection at least once in healthcare settings and at least annual rescreening of people at increased risk for infection. Yet, by 2017, less than 40% of the U.S. adult population had ever been tested for HIV. At the end of 2016, an estimated 1.1 million people had HIV; AI/ANs had a rate of 196 per 100,000 population.

It is important for everyone to know their HIV status. People who do not know they have HIV cannot take advantage of HIV care and treatment and may unknowingly pass HIV to others.

The United States has more than 574 federally recognized AI/AN tribes and many different languages. Because each tribe has its own culture, beliefs, and practices, creating culturally appropriate prevention programs for each group can be challenging.

Poverty, including limited access to high-quality housing, directly and indirectly increases the risk of HIV infection and affects the health of people who have and are at risk for HIV infection. Compared with other racial/ethnic groups, AI/ANs have higher poverty rates, have completed fewer years of education, are younger, are less likely to be employed, and have lower rates of health insurance coverage.

Figure 23 New HIV cases per 100,000 population age 13 and over, 2016

Columns showing rate per 100,000 population 2015 achievable benchmark: 4.2 per 100,000 population Total, 14.6, AI/AN, 11.9, White, 5.9

Source: National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, Division of HIV/AIDS, National HIV/AIDS Surveillance System, 2016.

- In 2016, the percentage of new HIV cases was higher for AI/ANs (11.9%) compared with Whites (5.9%) (Figure 23).
- The 2015 achievable benchmark was 4.2 per 100,000 population. At the current rate of increase, AI/ANs show no progress toward the benchmark.
- The top 10% of states and territories that reached the benchmark are Idaho, Iowa, Maine, West Virginia, and Wisconsin.

#### Resource

BESAFE: A Cultural Competency Model for American Indians, Alaska Natives, and Native Hawaiians is a Cultural Competency Guide for healthcare professionals who provide care for American Indian, Alaska Native, and Native Hawaiian patients infected with HIV/AIDS. It is based on the BE SAFE framework, which addresses:

- Barriers to Care.
- Ethics.
- Sensitivity of the Provider.
- Assessment.
- Facts.
- Encounters.

### Trends in Quality of Care for American Indians and Alaska Natives

Figure 24 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2000 through 2013, 2014, 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percent change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing: The average annual percent change is ≤1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percent change is 1% or greater in the undesirable direction, and p <0.10.

Different data sources have different data years. For example, the most recent data year available for trending from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems (CMS HCAHPS) is 2018.

Stacked bar chart showing number of quality measures Total (n=116), Improving, 45, Not Changing, 64, Worsening, 7 Person-Centered Care (n=23), Improving, 3, Not Changing, 18, Worsening, 2 Patient Safety (n=13), Improving, 5, Not Changing, 7, Worsening, 1 Healthy Living (n=52), Improving, 24, Not Changing, 28, Worsening, 0 Effective Treatment (n=20), Improving, 11, Not Changing, 6, Worsening, 3 Care Coordination (n=7), Improving, 2, Not Changing, 4, Worsening, 1 Affordable Care (n=1), Improving, 0, Not Changing, 1, Worsening, 0

- Among the 116 quality measures with data for AI/ANs, 45 (39%) were improving, 64 (55%) were not changing, and 7 (6%) were getting worse from 2000 through 2018 (Figure 24).
- Effective Treatment (55%) and Healthy Living (46%) showed the most improvement.

### Changes in Disparities for American Indians and Alaska Natives

Figure 25 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time, total and by priority area, from 2000 through 2013, 2014, 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: Different data sources have different data years. For example, the most recent data year available for trending from the National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems (CMS HCAHPS) is 2018.

Stacked bar chart showing number of quality measures Total (n=34), Improving, 2, Not Changing, 32, Worsening, 0 Person-Centered Care (n=11), Improving, 0, Not Changing, 11, Worsening, 0 Patient Safety (n=3), Improving, 0, Not Changing, 3, Worsening, 0 Healthy Living (n=12), Improving, 1, Not Changing, 11, Worsening, 0 Effective Treatment (n=3), Improving, 1, Not Changing, 2, Worsening, 0 Care Coordination (n=5), Improving, 0, Not Changing, 5, Worsening, 0 Affordable Care (n=0)

- Disparities between AI/ANs and Whites did not change for most of the quality measures from 2000 through 2018. Of 34 quality measures with a disparity at baseline, 32 (94%) were not changing (Figure 25).
- Only two measures showed narrowing disparities: Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population and children ages 2-17 for whom a health provider gave advice within the past 2 years about healthy eating.^iv^
- No affordable care measures were available with data for AI/ANs.

#### End Stage Renal Disease Due to Diabetes

Diabetes is the leading cause of kidney disease in the United States. According to the National Institute of Diabetes and Digestive and Kidney Diseases, Whites experience diabetes and kidney disease at a lower rate than other racial and ethnic groups.^35,36^

Figure 26 Adjusted incident rates of end stage renal disease due to diabetes per million population, 2001-2017

Note: For this measure, lower rates are better.

Line graph showing rate per million population AI/AN, 2001, 526.0, 2002, 494.3, 2003, 469.6, 2004, 478.2, 2005, 430.0, 2006, 367.7, 2007, 379.6, 2008, 390.0, 2009, 382.6, 2010, 347.6, 2011, 321.3, 2012, 322.6, 2013, 298.6, 2014, 288.6, 2015, 275.8, 2016, 285.9, 2017, 274.9 White, 2001, 133.3, 2002, 131.9, 2003, 132.3, 2004, 134.3, 2005, 135.0, 2006, 139.6, 2007, 136.2, 2008, 133.9, 2009, 135.0, 2010, 134.3, 2011, 129.2, 2012, 129.7, 2013, 132.5, 2014, 133.6, 2015, 139.8, 2016, 144.9, 2017, 138.4

Source: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases, United States Renal Data System, 2001-2017.

- From 2001 to 2017, the disparity between AI/ANs and Whites decreased for the adjusted incident rate of ESRD due to diabetes. For AI/ANs, the rate decreased from 526 per million population to 274.9 per million, and for Whites, there were no statistically significant changes (from 133.3 per million to 138.4 per million; Figure 26).
- Disparities have been persistent, with AI/ANs having higher incident rates of ESRD due to diabetes than Whites in all years.

## Disparities for Native Hawaiians and Pacific Islanders

More than 40% of Healthy Living measures for Native Hawaiians and Pacific Islanders showed worse performance compared with Whites.

Figure 27 Number and percentage of quality measures for which Native Hawaiians/Pacific Islanders experienced better, same, or worse quality of care compared with reference group (White) for the most recent data year, 2016, 2017, or 2018

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value <0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from the Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base (NCDB) is 2016 and from the Home Health Consumer Assessment of Healthcare Providers and Systems (CMS HHCAHPS) is 2018.

Stacked bar chart showing number of quality measures Total (n=72), Better, 11, Same, 37, Worse, 24 Person-Centered Care (n=17), Better, 1, Same, 12, Worse, 4 Patient Safety (n=12), Better, 2, Same, 8, Worse, 2 Healthy Living (n=27), Better, 5, Same, 10, Worse, 12 Effective Treatment (n=10), Better, 1, Same, 5, Worse, 4 Care Coordination (n=6), Better, 2, Same, 2, Worse, 2 Affordable Care (n=0)

- Data for the most recent year show that Native Hawaiians/Pacific Islanders (NHPIs) experienced worse quality care compared with Whites on one-third of all quality measures. Quality was better for NHPIs than for Whites on 15% of all quality measures (Figure 27).
- No Affordable Care measures with data for NHPIs were available.

### Largest Disparities

The measures with the largest disparities for NHPIs include:

- Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high.
- Hospital patients who received influenza vaccination.
- Adults who reported that home health providers always treated them with courtesy and respect in the last 2 months of care.

#### Blood Pressure Measurement

In the United States, hypertension accounted for more cardiovascular (CVD) deaths than any other modifiable CVD risk factor and was second only to cigarette smoking as a preventable cause of death for any reason.^37^ According to CDC, one-third of adults in the United States have hypertension, but about 20% of adults with hypertension do not know they have it.

Figure 28 Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high, 2017

Key: NHPI = Native Hawaiian or Pacific Islander

Columns showing percentage Total, 92.8, NHPI, 77, White, 92.8

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2017.

- In 2017, the percentage of adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high was lower for NHPIs (77.0%) than for Whites (92.8%) (Figure 28).

#### Treatment by Home Health Providers

Figure 29 Adults who reported that home health providers always treated them with courtesy and respect in the last 2 months of care, 2018

Column chart showing percentage 2015 achievable benchmark: 95% Total, 93.6 NHPI, 91 White, 94.3

Source: Agency for Healthcare Research and Quality, Home Health Consumer Assessment of Healthcare Providers and Systems, 2018.

- In 2018, the percentage of adults who reported that home health providers always treated them with courtesy and respect in the last 2 months was lower for NHPIs (91.0%) compared with Whites (94.3%) (Figure 29).
- The 2015 achievable benchmark was 95%. Overall, there was no progress toward the benchmark.
- The top 10% of states and territories that reached the benchmark are Alabama, Guam, Louisiana, Mississippi, Rhode Island, South Carolina, and West Virginia (more than 5 states reached the benchmark due to ties).

#### Influenza Vaccination

According to CDC, annual vaccination is the most important measure to prevent seasonal influenza infection. Achieving high influenza vaccination rates of healthcare personnel and patients is a critical step in preventing transmission of influenza from healthcare personnel to patients and from patients to healthcare personnel. According to current national guidelines, unless contraindicated, all people age 6 months and older should be vaccinated, including healthcare personnel, patients, and residents of long-term care facilities.^38^

Figure 30 Hospital patients who received influenza vaccination, 2017

Columns showing percentage 2015 achievable benchmark: 97% Total, 93.2, NHPI, 88.7, White, 93.8

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse for Hospital Inpatient Quality Reporting Program, 2017.

- In 2017, NHPI hospital patients were less likely than White patients to receive influenza vaccination (Figure 30).
- The 2015 achievable benchmark was 97%. Overall, there was no progress toward the benchmark (trend data not shown).
- The top 10% of states and territories that reached the benchmark are Florida, Indiana, Maryland, North Carolina, and South Carolina.

### Trends in Quality of Care for Native Hawaiians/Pacific Islanders

Nearly 40% of quality measures for NHPIs showed improvement.

Figure 31 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by priority area, from 2001 through 2012, 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percent change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing: The average annual percent change is ≤1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percent change is 1% or greater in the undesirable direction, and p <0.10.

Different data sources have different data years. For example, the most recent data year available for trending from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems (CMS HCAHPS) is 2018.

Stacked bar chart showing number of quality measures Total (n=60), Improving, 23, Not Changing, 34, Worsening, 3 Person-Centered Care (n=10), Improving, 2, Not Changing, 8, Worsening, 0 Patient Safety (n=12), Improving, 4, Not Changing, 7, Worsening, 1 Healthy Living (n=24), Improving, 13, Not Changing, 10, Worsening, 1 Effective Treatment (n=7), Improving, 3, Not Changing, 4, Worsening, 0 Care Coordination (n=7), Improving, 1, Not Changing, 5, Worsening, 1 Affordable Care (n=0)

- Among the 60 quality measures with data for NHPIs, 23 (38%) were improving, 34 (57%) were not changing, and 3 (5%) were getting worse from 2001 through 2018 (Figure 31).^v^
- No Affordable Care measures with data for NHPIs were available.

### Changes in Disparities for Native Hawaiians/Pacific Islanders

Figure 32 Number and percentage of all quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time, total and by priority area, from 2008 through 2016, 2017, or 2018

Key: n = number of measures.

Note: Different data sources have different data years. For example, the most recent data year available for trending from the Centers for Disease Control and Prevention, National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention (CDC NCHHSTP) is 2016 and from the Centers for Medicare & Medicaid Services, Home Health Consumer Assessment of Healthcare Providers and Systems (CMS HHCAHPS) is 2018.

Stacked bar chart showing number of quality measures Total (n=16), Improving, 1, Not Changing, 15, Worsening, 0 Person-Centered Care (n=5), Improving, 0, Not Changing, 5, Worsening, 0 Patient Safety (n=1), Improving, 0, Not Changing, 1, Worsening, 0 Healthy Living (n=5), Improving, 0, Not Changing, 5, Worsening, 0 Effective Treatment (n=2), Improving, 1, Not Changing, 1, Worsening, 0 Care Coordination (n=3), Improving, 0, Not Changing, 3, Worsening, 0 Affordable Care (n=0)

- Disparities between NHPIs and Whites did not change for most of the quality measures from 2008 through 2018. Of the 16 quality measures with a disparity at baseline, disparities were not changing for 15 measures (94%) (Figure 32).
- No measures showed widening disparities, and only one measure showed a narrowing disparity: People age 13 and over living with HIV who know their serostatus.
- No Affordable Care measures were available with data for NHPIs.

#### Knowledge of HIV Serostatus

It is important for everyone to know his or her HIV status. Getting an HIV test is the first step for people living with HIV to get care and treatment and control the infection. Taking HIV medicine as prescribed helps people living with HIV to live a long, healthy life and protect their sex partners from HIV. About 85% of people with HIV in the United States know they have the virus. However, 15% (162,500) of people with HIV do not know they have the virus, and about 40% of new HIV infections come from them.

Half of people with HIV had the virus 3 years or more before diagnosis. Most people at high risk who did not get tested last year saw a healthcare provider during the year. Everyone should get tested at least once, and people at high risk should be tested at least once a year. Healthcare providers can diagnose HIV sooner if they test more people and test people at high risk more often.^39^

Figure 33 People age 13 and over living with HIV who know their serostatus, 2010-2016

Line showing percentage 2015 achievable benchmark: 91.9% NHPI, 2010, 74.0, 2011, 75.6, 2012, 77.3, 2013, 79.3, 2014, 80.1, 2015, 82.2, 2016, 82.4 White, 2010, 86.4, 2011, 86.8, 2012, 87.1, 2013, 87.5, 2014, 87.9, 2015, 88.1, 2016, 88.5

Source: Centers for Disease Control and Prevention, National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, HIV AIDS Surveillance System, 2010-2016.

- Data from 2010 to 2016 show that the disparity between NHPIs and Whites was narrowing due to a larger increase in the percentage of NHPIs (74% to 82.4%) than Whites (86.4% to 88.5%) who are living with HIV and aware of their serostatus (Figure 33).
- The 2015 achievable benchmark was 91.9%. At the current rate of increase, overall, the benchmark could be achieved in 6 years.
- The top 10% of states and territories that reached the benchmark are Idaho, New Jersey, Pennsylvania, South Dakota, and Vermont.

## Disparities for Hispanics

Hispanics performed worse than non-Hispanic Whites on about 40% of Effective Treatment and Healthy Living quality measures.

Figure 34 Number and percentage of quality measures for which Hispanics experienced better, same, or worse quality of care compared with reference group (non-Hispanic White) for the most recent data year, 2014, 2016, 2017, or 2018

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value <0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Agency for Healthcare Research and Quality Healthcare Cost and Utilization Project (AHRQ HCUP) is 2017.

Stacked bar chart showing number of quality measures Total (n=177), Better, 38, Same, 78, Worse, 61 Person-Centered Care (n=17), Better, 2, Same, 9, Worse, 6 Patient Safety (n=26), Better, 9, Same, 13, Worse, 4 Healthy Living (n=71), Better, 12, Same, 31, Worse, 28 Effective Treatment (n=41), Better, 8, Same, 18, Worse, 15 Care Coordination (n=17), Better, 6, Same, 6, Worse, 5 Affordable Care (n=5), Better, 1, Same, 1, Worse, 3

- Data for the most recent year show that quality was worse for Hispanics compared with non-Hispanic Whites for 34% of all quality measures. Quality was better for Hispanics than for non-Hispanic Whites on 21% of all quality measures (Figure 34).

### Largest Disparities

The measures with some of the largest disparities for Hispanics include:

- New HIV cases per 100,000 population age 13 and over.
- Home health patients who had influenza vaccination during flu season.
- HIV infection deaths per 100,000 population.

#### New HIV Cases

From 2012 through 2016, the rate of new HIV cases remained stable for Hispanics. In 2017, Hispanics had the second highest rate of new HIV cases.^40^

Figure 35 New HIV cases per 100,000 population age 13 and over, 2016

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population 2015 achievable benchmark: 4.2 per 100,000 population Total, 14.6 Hispanic, 22.2 Non-Hispanic White, 5.9

Source: Centers for Disease Control and Prevention, National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, HIV-AIDS Surveillance System, 2016.

- In 2016, the rate of new HIV cases per 100,000 population age 13 and over was higher for Hispanics (22.2 per 100,000 population) compared with non-Hispanic Whites (5.9 per 100,000 population) (Figure 35).
- The 2015 achievable benchmark was 4.2 per 100,000 population. At the current rate of increase, overall, the benchmark could not be achieved for 26 years.
- The top 10% of states and territories that reached the benchmark are Idaho, Iowa, Maine, West Virginia, and Wisconsin.

##### Resource

- Federal resources include the Let’s Stop HIV Together campaign (formerly known as Act Against AIDS), which has resources (https://www.cdc.gov/stophivtogether/library?Sort=Last%20Updated%3A%3Adesc&Language=English%20(US)) and partnerships (https://www.cdc.gov/stophivtogether/partnerships/index.html) aimed at stopping HIV stigma (https://www.cdc.gov/stophivtogether/hiv-stigma/index.html) and promoting HIV testing (https://www.cdc.gov/stophivtogether/hiv-testing/index.html), prevention (https://www.cdc.gov/stophivtogether/hiv-prevention/index.html), and treatment (https://www.cdc.gov/stophivtogether/hiv-treatment/index.html). This campaign provides Hispanics/Latinos with culturally and linguistically appropriate messages about HIV testing, prevention, and treatment.
- Federal resources also include Ending the HIV Epidemic: A Plan for America (https://www.hiv.gov/federal-response/ending-the-hiv-epidemic/overview), which aims to end the HIV epidemic in the United States by 2030. The plan leverages critical scientific advances in HIV prevention, diagnosis, treatment, and outbreak response by coordinating the highly successful programs, resources, and infrastructure of many HHS agencies and offices.

#### Influenza Vaccination

Influenza vaccination is the primary method for preventing the illness and its severe complications, and annual vaccination is recommended for everyone age 6 months and over.^41^ All healthcare contacts, including hospitalizations, provide excellent opportunities for vaccination, particularly for people at the highest risk for complications and death from influenza.

Figure 36 Home health patients who had influenza vaccination during flu season, 2017

Columns showing percentage Total, 95 Hispanic, 89.8 Non-Hispanic White, 95.9

Source: Centers for Medicare & Medicaid Services, Home Health Quality Initiative, Chronic Condition Data Warehouse, Outcome and Assessment Information Set, 2017.

- In 2017, Hispanic home health patients (89.8%) were less likely than non-Hispanic White home health patients (95.9%) to receive an influenza vaccine (Figure 36).

#### HIV Infection Deaths

HIV infection mortality disproportionately affects some racial and ethnic groups more than others. According to CDC data, the HIV death rate has consistently been higher for Hispanics than for non-Hispanic Whites.^40^ Higher mortality rates may result from a number of factors, including difficulty accessing timely and appropriate care.

Figure 37 HIV infection deaths per 100,000 population, 2017

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population Total, 1.6 Hispanic, 1.7 Non-Hispanic White, 0.7

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics

- In 2017, the rate of HIV infection deaths was higher for Hispanics (1.7 per 100,000 population) than for non-Hispanic Whites (0.7 per 100,000 population) (Figure 37).

### Changes in Quality of Care for Hispanics

Figure 38 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total for Hispanics and by priority area, from 2000 through 2014, 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percent change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing: The average annual percent change is ≤1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percent change is 1% or greater in the undesirable direction, and p <0.10.

Different data sources have different data years. For example, the most recent data year available for trending from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems (CMS HCAHPS) is 2018.

Stacked bar chart showing number of quality measures Total (n=131), Improving, 76, Not Changing, 49, Worsening, 6 Person-Centered Care (n=19), Improving, 7, Not Changing, 12, Worsening, 0 Patient Safety (n=9), Improving, 6, Not Changing, 3, Worsening, 0 Healthy Living (n=66), Improving, 47, Not Changing, 18, Worsening, 1 Effective Treatment (n=28), Improving, 15, Not Changing, 11, Worsening, 2 Care Coordination (n=4), Improving, 0, Not Changing, 1, Worsening, 3 Affordable Care (n=5), Improving, 1, Not Changing, 4, Worsening, 0

- Of the 131 quality measures with data for Hispanics, 58% were improving, 37% were not changing, and 5% were getting worse from 2000 through 2018 (Figure 38).^vi^
- Hispanics were improving for about two-thirds of Healthy Living and Patient Safety measures.
- No care coordination measures were improving and 3 of the 4 measures showed a worsening trend.

### Changes in Disparities for Hispanics

Figure 39 Number and percentage of all quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening over time, total and by priority area, from 2000 through 2014, 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: Different data sources have different data years. For example, the most recent data year available for trending from the National Institute of Diabetes and Digestive and Kidney Diseases United States Renal Data System (NIDDK USRDS) is 2014 and from the Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems (CMS HCAHPS) is 2018.

Stacked bar chart showing number of quality measures Total (n=53), Improving, 5, Not Changing, 48, Worsening, 0 Person-Centered Care (n=7), Improving, 0, Not Changing, 7, Worsening, 0 Patient Safety (n=3), Improving, 0, Not Changing, 3, Worsening, 0 Healthy Living (n=29), Improving, 4, Not Changing, 25, Worsening, 0 Effective Treatment (n=11), Improving, 1, Not Changing, 10, Worsening, 0 Care Coordination (n=0) Affordable Care (n=3), Improving, 0, Not Changing, 3, Worsening, 0

- Of the 53 quality measures with a disparity at baseline, disparities between Hispanics and non-Hispanic Whites did not change for 48 (91%) from 2000 through 2018 (Figure 39).
- Five measures showed narrowing disparities—one Effective Treatment measure and four Healthy Living measures.
- The measure that showed the most improvement is an Effective Treatment measure: Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population. The other improving measures are:
  ■ Children ages 2-17 who had a preventive dental service in the calendar year,
  ■ Children ages 2-17 who had a dental visit in the calendar year,
  ■ Adults with obesity who ever received advice from a health professional about eating fewer high-fat or high-cholesterol foods, and
  ■ Home health patients whose shortness of breath decreased.
- No measure showed widening disparities between Hispanics and non-Hispanic Whites.
- No Care Coordination measures with data for Hispanics were available.

#### End Stage Renal Disease

Diabetes is the leading cause of kidney disease in the United States. According to the National Institute of Diabetes and Digestive and Kidney Diseases, non-Hispanic Whites experience diabetes and kidney disease at a lower rate than other racial and ethnic groups.^42^

Figure 40 Adjusted incident rates of end stage renal disease due to diabetes per million population, 2001-2017

Note: For this measure, lower rates are better.

Line graph showing rate per million population 2001 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 2017 Hispanic 410.0 411.0 412.1 398.9 378.5 376.8 366.6 366.6 358.9 355.2 346.5 323.2 316.7 299.8 302.6 300.9 267.6 2001 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 2017 Non-Hispanic White 133.3 131.9 132.3 134.3 135.0 139.6 136.2 133.9 135.0 134.3 129.2 129.7 132.5 133.6 139.8 144.9 131.0

Source: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases, United States Renal Data System, 2001-2017.

- Data from 2001 to 2017 show that the disparity between Hispanics and non-Hispanic Whites was narrowing (Figure 40).
- Rates of ESRD due to diabetes decreased for Hispanics, from 410.0 per million population to 276.6 per million population.
- Disparities have been persistent, with Hispanics having higher incident rates of ESRD due to diabetes than Whites in all years.

#### Pediatric Dental Care

Access to oral health care is essential to promoting and maintaining overall health and well-being, yet only half of the population visits a dentist each year. Poor and minority children are less likely to have access to oral health care than are their nonpoor and nonminority peers.^43^

Figure 41 Children ages 2-17 who had a preventive dental service in the calendar year, 2002-2017

Line graph showing percentage 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 2017 Hispanic 24.8 27.3 29.6 28.9 30.5 33.1 34.6 32.7 34.9 35.8 36.9 41.8 39.7 42.7 42.5 43.2 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 2017 Non-Hispanic White 48.1 50.5 50.0 50.1 51.8 51.2 46.0 49.0 48.5 48.0 51.2 51.4 51.3 51.2 50.1 53.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- Data from 2002 to 2017 show that the disparity between Hispanics and non-Hispanic Whites was narrowing over time. Hispanics showed improvement (24.8% to 43.2%) but the percentage was still higher for Whites even though they had no statistically significant changes over time (48.1% to 53.2%) (Figure 41).
- Disparities have been persistent, with Hispanics less likely than non-Hispanic Whites to receive preventive dental services in all 16 years where data were available.

Figure 42 Children ages 2-17 who had a dental visit in the calendar year, 2002-2017

Line graph showing percentage 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 2017 Hispanic 33.8 36.7 38.3 38.4 38.6 42.1 42.8 41.9 42.3 43.9 45.5 49.0 48.1 50.1 50.7 51.7 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 2017 Non-Hispanic White 57.6 59.6 59.0 58.5 59.7 58.6 54.1 57.2 55.9 56.1 59.0 59.3 59.7 59.3 59.8 60.0

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- Data from 2002 to 2017 show that the disparity between Hispanics and non-Hispanic Whites was narrowing. Hispanics showed improvement (33.8% to 51.7%), but the percentage was still higher for Whites even though they had no statistically significant changes over time (57.6% to 60.0%) (Figure 42).
- Disparities have been persistent, with Hispanics less likely than non-Hispanic Whites to have a dental visit in all 16 years where data were available.

#### Obesity

The prevalence of obesity is continuing to rise in the United States. More than one-third of adults are overweight or affected by obesity.^44^

Figure 43 Adults with obesity who ever received advice from a health professional about eating fewer high-fat or high-cholesterol foods, 2002-2016

Line graph showing percentage 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Hispanic 38.8 44.5 41.3 40.6 45.6 48.2 53.3 56.5 53.6 51.2 50.2 52.2 51.2 55.0 52.1 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Non-Hispanic White 49.5 49.8 49.9 51.0 50.0 50.1 49.0 50.5 50.1 50.4 49.5 51.5 50.4 50.7 46.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- Data from 2002 to 2016 show that the disparity between Hispanics and non-Hispanic Whites was narrowing; however, Hispanics showed improvement (38.8% to 52.1%), while Whites showed declining performance (49.5% to 46.6%) (Figure 43).
- In 2016, Hispanics with obesity were more likely than non-Hispanics with obesity to receive advice from a health professional about eating fewer high-fat or high-cholesterol foods (52.1% vs. 46.5%).

The National Institutes of Diabetes and Digestive and Kidney Diseases has outlined several strategies for healthcare providers to use to speak with their patients in a respectful manner about healthy eating habits.^45^

#### Improved Breathing Among Home Health Care Patients

Shortness of breath is uncomfortable. Many patients with heart or lung problems experience difficulty breathing and may tire easily or be unable to perform daily activities. Doctors and home health staff should monitor shortness of breath and may give advice, therapy, medication, or oxygen to help lessen this symptom.

Figure 44 Home health care patients whose shortness of breath decreased, 2013-2017

Line graph showing percentage Hispanics Non-Hispanic Whites 2013 53.7 66.7 2014 54.6 67.1 2015 61.1 70.9 2016 65.7 74.6 2017 71.4 78.8

Source: Centers for Medicare & Medicaid Services, Home Health Quality Initiative, Chronic Condition Data Warehouse, Outcome and Assessment Information Set, 2013-2017.

- From 2013 to 2017, the disparity between Hispanics and non-Hispanic Whites was narrowing for home health care patients whose shortness of breath decreased.
- Both Hispanics (53.7% to 71.4%) and Non-Hispanic Whites (66.7% to 78.8%) showed improvement over time (Figure 44).

## Disparities by Income

The NHQDR tracks disparities data for income and insurance categories. Income groups are based on the Federal Poverty Level (FPL) for a family of four:

- Poor: Less than 100% of FPL.
- Low income: 100% to less than 200% of FPL.
- Middle income: 200% to less than 400% of FPL.
- High income: 400% or more of FPL

The poverty guidelines are issued annually in the Federal Register by the Department of Health and Human Services, Assistant Secretary for Planning and Evaluation. The guidelines vary by family size and there are different family income criteria for the contiguous 48 states, Alaska, and Hawaii. Criteria for U.S. territories are unavailable.^46^ For HCUP measures, income is based on median income of the patient’s ZIP Code and is divided into quartiles.

The relationship between income and healthcare outcomes has been studied for many years, and researchers have shown the positive relationship between more income and better health outcomes.^47,48,49,50^ Income is not the same as wealth, which can include assets other than income. Wealth is disproportionately dispersed among higher income categories, and research also shows a positive association between greater wealth and better health outcomes.^47^

This section shows quality measures with the largest income disparities and trends in disparities.

High-income groups performed better than other income groups on more than half of all quality measures.

Figure 45 Number and percentage of quality measures for which income groups experienced better, same, or worse quality of care compared with reference group (high income) for the most recent data year, 2016, 2017, or 2018

Key: n = number of measures.

Note: The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from the Agency for Healthcare Research and Quality Healthcare Cost and Utilization Project (AHRQ HCUP) is 2016 and from the Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey (CDC NHIS) is 2018.

Stacked bar chart showing number of quality measures Total (n=366), Better, 8, Same, 156, Worse, 202 Poor (n=122), Better, 4, Same, 46, Worse, 72 Low Income (n=122), Better, 2, Same, 46, Worse, 74 Middle Income (n=122), Better, 2, Same, 64, Worse, 56

- Data for the most recent year show that high-income groups performed better than other income groups on 55% of all quality measures (Figure 45).
- Performance was worse for poor and low-income groups compared with high-income groups on about 60% of the measures. Compared with high-income groups, middle-income groups performed worse on 46% of the measures.

### Largest Disparities

The measure with the largest income disparities is “People without a usual source of care who indicated a financial or insurance reason for not having a source of care.”

Measures with the largest disparities for each income group include:

- People without a usual source of care who indicated a financial or insurance reason for not having a source of care (all income groups).
- People under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income (low income, middle income).
- Children who had their height and weight measured by a health provider within the past 2 years (middle income).
- Children ages 19-35 months who received 3 or more doses of polio vaccine (low income).
- Emergency department encounters for asthma, children ages 2-17 (lowest income group).
- Hospital admissions for short-term complications of diabetes per 100,000 population, adults (lowest income group).

#### Difficulty Accessing a Usual Source of Care

People with lower incomes may experience difficulty accessing affordable care and are less likely to have a usual source of care that is readily accessible.^51^ People who are unwell and have low incomes are also more likely to experience poverty.^7^

Figure 46 People without a usual source of care who indicated a financial or insurance reason for not having a source of care, 2017

Note: For this measure, lower rates are better.

Columns showing percentage Total 12.7 Poor 20.3 Low Income 18.3 Middle Income 12.7 High Income 6.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, the measure with the largest income disparities was people without a usual source of care who indicated a financial or insurance reason for not having a source of care (Figure 46).
- In 2017, the percentage of people without a usual source of care who indicated a financial or insurance reason for not having a source of care was higher for poor, low-income, and middle-income people compared with high-income people (20.3%, 18.3%, and 12.7%, respectively, vs. 6.5%).

#### High Family Medical Expenditures

The most prominent barriers to health coverage include affordability, eligibility for public coverage in a person’s state, immigration status, and lack of familiarity with signup procedures.^52^ Poor health may require a family to spend more on healthcare, resulting in less income. Costs will vary based on each person or family’s needs and may inhibit a family’s ability to reach other goals.^7^

Figure 47 People under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income, 2017

Note: For this measure, lower rates are better.

Columns showing percentage Total 16.3 Poor 24 Low Income 22 Middle Income 20.8 High Income 8.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, the percentage of people under age 65 whose family’ health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income was higher for poor (24.0%), low-income (22.0%), and middle-income people (20.8%) than high-income people (8.5%) (Figure 47).

#### Height and Weight Check

Body mass index (BMI) is a person’s weight in kilograms divided by the square of height in meters. For children and teens, BMI is age and sex specific and is often referred to as BMI-for-age. In children, a high amount of body fat can lead to weight-related diseases and other health issues and being underweight can also put one at risk for health issues.^53^

Figure 48 Children who had their height and weight measured by a health provider within the past 2 years, 2017

Columns showing percentage Total 94.3 Poor 91.8 Low Income 92.9 Middle Income 94.1 High Income 96.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, the percentage of children who had their height and weight measured by a health provider within the past 2 years was lower for middle-income children (94.1%) than high-income children (96.9%) (Figure 48).

#### Childhood Vaccinations

Polio, or poliomyelitis, is a debilitating and potentially deadly disease. The polio virus spreads from person to person and can invade an infected person’s brain and spinal cord, causing paralysis. Polio can be prevented with a vaccine. Ninety nine percent of children who get all the recommended doses of polio vaccine will be protected from polio.^54^

Figure 49 Children ages 19-35 months who received 3 or more doses of polio vaccine, 2017

Columns showing percentage Total 92.7 Poor 91.7 Low Income 89.1 Middle Income 93.6 High Income 96.2

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases, National Immunization Survey - Child, 2017.

- In 2017, the percentage of children ages 19-35 months who received 3 or more doses of polio vaccine was lower for low-income children (89.1%) compared with high-income children (96.2%) (Figure 49).

#### Emergency Department Visits for Asthma

According to CDC, 1 in 12 or about 6 million children in the United States ages 0-17 years have asthma; about 16% of Black children and 7% of White children have asthma.^17^ Learning to control asthma with an asthma action plan can prevent asthma attacks or at least make them less severe.

More than half of children with asthma had one or more attacks in 2016. Every year, 1 in 6 children with asthma visits the emergency department, with about 1 in 20 children with asthma hospitalized for asthma.^55^

Figure 50 Emergency department encounters for asthma, children ages 2-17, 2017

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population Total 618.7 First Quartile (Lowest Income) 1034.1 Second Quartile 609 Third Quartile 467.2 Fourth Quartile (Highest Income) 334.6

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2017.

- In 2017, the rate of emergency department encounters for asthma was higher for children from the lowest income group (1,034 per 100,000 population) than for children from the highest income group (335 per 100,000 population) (Figure 50).

#### Hospital Admissions for Diabetes Complications

More than 100 million people living in the United States have diabetes or are at risk for diabetes.^56^ Compared with other countries, the rate of hospital admissions for short-term complications of diabetes is higher in the United States.^57^ Such complications may be related to kidney disease, hypertension, vision problems, pain, or other problems.

Figure 51 Hospital admissions for short-term complications of diabetes per 100,000 population, adults, 2017

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population Total 62.8 First Quartile (Lowest Income) 101 Second Quartile 67.5 Third Quartile 49.7 Fourth Quartile (Highest Income) 32.9

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2017.

- In 2017, the rate of hospital admissions for short-term complications of diabetes was three times as high for adults in the lowest income group (101.0 per 100,000 population) compared with adults in the highest income group (32.9 per 100,000 population) (Figure 51).

### Trends in Quality of Care for Income Groups

Poor people and low-income people had a higher percentage of improving measures and a lower percentage of worsening measures compared with high-income people.

Figure 52 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by income group, from 2000 through 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percentage change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing: The average annual percentage change is ≤1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percentage change is 1% or greater in the undesirable direction, and p <0.10.

Different data sources have different data years. For example, the most recent data year available for trending from the Medical Expenditure Panel Survey (AHRQ MEPS) is 2015 and from the Centers for Disease Control and Prevention National Health Interview Survey (CDC NHIS) is 2018.

Stacked bar chart showing number of quality measures Total (n=327), Improving, 170, Not Changing, 134, Worsening, 23 Poor (n=82), Improving, 48, Not Changing, 30, Worsening, 4 Low Income (n=82), Improving, 45, Not Changing, 33, Worsening, 4 Middle Income (n=82), Improving, 41, Not Changing, 34, Worsening, 7 High Income (n=81), Improving, 36, Not Changing, 37, Worsening, 8

- The percentage of measures that showed improvement was 59% for poor people, 55% for low-income people, 50% for middle-income people, and 44% for high-income people (Figure 52).

### Changes in Income Disparities

Most disparities by income showed no statistically significant changes over time.

Figure 53 Number and percentage of quality measures with disparity at baseline for which disparities related to income were improving, not changing, or worsening over time, 2000 through 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: Different data sources have different data years. For example, the most recent data year available for trending from the Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base (NCDB) is 2016 and from the Centers for Disease Control and Prevention, National Health Interview Survey (CDC NHIS) is 2018.

Stacked bar chart showing number of quality measures Total (n=161), Improving, 8, Not Changing, 148, Worsening, 5 Poor (n=55), Improving, 4, Not Changing, 49, Worsening, 2 Low Income (n=55), Improving, 3, Not Changing, 50, Worsening, 2 Middle Income (n=51), Improving, 1, Not Changing, 49, Worsening, 1

- Disparities by income were unchanged for about 90% of quality measures (Figure 53).
- Only 8 measures showed narrowing disparities and 5 measures showed widening disparities.
- Measures that showed improvements in disparities include:
  ■ Adults with limited English proficiency who had a usual source of care (poor, low income, middle income).
  ■ Adolescents ages 16-17 who received 1 or more doses of meningococcal conjugate vaccine (low income).
  ■ People unable to get or delayed in getting needed medical care due to financial or insurance reasons (poor).
  ■ People unable to get or delayed in getting needed dental care due to financial or insurance reasons (poor).
  ■ Children ages 2-17 who had a preventive dental service in the calendar year (low income).

According to the Migration Policy Institute, in 2015, an estimated 25.9 million individuals living in the United States reported having limited English proficiency.^58^ LEP patients are at a higher risk for adverse events than English-speaking patients. Language barriers significantly affect safe and effective healthcare.^59^ Income differences also can play a role for this population.

Figure 54 Adults with limited English proficiency who had a usual source of care, by income, 2014-2017

Line graph showing percentage Poor Low Income Middle Income High Income 57.9 57.2 56.2 71.5 59.4 61.8 62.4 66.9 64.6 62.9 60.4 66.3 65.2 64.1 66.3 70

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017.

- From 2014 to 2017, the percentage of poor adults with limited English proficiency who had a usual source of care increased from 57.9% to 65.2% (Figure 54).
- From 2014 to 2017, the percentage of low-income adults with limited English proficiency who had a usual source of care increased from 57.2% to 64.1%.
- Data from 2014 to 2017 show that disparities between high-income and poor people were narrowing over time.

#### Adolescent Vaccination

Meningococcal disease refers to any illness caused by bacteria called Neisseria meningitidis, also known as meningococcus. These illnesses are often severe and can be deadly. They include infections of the lining of the brain and spinal cord (meningitis) and bloodstream infections (bacteremia or septicemia).^60^

Vaccines can help prevent meningococcal disease, which is any type of illness caused by Neisseria meningitidis bacteria. Two types of meningococcal vaccines are available in the United States:

- Meningococcal conjugate or MenACWY vaccines, which help protect against four types of the bacteria that cause meningococcal disease (serogroups A, C, W, and Y).
- Serogroup B meningococcal or MenB vaccines, which help protect against serogroup B meningococcal disease.

All children ages 11 to 12 years old should get a meningococcal conjugate vaccine, with a booster dose at 16 years old.^61^

Figure 55 Adolescents ages 16-17 who received 1 or more doses of meningococcal conjugate vaccine, 2008-2017

Line graph showing percentage Poor Low Income Middle Income High Income 2008 33.9 31.9 36.3 46.8 2009 52 44.5 47.5 60 2010 60.2 52.6 54.7 66.2 2011 69.4 65.4 63.8 75.2 2012 72.6 71.2 71.7 79.9 2013 76.1 73.2 76 81.9 2014 79.4 75 77.4 83.7 2015 82.3 80.3 80.5 83.8 2016 83.8 80.7 80.2 85.6 2017 84 85.8 85.8 85.7

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases, National Immunization Survey-Teen, 2008-2017.

- In 2008, 31.9% of low-income adolescents ages 16-17 received 1 or more doses of meningococcal conjugate vaccine, and by 2017, the percentage had increased to 85.8% (Figure 55).
- From 2008 to 2017, the percentage of high-income adolescents who received 1 or more doses of meningococcal conjugate vaccine increased from 46.8% to 85.7%.
- Data from 2008 to 2017 show that disparities between high-income and poor adolescents were narrowing over time and both populations were improving.

#### Children Who Had a Preventive Dental Service

Preventive oral health care, early detection, and management of caries is critical to improving the oral health of children and adolescents but preventive oral health services are lagging among young children and children from lower socioeconomic backgrounds.^62^

Figure 56 Children ages 2-17 who had a preventive dental service in the calendar year, 2002-2017

Line graph showing percentage 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 2017 High Income 56.3 59.7 58.5 56.3 61.1 59.8 55.7 57.0 55.2 53.7 59.9 55.6 60.1 54.8 56.0 58.2 Middle Income 42.0 44.4 45.1 43.9 44.0 46.1 42.8 45.1 43.2 44.8 45.3 47.6 44.3 48.4 43.6 48.5 Low Income 27.6 28.3 30.7 32.4 33.6 31.1 31.9 33.0 38.3 36.1 37.5 43.2 37.9 42.5 40.9 38.2 Poor 24.7 25.5 28.4 28.5 30.3 30.3 28.3 31.2 32.3 32.2 32.6 37.1 37.2 35.5 37.4 34.1

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- In 2002, 27.6% of children in low-income households had preventive dental appointments and the percentage increased to 38.2% in 2017 (Figure 56).
- Data from 2002 to 2017 show that the disparities between high-income and low-income children were narrowing over time.

##### Resources

- Efforts are underway within HHS to improve children’s access to dental care, including the Health Resources and Services Administration (HRSA) initiative Integration of Oral Health and Primary Care Practice and school-based sealant programs. HRSA published a report on the initiative that summarized recommendations for improving preventive oral healthcare (https://www.hrsa.gov/sites/default/files/hrsa/oralhealth/integrationoforalhealth.pdf).
- As part of CDC’s State Actions to Improve Oral Health Outcomes, CDC funds states and territories to implement evidence-based preventive interventions (https://www.cdc.gov/oralhealth/state_programs/preventive-interventions/index.html) that include expanding sealant delivery in low-income and rural schools. School-based sealant programs increase sealant use and reduce caries. Programs target schools that serve children from low-income families and focus on sealing newly erupted permanent molars.

#### Financial Barriers to Medical Care

The most prominent barriers to health coverage include affordability, eligibility for public coverage in a person’s state, immigration status, and lack of familiarity with signup procedures.^52^ Uninsured patients may delay visiting a provider until their health concern becomes unbearable or skip preventive visits if they feel healthy.^63^

Figure 57 People unable to get or delayed in getting needed medical care due to financial or insurance reasons, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing percentage 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 2017 Poor 67.9 71.5 72.1 72.6 73.5 72.3 70.6 69.4 72.6 66.7 64.7 70.3 66.1 50.9 45.6 51.5 Low Income 63.6 64.8 70.7 70.2 68.8 63.5 69.1 70.6 74.4 71.1 66.9 62.7 64.2 60.2 54.8 50.2 Middle Income 52.6 52.1 55.3 56.7 57.1 53.3 56.5 62.6 59.9 61.5 59.6 55.7 52.8 53.1 42.6 44.1 High Income 32.7 35.4 31.0 30.8 30.4 32.2 37.3 39.3 43.4 32.5 44.9 43.8 38.8 33.5 32.3 27.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- In 2002, 67.9% of poor people were unable to get or delayed in getting needed medical care due to financial or insurance reasons (Figure 57). In 2017, the percentage had dropped to 51.5%.
- From 2002 to 2017, disparities narrowed between high-income and poor people who were unable to get or delayed in getting needed medical care due to financial or insurance reasons.

#### Financial Barriers to Dental Care

The most prominent barriers to health coverage include affordability, eligibility for public coverage in a person’s state, immigration status, and lack of familiarity with signup procedures.^52^ Research shows that lack of access to oral healthcare also worsens physical and mental health.^63^

Figure 58 People unable to get or delayed in getting needed dental care due to financial or insurance reasons, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing percentage 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 2017 High Income 48.5 48.7 45.3 55.5 59.0 63.7 52.2 58.5 67.2 60.1 72.0 59.3 59.6 61.6 56.2 56.0 Middle Income 75.1 73.8 77.9 75.4 75.6 81.8 80.1 81.5 82.6 80.6 79.0 80.2 78.0 75.1 73.1 75.9 Low Income 85.5 82.2 79.2 86.5 84.4 79.6 85.0 84.3 90.4 86.1 84.4 85.9 83.3 78.2 79.6 78.3 Poor 82.9 81.6 81.4 83.4 84.6 82.6 84.8 86.7 85.9 88.0 89.4 80.5 74.9 73.5 73.7 76.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- In 2002, 82.9% of poor people were unable to get or delayed in getting needed dental care due to financial or insurance reasons. The percentage decreased to 76.5% in 2017 (Figure 58).
- Data from 2002 to 2017 show that disparities between high-income and poor people were narrowing over time.

#### High Family Medical Expenditures

Figure 59 People under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income, 2002-2017

Line graph showing percentage Poor Low Income Middle Income High Income 2002 32.6 20.5 15.7 4.5 2003 34.8 23.1 17.4 5.4 2004 30.0 23.5 15.7 5.9 2005 30.7 21.5 18.3 7.3 2006 33.9 23.6 18.8 8.2 2007 29.7 23.6 18.7 6.7 2008 29.1 25.3 20.2 6.7 2009 29.2 25.1 19.1 7.3 2010 26.3 23.9 20.5 8.2 2011 26.6 25.3 19.2 7.6 2012 28.1 21.3 20.7 8.3 2013 24.3 21.3 20.2 9.8 2014 24.5 20.9 19.4 7.5 2015 22.7 22.6 20.4 9.2 2016 24.3 19.9 21 10.9 2017 24.0 22 20.8 8.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- In 2002, 32.6% of poor people under age 65 had family health insurance premiums and out-of-pocket medical expenditures that were more than 10% of total family income. The percentage decreased to 24.0% in 2017 (Figure 59).
- Data from 2002 to 2017 show that disparities between high-income and poor people were narrowing over time.

## Disparities by Insurance Status

This section examines trends and disparities among quality measures by insurance status. Insurance categories differ for ages 0-64 years and for adults age 65 years and over. Insurance categories for people ages 0-64 years are:

- Private Insurance: Person has access to insurance from a private insurer.
- Public Insurance: Person receives insurance from one or more government-sponsored sources, including Medicaid, State Children’s Health Insurance Program, state-sponsored or other government-sponsored health plans, Medicare, and military plans.
- Uninsured: Person does not have any health insurance.

Quality measures that examine health insurance status for adults age 65 and over include a distinction for access to Medicare:

- Private Insurance: Person has access to insurance from a private insurer and Medicare.
- Public Insurance: Person receives insurance from Medicare only. Person may also receive insurance from Medicare and other government-sponsored sources, including Medicaid, state-sponsored or other government-sponsored health plans, and military plans.

Adults 65 years or over usually have Medicare coverage at a minimum.^64^ In addition, the Indian Health Service (IHS) offers public coverage to and is considered a comprehensive healthcare delivery system for AI/ANs. Currently, IHS serves 2.6 million AI/ANs who belong to 573 federally recognized tribes in 37 states. IHS is not described as a health plan in this report. Non-IHS data sources, including CDC’s National Center for Health Statistics, also track disparities for AI/AN populations.

The bar chart below summarizes 137 quality measures, including 71 measures with data for people with public insurance and 66 measures with data for people who are uninsured. All measures compared these groups with adults with private insurance.

Quality for uninsured people was better than quality for those with private insurance on only 8% of measures.

Figure 60 Number and percentage of quality measures for which insurance groups experienced better, same, or worse quality of care compared with reference group (privately insured) for the most recent data year, 2016, 2017, or 2018

Key: n = number of measures.

Note: The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from the Agency for Healthcare Research and Quality Healthcare Cost and Utilization Project (AHRQ HCUP) is 2016 and from the Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey (CDC NHIS) is 2018.

Stacked bar chart showing number of quality measures Total (n=143), better, 14, same, 51, worse, 78 Public (n=74), better, 9, same, 30, worse, 35 Uninsured (n=69), better, 5, same, 21, worse, 43

- Data for the most recent year show that compared with people with private insurance, people with public insurance experienced better quality for 12% of measures and uninsured people experienced better quality for 7% of measures (Figure 60).
- Uninsured people had worse care for 62% of quality measures, and people with public insurance had worse care for 47% of quality measures.

### Largest Disparities for People With Public Insurance

The three quality measures with the largest disparities between people with public insurance and people with private insurance are:

- People without a usual source of care who indicated a financial or insurance reason for not having a source of care.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say.
- Sepsis diagnoses per 1,000 elective-surgery admissions of length 4 or more days, adults.

The three quality measures with the largest disparities between people who were unininsured and people with private insurance are:

- People without a usual source of care who indicated a financial or insurance reason for not having a source of care.
- Children who had their height and weight measured by a health provider within the past 2 years.
- Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high.

#### Difficulty Getting a Usual Source of Care

Figure 61 People without a usual source of care who indicated a financial or insurance reason for not having a source of care, 2017

Note: For this measure, lower rates are better.

Columns showing percentage Total, 12.7 Private, 6.0 Public, 13.4 Uninsured, 36.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, the percentage of people without a usual source of care who indicated a financial or insurance reason for not having a source of care was more than twice as high for adults with public insurance (13.4%) compared with adults with private insurance (6.0%) (Figure 61).
- In 2017, the percentage of people without a usual source of care who indicated a financial or insurance reason for not having a source of care was more than six times as high for uninsured adults (36.8%) compared with adults with private insurance (6.0%).

#### Providers Who Showed Respect for What Patients Had To Say

Figure 62 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say, 2017

Note: For this measure, lower rates are better.

Columns showing percentage Total, 6.9 Private, 6.4 Public, 12.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say was nearly twice as high for people with public insurance (12.2%) compared with people with private insurance (6.4%) (Figure 62).

#### Sepsis

Sepsis is a potentially life-threatening bloodstream infection that can be acquired in various settings. Sepsis can occur after surgery, and one study showed that postoperative sepsis occurred in 5% of emergency surgery patients and 2% of elective-surgery patients.^65^ One way to reduce the risk of sepsis is to give patients appropriate prophylactic antibiotics, starting 1 hour prior to surgical incision.

Figure 63 Sepsis diagnoses per 1,000 elective-surgery admissions of length 4 or more days, 2017

Note: For this measure, lower rates are better.

Columns showing rate per 1,000 admissions Total 3.8 Private 2.4 Public 4.6

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), State Inpatient Databases, 2017, weighted to provide national estimates; and the AHRQ Quality Indicators, version 2019.01 for the 2017 data. For more information, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp), 2017.

- In 2017, the rate of adults diagnosed with sepsis per 1,000 elective-surgery admissions of length 4 or more days was nearly twice as high for people with public insurance (4.6%) compared with people with private insurance (2.4%) (Figure 63).

##### Resources

- The CDC’s Hospital Toolkit for Adult Sepsis Surveillance allows healthcare professionals who are interested in using the sepsis surveillance methodology from the national burden study to track healthcare facility-level sepsis incidence and outcomes using an objective definition based on clinical data. Necessary data may be obtained and processed directly from electronic health records but could also be obtained using manual chart review. These data may be useful for understanding the effectiveness of local sepsis prevention, early recognition, and treatment programs.

### Largest Disparities for Uninsured People

#### Measurement of Children’s Height and Weight

Regularly checking a child’s height and weight helps assess growth and development and can alert healthcare providers and families to potential concerns. Having health insurance facilitates access to providers for recommended well-child visits.

Figure 64 Children who had their height and weight measured by a health provider within the past 2 years, 2017

Columns showing percentage Total 94.3 Private 95.6 Uninsured 79.7

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, children who were privately insured (95.6%) were more likely than uninsured children (79.7%) to have their height and weight measured by a health provider within the past 2 years) (Figure 64).

#### Blood Pressure Management

Hypertension, also called high blood pressure (https://www.nhlbi.nih.gov/health-topics/high-blood-pressure), affects about one in three U.S. adults. Over time, it can damage the heart, blood vessels, kidneys, and other parts of the body. Complications can include heart attacks, heart failure, stroke, and chronic kidney disease. High blood pressure is managed with lifestyle changes, including eating healthy foods, being physically active, maintaining a healthy weight, limiting alcohol intake, and managing and coping with stress.^66^

Figure 65 Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high, 2017

Columns showing percentage Total 92.8 Private 94.3 Uninsured 78.4

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2017.

- In 2017, privately insured adults ages 18-64 (94.3%) were more likely than uninsured adults (78.4%) to receive a blood pressure measurement in the last 2 years and be able to state whether their blood pressure was normal or high) (Figure 65).

### Changes in Quality of Care by Insurance Status

About half of quality measures for those with private and public insurance were improving over time but only a third of quality measures for uninsured people showed improvement.

Figure 66 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by insurance status, from 2000 through 2016, 2017, or 2018

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percentage change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing: The average annual percentage change is ≤1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percentage change is 1% or greater in the undesirable direction, and p <0.10.

Different data sources have different data years. For example, the most recent data year available for trending from the Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base (NCDB) is 2016 and from the Centers for Disease Control and Prevention, National Health Interview Survey (CDC NHIS) is 2018.

Stacked bar chart showing number of quality measures Total (n=155), Improving, 69, Not Changing, 76, Worsening, 10 Private (n=52), Improving, 25, Not Changing, 22, Worsening, 5 Public (n=52), Improving, 27, Not Changing, 23, Worsening, 2 Uninsured (n=51), Improving, 17, Not Changing, 31, Worsening, 3

- From 2000 through 2018, across 155 measures of healthcare quality with data by insurance status, a higher percentage of measures was improving for people with public insurance (52%) and people with private insurance (48%) compared with uninsured people (33%) (Figure 66).
- The percentage of worsening measures was lower for people with public insurance (4%) compared with uninsured people (6%) and people with private insurance (10%).

### Changes in Disparities by Insurance

Figure 67 Number and percentage of quality measures with disparity at baseline for which disparities related to insurance were improving, not changing, or worsening over time, 2000 through 2014, 2015, 2016, 2017, or 2018

Key: n = number of measures.

Note: Different data sources have different data years. For example, the most recent data year available for trending from the Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base (NCDB) is 2016 and from the Centers for Disease Control and Prevention, National Health Interview Survey (CDC NHIS) is 2018.

Stacked bar chart showing number of quality measures Total (n=59), Improving, 2, Not Changing, 56, Worsening, 1 Public (n=23), Improving, 0, Not Changing, 23, Worsening, 0 Uninsured (n=36), Improving, 2, Not Changing, 33, Worsening, 1

- Disparities by insurance status were not changing for most quality measures (Figure 67).
- Two measure showed improvement over time in disparities between uninsured people and people with private insurance:
  ■ Adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year.
  ■ Adults with limited English proficiency who had a usual source of care.
- One measure showed a widening disparity between uninsured people and people with private insurance: People without a usual source of care who indicated a financial or insurance reason for not having a source of care.

#### Receipt of Flu Vaccine by Patients With Diabetes

Some patients are at higher risk of contracting the flu. These include children, older adults, and people with diabetes. The flu also has a greater likelihood of exacerbating diabetes in affected patients.^67^

Figure 68 Adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year, 2008-2017

Note: Data for uninsured did not meet criteria for statistical reliability in 2017.

Line graph showing percentage, indicating an increase over time for uninsured adults. Adults with private insurance showed no statistically significant changes: uninsured, 2008, 36.7, 2016, 49.7; public insurance, 2008, 52.5, 2017, 55.7; private insurance, 2008, 60.6, 2017, 62.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2008-2017.

- From 2008 to 2016, the disparity between adults with private insurance and uninsured adults narrowed in the percentage of adults age 40 and over with diabetes who received a flu vaccine. This percentage increased from 36.7% in 2008 to 49.7% in 2016 for uninsured adults. There were no statistically significant changes over time for people with private insurance in the percentage with diabetes who got a flu vaccine (Figure 68).

##### Resources

- What You Need To Know About Diabetes and Adult Vaccines: a CDC information series for adults that provides information on the importance of vaccines for people with diabetes.^68^
- Everyone with Diabetes Counts (EDC): a diabetes self-management education program launched by the Centers for Medicare & Medicaid Services (CMS) that offers evidence-based diabetes self-management training. The program is designed to improve health outcomes and quality of life among disparate and underserved Medicare populations.
- Medicare’s Diabetes Prevention Program: a proven health behavior change program to help prevent type 2 diabetes. The program begins with 16 core sessions offered in a group setting over a 6-month period. These sessions include:
  ■ Training to make realistic, lasting behavior changes.
  ■ Tips on how to get more exercise.
  ■ Strategies for controlling one’s weight.
  ■ A behavior coach, specially trained to help keep people motivated.
  ■ Support from people with similar goals.

#### Patients With Limited English Proficiency and Usual Source of Care

Figure 69 Adults with limited English proficiency who had a usual source of care, 2014-2017

Line graph showing percentage Private Public Uninsured 2014 67.1 69.4 33.2 2015 67.7 70.6 38.6 2016 66.7 70.4 39.7 2017 68 76.1 39.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017.

- In 2014, 33.2% of uninsured adults with limited English proficiency had a usual source of care. The percentage increased to 39.2% in 2017 (Figure 69).
- Data from 2014 to 2017 show that the disparities between privately insured and uninsured people were narrowing over time.

#### Financial or Insurance Barriers to Care

As noted earlier, people with lower incomes may have difficulty accessing a usual source of care. They may face high copays or have problems getting insurance.

Figure 70 People without a usual source of care who indicated a financial or insurance reason for not having a source of care, 2002-2017

Line graph showing percentage, indicating an increase over time for uninsured adults. Adults with private insurance showed no statistically significant changes: uninsured, 2008, 28.0, 2017, 36.8; public insurance, 2008, 18.5, 2017, 13.4; private insurance, 2008, 8.9, 2017, 6.0

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, the disparity between adults with private insurance and uninsured adults widened in the percentage of people without a usual source of care who indicated a financial or insurance reason for not having a source of care. The estimate for uninsured people without a usual source of care increased from 28% in 2002 to 36.8% in 2017, and there were no statistically significant changes for people with private insurance (Figure 70).

## Disparities by Residence Location

Where people live affects their access to healthcare and the quality of their healthcare. Current research shows that disparities by residence location affect both adults and children.^69,70,71,72,73,74^

### Residence Location Groups

This report uses the 2013 National Center for Health Statistics (NCHS) classification for analyzing healthcare quality and disparities by residence location, replacing the previously used 2006 classification scheme.

The 2013 scheme includes six urbanization categories, including:

- Four metropolitan county designations:
  ■ Large Central Metropolitan: Large central metropolitan counties in a metropolitan statistical area (MSA) of 1 million or more population:
    1. That contain the entire population of the largest principal city of the MSA, or
    2. Whose entire population is contained within the largest principal city of the MSA, or
    3. That contain at least 250,000 residents of any principal city in the MSA.
  ■ Large Fringe Metropolitan: Counties in MSAs of 1 million or more population that do not qualify as large central.^vii^ Large Fringe Metropolitan areas are also described as suburban areas. This category is the reference group that all other residence locations are compared with in this report.
  ■ Medium Metropolitan: Counties in MSAs of 250,000 to 999,999 population.
  ■ Small Metropolitan: Counties in MSAs of less than 250,000 population.
- Two nonmetropolitan county designations:
  ■ Micropolitan: Counties in a micropolitan statistical area.
  ■ Noncore: Nonmetropolitan counties that are not in a micropolitan statistical area.

The key differences between the 2006 and the 2013 NCHS Urban-Rural Classification schemes are noted in the description of small metropolitan, micropolitan, and noncore areas. The 2013 classification broadens the inclusion criteria for each residence location. All other definitions are unchanged (Table 1).^75^

Table 1 NCHS Urban-Rural Classification Scheme, 2006 vs. 2013

Areas | 2006 Classification | 2013 Classification
Small Metropolitan | Counties in MSAs of 50,000 to 249,999 population | Counties in MSAs of less than 250,000 population.
Micropolitan | Urban cluster population of 10,000-49,999 individuals. | Counties in a micropolitan statistical area.
Noncore | Nonmetropolitan counties that did not qualify as micropolitan. | Nonmetropolitan counties that are not in a micropolitan statistical area.

Figure 71 shows a map of U.S. county classifications according to the 2013 NCHS Urban-Rural Classification system. Counties across the United States are listed below the map to show examples of the corresponding areas.

Figure 71 Map showing 2013 NCHS Urban-Rural County Classifications in the United States

Map of United States showing county groupings, which are described in the text after the map

- Metropolitan Areas:
  ■ Large Central Metropolitan Areas: Denver County, Colorado; Washington, DC; Cook County, Illinois.
  ■ Large Fringe Metropolitan Areas: San Bernardino County, California; Broward County, Florida; Bergen County, New Jersey.
  ■ Medium Metropolitan Areas: Scott County, Kentucky; York County, Maine; Douglas County, Nebraska.
  ■ Small Metropolitan Areas: Baldwin County, Alabama; Wayne County, North Carolina; Allen County, Ohio.
- Nonmetropolitan Areas:
  ■ Micropolitan Areas: Woodward County, Oklahoma; Cherokee County, South Carolina; Harrison County, West Virginia.
  ■ Noncore Areas: Wallowa County, Oregon; Bedford County, Pennsylvania; Crane County, Texas.

The NHQDR uses the NCHS classification to analyze performance of quality measures that have data available by residence location. In addition to the annual report, data on state-based performance metrics are available through the NHQDR State Snapshots (https://nhqrnet.ahrq.gov/inhqrdr/state/select).^76^

With the State Snapshots tool, users can explore the quality of their state’s healthcare and compare their state’s data with national data or data from the best performing states. Users can access a state dashboard showing performance compared with benchmarks for more than 80 measures. Some of these measures are also stratified by subpopulations to show disparities.

### Overview of Disparities by Residence Location

Nonmetropolitan areas had worse performance on one-third of all quality measures compared with suburban areas in the latest data year.

Figure 72 Number and percentage of quality measures for which members of selected groups experienced better, same, or worse quality of care compared with reference group (large fringe metropolitan) for the most recent data year, 2016, 2017, or 2018, by residence location

Key: n = number of measures.

Note: The difference between two groups is meaningful only if the absolute difference between the two groups is statistically significant with a p-value <0.05 on a two-tailed test and the relative difference between the two groups is at least 10%. Definitions of residence locations are available at https://www.cdc.gov/nchs/data_access/urban_rural.htm. The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from the Agency for Healthcare Research and Quality Medical Expenditure Panel Survey (MEPS) is 2016 and from the Centers for Disease Control and Prevention, National Health Interview Survey (CDC NHIS) is 2018.

Stacked bar chart showing number of quality measures Total Measures (n=492), Better, 29, Same, 343, Worse, 120 Large Central Metro (n=102), Better, 9, Same, 69, Worse, 24 Medium Metro (n=100), Better, 6, Same, 78, Worse, 16 Small Metro (n=99), Better, 5, Same, 77, Worse, 17 Micropolitan (n=98), Better, 4, Same, 62, Worse, 32 Noncore (n=93), Better, 5, Same, 57, Worse, 31

- Large Central Metropolitan areas (9%) had the highest percentage of quality measures for which performance was better than in large fringe metropolitan areas (Figure 72).
- Nonmetropolitan areas had the highest percentage of measures for which performance was worse than in large fringe metropolitan areas: Noncore, 33%; Micropolitan, 33%; Large Central Metropolitan, 24%; Small Metropolitan, 17%; and Medium Metropolitan, 16%.

### Largest Disparities

Measures with the largest disparities for residence location can be grouped into five categories:

- Largest disparities among measures of care coordination in hospital setting include:
  ■ Emergency department encounters for asthma, children ages 2-17 (large central metropolitan).
  ■ Hospital admissions for asthma per 100,000 population, children ages 2-17 (large central metropolitan).
  ■ Emergency department visits with a principal diagnosis related to dental conditions (micropolitan).
  ■ Hospital admissions for community-acquired pneumonia per 100,000 population, adults age 18 and over (noncore).
- Largest disparities among measures of effective treatment (no specific setting of care) is for:
  ■ HIV infection deaths per 100,000 population (large central metropolitan).
- Largest disparities among measures of healthy living in ambulatory setting include:
  ■ Children ages 0-17 with a wellness checkup in the past 12 months (medium metropolitan).
  ■ Adults who received a blood cholesterol measurement in the last 5 years (small metropolitan, micropolitan).
- Largest disparities among measures of patient safety in hospital setting include:
  ■ Deaths per 1,000 hospital admissions with expected low mortality, adults (medium metropolitan, noncore).
  ■ Reclosure of postoperative abdominal wound dehiscence per 1,000 abdominopelvic-surgery admissions of length 2 or more days, adults (medium metropolitan, noncore).
- Largest disparities among measures of person-centered care in ambulatory setting include:
  ■ Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say (small metropolitan, micropolitan).
  ■ Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never listened carefully to them (small metropolitan).

#### Care Coordination: Emergency Department Visits for Asthma

Asthma is one of the most common chronic pediatric diseases, and acute asthma exacerbation is a leading cause of emergency department (ED) visits for children.^77^ Given the severity of asthma, timely treatment is crucial. Current research shows that ED overcrowding, acuity, and age affect treatment time for children visiting the ED.^78,79^

Figure 73 Emergency department encounters for asthma, children ages 2-17, 2017

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population Total 619 Large Central Metro 830 Large Fringe Metro 476

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2017.

- In 2017, the rate of children ages 2-17 with ED visits for asthma was almost twice as high in large central metro areas (830 per 100,000 population) as it was in large fringe metro areas (476 per 100,000 population) (Figure 73).

#### Care Coordination: Hospital Admissions for Asthma

Asthma is the most common chronic lung condition among children under 17 years in the United States.^80^ Asthma has no cure and without treatment, patients can die. CDC research shows that from 2001 to 2016, 8% fewer children experienced one or more asthma attacks. Nonetheless, in 2017, about 1 in 12 children ages 0-17 had asthma and among them, asthma disproportionately affected males, non-Hispanic Black children, and children from low-income households.^81^

Figure 74 Hospital admissions for asthma per 100,000 population, children ages 2-17, 2017

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population Total 81.8 Large Central Metro 124.3 Large Fringe Metro 70.4

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), State Inpatient Databases, 2017, weighted to provide national estimates; and the AHRQ Quality Indicators, version 2019.01 for the 2017 data. For more information, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

- In 2017, the rate of hospital admissions for children ages 2-17 with asthma was almost twice as high in large central metro areas (124.3 per 100,000 population) as in large fringe metro areas (70.4 per 100,000 population) (Figure 74).

#### Care Coordination: Emergency Department Visits for Dental Conditions

More people across the United States are using the ED for dental complaints.^82^ In 2016, the rate of ED visits for dental complaints was 45.8 visits per 100 people.^83^ Research shows that many of these visits could be prevented through appropriate preventive care.

Figure 75 Emergency department visits with a principal diagnosis related to dental conditions, 2017

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population Total 307.1 Micropolitan 491.7 Large Fringe Metro 207.1

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2017.

- In 2017, the rate of ED visits related to dental conditions in micropolitan areas (491.7 per 100,000 population) was more than twice the rate in large fringe metro areas (207.1 per 100,000 population) (Figure 75).

#### Care Coordination: Hospital Admissions for Pneumonia

Pneumonia is a devastating and life-threatening condition that can strike anyone, but older adults have increased susceptibility for community-acquired pneumonia (CAP).^84,85^ The costs associated with CAP can be mitigated by preventive efforts, including vaccinations. CDC recommends pneumococcal vaccination for all adults 65 years and over, as well as adults ages 19-64 years who have certain medical conditions (e.g., HIV, leukemia) or who smoke.^86^

Figure 76 Hospital admissions for community-acquired pneumonia per 100,000 population, adults age 18 and over, 2017

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population Total 171 Noncore 376.5 Large Fringe Metro 166.6

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2017.

- In 2017, the rate of hospital admissions for CAP was more than twice as high in noncore areas (376.5 per 100,000 population) compared with large fringe metro areas (166.6 per 100,000 population) (Figure 76).

#### Effective Treatment: HIV Infection Deaths

New HIV diagnoses are concentrated primarily in large U.S. metropolitan areas (80% in 2017), with Miami, Orlando, and Atlanta topping the list of the areas most heavily burdened.^87^

Figure 77 HIV infection deaths per 100,000 population, 2017

Note: For this measure, lower rates are better. HIV diagnosis data are estimates from 50 states, the District of Columbia, and 6 U.S. dependent areas. Estimates for 2017 are preliminary and are not included in trend calculations.

Column showing rate per 100,000 population 2015 achievable benchmark: 0.75 per 100,000 population Total 1.6 Large Central Metro 2.5 Large Fringe Metro 1.1

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics Survey - Mortality, 2017.

- In 2017, the death rate from HIV infections was higher in large central metro areas (2.5 per 100,000 population) compared with the rate in large fringe metro areas (1.1 per 100,000 population) (Figure 77).
- The 2015 achievable benchmark was 0.75 per 100,000 population. At the current rate of decrease, overall, the benchmark could be achieved in 4 years for large central metro and in 2 years for large fringe metro areas.
- The top 10% of states and territories that reached the benchmark are Kansas, Kentucky, Minnesota, Missouri, Ohio, and Washington (more than 5 states reached the benchmark due to ties).

An HHS initiative to eliminate new HIV infections is underway. The goal is “to reduce new HIV infections in the United States by 75 percent in five years and by 90 percent by 2030.”^88^ For the first 5 years, this initiative (https://www.hiv.gov/federal-response/ending-the-hiv-epidemic/overview) will focus on 57 priority jurisdictions where more than 50% of new HIV diagnoses occurred in 2016 and 2017 and 7 states with a disproportionate occurrence of HIV in rural areas.

Federal efforts to reduce HIV-related mortality include the promotion of treatment therapies such as antiretroviral therapy, as well as pre-exposure prophylaxis and postexposure prophylaxis.^89^ Several HHS agencies provide a federal response to the HIV epidemic, including HRSA’s HIV/AIDS Bureau, which administers the Ryan White HIV/AIDS Program (RWHAP). RWHAP is the largest federal program focused on providing HIV care and treatment to patients with inadequate or no insurance. Through RWHAP’s partnerships, more than 512,000 people receive care annually.

#### Healthy Living Measure: Wellness Visits

Wellness visits for children offer preventive care, allow tracking of growth and development, identify concerns, and establish a team-based model of care for the provider, the child, and his or her parents or caregivers. The American Academy of Pediatrics has provided an online schedule for wellness visits.^90^

Figure 78 Children ages 0-17 with a wellness checkup in the past 12 months, 2018

Columns showing percentage Total, 86.5 Medium Metro, 84.9 Large Fringe Metro, 89.8

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2018.

- In 2018, the percentage of children ages 0-17 who had a wellness checkup in the past year was lower in medium metro (84.9%) than in large fringe metro areas (89.8%) (Figure 78).

#### Healthy Living Measure: Cholesterol Check

Optimal cholesterol management is an important part of reducing atherosclerotic cardiovascular disease. Evidence-based treatments are readily available. Treatment protocols and decision aids can assist clinical teams and their patients in making informed decisions that can lead to fewer heart attacks and strokes.

Figure 79 Adults who received a blood cholesterol measurement in the last 5 years, 2017

Columns showing percentage Total 88 Small Metro 83.9 Micropolitan 81.3 Large Fringe Metro 89

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2017.

- In 2017, the percentage of adults who received a blood cholesterol measurement in the last 5 years was lower in small metropolitan (83.9%) and micropolitan areas (81.3%) than in large fringe metro areas (89.0%) Figure 79).

#### Patient Safety Measure: Unexpected Deaths After Hospital Admission

Death within 30 days of a hospital discharge may indicate that patients did not receive appropriate care during their hospital admission.^91^ Factors contributing to death include noncontinuous care or treatment and inadequate communication with the care team.^92^

Figure 80 Deaths per 1,000 hospital admissions with expected low mortality, 2017

Note: For this measure, lower rates are better.

Columns showing deaths per 1,000 hospital admissions Total 0.2 Medium Metro 0.24 Noncore 0.32 Large Fringe Metro 0.17

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2017.

- In 2017, the death rate for conditions with expected low mortality was higher in medium metropolitan (0.24 per 1,000 admission) and noncore areas (0.32 per 1,000 admission) than in large fringe metro areas (0.17 per 1,000 admission) (Figure 80).

#### Patient Safety Measure: Surgical Complications

Wound dehiscence is when an incision breaks open and does not heal properly after surgery, often within 10 days.^93^ This postoperative complication can result in increased morbidity and mortality for patients who have had abdominopelvic surgeries.^94^

Figure 81 Reclosure of postoperative abdominal wound dehiscence per 1,000 abdominopelvic surgery admissions of length 2 or more days, adults, 2017

Note: For this measure, lower rates are better.

Columns showing rate per 1,000 surgery admissions Total, 0.67 Medium Metro, 0.77 Noncore, 0.99 Large Fringe Metro, 0.53

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2017.

- In 2017, the rate of adults who had a wound reclosed after abdominopelvic surgery was worse in noncore areas (0.99 per 1,000 surgery admissions) and medium metro areas (0.77 per 1,000 surgery admissions) compared with large fringe metro areas (0.53 per 1,000 surgery admissions) (Figure 81).

#### Person-Centered Measure: Treatment by Healthcare Providers

Overall, effective communication leads to increased patient and clinician satisfaction, increased trust with the clinician, and functional and psychological well-being. Effective communication also leads to improved outcomes in specific diseases, including:

- A small but significant absolute risk reduction of mortality from coronary artery disease,
- Improved control of diabetes and hyperlipidemia,
- Better adherence to antihypertensives,
- Bereavement adjustment in caregivers of cancer patients, and
- Higher self-efficacy of adherence to HIV medications.^95^

Figure 82 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say, 2017

Note: For this measure, lower rates are better.

Columns showing percentage Total 6.9 Small Metro 9.1 Micropolitan 8.9 Large Fringe Metro 5.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey. 2017.

- In 2017, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say was higher in small metro areas (9.1%) and micropolitan areas (8.9%) compared with large fringe metro areas (5.3%) (Figure 82).

Figure 83 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never listened carefully to them, 2017

Note: For this measure, lower rates are better.

Columns showing percentage Total, 8.2 Small Metro, 10.4 Large Fringe Metro, 6.4

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never listened carefully to them was higher in small metro areas (10.4%) compared with large fringe metro areas (6.4%) (Figure 83).

### Changes in Quality of Care by Residence Location

Nearly half of quality measures for micropolitan areas showed improvement over time but only a third of noncore measures showed improvement.

Figure 84 Number and percentage of all quality measures that were improving, not changing, or worsening over time, total and by residence location, from 2002 through 2016, 2017, or 2018

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percent change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving: The average annual percentage change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing: The average annual percentage change is ≤1% in either the desirable or undesirable direction or p >0.10.
- Worsening: The average annual percentage change is 1% or greater in the undesirable direction, and p <0.10.

Different data sources have different data years. For example, the most recent data year available for trending from the Medical Expenditure Panel Survey (AHRQ MEPS) is 2016 and from the Centers for Disease Control and Prevention, National Health Interview Survey (CDC NHIS) is 2018.

Stacked bar chart showing number of quality measures Total (n=343), Improving, 145, Not Changing, 165, Worsening, 33 Large Central Metro (n=58), Improving, 24, Not Changing, 31, Worsening, 3 Large Fringe Metro (n=58), Improving, 26, Not Changing, 25, Worsening, 7 Medium Metro (n=58), Improving, 24, Not Changing, 28, Worsening, 6 Small Metro (n=58), Improving, 25, Not Changing, 27, Worsening, 6 Micropolitan (n=57), Improving, 28, Not Changing, 25, Worsening, 4 Noncore (n=54), Improving, 18, Not Changing, 29, Worsening, 7

- Across 58 quality measures, 12% showed worsening for large fringe metro, and 10% showed worsening for medium metro and small metro. Approximately 40% were improving for large central metro, large fringe metro, medium metro, and small metro (Figure 84).
- Micropolitan areas showed the most improvement, with 49% of measures improving.
- Noncore areas had fewer improving measures (33%) and more measures worsening (13%) compared with other areas.

### Changes in Disparities by Residence Location

Nonmetropolitan areas showed no improvement in disparities during the most recent data year.

Figure 85 Number and percentage of quality measures with disparity at baseline for which disparities related to residence location were improving or not changing over time, 2002 through

Key: n = number of measures.

Stacked bar chart showing number of quality measures Reference group is large fringe metro--no disparities were worsening (widening) Total (n=73), Improving, 4, Not Changing, 69 Large Central Metro (n=19), Improving, 1, Not Changing, 18 Medium Metro (n=9), Improving, 1, Not Changing, 9 Small Metro (n=10), Improving, 2, Not Changing, 8 Micropolitan (n=16), Improving, 0, Not Changing, 16 Noncore (n=18), Improving, 0, Not Changing, 18

- Disparities by residence location remained unchanged for most quality measures (Figure 85).
- Four measures showed improvement in disparities:
  ■ One Effective Treatment: Hospital inpatient stays involving opioid-related diagnoses (large central metro)
  ■ Two Affordable Care:
    ♦ People unable to get or delayed in getting needed medical care due to financial or insurance reasons (medium metro, small metro)
    ♦ People unable to get or delayed in getting needed prescription medicines due to financial or insurance reasons (small metro)^viii^

#### Inpatient Stays Due to Opioid Use

Increased availability and overuse of opioid medications (both prescription and nonprescription drugs) have contributed to adverse outcomes for patients, including increased risk of opioid use disorder, misuse of medications, and potential overdoses. The rapid and ongoing rise in both numbers of hospitalizations and their costs suggests that the burden of prescription opioid overdoses may threaten the infrastructure and finances of U.S. hospitals.^96^

Figure 86 Hospital inpatient stays involving opioid-related diagnoses per 100,000 population, 2005-2017

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population 2015 achievable benchmark: 102.9 per 100,000 population 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 2017 Large Central Metro 195.8 257.8 206.4 192.0 239.0 244.7 266.0 250.2 243.9 250.5 276.9 311.2 314.6 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 2017 Large Fringe Metro 111.5 142.8 132.4 157.5 143.5 170.5 202.8 202.0 206.1 213.6 239.2 284.8 288.4

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2005-2017.

- From 2005 to 2017, the gap between people in large fringe metro areas and those in large central metro areas in opioid-related hospital stays narrowed. However, a disparity remained and the rates for both populations were worsening.
- In 2005, the rate was 111.5 per 100,000 population in large fringe metro areas vs. 195.8 per 100,000 population in large central metro areas. In 2017, both rates had risen, to 288.4 in large fringe metro areas and 314.6 in large central metro areas (Figure 86).
- The 2015 achievable benchmark was 103 per 100,000 population. Neither the large central metropolitan population nor the large fringe metro population has made progress toward the benchmark.
- The top 10% of states and territories that reached the benchmark are Georgia, Iowa, Nebraska, Texas, and Wyoming. In 2016, Georgia, Iowa, Nebraska, South Carolina, South Dakota, Texas, and Wyoming reached the benchmark.

##### Resources

- In 2017, HHS launched a departmentwide initiative with a five-point strategy to combat the opioid epidemic. Many agencies supported this initiative by establishing specific research opportunities, resources, and data to support providers, patients, and researchers. More information is available at https://www.hhs.gov/opioids/.
- The U.S Department of Justice, Office of Justice Programs’ Comprehensive Opioid Abuse Program (COAP), provides funding supports to more than 200 state, local, and tribal grantees and provides training and technical assistance. Through grantees in 47 states, COAP provides innovative, systemwide approaches to identify, address, treat, and support people affected by the opioid epidemic.

#### Delays in Needed Care

Figure 87 People unable to get or delayed in getting needed medical care due to financial or insurance reasons, 2002-2017

Note: For this measure, lower rates are better.

Line graph shows that from 2002 to 2017, the gap narrowed between people in large fringe metro areas and those in small and medium metro areas who were unable to get or delayed in getting needed medical care due to financial or insurance reasons; between 2002 and 2017, for residents of small metro areas, the percentage delayingcare decreased from 61% to 35.6%. Among residents of medium metro areas, the percentage decreased from 55.2% to 40.3%.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, the gap narrowed between people in large fringe metro areas and those in small and medium metro areas who were unable to get or delayed in getting needed medical care due to financial or insurance reasons.
- Between 2002 and 2017, for residents of small metro areas, the percentage delaying care decreased from 61% to 35.6%. Among residents of medium metro areas, the percentage decreased from 55.2% to 40.3% (Figure 87).

##### Resources

- Healthy Rural Hometown Initiative: a 5-year multiprogram effort to identify strategies to address the underlying factors that drive growing rural disparities related to heart disease, cancer, unintentional injury, chronic lower respiratory disease, and stroke. In the first phase of this initiative, HRSA is implementing strategies to encourage its rural community-based programs to focus on these disparities. The second phase of this initiative will work across other HHS entities to leverage other programs and research funding streams to ensure the Department’s efforts address the underlying factors that drive rural disparities in these causes of potential excess death.
- Area Health Education Centers (AHECs): HRSA funded programs that develop and enhance education and training networks within communities, academic institutions, and community-based organizations to increase diversity among health professionals. AHECS also work to broaden the distribution of the health workforce, enhance healthcare quality, and improve healthcare delivery to rural and underserved areas and populations. AHECs provide necessary health literacy initiatives to rural communities, which include literacy initiatives on oral health, through its community-based activities to increase the primary care workforce in rural and underserved sites.

i Due to a change in the Healthcare Cost and Utilization Project (HCUP) data, the same measures reported in past reports are not represented in this report. HCUP converted all measures from International Classification of Diseases, Ninth Revision (ICD-9) to Tenth Revision (ICD-10) codes, thus changing the outcomes of these measures. Therefore, trend data are not available at this time.

ii Due to a change in the Healthcare Cost and Utilization Project (HCUP) data, the same measures reported in past reports are not represented in this report. HCUP converted all measures from International Classification of Diseases, Ninth Revision (ICD-9) to Tenth Revision (ICD-10) codes, thus changing the outcomes of these measures. Therefore, trend data are not available at this time.

iii Due to a change in the Healthcare Cost and Utilization Project (HCUP) data, the same measures reported in past reports are not represented in this report. HCUP converted all measures from International Classification of Diseases, Ninth Revision (ICD-9) to Tenth Revision (ICD-10) codes, thus changing the outcomes of these measures. Therefore, trend data are not available at this time.

iv Chart not shown for children ages 2-17 for whom a health provider gave advice within the past 2 years about healthy eating because Data for AI/AN do not meet the criteria for statistical reliability, data quality or confidentiality for data years 2004, 2004, 2005, 2006, 2007, 2010, 2011, 2012, 2014, 2016 and 2017.

v Due to a change in the Healthcare Cost and Utilization Project (HCUP) data, the same measures reported in past reports are not represented in this report. HCUP converted all measures from International Classification of Diseases, Ninth Revision (ICD-9) to Tenth Revision (ICD-10) codes, thus changing the outcomes of these measures. Therefore, trend data are not available at this time.

vi Due to a change in the Healthcare Cost and Utilization Project (HCUP) data, the same measures reported in past reports are not represented in this report. HCUP converted all measures from International Classification of Diseases, Ninth Revision (ICD-9) to Tenth Revision (ICD-10) codes, thus changing the outcomes of these measures. Therefore, trend data are not available at this time.

vii For comparisons across residence locations, large fringe MSAs (large city suburbs) are used as the reference group since these counties have the lowest levels of poverty and typically have the best quality and access to healthcare.

viii The figure was not included for this measure because 5 years of data do not meet the criteria for statistical reliability, data quality, or confidentiality.