# QUALITY IN HEALTHCARE

The foundation of quality healthcare is doing the right thing at the right time in the right way for the right person and having the best results possible. Quality healthcare often means striking the right balance in the provision of health services by avoiding overuse (e.g., getting unnecessary tests), underuse (e.g., not being screened for high blood pressure), or misuse (e.g., being prescribed drugs that have dangerous interactions).^1^

The quality of healthcare can be measured, monitored, and improved over time. By specifying clearly, based on current science, which services should be provided to patients who have or are at risk for certain conditions and finding out whether those services are being correctly provided at the right time, we can track the performance of our medical care system. Experts in a field can propose a measure of performance, then test, adopt, and implement it.

Measures of healthcare quality tracked in the NHQDR encompass a broad array of services (prevention, acute treatment, and chronic disease management) and settings (doctors’ offices, emergency departments, dialysis centers, hospitals, nursing homes, hospices, and home health). Most NHQDR quality measures quantify processes that make up high-quality healthcare or outcomes related to receipt of high-quality healthcare. A few structural measures are included, such as the availability of health information technologies and workforce diversity.

Data used to generate NHQDR measures include results from more than three dozen datasets that provide estimates for various population subgroups and data years. Sources used to assess healthcare quality in the report include:

- Surveys of patients, patients’ families, and providers;
- Administrative data from healthcare facilities;
- Abstracts of clinical charts;
- Registry data; and
- Vital statistics.

Most data are reported annually and are generally available through 2016, 2017, or 2018.

As defined by the landmark Institute of Medicine report Crossing the Quality Chasm: A New Health System for the 21st Century, “equity” aims to ensure that quality care is available to all and that the quality of care provided does not differ by race, ethnicity, or other personal characteristics unrelated to a patient’s reason for seeking care.^2^

Historically, quality of healthcare has varied based on race, ethnicity, socioeconomic status, age, sex, disability status, sexual orientation, and residence location. As specified in the Healthcare Research and Quality Act, this report focuses on disparities related to race, ethnicity, socioeconomic status, as well as geographic location. Through the examination of disparities in care, policymakers, researchers, providers, and public health practitioners can better understand the relationship between quality and equity in care.

## TRENDS IN QUALITY

Quality of healthcare improved generally through 2018, but the pace of improvement varied by priority area.

Figure 1 Number and percentage of all quality measures that were improving, not changing, or worsening, total and by priority area, from 2000 through 2018

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p <0.10.

Stacked bar chart showing number of quality measures Total (n=174), Improving, 87, Not Changing, 77, Worsening, 10 Person-Centered Care (n=29), Improving, 14, Not Changing, 5, Worsening, 0 Patient Safety (n=26), Improving, 12, Not Changing, 13, Worsening, 1 Care Coordination (n=8), Improving, 3, Not Changing, 2, Worsening, 3 Affordable Care (n=5), Improving, 2, Not Changing, 3, Worsening, 0 Effective Treatment (n=36), Improving, 15, Not Changing, 18, Worsening, 3 Healthy Living (n=70), Improving, 41, Not Changing, 26, Worsening, 3

- Through 2018, across a broad spectrum of measures of healthcare quality, 50% showed improvement (Figure 1).
- Almost half of measures of person-centered care improved (48%).
- Almost half (46%) of patient safety measures and almost 60% of healthy living measures improved.
- More than 40% of effective treatment measures improved.
- Nearly 40% of care coordination measures improved.
- Forty percent of affordable care measures improved.

Before the 2018 and 2019 NHQDR, the reports included longitudinal reporting of Healthcare Cost and Utilization Project (HCUP) Quality Indicator (QI) trends based on ICD-9-CM^i^ coding. Because of the transition from ICD-9-CM to ICD-10-CM/PCS^ii^ on October 1, 2015, the 2019 and 2018 NHQDR include QI estimates only for 2017 and 2016, respectively, and do not report on trends. Longitudinal trends may be reported in future NHQDR releases.

## Trends in Person-Centered Care

The NHQDR addresses six priority areas, including person-centered care, defined as ensuring that each person and family is engaged as partners in their care. The rationale is that “[h]ealth care should give each individual patient and family an active role in their care. Care should adapt readily to individual and family circumstances, as well as differing cultures, languages, disabilities, health literacy levels, and social backgrounds.” Examples of person-centered care could be ensuring that patients’ feedback on their preferences, desired outcomes, and experiences of care is integrated into care delivery and enabling patients to effectively manage their care.

The National Academy of Medicine identifies patient centeredness as a core component of quality healthcare.^2^ Patient centeredness is defined as:

[H]ealth care that establishes a partnership among practitioners, patients, and their families (when appropriate) to ensure that decisions respect patients’ wants, needs, and preferences and that patients have the education and support they need to make decisions and participate in their own care.^3^

Patient centeredness “encompasses qualities of compassion, empathy, and responsiveness to the needs, values, and expressed preferences of the individual patient.”^2^ In addition, translation and interpretation services, as well as auxiliary aids and services, facilitate communication between the provider and the patient and are often a legal requirement.^iii^ The patient-centered approach includes viewing the patient as a unique person, rather than focusing strictly on the illness, building a therapeutic alliance based on the patient’s and the provider’s perspectives.

Patient-centered care is supported by good provider-patient communication so that patients’ needs and wants are understood and addressed and patients understand and participate in their own care. This approach to care has been shown to improve patients’ health and healthcare.^4,5,6,7,8^

Unfortunately, many barriers exist to good communication. Providers differ in communication proficiency, including varied listening skills and different views from their patients of symptoms and treatment effectiveness.^9^ Additional factors influencing patient centeredness and provider-patient communication include:

- Language barriers.
- Racial and ethnic concordance between the patient and provider.
- Effects of disabilities on patients’ healthcare experiences.
- Providers’ cultural competency.

### Importance of Person-Centered Care

#### Morbidity and Mortality

- Patient-centered decision making (when physicians take into account the needs and circumstances of a patient) for planning a patient’s care has been shown to improve healthcare outcomes.^10^
- Patient-centered approaches to care have been shown to improve patients’ health status. These approaches rely on building a provider-patient relationship, improving communication, fostering a positive atmosphere, and encouraging patients to actively participate in provider-patient interactions.^11^
- Patient-centered care can reduce the chance of misdiagnosis due to poor communication.^12^

Overall, effective communication leads to increased patient and clinician satisfaction, increased trust with the clinician, and functional and psychological well-being. Effective communication also leads to improved outcomes in specific diseases, including:

- A small but significant absolute risk reduction of mortality from coronary artery disease,
- Improved control of diabetes and hyperlipidemia,
- Better adherence to antihypertensives,
- Bereavement adjustment in caregivers of cancer patients, and
- Higher self-efficacy of adherence to HIV medications.^13^

#### Cost

- Poor communication, lack of collaboration, and lack of support for self-care are associated with suffering and waste in healthcare.^14^
- Patient centeredness has been shown to reduce overuse of medical care.^15^
- Patient centeredness can reduce the strain on system resources and save money by reducing the number of diagnostic tests and referrals.^16^
- Improving provider-patient communication during medical decision making can reduce costs.^17^

### Findings on Person-Centered Care

The person-centered care priority area includes measures of:

- Patient Experience of Care.
- Hospital Communication.
- Home Health Communication.
- Hospice Care.

Data for these measures can be found at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

The average annual increase in the percentage of adults with limited English proficiency who had a usual source of care was about 6%.

Measures of provider-patient communication showed the greatest improvement among person-centered care measures:

- Adults with limited English proficiency who had a usual source of care.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always gave them easy-to-understand instructions about what to do for a specific illness or health conditions.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand.

#### Improving Trend: Usual Source of Care for Patients With Limited English Proficiency

Adults who have limited English proficiency may experience disparities in their care and gaps in communication with their healthcare team.^18^ According to the Migration Policy Institute, in 2015, an estimated 25.9 million individuals living in the United States reported having limited English proficiency.^19^ “More than one in four people aged 5 and over with LEP are born in the U.S.”^20^ Language assistance such as access to translation services, health education materials written in a known language, and other resources are required by law, but not all patients have access to these services at their usual source of care.^21^

Figure 2 Adults with limited English proficiency who had a usual source of care, 2014-2017

Line graph showing percentage 2014, 58.5 2015, 61.9 2016, 62.9 2017, 65.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014-2017.

- From 2014 to 2017, overall, the percentage of adults with limited English proficiency who had a usual source of care increased from 58.5% to 65.9% (Figure 2).

Among the 19 person- and family-centered care measures in this year’s report, one measure showed the top three greatest reductions in disparities over time between high-income populations and other income groups. This measure is Adults with limited English proficiency who had a usual source of care (see Disparities section, Income).

#### Improving Trend: Clear Instructions From Health Providers

Many patients leave their healthcare visit unsure of what their provider asked them to do or what was discussed. Nationwide, only 12% of adults have proficient health literacy.^22^ That means almost 9 out of 10 Americans find it challenging “to obtain, process, and understand basic health information and services needed to make appropriate health decisions.”^23^ Several communication strategies help patients and providers understand each other better, including the teach-back method. It is an evidence-based technique to confirm that people have explained things in a manner others understand.^24^

Figure 3 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always gave them easy-to-understand instructions about what to do for a specific illness or health condition, 2011-2017

Line graph showing percentage 2011, 64.1 2012, 65.8 2013, 66.9 2014, 68.8 2015, 68.4 2016, 69.2 2017, 73.0

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2011-2017.

- From 2011 to 2017, overall, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always gave them easy-to-understand instructions about what to do for a specific illness or health condition increased from 64.1% to 73.0% (Figure 3).

#### Improving Trend: Adequate Doctor’s Explanation

When healthcare providers use teach-back with their patients, they ask them to describe in their own words what they have heard. If patients cannot teach the information back correctly, providers have to instruct them again using a different way of explaining, until patients are able to teach back what they have learned correctly.^25^ The use of strategies such as teach-back and shared decision making are contributing to improvements in patient-provider communication. Breakdowns in communication still exist and require close examination of modes communication, implicit bias and trust building.^26^

Figure 4 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing percentage 2002, 9.0 2003, 8.1 2004, 8.4 2005, 8.3 2006, 8.2 2007, 7.8 2008, 8.5 2009, 7.6 2010, 7.4 2011, 6.7 2012, 6.4 2013, 6.1 2014, 4.8 2015, 5.1 2016, 5.2 2017, 7.4

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, overall, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand decreased from 9.0% to 7.4% (Figure 4).

#### Resources

Efforts to promote person-centered care are underway within the Department of Health and Human Services (HHS). For example:

- The HHS Office of Minority Health has developed Think Cultural Health (https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=1&lvlid=6), a website featuring information, resources, and continuing education opportunities related to culturally and linguistically appropriate services (CLAS) and the National CLAS Standards for healthcare professionals.
- The HHS Office for Civil Rights’ (OCR) Medical School Curriculum Initiative (https://www.hhs.gov/civil-rights/for-individuals/special-topics/health-disparities/medical-school-curriculum-initiative/index.html) educates college students, medical students, and health professionals about health disparities, cultural competency, and OCR’s civil rights authorities. As part of this initiative, OCR takes part in the Association of American Medical Colleges’ Summer Health Professionals Education Program (SHPEP). Through the SHPEP, OCR has provided training to nearly 1,000 premedical and predental college students at a dozen universities every summer since 2014.
  Currently, SHPEP trainings consist of two presentations. The first presentation has been given to SHPEP students every summer since 2014. It covers racial and ethnic health disparities, cultural and linguistic competence in healthcare, and compliance with Title VI of the Civil Rights Act of 1964. It also covers other civil rights authorities, such as authorities prohibiting sex discrimination (including sexual harassment) in education and health programs or activities funded by HHS. In 2020, OCR added a second presentation on effective communication requirements for individuals who are deaf or hard of hearing, per Section 504 of the Rehabilitation Act of 1973, Title II of the Americans With Disabilities Act, and Section 1557 of the Affordable Care Act.

Patient experience is also affected by a patient’s health literacy levels. The Agency for Healthcare Research and Quality (AHRQ) has produced a toolkit called the SHARE approach (https://www.ahrq.gov/health-literacy/curriculum-tools/shareddecisionmaking/index.html), which involves a five-step process for shared decision making and tools to help patients and providers ensure clear understanding and communication with one another.

#### Examining Person-Centered Care Quality Measures by Setting of Care

Figure 5 Number and percentage of all person-centered care measures improving, not changing, or worsening from 2002 to 2018, by setting of care

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p <0.10.

Stacked bar chart showing number of measures in each category; no measures were worsening Hospital (n=1), 1 improving, 0 not chinging Ambulatory (n=11), 8 improving, 3 not changing Home Health (n=9), 4 improving, 5 not changing Hospice Care (n=8), 1 improving, 7 not changing

Core measures listed below are noted as improving (green), not changing (yellow), or worsening (red) over time. For more information on how this analysis is conducted, consult the NHQDR Introduction and Methods (https://www.ahrq.gov/sites/default/files/wysiwyg/research/findings/nhqrdr/2019qdr-intro-methods.pdf). For more details about the measures shown here, visit the NHQDR website (https://nhqrnet.ahrq.gov/inhqrdr/).

Table 1 Hospital Measures

Among the core person-centered care measures, only one speaks to inpatient quality of care.

Sub-Area | Measure Title (Data Source)
Communication – Medication | Adult hospital patients who sometimes or never had good communication about medications they received in the hospital (HCAHPS)

Table 2 Ambulatory Measures

Among 11 measures related to ambulatory care, 8 were improving over time and 3 were not changing. These measures include patient experience of care measures that examine communication between patients and their providers over the course of a year.

Sub-Area | Measure Title (Data Source)
Health Literacy | Adults with limited English proficiency who had a usual source of care (MEPS)
Health Literacy | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always gave them easy-to-understand instructions about what to do for a specific illness or health condition (MEPS)
Health Literacy | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand (MEPS)
Health Literacy | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never spent enough time with them (MEPS)
Respect | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say (MEPS)
Respect | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never listened carefully to them (MEPS)
Shared Decision Making | People with a usual source of care whose providers sometimes or never asked them to help make decisions when there was a choice between treatments (MEPS)
Healthcare Experience | Adults who rated their healthcare received in the last 12 months as poor (0-6) on a scale of 0-10 (where 0 is the worst and 10 is the best) (MEPS)
Health Literacy | Adults with limited English proficiency and a usual source of care (USC) whose USC had language assistance (MEPS)
Health Literacy | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always asked them to describe how they would follow the instructions (MEPS)
Health Literacy | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always offered help in filling out forms (MEPS)

Table 3 Home Health Care Measures

Among 9 home health care measures, 4 were noted as improving over time. The 4 outcome measures that improved pertained to adults reporting on how they engaged with their home health providers. Five measures showed no change.

Sub-Area | Measure Title (Data Source)
Pain | Adults who reported that home health providers talked about pain in the last 2 months of care (HHCAHPS)
Caregiving | Adults who reported being told what care and services they would get when they first started getting home health care (HHCAHPS)
Health Literacy | Adults who reported that home health providers always explained things in a way that was easy to understand in the last 2 months of care (HHCAHPS)
Respect | Adults who reported that home health providers always treated them with courtesy and respect in the last 2 months of care (HHCAHPS)
Caregiving | Adults who reported that home health providers always kept them informed about when they would arrive at their home in the last 2 months of care (HHCAHPS)
Respect | Adults who reported that home health providers always listened carefully to them in the last 2 months of care (HHCAHPS)
Caregiving | Adults who did not have any problem with the care they received from their home health providers in the last 2 months of care (HHCAHPS)
Pain | Adults who reported that home health providers always treated them as gently as possible in the last 2 months of care (HHCAHPS)
Shared Decision Making | Adults who reported getting the help or advice they needed when they contacted their home health providers in the last 2 months of care (HHCAHPS)

Table 4 Hospice Care Measures

Among 8 hospice care outcome measures, only one improved over time.

Sub-Area | Measure Title (Data Source)
Caregiving | Hospice patients whose hospice care team always communicated well with their family caregivers about taking care of them (Hospice CAHPS)
Caregiving | Family caregivers who received right amount of emotional and spiritual support from hospice care team (Hospice CAHPS)
Caregiving | Hospice patients whose hospice care team always treated them with dignity and respect, and really cared about them (Hospice CAHPS)
Caregiving | Family caregivers who rated the hospice care for their family member best (9-10) on a scale of 0-10 (where 0 is the worst and 10 is the best) (Hospice CAHPS)
Caregiving | Family members who definitely received training about taking care of their family member from hospice care team (Hospice CAHPS)
Caregiving | Hospice patients who always received enough help for pain, sadness, breathing, or constipation from hospice care team (Hospice CAHPS)
Caregiving | Family caregivers who would definitely recommend this hospice to their friends and family (Hospice CAHPS)
Caregiving | Hospice patients and family caregivers who always got help as soon as they needed from hospice care team (Hospice CAHPS)

## Trends in Patient Safety

The Institute of Medicine (IOM)^iv^ defines patient safety as “freedom from accidental injury due to medical care or medical errors.”^27^ In 1999, the IOM published their landmark report, To Err Is Human: Building a Safer Health System,^27^ which called for a national effort to reduce medical errors and improve patient safety. Since then, the Agency for Healthcare Research and Quality (AHRQ) has been mandated to lead federal patient safety research. As part of this effort, AHRQ has supported research and quality improvement programs to reduce healthcare-associated infections and healthcare acquired conditions, adverse drug events, and other preventable adverse events.

AHRQ has identified three long-term goals related to patient safety. These include reducing preventable hospital admissions and readmissions, reducing the incidence of adverse healthcare-associated conditions, and reducing harm from inappropriate or unnecessary care.

A common cause of adverse events is gaps in communication either among healthcare providers or with patients and their family members. Such communication gaps may occur unintentionally and may sometimes result from implicit biases. Researchers have found that patient safety as a quality domain connects directly with person-centered care and care coordination. Researchers, providers, and policymakers need to connect these areas of quality to better understand breakdowns in care so that patients experience safer care and better health outcomes.

In 2015, the National Academy of Medicine (NAM) built on their initial report by publishing Improving Diagnosis in Health Care, which identifies eight major goals for effecting progress on diagnostic error and improving patient safety outcomes. Diagnostic performance was not carefully addressed in To Err is Human; however, the patient safety field has now established consensus that more attention needs to be placed on both diagnostic error and performance.

AHRQ has also published on the best patient safety practices and most recently published Making Healthcare Safer III (https://www.ahrq.gov/research/findings/making-healthcare-safer/mhs3/index.html) in 2020. This compendium summarizes the most widely recognized patient safety implementation practices and frameworks in the United States.

### Importance of Patient Safety

#### Mortality

Number of Americans who die in hospitals each year from medical errors (1999 est.) …………………………………………………………………………… 44,000-98,00027

Age-standardized mortality rate due to adverse effects of medical treatment …………………………………………………… 1.15 per 100,000 population28

#### Prevalence

Number of hospital-acquired conditions in U.S. hospitals (2017) ………………. 2,550,00029

All-payer 30-day readmission rate (2016) …………………………………. 13.9% of admissions30

#### Cost

Additional hospital inpatient cost due to hospital-acquired conditions29:

- Central line-associated bloodstream infection ……………………………………… $48,108
- Ventilator-associated pneumonia ……………………………………………………….. $47,238
- Surgical site infection ………………………………………………………………………… $28,219
- Venous thromboembolism …………………………………………………………………. $17,367

### Findings on Patient Safety

The patient safety priority area includes measures of:

- Healthcare-Associated Infections.
- Surgical Care.
- Other Complications of Hospital Care.
- Complications of Medication.
- Birth-Related Complications.
- Maternal Morbidity and Mortality.
- Inappropriate Treatment.
- Supportive and Palliative Care.
- Home Health Communication.

Data for these measures can be found at https://nhqrnet.ahrq.gov/inhqrdr/data/query. More information on maternal morbidity and mortality measures can be found in the NHQDR Chartbook on Patient Safety.

Almost 50% of Patient Safety measures showed improvement.

The following 3 measures showed the most improvement:

- Hospital patients with an anticoagulant-related adverse drug event to low-molecular-weight heparin (LMWH) and factor Xa.
- Adverse drug event with IV heparin in adult hospital patients who received an anticoagulant.
- Long-stay nursing home residents with a urinary tract infection.

One measure was worsening:

- Adults who reported a home health provider asking to see all the prescription and over-the-counter medicines they were taking, when they first started getting home health care.

#### Improving Trend: Adverse Drug Events With Heparin and Factor Xa

Adverse drug events (ADEs) include medication errors and adverse drug reactions, representing a major source of harm among hospitalized patients. Anticoagulant drugs, including warfarin, unfractionated heparin, and low-molecular-weight heparin, are among the most commonly implicated medications that cause ADEs in hospitalized patients. Low-molecular-weight heparin (LMWH) is used to prevent venous thromboembolic disease on acute or elective admission to the hospital and to treat deep vein thrombosis and pulmonary embolism.^31^

Figure 6 Adult inpatients with an anticoagulant-related adverse drug event to low-molecular-weight heparin (LMWH) and factor Xa, United States, 2014-2017

Note: For this measure, lower rates are better.

Line graph showing percentage 2014, 3.5 2015, 3.0 2016, 2.2 2017, 1.7

Source: Agency for Healthcare Research and Quality and Centers for Medicare & Medicaid Services, Medicare Patient Safety Monitoring System, 2014-2017.

- From 2014 to 2017, overall, the percentage of adult inpatients with an anticoagulant-related adverse drug event to LMWH and factor Xa decreased from 3.5% to 1.7% (Figure 6).

#### Improving Trend: Inpatient Adverse Drug Events With Anticoagulants

Blood clots in arteries and veins can cause a blockage of blood flow and lead to strokes and heart attacks. Stroke survivors have an increased risk of another stroke, and individuals with obesity are at higher risk of blood clots. Anticoagulants, such as warfarin, reduce this risk but pose an increased risk of bleeding.^32^

Figure 7 Adverse drug event with IV heparin in adult hospital patients who received an anticoagulant, 2014-2017

Note: For this measure, lower rates are better.

Line graph showing percentage 2014, 11.1 2015, 10.8 2016, 7.2 2017, 6.1

Source: Agency for Healthcare Research and Quality and Centers for Medicare & Medicaid Services, Medicare Patient Safety Monitoring System, 2014-2017.

- From 2014 to 2017, overall, the percentage of inpatient adults who received an anticoagulant and experienced an adverse drug event associated with IV heparin decreased from 11.1% to 6.1% (Figure 7).

#### Improving Trend: Urinary Tract Infections Among Nursing Home Residents

Urinary tract infections are the second most frequent type of infection among nursing home residents. These residents typically have other comorbidities and may not receive timely diagnoses, “leading to increased rates of adverse drug effects and more recurrent infections with drug-resistant bacteria.”^33^

Figure 8 Long-stay nursing home residents with a urinary tract infection, 2013-2017

Note: For this measure, lower rates are better.

Line graph showing percentage 2015 achievable benchmark: 2.8% 2013, 4.9 2014, 4.4 2015, 3.7 2016, 3.0 2017, 2.2

Source: Centers for Medicare & Medicaid Services, Minimum Data Set, 2013-2017.

- From 2013 to 2017, overall, the percentage of long-stay nursing home residents with a urinary tract infection decreased from 4.9% to 2.2% (Figure 8).
- The 2015 achievable benchmark was 2.8%. The national rate in 2017 was better than the benchmark percentage.
- The top 5 states that reached the achievable benchmark are California, Connecticut, Hawaii, New Jersey, and New Mexico.

#### Worsening Trend: Home Health Provider Checking Medication

Home health providers’ asking to see all medications is a preliminary step in ensuring that patients take only medications appropriate to their condition and understand why, when, and how much of each medication to take. This step may be especially important in protecting against medication errors and adverse events after transitions from facility-based care to home care.

This measure focuses on patients’ recollection of their experience with the home health agency. It is important to note that the skill sets and required background training of home health care workers varies substantially across States. While home health care workers in some States may be trained to assist providers in medication reconciliation, workers in other States may not. Medication reconciliation is a key part of ambulatory care.

Figure 9 Adults who reported a home health provider asking to see all the prescription and over-the-counter medicines they were taking when they first started getting home health care, 2012-2018

2015 Achievable Benchmark: 86% 2012, 78.8 2013, 78.9 2014, 78.3 2015, 77.8 2016, 77.6 2017, 77.1 2018, 76.5

Source: Centers for Medicare & Medicaid Services, Home Health Consumer Assessment of Healthcare Providers and Systems, 2012-2018.

- From 2012 to 2018, overall, the percentage of adults who reported a home health provider asking to see all the prescription and over-the-counter medicines they were taking when they first started getting home health care decreased from 78.8% to 76.5% (Figure 9).
- The 2015 achievable benchmark was 86%. There is no evidence of progress toward the benchmark.
- The top 10% of states and territories that reached the achievable benchmark are Alabama, Arkansas, Guam, Louisiana, Mississippi, Northern Mariana Islands, Puerto Rico, Texas, Virgin Islands, and West Virginia (more than 5 states reached the benchmark due to ties).

One home health measure showed widening disparities over time: Oral medication management among home health care patients (see Disparities section, Racial and Ethnic Disparities).

#### Resources

Efforts to promote patient safety are underway within HHS. For example:

- The National Steering Committee for Patient Safety, which published the National Action Plan to Advance Patient Safety (https://www.ahrq.gov/patient-safety/reports/safer-together.html), is co-chaired by AHRQ and the Institute for Healthcare Improvement. The National Steering Committee for Patient Safety, with members from the healthcare, policy, regulatory, and advocacy communities, is charged with creating a national action plan to guide patient safety efforts across the country in a cohesive and coordinated fashion.
- AHRQ sponsors the Comprehensive Unit-based Safety Program (https://www.ahrq.gov/professionals/education/curriculum-tools/cusptoolkit/index.html) [underlined: (CUSP).] This patient safety method combines improvement in safety culture, teamwork, and communication with a set or checklist of evidence-based practices known to be effective in preventing the target healthcare-associated infection or other harms. It builds the capacity to address safety issues by combining clinical best practices and the science of safety. The core CUSP principles can be applied to reduce and eliminate healthcare associated infections and perinatal safety events. AHRQ has sponsored 10 related programs (https://www.ahrq.gov/hai/cusp/index.html) to date.
- AHRQ, with the Department of Defense, sponsored the development of Team Strategies and Tools to Enhance Performance and Patient Safety (TeamSTEPPS (https://www.ahrq.gov/teamstepps)). TeamSTEPPS® is an evidence-based set of teamwork tools aimed at optimizing patient outcomes by improving communication and teamwork skills among healthcare professionals. Today, TeamSTEPPS® training is available online and can be used to train inpatient, nursing home, and medical office providers.
- AHRQ has created the On-Time Pressure Ulcer Prevention Toolkit (https://www.ahrq.gov/patient-safety/settings/long-term-care/resource/ontime/pruprev/index.html) to help nursing homes with electronic medical records reduce the occurrence of in-house pressure ulcers.
- Communication and Optimal Resolution (CANDOR) is a process healthcare institutions and practitioners can use to respond in a timely, thorough, and just way when unexpected events cause patient harm. AHRQ has pilot tested and produced the CANDOR Toolkit (https://www.ahrq.gov/patient-safety/capacity/candor/modules.html) for hospitals and healthcare systems to implement as a way to respond to harm events and initiate improvements in safety outcomes.

#### Examining Patient Safety Quality Measures by Setting of Care

Figure 10 Number and percentage of all patient safety measures improving, not changing, or worsening from 2002 to 2018, by setting of care

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p <0.10.

Stacked bar chart showing number of measures in each category Hospital (n=11), 3 improving, 8 not chinging, 0 worsening Ambulatory (n=2), 2 improving, 0 not changing, 0 worsening Home Health (n=8), 3 improving, 4 not changing, 1 worsening Hospice Care (n=5), 4 improving, 1 not changing

Core measures listed below are noted as improving (green), not changing (yellow), or worsening (red) over time. For more information on how this analysis is conducted, consult the NHQDR Introduction and Methods (https://www.ahrq.gov/sites/default/files/wysiwyg/research/findings/nhqrdr/2019qdr-intro-methods.pdf). For more details about the measures shown here, visit the NHQDR website (https://nhqrnet.ahrq.gov/inhqrdr/).

Table 5 Hospital Measures

Among the core patient safety measures, 3 measures were improving and 8 were not changing in the inpatient setting. The improving measures include medication safety and procedural events.

Sub-Area | Measure Title (Data Source)
Medication Safety | Hospital patients with an anticoagulant-related adverse drug event to low-molecular-weight heparin (LMWH) and factor Xa (MPSMS)
Medication Safety | Adverse drug event with IV heparin in adult hospital patients who received an anticoagulant (MPSMS)
Procedural Event | Mechanical adverse events in adult patients receiving central venous catheter placement (MPSMS)
Healthcare-Associated Infections | Adult surgery patients with postoperative pneumonia events (MPSMS)
Medication Safety | Hospital patients with an anticoagulant-related adverse drug event to warfarin (MPSMS)
Medication Safety | Hospital patients who received a hypoglycemic agent who had an adverse drug event with a hypoglycemic agent (MPSMS)
Healthcare-Associated Infections | Adult surgery patients with catheter-associated urinary tract infection (MPSMS)
Surgical Safety | Inpatient adverse events in adults receiving hip joint replacement due to degenerative conditions (MPSMS)
Surgical Safety | Inpatient adverse events in adults receiving hip joint replacement due to fracture (MPSMS)
Surgical Safety | Inpatient adverse events in adults receiving knee replacement (MPSMS)
Venous Thromboembolism | Adult surgery patients with postoperative venous thromboembolic events (MPSMS)

Table 6 Ambulatory Measures

Both of the 2 ambulatory care process measures were improving over time. Both measures also pertain to prescription medication prescribing.

Sub-Area | Measure Title (Data Source)
Medication Safety | Adults age 65 and over who received in the calendar year at least 1 of 11 prescription medications that should be avoided in older adults (MEPS)
Medication Safety | Adults age 65 and over who received in the calendar year at least 1 of 33 potentially inappropriate prescription medications for older adults (MEPS)

Table 7 Home Health Care Measures

Among 8 home health care measures, 3 measures were improving over time, one of which examines a healthcare outcome by looking at oral medication management. All other measures in this setting of care are process measures. One measure examining home health care provider assessment of patient medications was worsening over time.

Sub-Area | Measure Title (Data Source)
Medication Safety | Home health care patients whose management of oral medications improved (OASIS)
Surgical Safety | Home health care patients whose surgical wound was improved (OASIS)
Falls | Adults who reported a home health provider talking with them about how to set up their home so they could move around safely when they first started getting home health care (HHCAHPS)
Medication Safety | Adults who reported a home health provider talking with them about all the prescription and over-the-counter medicines they were taking when they first started getting home health care (HHCAHPS)
Medication Safety | Adult home health patients age 18 and over who reported that home health providers talked with them about the side effects of medicines in the last 2 months of care (HHCAHPS)
Medication Safety | Adults who reported that home health providers talked with them about the purpose for taking their new or changed prescription medicines in the last 2 months of care (HHCAHPS)
Medication Safety | Adults who reported that home health providers talked with them about when to take medicines in the last 2 months of care (HHCAHPS)
Medication Safety | Adults who reported a home health provider asking to see all the prescription and over-the-counter medicines they were taking when they first started getting home health care (HHCAHPS)

Table 8 Nursing Home Care Measures

Among 5 nursing home care measures, 4 were improving over time. The one measure that was not changing over time examines long-stay nursing home patients who experience injuries after falls.

Sub-Area | Measure Title (Data Source)
Procedural Event | Long-stay nursing home residents with a urinary tract infection (MDS)
Pressure Ulcers | Short-stay nursing home patients with new or worsening pressure ulcers (MDS)
Healthcare-Associated Infections | Low-risk, long-stay nursing home residents with a catheter inserted and left in the bladder (MDS)
Pressure Ulcers | High-risk, long-stay nursing home patients with pressure ulcer (MDS)
Falls | Long-stay nursing home patients experiencing one or more falls with major injury (MDS)

## Trends in Care Coordination

Healthcare delivery in the United States can be fragmented. Clinical services are frequently organized around small groups of providers who function autonomously and specialize in specific symptoms or organ systems. Therefore, many patients receive attention only for individual health conditions rather than receiving coordinated care. For example, the typical Medicare beneficiary sees two primary care providers and five specialists each year.^34^ Communication of important information among providers and between providers and patients may entail delays or inaccuracies or may fail to occur.

Care coordination is a conscious effort to ensure that all key information needed to make care decisions is available to patients and providers. It is defined as the deliberate organization of patient care activities between two or more participants involved in a patient’s care to facilitate appropriate delivery of healthcare services.^35^ Care coordination is multidimensional and essential to preventing adverse events, ensuring efficiency, and making care patient centered.^36^

Patients in greatest need of care coordination include those with:

- Multiple chronic medical conditions,
- Concurrent care from several health professionals,
- Many medications,
- Extensive diagnostic workups, or
- Transitions from one care setting to another.

Effective care coordination requires well-defined multidisciplinary teamwork based on the principle that all who interact with a patient must work together to ensure the delivery of safe, high-quality care.

The goal of care coordination is to enable healthcare providers, patients, and caregivers to all work together to understand and make sure that “patient’s needs and preferences are known and communicated at the right time to the right people, and that this information is used to guide the delivery of safe, appropriate, and effective care.”^37^ While measurement of care coordination is at an early stage of development, key goals include coordinating transitions of care, reducing hospital readmissions, communicating medication information, and reducing preventable emergency department visits.

### Importance of Care Coordination

#### Morbidity and Mortality

Care coordination interventions have been shown to:

- Reduce mortality among patients with heart failure;
- Reduce mortality and dependency among patients with stroke;
- Reduce symptoms among patients with depression and at the end of life; and
- Improve glycemic control among patients with diabetes.^35^

#### Cost

Care coordination interventions have been shown to:

- Reduce hospitalizations among patients with heart failure;
- Reduce readmissions among patients with mental health conditions; and
- Be cost-effective when applied to treatment of depression.^35^

### Findings on Care Coordination

The care coordination priority area includes measures of:

- Medication Information.
- Preventable Emergency Department Visits.
- Preventable Hospitalizations among Home Health Patients.
- Supportive and Palliative Care.
- Transitions of Care.

Other areas represented in the supplemental dataset include:

- Preventable Hospitalizations.
- Potentially Harmful Services without Benefit.
- Potentially Avoidable Admissions.

Data for these measures can be found at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

Progress in Care Coordination has been slow, with little improvement and three measures getting worse.

Only three measures showed improvement overall:

- Adult hospital patients who did not receive good communication about discharge information.
- People with a usual source of care who usually asks about prescription medications and treatments from other doctors.
- Adults who reported that home health providers always seem informed and up to date about all the cares or treatments they got at home in the last 2 months of care.

Three measures were worsening:

- Home health care patients who had an emergency department visit without a hospitalization.
- Home health care patients who had an emergency department visit and were then hospitalized.
- Emergency department visits for asthma per 10,000 population, ages 2-19.

#### Improving Trend: Communication About Discharge Information

Effective care coordination begins with ensuring that accurate clinical information is available to support medical decisions by patients and providers. A common transition of care is discharge from the hospital. Giving patients and caregivers self-management support after discharge has been shown to reduce readmissions to the hospital and lower costs.^38^

Figure 11 Adult hospital patients who did not receive good communication about discharge information, 2009-2018

Note: For this measure, lower rates are better.

Line graph showing percentage 2015 Achievable Benchmark: 7.7% 2009, 15.8 2010, 14.6 2011, 13.7 2012, 12.9 2013, 11.8 2014, 11.3 2015, 10.9 2016, 10.5 2017, 10.4 2018, 10.7

Source: Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems, 2009-2018.

- From 2009 to 2018, overall, the percentage of hospital patients who did not receive good communication about discharge information decreased from 15.8% to 10.7% (Figure 11).
- The 2015 achievable benchmark was 7.7%. At the current rate of decrease, overall, the benchmark could be achieved in 4 years.
- The top 5 states that reached the achievable benchmark are Colorado, Nebraska, New Hampshire, South Dakota, and Utah.

#### Improving Trend: Communication About Treatment From Other Doctors

Different providers may prescribe medications for the same patient. Patients are responsible for keeping track of all their medications, but medication information can be confusing, especially for patients on multiple medications. When care is not well coordinated and some providers do not know about all of a patient’s medications, patients are at greater risk for adverse events related to drug interactions, overdosing, or underdosing.

In addition, providers need to periodically review all of a patient’s medications to ensure that they are taking what is needed and only what is needed. Medication reconciliation has been shown to reduce both medication errors and adverse drug events.^39^

Figure 12 People with a usual source of care who usually asks about prescription medications and treatments from other doctors, 2002-2017

Line graph showing percentage 2002, 75.1 2003, 76.4 2004, 77.8 2005, 77.7 2006, 79 2007, 80.1 2008, 80.5 2009, 79.3 2010, 82.8 2011, 81.7 2012, 82.7 2013, 79.9 2014, 80 2015, 81 2016, 80.9 2017, 81.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, overall, the percentage of people with a usual source of care who usually asks about prescription medications and treatments from other doctors increased from 75.1% to 81.5% (Figure 12).

#### Improving Trend: Home Health Care Provider Communication

Home health care providers play a critical role in the management of home health care patients, especially those receiving supportive and palliative care. Many of these patients are managing multiple chronic conditions, severe morbidities, and terminal illnesses. Effective home health care coordination and treatment management can prevent patients from experiencing recurring hospital admissions or having to resort to long-term care facilities.

Figure 13 Adults who reported that home health providers always seemed informed and up to date about all the care or treatments they got at home in the last 2 months of care, 2012-2018

Line graph showing percentage 2015 Achievable Benchmark: 67.6% 2012, 62.2 2013, 62.5 2014, 63.1 2015, 63.1 2016, 63.5 2017, 64.0 2018, 64.7

Source: Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems, 2012-2018.

- From 2012 to 2018, overall, the percentage of adults who reported that home health providers always seemed informed about their care and treatment received at home during the last 2 months of care improved from 62.2% to 64.7% (Figure 13).
- The 2015 achievable benchmark was 67.6%. At the current rate of decrease, overall, the benchmark could be achieved in 7 years.
- The states and territories that reached the achievable benchmark are Alabama, Georgia, Kentucky, Louisiana, South Carolina, Tennessee, and Virgin Islands (more than 5 states reached the benchmark due to ties).

#### Worsening Trend: Emergency Department Visits of Home Health Patients

Home health care patients can usually manage their lives with a home health care provider’s support and coordination. When home health care cannot meet a patient’s needs, he or she may be referred to the emergency department.

An emergency department visit for an urgent need/assessment without a hospitalization is a positive outcome; however, without care coordination, patients may experience similar or related emergencies and find themselves in the emergency department again. Such recurrences can lead to increased costs to the patient and family and poor health outcomes for the patient.

Figure 14 Home health care patients who had an emergency department visit without a hospitalization, 2013-2017

Note: For this measure, lower rates are better.

Line graph showing percentage 2015 Achievable Benchmark: 2.8% 2013, 3.5 2014, 3.6 2015, 3.8 2016, 3.8 2017, 3.9

Source: Centers for Medicare & Medicaid Services, Outcome and Assessment Information Set, 2013-2017.

- From 2013 to 2017, overall, the percentage of home health care patients who had an emergency department visit without a hospitalization increased from 3.5% to 3.9% (Figure 14).
- The 2015 achievable benchmark was 2.8%. There is no evidence of progress toward the benchmark.
- The states and territories that reached the achievable benchmark are Alabama, District of Columbia, Florida, New Jersey, Puerto Rico, and Texas (more than 5 states or territories reached the benchmark due to ties).

#### Worsening Trend: Hospitalization of Home Health Patients

Acute care hospitalization is the hospital admission rate for Medicare beneficiaries receiving skilled home health benefits, and its reduction is seen as a way to improve quality and reduce healthcare costs. Nearly 20% of all Medicare beneficiaries discharged from hospitals are rehospitalized within 30 days and 34% are rehospitalized within 90 days.^40^

Figure 15 Home health care patients who had an emergency department visit and were then hospitalized, 2013-2017

Note: For this measure, lower rates are better.

2015 Achievable Benchmark: 8.9% 2013, 11 2014, 11.3 2015, 12 2016, 11.8 2017, 12.2

Source: Centers for Medicare & Medicaid Services, Outcome and Assessment Information Set, 2013-2017.

- From 2013 to 2017, overall, the percentage of home health care patients who had an emergency department visit and were then hospitalized increased from 11% to 12.2% (Figure 15).
- The 2015 achievable benchmark was 8.9%. There is no evidence of progress toward the benchmark.
- The top 10% of states and territories that reached the achievable benchmark are California, Colorado, District of Columbia, Montana, Puerto Rico, and Utah (more than 5 states or territories reached the benchmark due to ties).

#### Worsening Trend: Emergency Department Visits for Asthma Among Children

In 2018, 19.2 million adults and 5.5 million children in the United States had asthma.^41^ Access to care is hampered by socioeconomic disparities, shortages of primary care physicians in minority communities, and language and literacy barriers.^42^

Figure 16 Emergency department visits for asthma per 10,000 population, ages 2-19, 2006-2016

Note: For this measure, lower rates are better.

Line graph showing rate per 10,000 population 2008, 82.5 2009, 93.9 2011, 91.3 2012, 87.4 2013, 85.4 2014, 97.7 2015, 104 2016, 103

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2006-2016.

- From 2006 to 2016, overall, the rate of emergency department visits for asthma among children ages 2–19 years increased from 82.5 to 102.7 per 10,000 population (Figure 16).

#### Resources

Efforts to promote care coordination are underway within HHS. AHRQ has produced several resources and reports to support improved care coordination in healthcare delivery, including:

- The Care Coordination Measures Atlas Update (https://www.ahrq.gov/professionals/prevention-chronic-care/improve/coordination/atlas2014/index.html) (published in 2014) expands on the atlas first published by AHRQ in 2011. The updated compendium of care coordination measures offers new measures with a focus on those that reflect coordination efforts within the primary care setting. It also includes a section on emerging trends in care coordination measurement.
- Care Coordination Accountability Measures for Primary Care Practice (https://www.ahrq.gov/research/findings/final-reports/pcpaccountability/index.html) presents measures selected systematically from the Care Coordination Measures Atlas that are well suited for use by health plans and insurers to assess the quality of coordination in primary care practices. Primary care practices can also use the measures to assess their own performance.
- The Care Coordination Quality Measure for Primary Care (https://www.ahrq.gov/professionals/prevention-chronic-care/improve/coordination/ccqmpc/index.html) (CCQM-PC) is a survey of adult patients’ experiences with care coordination in primary care settings. It was developed to comprehensively assess patient perceptions of the quality of their care coordination experiences. The CCQM-PC is designed to be used in primary care research and evaluation, with potential applications to primary care quality improvement. Guidance regarding the fielding of the survey is provided in addition to the full survey, which is in the public domain and may be used without additional permission.
- The Clinical-Community Relationships Measures Atlas (https://www.ahrq.gov/professionals/prevention-chronic-care/resources/clinical-community-relationships-measures-atlas/index.html) was published in 2013 to identify ways to further define, measure, and evaluate programs based on clinical-community relationships for the delivery of clinical preventive services. This atlas provides a measurement framework and lists existing measures of clinical-community relationships and is intended to support research and evaluation in the field.

#### Examining Care Coordination Quality Measures by Topic Areas

Figure 17 Number and percentage of all care coordination measures improving, not changing, or worsening from 2002 to 2018, by sub-area

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p <0.10.

Stacked column chart showing number of measures improving, not changing, worsening Medication Information (n=1), 1 improving, 0 not chinging, 0 worsening Preventable Emergency Department Visits (n=1), 0 improving, 0 not changing, 1 worsening Preventable Hospitalizations Among Home Health and Nursing Home Patients (n=1), 0 improving, 0 not changing, 1 worsening Supportive and Palliative Care (n=3), 1 improving, 1 not changing, 1 worsening Transitions of Care (n=2), 1 improving, 1 not changing, 0 worsening

Core measures listed below are noted as improving (green), not changing (yellow), or worsening (red) over time. For more information on how this analysis was conducted, go to NHQDR Introduction and Methods (https://www.ahrq.gov/sites/default/files/wysiwyg/research/findings/nhqrdr/2019qdr-intro-methods.pdf). For more details about the measures shown here, visit the NHQDR website (https://nhqrnet.ahrq.gov/inhqrdr/).

Table 9 Medication Information Measures

Among all care coordination core measures, one medication information measure improved over time.

Sub-Area | Measure Title (Data Source)
Prescription Medications and Treatment | People with a usual source of care who usually asks about prescription medications and treatments from other doctors (MEPS)

Table 10 Preventable Emergency Department Visit Measures

Among all care coordination core measures, one measure pertaining to emergency department visits for asthma worsened over time.

Sub-Area | Measure Title (Data Source)
Asthma | Emergency department visits for asthma per 10,000 population, ages 2-19 (NHAMCS)

Table 11 Preventable Hospitalizations Among Home Health and Nursing Home Patient Measures

Among all care coordination core measures, one measure pertaining to preventable emergency department visits worsened over time.

Sub-Area | Measure Title (Data Source)
Emergency Department Visits | Home health care patients who had an emergency department visit and were then hospitalized (OASIS)

Table 12 Supportive and Palliative Care Measures

Three measures under supportive and palliative care examine the experiences of home health patients. Patient reporting of home health provider awareness of their past treatment plan showed improvement whereas number of patients who had an emergency department visit without a hospitalization worsened over time.

Sub-Area | Measure Title (Data Source)
Patient-Provider Communication | Adults who reported that home health providers always seemed informed and up to date about all the care or treatments they got at home in the last 2 months of care (HHCAHPS)
Hospital Admissions | Home health care patients who had to be admitted to the hospital (OASIS)
Emergency Department Visits | Home health care patients who had an emergency department visit without a hospitalization (OASIS)

Table 13 Transitions of Care Measures

Among all care coordination core measures, one measure pertaining to communication about discharge information improved over time and another examining patient experience of providers who considered their preferences did not change over time.

Sub-Area | Measure Title (Data Source)
Patient Discharge | Adult hospital patients who did not receive good communication about discharge information (HCAHPS)
Patient Discharge | Adult hospital patients who strongly disagree or disagree that staff took their preferences and those of their family and caregiver into account when deciding what the patient’s discharge healthcare would be (HCAHPS)

## Trends in Affordable Care

The Affordable Care Act of 2010 established the Triple Aim to support better care for individuals, better health for populations, and lower costs for care. The law also created a platform to test new healthcare payment and delivery models. Tracking this quality domain helps healthcare professionals, researchers, and policymakers better understand the status of affordable care (https://www.commonwealthfund.org/blog/2018/aiming-best-defining-measuring-and-promoting-health-care-quality).

Reducing the cost of healthcare will support two related goals under this quality domain. The first includes ensuring affordable and accessible high-quality healthcare for people, families, employers, and governments. The second is supporting and enabling communities to ensure accessible, high-quality care while reducing waste and fraud.

### Importance of Affordable Care

#### Morbidity and Mortality

Affordability of care remains a central barrier to access to care for many individuals and families. Several financial and nonfinancial barriers contribute to the inaccessibility of care. Financial barriers include high premiums, lack of insurance, and underinsurance. Nonfinancial barriers include transportation challenges, negative interactions with care teams, delayed access to a healthcare provider, and inability to access care due to competing demands (e.g., childcare, work schedules)^43^ Past research continues to show that lack of insurance and inaccessible care are linked to patient mortality.^44,45^

#### Cost

Care coordination interventions have been shown to:

- Reduce hospitalizations among patients with heart failure;
- Reduce readmissions among patients with mental health conditions; and
- Be cost-effective when applied to treatment of depression.^35^

### Findings on Affordable Care

The affordable care priority area includes measures of:

- Usual Source of Care.
- Financial Burden of Healthcare.

Data for these measures can be found at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

Among the five Affordable Care measures, two improved and three did not change over time.

Half of the measures examining usual source of care showed improvement:

- People unable to get or delayed in getting needed medical care due to financial or insurance reasons.
- People unable to get or delayed in getting needed prescription medicines due to financial or insurance reasons.

#### Improving Trend: Barriers to Medical Care

The high cost of care continues to be an affordability challenges for patients. In recent years, the United States has observed lower rates of inaccessibility due to improved insurance access. Underinsurance and cost barriers continue to pose challenges with accessibility.

Figure 18 People unable to get or delayed in getting needed medical care due to financial or insurance reasons, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing percentage 2002, 52.3 2003, 54.7 2004, 56.0 2005, 56.7 2006, 55.2 2007, 53.8 2008, 57.2 2009, 60.8 2010, 62.4 2011, 58.1 2012, 59.5 2013, 57.4 2014, 54.0 2015, 47.7 2016, 42.2 2017, 41.1

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, overall, the percentage of people who were unable to get or delayed in getting needed medical care due to financial or insurance reasons decreased from 52.3% to 41.1% (Figure 18).

#### Improving Trend: Barriers to Getting Prescription Medicines

Prescription medications costs continue to pose challenges with affordability and accessibility for patients, especially since prescription drug costs for some diseases continue to rise.^46^ Many adults who are managing multiple chronic conditions and those who require specialty prescriptions and therapies may experience higher and unaffordable costs of treatment.

Figure 19 People unable to get or delayed in getting needed prescription medicines due to financial or insurance reasons, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing percentage 2002, 65.8 2003, 71.1 2004, 71.6 2005, 68.4 2006, 67.8 2007, 66.0 2008, 67.7 2009, 71.0 2010, 68.9 2011, 68.6 2012, 69.2 2013, 64.8 2014, 60.2 2015, 61.0 2016, 60.1 2017, 57.6

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, overall, the percentage of people who were unable to get or delayed in getting needed prescription medicines due to financial or insurance reasons decreased from 65.8% to 57.6% (Figure 19).

#### Resources

Efforts to promote affordable care are underway within the Department of Health and Human Services (HHS). For example:

- The Department is working to transform our system from one that pays for procedures and sickness (volume-based care) to one that pays for outcomes and health (value-based care, or VBC). The Centers for Medicare & Medicaid Services (CMS) operates multiple VBC programs (https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/Value-Based-Programs/Value-Based-Programs), which span different settings of care (e.g., inpatient, home health) and conditions (e.g., end stage renal disease and hospital-acquired conditions). In January 2017, CMS implemented the Quality Payment Program (https://qpp.cms.gov/about/qpp-overview) [underlined: for clinicians,] which consists of two tracks: the Merit-based Incentive Payment Systems (MIPS); and participation in Advanced Alternative Payment Models (APMs). Both tracks commit clinicians to practicing VBC.
- Health Resources and Services Administration (HRSA)-sponsored Federally Qualified Health Centers (https://www.hrsa.gov/opa/eligibility-and-registration/health-centers/fqhc/index.html) function as part of the nation’s safety net. These providers receive funds from the HRSA Health Center Program (https://bphc.hrsa.gov/about/index.html) to provide primary care services in underserved areas.
- CMS offers the Consumer Assistance Program (https://www.cms.gov/CCIIO/Resources/Consumer-Assistance-Grants), which originated as a state-based federal grant program. State CAPs offer direct assistance by phone, direct mail, email, or walk-in locations to help consumers learn how to obtain or use their insurance effectively.
- CMS’s Office of Minority Health produces Coverage to Care (C2C) (https://www.cms.gov/About-CMS/Agency-Information/OMH/equity-initiatives/from-coverage-to-care), which offers healthcare coverage information in multiple languages for providers and patients.

#### Examining Affordable Care Quality Measures by Sub-Areas

Figure 20 Number and percentage of all affordable care measures improving, not changing, or worsening from 2002 to 2017, by sub-areas

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p <0.10.

Stacked bar chart showing number of measures improving and not changing; no measures were worsening Usual Source of Care (n = 4), 2 improving, 2 not changing Financial Burden (n = 1), 0 improving, 1 not changing, 0 worsening

Core measures listed below are noted as improving (green), not changing (yellow), or worsening (red) over time. For more information on how this analysis was conducted, consult the NHQDR Introduction and Methods (https://www.ahrq.gov/sites/default/files/wysiwyg/research/findings/nhqrdr/2019qdr-intro-methods.pdf). For more details about the measures shown here, visit the NHQDR website (https://nhqrnet.ahrq.gov/inhqrdr/).

Table 14 Usual Source of Care Measures

Among a total of 4 measures, 2 were improving over time and 2 were not changing over time. These include measures regarding affordability of medical and dental care.

Sub-Area | Measure Title (Data Source)
Medical Care | People unable to get or delayed in getting needed medical care due to financial or insurance reasons (MEPS)
Prescription Medication | People unable to get or delayed in getting needed prescription medicines due to financial or insurance reasons (MEPS)
Dental Care | People unable to get or delayed in getting needed dental care due to financial or insurance reasons (MEPS)
Primary Care | People without a usual source of care who indicated a financial or insurance reason for not having a source of care (MEPS)

Table 15 Financial Burden of Healthcare Measures

The core set of measures includes only one measure that specifically examines the financial burden of healthcare. This measure was not changing over time.

Sub-Area | Measure Title (Data Source)
Medical Care | People under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income (MEPS)

## Trends in Effective Treatment

As better understanding of health and sickness has led to superior ways of preventing, diagnosing, and treating diseases, the health of most Americans has improved dramatically; however, more than half of all Americans are managing one chronic disease and do not receive the full benefits of high-quality care.^47,48^

The effective treatment quality domain focuses on promoting the most effective prevention and treatment practices for the leading causes of mortality, with a particular emphasis on cardiovascular disease. The NHQDR focuses on leading causes of mortality because these conditions have more robust data available. Musculoskeletal disease is not a leading cause of death, but it is included in the report because it is a leading cause of functional limitation in the United States.

### Importance of Effective Treatment

#### Morbidity and Mortality

Effective treatment interventions have been shown to reduce mortality and morbidity among patients with chronic diseases. The number of deaths for the following conditions show some of the leading causes of death in the United States in 2018:

- Heart disease: 655,381
- Cancer: 599,274
- Chronic lower respiratory diseases: 159,486
- Stroke (cerebrovascular diseases): 147,810
- Alzheimer’s disease: 122,019
- Diabetes: 84,946
- Influenza and pneumonia: 59,120
- Nephritis, nephrotic syndrome, and nephrosis: 51,386
- Intentional self-harm (suicide): 48,344^49^

The prevention of these conditions and reductions in mortality can be supported with effective primary and preventive care.

### Findings on Effective Treatment

The effective treatment priority area includes measures of the following:

- Cancer
  ■ Breast Cancer
  ■ Colorectal Cancer
  ■ Other Cancers
- Cardiovascular Disease
  ■ Prevention of Heart Disease
  ■ Treatment of Heart Attack
  ■ Treatment of Heart Failure
  ■ Surgery for Heart and Vascular Disease
  ■ Stroke
- Chronic Kidney Disease
  ■ Care of End Stage Renal Disease
- Diabetes
  ■ Management of Diabetes
  ■ Control of Diabetes
  ■ Hospitalizations for Diabetes
- HIV/AIDS
  ■ Management of HIV/AIDS
- Mental Health and Substance Use Disorder
  ■ Treatment of Depression
  ■ Treatment of Substance Use Disorder
- Musculoskeletal Disease
- Respiratory Diseases
  ■ Treatment of Respiratory Infections
  ■ Management of Asthma

Measures cover preventive care, treatment of illness, chronic disease management, and outcomes of care. Data for these measures can be found at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

More than 40% of Effective Treatment measures improved, 50% did not change, and about 8% got worse.

The three measures of effective treatment that showed the greatest improvement were measures related to the treatment of illness:

- Adult hemodialysis patients with adequate dialysis - Kt/V 1.2 or higher.
- Doctor’s office and emergency department visits where antibiotics were prescribed for a diagnosis of common cold per 10,000 population.
- Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined.

Three effective treatment measures worsened over time, including two measures pertaining to opioid use and one that looks at suicide mortality:

- Emergency department visits involving opioid-related diagnoses per 100,000 population.
- Hospital inpatient stays involving opioid-related diagnoses per 100,000 population.
- Suicide deaths among people age 12 and over per 100,000 population.

#### Improving Trend: Dialysis Treatment for Patients on Hemodialysis

Dialysis or even a kidney transplant can improve the longevity of patients with kidney failure. Without adequate dialysis, patients on hemodialysis are more likely to incur frequent hospitalizations and emergency department visits. In 2016, nearly 125,000 people in the United States started treatment for end stage renal disease (ESRD), and 2 in every 1,000 people were on dialysis or were living with a kidney transplant. Each day, more than 240 people receiving dialysis will die.^50^

Figure 21 Adult hemodialysis patients with adequate dialysis - Kt/V 1.2 or higher, 2015-2018

Line graph showing percentage 2015 achievable benchmark: 96.5% 2015, 93 2016, 95.2 2017, 96.2 2018, 96.4

Source: University of Michigan Kidney Epidemiology and Cost Center, Dialysis Facility Reports, 2015-2018.

- From 2015 to 2018, overall, the percentage of adult hemodialysis patients with adequate dialysis (kt/V 1.2 or higher) improved from 93% to 96.4% (Figure 21).
- The 2015 achievable benchmark was 96.5%. At the current rate of increase, overall, the benchmark could be achieved in 1 year.
- The top 10% of states that reached the achievable benchmark are Alaska, Hawaii, Maine, Rhode Island, Utah, and Vermont (more than 5 states reached the benchmark due to ties).

#### Improving Trend: Antibiotics for Common Cold

Most people around the world will have one or more common cold episodes each year. However, common colds are caused by viruses, which do not respond to antibiotics, and antibiotics can cause side effects, especially diarrhea. Overuse of antibiotics leads to bacteria becoming resistant to antibiotics.^51^

Figure 22 Doctor’s office and emergency department visits where antibiotics were prescribed for a diagnosis of common cold per 10,000 population, 2010-2011 to 2015-2016

Note: For this measure, lower rates are better.

Line graph showing rate per 10,000 population 2010-2011, 108.8 2011-2012, 106 2012-2013, 72.4 2013-2014, 72.1 2014-2015, 62.3 2015-2016, 42.9

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Ambulatory Medical Care Survey and National Hospital Ambulatory Medical Care Survey, 2010-2011 to 2015-2016.

- From 2010-2011 to 2015-2016, overall, the rate of doctor’s office and emergency department visits where antibiotics were prescribed for a diagnosis of common cold per 10,000 population decreased from 108.8 to 42.9 per 10,000 population (Figure 22).

#### Improving Trend: Colon Cancer Treatment

Surgical treatment is a typical treatment for early stage colon cancers.^52^ Oncology research has shown that the examination and removal of lymph nodes during surgical treatment of colon cancer is linked with better patient outcomes and survival.^53,54^

Figure 23 Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined, 2005-2016

Line graph showing percentage 2015 achievable benchmark: 95.4% 2005, 59.9 2006, 66.8 2007, 76.7 2008, 80.5 2009, 83.5 2010, 85.1 2011, 86.5 2012, 87.9 2013, 89.7 2014, 90.7 2015, 91.7 2016, 92.5

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2016.

- From 2005 to 2016, overall, the percentage of patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined increased from 59.9% to 92.5% (Figure 23).
- The 2015 achievable benchmark was 95.4%. At the current rate of increase, overall, the benchmark could be achieved in 1 year.
- The top 10% of states that reached the achievable benchmark are District of Columbia, Hawaii, Iowa, Maine, Massachusetts, Rhode Island, Vermont, and Wyoming (more than 5 states reached the benchmark due to ties).

#### Worsening Trend: Emergency Department Visits Involving Opioids

The U.S. opioid overdose epidemic continues to evolve. In 2016, 66.4% of the 63,632 drug overdose deaths involved an opioid. In 2017, among 70,237 drug overdose deaths, 47,600 (67.8%) involved opioids, with increases across age groups, racial and ethnic groups, county urbanization levels, and multiple states. From 2013 to 2017, synthetic opioids contributed to increases in drug overdose death rates in several states. From 2016 to 2017, synthetic opioid-involved overdose death rates increased 45.2%.55

Figure 24 Emergency department visits involving opioid-related diagnoses per 100,000 population, 2005-2017

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population 2015 achievable benchmark: 65.3 per 100,000 population 2005, 89.1 2006, 91.8 2007, 82.6 2008, 94.1 2009, 107.4 2010, 117.5 2011, 131.2 2012, 146.8 2013, 166.2 2014, 177.7 2015, 210 2016, 243.5 2017, 249.1

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample and Nationwide Emergency Department Sample, 2005-2017.

- From 2005 to 2017, overall, the rate of emergency department visits related to opioid use per 100,000 population increased from 89.1 to 249.1 per 100,000 population (Figure 24).
- The 2015 achievable benchmark was 65.3 per 100,000 population. There is no evidence of progress toward the benchmark.
- The top 4 states that reached the achievable benchmark are Iowa, Kansas, Nebraska, and South Dakota (only 30 states had data, but there were ties, yielding 4 top states).

#### Worsening Trend: Hospital Stays Involving Opioids

Increased availability and overuse of opioid medications (both prescription and nonprescription drugs) have contributed to adverse outcomes for patients, including increased risk of opioid use disorder, misuse of medication, and overdoses.^56^ The National Survey on Drug Use and Health shows that in 2017, nearly 11.4 million people age 12 and over misused opioids in the past year.^57^ This treatment measure examines inpatient stays associated with an opioid-related diagnoses.

Figure 25 Hospital inpatient stays involving opioid-related diagnoses per 100,000 population, 2005-2017

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population 2015 achievable benchmark: 103 per 100,000 population 2005, 136.8 2006, 164.2 2007, 159 2008, 165.7 2009, 181.4 2010, 197.1 2011, 207.8 2012, 210.4 2013, 213.7 2014, 224.6 2015, 252.5 2016, 296.9 2017, 300

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample and Nationwide Emergency Department Sample, 2005-2017.

- From 2005 to 2017, overall, the rate of hospital inpatient stays related to opioid use increased from 136.8 to 300.0 per 100,000 population (Figure 25).
- The 2015 achievable benchmark was 103 per 100,000 population. There is no evidence of progress toward the benchmark.
- The top 5 states that reached the achievable benchmark are Georgia, Iowa, Nebraska, Texas, and Wyoming.

#### Worsening Trend: Suicide Mortality

Many patients who have completed suicide have encountered or sought healthcare treatment for comorbidities such as depression and anxiety within a year of their death. Still, some patients contemplating suicide go undetected by healthcare providers across multiple settings of care. Researchers have demonstrated that suicide ideation and completion is highest among adults age 65 and over, some of whom may receive care in long-term care facilities such as nursing homes.^58,59^

Figure 26 Suicide deaths among people age 12 and over, per 100,000 population, 2008-2017

Line graph showing rate per 100,000 population 2015 achievable benchmark: 9.4 per 100,000 population 2008 14.0 2009 14.2 2010 14.6 2011 14.9 2012 15.2 2013 15.2 2014 15.7 2015 16.0 2016 16.3 2017 16.9

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System-Mortality, 2000-2017.

- From 2008 to 2017, overall, the rate of suicide deaths among people age 12 and over increased from 14.0 to 16.9 per 100,000 population (Figure 26). In 2017, this rate represented more than 47,109 deaths.
- The 2015 achievable benchmark was 9.4 per 100,000 population. There is no evidence of progress toward the benchmark.
- The top 5 states that reached the achievable benchmark are District of Columbia, Maryland, Massachusetts, New Jersey, and New York.

#### Resources

Efforts to promote effective treatment are underway within HHS:

- At the Agency for Healthcare Research and Quality, the agency has published an evidence reviews, a rapid review, several statistical briefs on opioid use. In May 2020, the U.S. Preventive Services Task Force published a recommendation statement on Illicit Drug Use in Children, Adolescents, and Young Adults: Primary Care-Based Interventions (https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/drug-use-illicit-primary-care-interventions-for-children-and-adolescents).
- AHRQ has also sponsored the development of tools and grant programs, including:
  ■ Six Building Blocks: A Team-Based Approach to Improving Opioid Management in Primary Care (https://www.ahrq.gov/professionals/prevention-chronic-care/improve/six-building-blocks.html). An AHRQ grantee developed a structured systems-based approach for primary care providers and their staff members to improve management of patients on chronic opioid therapy.
  ■ The Academy: Integrating Behavioral Health and Primary Care (https://integrationacademy.ahrq.gov/). AHRQ has previously sponsored the Academy works to expand the integration of behavioral healthcare and primary care. It also supports those who are implementing medication-assisted treatment (MAT) in primary care settings.
- Civil Rights and the Opioid Crisis (https://www.hhs.gov/civil-rights/for-individuals/special-topics/opioids/index.html), a public education campaign implemented by the HHS Office for Civil Rights (OCR) to improve access to evidence-based opioid use disorder treatment and recovery services, such as MAT. This campaign helps covered entities know their obligations under federal nondiscrimination laws, including laws prohibiting discrimination on the basis of disability or limited English proficiency. The campaign includes a video by OCR Director Roger Severino, fact sheets, digital postcards, and a newsletter.
- The National Institutes of Health published How To Help Someone Thinking of Suicide (https://healthreach.nlm.nih.gov/document/117/How-to-Help-Someone-Thinking-of-Suicide), a one-page handout available in 10 languages that teaches people how to help someone thinking of suicide. It identifies signs, symptoms, and behaviors of someone who may be thinking of suicide. It also provides a list of actions people can take to assist a person in crisis. Finally, the handout provides the phone number and web link for the Suicide Prevention Lifeline.
- The Centers for Disease Control and Prevention have published Preventing Suicide: A Technical Package of Policy, Programs, and Practices (https://www.cdc.gov/violenceprevention/pdf/suicidetechnicalpackage.pdf), a select group of strategies based on the best available evidence to help communities and states sharpen their focus on prevention activities with the greatest potential to prevent suicide. These strategies include strengthening economic supports; strengthening access and delivery of suicide care; creating protective environments; promoting connectedness; teaching coping and problem-solving skills; identifying and supporting people at risk; and lessening harms and preventing future risk.
- The Substance Abuse and Mental Health Services Administration (SAMHSA) has several suicide prevention resources, including tools focused on American Indian and Alaska Native communities (https://www.samhsa.gov/tribal-ttac/resources/suicide-prevention), a toolkit for high schools (https://store.samhsa.gov/product/Preventing-Suicide-A-Toolkit-for-High-Schools/SMA12-4669), and videos (https://www.samhsa.gov/suicide/resources).
- In fiscal year 2020, SAMHSA implemented a grant program called Implement Zero Suicide in Health Systems. The Zero Suicide model is a comprehensive, multisetting approach to suicide prevention in health systems. This program is designed to raise awareness of suicide, establish referral processes, and improve care and outcomes for individuals age 25 years and over who are at risk for suicide. Grant recipients, such as the Suicide Prevention Resource Center (https://www.sprc.org/zero-suicide), work to implement the Zero Suicide model throughout their health system.

#### Examining Effective Treatment Measures by Topic Areas

Figure 27 Number and percentage of all effective treatment measures improving, not changing, or worsening from 2000 to 2018, by disease category

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p <0.10.

Stacked column chart showing number of measures improving, not changing, and worsening Cancer (n=6), 6 improving, 0 not changing, 0 worsening Cardiovascular Disease (n=1), 0 improving, 1 not changing, 0 worsening Chronic Kidney Disease (n=6), 3 improving, 3 not changing, 0 worsening Diabetes (n=7), 0 improving, 7 not changing, 0 worsening HIV/AIDS (n=3), 3 improving, 0 not changing, 0 worsening Mental Health and Substance Abuse (n=9), 1 improving, 5 not changing, 3 worsening Musculoskeletal Disease (n=1), 0 improving, 1 not changing, 0 worsening Respiratory Diseases (n=3), 2 improving, 1 not changing, 0 worsening

Core measures listed below are noted as improving (green), not changing (yellow) or worsening (red) over time. For more information on how this analysis was conducted, consult the NHQDR Introduction and Methods (https://www.ahrq.gov/sites/default/files/wysiwyg/research/findings/nhqrdr/2019qdr-intro-methods.pdf). For more details about the measures shown here, please visit the NHQDR website (https://nhqrnet.ahrq.gov/inhqrdr/).

Table 16 Cancer Measures

Among a total of 6 cancer measures, all measures improved over time. These include measures regarding colorectal, breast, and lung cancer.

Sub-Area | Measure Title (Data Source)
Colorectal Cancer | Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined (NCDB)
Breast Cancer | Women under age 70 treated for breast cancer with breast-conserving surgery who received radiation therapy to the breast within 1 year of diagnosis (NCDB)
Breast Cancer | Women with clinical Stage I-IIb breast cancer who received axillary node dissection or sentinel lymph node biopsy (SLNB) at the time of surgery (lumpectomy or mastectomy) (NCDB)
Colorectal Cancer | Colorectal cancer deaths per 100,000 population per year (NVSS-M)
Lung Cancer | Lung cancer deaths per 100,000 population per year (NVSS-M)
Breast Cancer | Breast cancer deaths per 100,000 female population per year (NVSS-M)

Table 17 Cardiovascular Disease Measures

The core set of measures includes one measure examining hypertension. It is not changing over time.

Sub-Area | Measure Title (Data Source)
CVD - Prevention of Heart Disease | Adults with hypertension with blood pressure less than 140/90 mm/Hg (NHANES)

Table 18 Chronic Kidney Disease Measures

All 6 chronic kidney measures pertain to the care of end stage renal disease (ESRD).

Three measures improved, and 3 did not change over time.

Sub-Area | Measure Title (Data Source)
Chronic Care of ESRD | Adult hemodialysis patients with adequate dialysis - Kt/V 1.2 or higher (UMKECC)
Chronic Care of ESRD | Adult end stage renal disease patients who saw a nephrologist at least 12 months prior to initiation of renal replacement therapy (USRDS)
Chronic Care of ESRD | Adult hemodialysis patients who use arteriovenous fistulas as the primary mode of vascular access (USRDS)
Chronic Care of ESRD | Dialysis patients who were registered on a waiting list for transplantation (USRDS)
Chronic Care of ESRD | Patients with treated chronic kidney failure who received a transplant within 3 years of date of renal failure (USRDS)
Chronic Care of ESRD | Hemodialysis patients whose hemoglobin level was less than 10 g/dL (UMKECC)

Table 19 Diabetes Measures

Seven measures relate to diabetes care and none were changing over time.

Sub-Area | Measure Title (Data Source)
Diabetes – Management | Adults age 40 and over with diabetes whose condition was diagnosed (NHANES)
Diabetes – Control | Adults age 40 and over with diagnosed diabetes with blood pressure less than 130/80 mm Hg (NHANES)
Diabetes – Hospitalizations | Adjusted incident rates of end stage renal disease due to diabetes per million population (USRDS)
Diabetes – Management | Adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year (MEPS)
Diabetes – Management | Adults age 40 and over with diagnosed diabetes who received a dilated eye examination in the calendar year (MEPS)
Diabetes – Management | Adults age 40 and over with diagnosed diabetes who received at least two hemoglobin A1c measurements in the calendar year (MEPS)
Diabetes – Management | Adults age 40 and over with diagnosed diabetes who had their feet checked for sores or irritation in the calendar year (MEPS)

Table 20 HIV/AIDS Measures

The core set of measures includes 3 measures that examine HIV management, among which one examines HIV infection mortality. All 3 measures were improving over time.

Sub-Area | Measure Title (Data Source)
HIV/AIDS – Management | HIV infection deaths per 100,000 population (NVSS-M)
HIV/AIDS – Management | New HIV cases per 100,000 population age 13 and over (HIV-AIDSSS)
HIV/AIDS – Management | People age 13 and over living with HIV who know their serostatus (HIV-AIDSSS)

Table 21 Mental Health and Substance Use Disorder Measures

The core set of measures includes only one measure improving over time, which examines depression treatment among nursing home residents. Five measures were not changing and 3 were worsening. The worsening measures include opioid-related diagnoses and suicide mortality among people age 12 and over.

Sub-Area | Measure Title (Data Source)
Depression Treatment | Long-stay nursing home residents with depression symptoms (MDS)
Depression Treatment | Children ages 12-17 with a major depressive episode in the last 12 months who received treatment for depression in the last 12 months (NSDUH)
Substance Use Disorder Treatment | People age 12 and over who needed treatment for an alcohol problem who received such treatment at a specialty facility in the last 12 months (NSDUH)
Substance Use Disorder Treatment | People age 12 and over treated for substance abuse who completed treatment course (TEDS)
Depression Treatment | Adults with a major depressive episode in the last 12 months who received treatment for depression in the last 12 months (NSDUH)
Substance Use Disorder Treatment | People age 12 and over who needed treatment for illicit drug use and who received such treatment at a specialty facility in the last 12 months (NSDUH)
Substance Use Disorder Treatment | Emergency department visits involving opioid-related diagnoses per 100,000 population (HCUP, NEDS)
Substance Use Disorder Treatment | Hospital inpatient stays involving opioid-related diagnoses per 100,000 population (HCUP)
Depression Treatment | Suicide deaths among people age 12 and over per 100,000 population (NVSS-M)

Table 22 Musculoskeletal Disease Measures

The core set of measures includes only one measure that examines musculoskeletal disease. This measure was not changing over time.

Sub-Area | Measure Title (Data Source)
Musculoskeletal | Adults with chronic joint symptoms who have ever seen a doctor or other health professional for joint symptoms (NHIS)

Table 23 Respiratory Disease Measures

The core set of measures includes 3 measures pertaining to respiratory disease. Two measures pertaining to respiratory treatment were improving over time. The core set also includes a care coordination measure pertaining to emergency department visits for asthma among children ages 2-19. Under the effective treatment quality domain, one measure pertaining to asthma management was not changing over time.

Sub-Area | Measure Title (Data Source)
Treatment of Respiratory Infections | Doctor’s office and emergency department visits where antibiotics were prescribed for a diagnosis of common cold per 10,000 population (NAMCS/NHAMCS)
Treatment of Respiratory Infections | Patients with tuberculosis who completed a curative course of treatment within 1 year of initiation of treatment (NTBSS)
Management of Asthma | People with current asthma who are now taking preventive medicine daily or almost daily (either oral or inhaler) (MEPS)

## Trends in Healthy Living

Many illnesses associated with chronic conditions are related to unhealthy behaviors, environmental hazards, and poor social supports. These illnesses can be prevented by increasing access to effective clinical preventive services and promoting community interventions that advance public and population health. Working with communities is critical to ensure that immunizations and early detection and prevention services reach everyone who needs them and to build healthy neighborhoods and support networks.

Promoting healthy lifestyles that prevent disease and disability is better for people and more efficient than treating conditions after organ damage has occurred.

### Importance of Healthy Living

#### Morbidity and Mortality

Healthy living is supported through preventive care strategies that cross all age groups and the care continuum. Among the most impactful preventive strategies include immunization and vaccination for children and prenatal care.

Advances in medical science protect children against more diseases than ever before. Some diseases that once injured or killed thousands of children have been eradicated completely and others are close to eradication, primarily due to safe and effective vaccines. Polio is one example of the great impact vaccines have had in the United States. Polio was once America’s most feared disease, causing death and paralysis across the country, but today, thanks to vaccination, there are no reports of polio in the United States.

Effective and continuous prenatal care can also improve the birth and health outcomes for mothers and children. Currently, the NHQDR tracks one preventive health measure related to maternal health (i.e., women who completed a pregnancy in the last 12 months who received early and adequate prenatal care).

Research has shown that most cases of maternal mortality and severe maternal morbidity are preventable, and prevention strategies can directly reduce morbidity and mortality.^60,61,62^ Recognition is growing of the need to develop, monitor, and improve performance on quality measures in obstetrics care, particularly around disparities.^63^ Addressing disparities in maternal health and birth outcomes is a national priority, covered in The Surgeon General’s Call to Action To Improve Maternal Health (https://www.hhs.gov/sites/default/files/call-to-action-maternal-health.pdf).^64^

#### Cost

There is a strong body of research that shows the cost effectiveness of immunization; however, there are still opportunities for providers, patients and systems to optimize immunization participation. It is less expensive to prevent a disease using immunization than to treat it. In a 2005 study on the economic impact of routine childhood immunization in the United States, researchers estimated that for every dollar spent, the vaccination program saved more than $5 in direct costs and approximately $11 in additional costs to society.^65^

### Findings on Healthy Living

The healthy living priority area includes measures of:

- Maternal and Child Health.
- Lifestyle Modification.
- Functional Status Preservation and Rehabilitation.
- Supportive and Palliative Care.
- Clinical Preventive Services.

Data for these measures can be found at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

Out of 70 Healthy Living measures, 44 focus on Clinical Preventive Services (e.g., immunizations, screenings and counseling).

Almost 60% of Healthy Living measures improved and three worsened over time.

The top healthy living measures that showed improvement over time included two vaccination measures:

- Home health patients who had influenza vaccination during flu season.
- Long-stay nursing home residents with physical restraints.
- Adolescents ages 16-17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of 10 years.

Three healthy living measures worsened over time, including two that examined care for nursing home residents and one on cervical cancer screening for women:

- Long-stay nursing home residents who were assessed for pneumococcal vaccination.
- Low-risk, long-stay nursing home residents with loss of control of bowels or bladder.
- Women ages 21-65 who received a Pap smear in the last 3 years.

These measures are also discussed in the disparities section to show narrowing and widening disparities gaps (see Disparities section, Race, Income).

#### Improving Trend: Influenza Vaccinations in Home Health Patients

Influenza vaccination is a proven preventative strategy for reducing the incidence of influenza. All people ages 6 months or older are recommended to receive the vaccination and vulnerable populations including home health patients are especially encouraged to do so.^66^

Figure 28 Home health patients who had influenza vaccination during flu season, 2013-2017

Line graph showing percentage 2015 achievable benchmark: 94.1% 2013, 71.5 2014, 72.1 2015, 87.3 2016, 93 2017, 95

Source: Centers for Medicare & Medicaid Services, Outcome and Assessment Information Set, 2013-2017.

- From 2013 to 2017, overall, the percentage of home health patients who had influenza vaccinations during the flu season increased from 71.5% to 95.0% (Figure 28).
- The 2015 achievable benchmark was 94.1%. The outcome in 2017 was better than the benchmark.
- The top 10% of states that reached the achievable benchmark are Montana, Nebraska, North Dakota, South Dakota, Vermont, and Wisconsin (more than 5 states reached the benchmark due to ties).

#### Improving Trend: Physical Restraint Use in Nursing Home Residents

Long-stay residents typically enter a nursing facility because they can no longer care for themselves at home. They tend to remain in the facility for several months or years. Most residents want to care for themselves, and the ability to perform daily activities is important to their quality of life. While some functional decline among residents cannot be avoided, high-quality nursing home care should minimize the rate of decline and the number of patients experiencing decline.

Figure 29 Long-stay nursing home residents with physical restraints, 2013-2017

Note: For this measure, lower rates are better.

Line graph showing percentage 2015 achievable benchmark: 0.27% 2013, 1.33 2014, 1.05 2015, 0.78 2016, 0.51 2017, 0.38

Source: Centers for Medicare & Medicaid Services, Minimum Data Set, 2013-2017.

- From 2013 to 2017, overall, the percentage of long-stay nursing home patients with physical restraints decreased from 1.33% to 0.38% (Figure 29).
- The 2015 achievable benchmark was 0.27%. At the current rate of decrease, the benchmark could be met in about 1 year.
- The top 10% of states (based on 35 states with data) that reached the achievable benchmark are Arizona, Kansas, Minnesota, Nebraska, and New Hampshire (more than 4 states reached the benchmark due to ties).

#### Improving Trend: Adolescent Tdap Vaccination

CDC’s Advisory Committee on Immunization Practices recommends routine vaccination for tetanus, diphtheria, and pertussis. Infants and young children are recommended to receive a 5-dose series of diphtheria and tetanus toxoids and acellular pertussis (DTaP) vaccines, with one adolescent booster dose of Tdap vaccine. One study noted that the cost per quality-adjusted life-year saved from immunization would be approximately $163,361 (booster at 16 years) and $204,556 (booster at 21 years).^67^

Figure 30 Adolescents ages 16-17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of 10 years, 2008-2017

Line graph showing percentage 2015 achievable benchmark: 96% 2008, 31.9 2009, 45.3 2010, 60.2 2011, 74.8 2012, 83.6 2013, 83.7 2014, 86.6 2015, 85.3 2016, 88 2017, 89

Source: Centers for Disease Control and Prevention, National Center for Immunization and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2017.

- From 2008 to 2017, overall, the percentage of adolescents ages 16-17 years who received 1 or more doses of Tdap vaccine increased from 31.9% to 89.0% (Figure 30).
- The 2015 achievable benchmark was 96%. At the current rate of increase, overall, the benchmark could be achieved in 1 year.
- The top 5 states that reached the achievable benchmark are Alabama, Georgia, Missouri, Rhode Island, and Vermont.

#### Worsening Trend: Pneumococcal Vaccinations in Nursing Home Residents

The Advisory Committee on Immunization Practices (ACIP) recommends that all adults over 65 years of age and those with risk factors including chronic disease diagnosis should receive pneumococcal vaccinations.^68^

Figure 31 Long-stay nursing home residents who were assessed for pneumococcal vaccination, 2013-2017

Line graph showing percentage 2015 achievable benchmark: 97% 2013, 93.8 2014, 93.3 2015, 92.9 2016, 92.7 2017, 92.5

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Residence Assessment Files, MDS 3.0, 2013-2017.

- From 2013 to 2017, overall, the percentage of long-stay nursing home residents who were assessed for pneumococcal vaccination decreased from 93.8% to 92.5% (Figure 31).
- The 2015 achievable benchmark was 97%. There is no evidence of progress toward the benchmark.
- The top 10% of states that reached the achievable benchmark are Delaware, Mississippi, New Hampshire, North Dakota, Utah, and Wisconsin (more than 5 states reached the benchmark due to ties).

#### Worsening Trend: Incontinence in Nursing Home Residents

Urinary and fecal incontinence affect 50% or more of nursing home residents. This condition is exacerbated by residents facing increased prevalence of dementia and inability to care for themselves independently.^69^ Research has shown that incontinence can be cured or successfully managed. However, some caregivers lack sufficient knowledge to intervene appropriately.^70^

Figure 32 Low-risk, long-stay nursing home residents with loss of control of bowels or bladder, 2013-2017

Line graph showing percentage 2015 achievable benchmark: 63% 2013, 64.2 2014, 71.8 2015, 72.5 2016, 73 2017, 74.3

Source: Centers for Medicare & Medicaid Services, Skilled Nursing Facility Quality Reporting Program, Residence Assessment Files, MDS 3.0, 2013-2017.

- From 2013 to 2017, overall, the percentage of low-risk, long-stay nursing home residents with loss of control of bowels or bladders increased from 64.2% to 74.3% (Figure 32).
- The 2015 achievable benchmark was 63%. There is no evidence of progress toward the benchmark.
- The top 10% of states (based on 34 states) that reached the achievable benchmark are Missouri, Nebraska, and New Jersey.

#### Worsening Trend: Receipt of Pap Smear

The U.S. Preventive Services Task Force recommends cervical cancer screening as part of routine health maintenance for women ages 21 through 65. Cervical cancer incidence and mortality rates have declined since the introduction of the Pap smear in the mid-20th century, and rates continue to decline to this day; however, the overall rate of women receiving preventive care is declining.^71^

Figure 33 Women ages 21-65 who received a Pap smear in the last 3 years, 2000-2018

Note: The NHIS cancer supplement is not administered annually. U.S. Preventive Services Task Force guidelines for cervical cancer screening changed in 2012 and 2018 to include additional screening options (e.g., HPV testing). Thus, these data may not reflect the full extent of cervical cancer screening. It is also possible that decreases in receipt of Pap smears were related to receipt of other forms of testing. The 2018 U.S. Preventive Services Task Force guidelines recommend screening for cervical cancer with a Pap smear every 3 years in women ages 21-29 years. For women ages 30-65 years, the recommendations are screening every 3 years with a Pap smear alone, every 5 years with HPV testing alone, or every 5 years with HPV testing in combination with a Pap smear.

Line graph showing percentage 2015 achievable benchmark: 84.2% 2000, 87.5 2005, 85.3 2008, 84.5 2010, 82.8 2013, 80.7 2015, 81.2 2018, 80.5

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2000-2018.

- From 2000 to 2018, overall, the percentage of women ages 21-65 who received a Pap smear in the last 3 years decreased from 87.5% to 80.5%% (Figure 33).
- The 2015 achievable benchmark was 84.2%. There is no evidence of progress toward the benchmark.
- The top 10% of states (based on 43 states) that reached the achievable benchmark are District of Columbia, Illinois, Massachusetts, and North Carolina.

#### Resources

Efforts to promote healthy living are underway within HHS. For example:

- AHRQ sponsors the U.S. Preventive Services Task Force (https://www.uspreventiveservicestaskforce.org/uspstf/), a group of independent volunteer clinicians who review evidence-based clinical guidelines and offer clinical recommendations to the provider community. Their recommendations include preventive healthcare strategies, such as cervical cancer screening (https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/cervical-cancer-screening).
- The CAHPS Ambulatory Care Improvement Guide includes Strategy 6R, Reminder Systems for Immunizations and Preventive Services (https://www.ahrq.gov/cahps/quality-improvement/improvement-guide/6-strategies-for-improving/health-promotion-education/strategy6r-reminder-systems.html) directed to patients and to clinicians.

#### Summarizing Healthy Living Measures by Topic Areas

The core healthy living measure trends in the 2019 NHQDR are summarized in Figure 34 by topic area. The topic areas are clinical preventive services, functional status preservation and rehabilitation, supportive and palliative care, lifestyle modification, and maternal and child health.

Figure 34 Number and percentage of all healthy living measures improving, not changing, or worsening from 2000 to 2018, by topic areas

Stacked bar chart showing number of measures improving, not changing, and worsening Clinical Preventive Services (n=44), 24 improving, 18 not changing, 2 worsening Functional Status Preservation and Rehabilitation (n=6), 5 improving, 1 not changing, 0 worsening Supportive and Palliative Care (n=9), 6 improving, 2 not changing, 1 worsening Lifestyle Modification (n=8), 5 improving, 3 not changing, 0 worsening Maternal and Child Health (n=3), 1 improving, 2 not changing, 0 worsening

The Clinical Preventive Services measures (n=44) in the Healthy Living section are further broken out by sub-areas due to the volume of measures in Figure 34. These sub-areas include adult preventive care, childhood immunization, other childhood preventive care, and overall preventive care.

Figure 35 Number and percentage of all clinical preventive services measures improving, not changing, or worsening from 2000 to 2018, by sub-areas

Key: n = number of measures.

Note: For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p <0.10.

Stacked bar chart showing number of measures improving, not changing, and worsening Adult Preventive Care (n=14), 7 improving, 6 not changing, 1 worsening Childhood Immunization (n=14), 9 improving, 5 not changing, 0 worsening Other Childhood Preventive Care (n=11), 6 improving, 5 not changing, 0 worsening Overall Preventive Care (n=5), 2 improving, 2 not changing, 1 worsening

Core measures listed below are noted as improving (green), not changing (yellow), or worsening (red) over time. For more information on how this analysis was conducted, consult the NHQDR Introduction and Methods (https://www.ahrq.gov/sites/default/files/wysiwyg/research/findings/nhqrdr/2019qdr-intro-methods.pdf). For more details about the measures shown here, visit the NHQDR website (https://nhqrnet.ahrq.gov/inhqrdr/).

The measures represented in Figures 34 and 35 are represented in tables 24-31 below. For more information about the average annual percentage change and the statistical significance for these measures, visit {insert link here}.

Table 24 Clinical Preventive Measures: Adult Preventive Care

The core set of measures includes 7 measures that were improving. Improving measures included 1 measure examining adult cholesterol, 2 cancer screening measures, and 4 measures pertaining to influenza or pneumonia vaccination. Six measures were not changing over time and one measure examining cervical cancer screening worsened over time.

Sub-Area | Measure Title (Data Source)
Adult Cholesterol | Adults who received a blood cholesterol measurement in the last 5 years (NHIS)
Colorectal Cancer Diagnosis | Colorectal cancer diagnosed at advanced stage (tumors diagnosed at regional or distant stage) per 100,000 population age 50 and over (NPCR-USCS)
Adult Influenza Vaccination | Adults age 65 and over who received an influenza vaccination in the last flu season (NHIS)
Adult Pneumonia Vaccination | Adults age 65 and over who ever received pneumococcal vaccination (NHIS)
Adult Influenza Vaccination | Adults ages 18 and over who received influenza vaccination in the last flu season (NHIS)
Cervical Cancer Diagnosis | Cervical cancer diagnosed at advanced stage (all invasive tumors) per 100,000 women age 20 and over (NPSC-USCS)
Adult Influenza Vaccination | Adults ages 18-64 at high risk (e.g., COPD) who received an influenza vaccination in the last flu season (NHIS)
Adult Blood Pressure | Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high (NHIS)
Adult Pneumonia Vaccination | Adults ages 18-64 at high risk (e.g., COPD) who ever received pneumococcal vaccination (NHIS)
Breast Cancer Diagnosis | Breast cancer diagnosed at advanced stage (regional, distant stage, or local stage with tumor greater than 2 cm) per 100,000 women age 40 and over (NPCR-USCS)
Adult Dental Visit | Adults with a dental visit in the calendar year (MEPS)
Adult Preventive Dental Service | Adults who received a preventive dental service in the calendar year (MEPS)
Breast Cancer Screening | Women ages 50-74 who received a mammogram in the last 2 years (NHIS)
Cervical Cancer Screening | Women ages 21-65 who received a Pap smear in the last 3 years (NHIS)

Table 25 Clinical Preventive Measures: Childhood Immunization

The core set of childhood immunization measures includes 9 measures that were improving and 5 measures that were not changing over time. These measures pertain to vaccines for tetanus-diphtheria-acellular pertussis (Tdap), meningitis, human papillomavirus (HPV), varicella, influenza, polio, diphtheria-tetanus-pertussis (DTP), hepatitis B, and measles-mumps-rubella (MMR).

Sub-Area | Measure Title (Data Source)
Adolescent – Tdap | Adolescents ages 16-17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis since the age of 10 years (NIS-TEEN)
Adolescent – Tdap | Adolescents ages 13-15 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis since the age of 10 years (NIS-TEEN)
Adolescent – Meningitis | Adolescents ages 16-17 who received 1 or more doses of meningococcal conjugate vaccine (NIS-TEEN)
Adolescent – HPV | Adolescent males ages 13-15 who received 3 or more doses of human papillomavirus vaccine (NIS-TEEN)
Adolescent – HPV | Adolescent females ages 16-17 who received 3 or more doses of human papillomavirus vaccine (NIS-TEEN)
Pediatric – Varicella | Children ages 19-35 months who received 1 or more doses of varicella vaccine (NIS)
Adolescent – HPV | Adolescent females ages 13-15 who received 3 or more doses of human papillomavirus vaccine (NIS-TEEN)
Pediatric –Influenza | Children ages 6 months to 17 years who received influenza vaccination in the last flu season (NHIS)
Pediatric – Polio | Children ages 19-35 months who received 3 or more doses of polio vaccine (NIS)
Adolescent – HPV | Adolescent males ages 16-17 who received 3 or more doses of human papillomavirus vaccine (NIS-TEEN)
Pediatric –DTP | Children ages 19-35 months who received 4 or more doses of diphtheria-tetanus-pertussis vaccine (NIS)
Pediatric – Hepatitis B | Children ages 19-35 months who received 3 or more doses of hepatitis B vaccine (NIS)
Pediatric – MMR | Children ages 19-35 months who received 1 or more doses of measles-mumps-rubella vaccine (NIS)
Adolescent – Meningitis | Adolescents ages 13-15 who received 1 or more doses of meningococcal conjugate vaccine (NIS-TEEN)

Table 26 Clinical Preventive Measures: Other Childhood Preventive Care

Six improving measures pertain to multiple sub-areas, including height/weight measurement, wellness visits, vision screening, and counseling about travel safety. Five measures were not changing over time, including dental care, counseling about secondhand smoke, and counseling for travel safety.

Sub-Area | Measure Title (Data Source)
Pediatric Height and Weight | Children who had their height and weight measured by a health provider within the past 2 years (MEPS)
Pediatric Wellness Visit | Children ages 0-17 with a wellness checkup in the past 12 months (NHIS)
Pediatric Vision Screening | Children ages 3-5 who ever had their vision checked by a health provider (MEPS)
Counseling – Travel Safety | Children 41-80 lb for whom a health provider gave advice within the past 2 years about using a booster seat when riding in the car (MEPS)
Counseling – Travel Safety | Children 0-40 lb for whom a health provider gave advice within the past 2 years about using a child safety seat while riding in the car (MEPS)
Counseling – Travel Safety | Children over 80 lb for whom a health provider gave advice within the past 2 years about using lap or shoulder belts when riding in a car (MEPS)
Pediatric Dental Caries | Children ages 5-17 with untreated dental caries (NHANES)
Counseling – Secondhand Smoke | Children for whom a health provider gave advice within the past 2 years about how smoking in the house can be bad for a child (MEPS)
Counseling – Travel Safety | Children ages 2-17 for whom a health provider gave advice within the past 2 years about using a helmet when riding a bicycle or motorcycle (MEPS)
Pediatric Dental Visit | Children ages 2-17 who had a dental visit in the calendar year (MEPS)
Pediatric Preventive Dental Service | Children ages 2-17 who received a preventive dental service in the calendar year (MEPS)

Table 27 Clinical Preventive Measures: Overall Preventive Care

The core set of measures includes 2 measures improving over time that look at influenza vaccination in home health care and nursing home care. Two nursing home measures did not change over time and one measure examining pneumococcal vaccination in long-stay nursing home residents worsened.

Sub-Area | Measure Title (Data Source)
Home Health | Home health patients who had influenza vaccination during flu season (OASIS)
Nursing Home | Long-stay nursing home patients who were assessed and appropriately given the seasonal influenza vaccine (MDS)
Nursing Home | Short-stay nursing home patients who had flu vaccination appropriately given (MDS)
Nursing Home | Short-stay nursing home residents who were assessed for pneumococcal vaccination (MDS)
Nursing Home | Long-stay nursing home residents who were assessed for pneumococcal vaccination (MDS)

Table 28 Functional Status Preservation and Rehabilitation Measures

The core set of measures includes four home health measures that were improving over time. One nursing home measure also improved and one measure was not changing over time.

Sub-Area | Measure Title (Data Source)
Home Health | Home health care patients whose ability to get in and out of bed improved (OASIS)
Home Health | Home health care patients whose ability to walk or move around improved (OASIS)
Home Health | Home health care patients whose bathing improved (OASIS)
Home Health | Home health care patients who had improvement in toileting (OASIS)
Nursing Home | Long-stay nursing home residents whose need for help with daily activities increased (MDS)
Nursing Home | Long-stay nursing home residents whose ability to move independently worsened (MDS)

Table 29 Supportive and Palliative Care Measures

Six measures pertaining to nursing home care and home health care improved over time. Two measures, one examining weight loss in nursing home residents and one related to home health care, did not change over time. One nursing home measure examining bowel and bladder control among residents worsened over time.

Sub-Area | Measure Title (Data Source)
Nursing Home | Long-stay nursing home residents with physical restraints (MDS)
Home Health | Home health care patients whose shortness of breath decreased (OASIS)
Nursing Home | Short-stay nursing home residents with moderate to severe pain (MDS)
Home Health | Home health care patients whose pain when moving around decreased (OASIS)
Nursing Home | Long-stay nursing home residents with moderate to severe pain (MDS)
Home Health | Home health patients who had improvement in upper body dressing (OASIS)
Nursing Home | Long-stay nursing home residents with too much weight loss (MDS)
Home Health | Home health care patients who stayed at home after an episode of home health care (OASIS)
Nursing Home | Low-risk, long-stay nursing home residents with loss of control of bowels or bladder

Table 30 Lifestyle Modification Measures

Five core measures improved over time. These measures examine related topics, including diet, obesity, smoking in adults, and exercise or fitness. Three measures were not changing over time and include measures examining pediatric and adult obesity.

Sub-Area | Measure Title (Data Source)
Pediatric Diet and Obesity | Children ages 2-17 for whom a health provider gave advice within the past 2 years about healthy eating (MEPS)
Smoking in Adults | Adult current smokers who had a doctor’s office or clinic visit in the last 12 months who received advice from their providers to quit smoking (MEPS)
Pediatric Exercise and Fitness | Children ages 2-17 for whom a health provider gave advice within the past 2 years about the amount and kind of exercise, sports, or physically active hobbies they should have (MEPS)
Adult Diet and Obesity | Adults with obesity age 20 and over who had been told by a doctor or health professional that they were overweight (NHANES)
Adult Exercise and Fitness | Adults with obesity who ever received advice from a health professional to exercise more (MEPS)
Pediatric Weight | Children with obesity 2-19 years of age who had been told by a doctor or health professional that they were overweight (NHANES)
Adult Diet and Obesity | Adults with obesity who ever received advice from a health professional about eating fewer high-fat or high-cholesterol foods (MEPS)
Pediatric Diet and Obesity | Children ages 2-19 with obesity (NHANES)

Table 31 Maternal and Child Health Measures

The core set of measures includes only one measure that examines breastfeeding and this measure improved over time. Two measures examined infant mortality and low birth weight. These measures were not changing over time.

Sub-Area | Measure Title (Data Source)
Breastfeeding | Infants born in the calendar year who were breastfed exclusively through 3 months (NIS)
Infant Mortality | Infant mortality per 1,000 live births, birth weight 2,500 grams or more (NVSS-L)
Infant Birth Weight | Live-born infants with low birth weight (less than 2,500 g) (NVSS-L)

i ICD-9-CM: International Classification of Diseases, Ninth Revision, Clinical Modification.

ii ICD-10-CM/PCS: International Classification of Diseases, Tenth Revision, Clinical Modification and Procedure Coding System.

iii For example, Section 1557 of the Affordable Care Act (ACA), 42 U.S.C. 18116, and Title VI of the Civil Rights Act of 1964, 42 U.S.C. 2000d, require the practitioner or hospital to take reasonable steps to ensure meaningful access to individuals with limited English proficiency, such as providing language interpreters and translating vital documents. Section 1557 of the ACA and Section 504 of the Rehabilitation Act of 1973, 29 U.S.C. 794, require the practitioner or hospital to take appropriate steps to ensure effective communication with individuals with disabilities, such as by providing sign language interpreters, materials in Braille, and/or accessible electronic formats.

iv The Institute of Medicine formally changed its name to the National Academy of Medicine (NAM) in 2015.