# ACCESS TO HEALTHCARE AND DISPARITIES IN ACCESS

Access to healthcare means having “the timely use of personal health services to achieve the best health outcomes.”^1^ Access to comprehensive, quality healthcare services is important for promoting and maintaining health, preventing and managing disease, reducing unnecessary disability and premature death, and achieving health equity for all Americans.^2^ Attaining good access to care means having:

- Health insurance that facilitates entry into the healthcare system.
- Timely access to needed care.
- A usual source of care with whom the patient can develop a relationship.
- The ability to receive care when there is a perceived need for care.

Measures of access to care tracked in the NHQDR include having health insurance, having a usual source of care, encountering difficulties when seeking care, and receiving care as soon as wanted.

Historically, Americans have experienced variable access to care based on race, ethnicity, socioeconomic status, age, sex, disability status, sexual orientation, gender identity, and residential location.^3^ This report discusses findings that showed the largest statistically significant disparities related to some of these variables for which data were available.

Figure 1 Number and percentage of access measures for which measures were improving, not changing, or worsening, by access area, 2000 through 2016, 2017, or 2018

Key: n = number of measures.

Note: Worsening Health Insurance measures include adults age 65 and over with any private insurance. However, the figures in this section do not include this measure, because the data are open to interpretation. While the percentage of people age 65 and over with any private insurance has decreased, it is not “worsening,” per se, and does not necessarily represent gaps in access to care. The decrease might represent a shift in the insurance market, with people opting for Medicare Advantage.

For each measure with at least four data points over time, the estimates are realigned to the negative direction. Then, unweighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Progress on individual measures is determined as follows:

- Improving = The average annual percentage change is 1% or greater in the desirable direction, and p <0.10.
- Not Changing = The average annual percentage change is less than 1% in either the desirable or undesirable direction or p >0.10.
- Worsening = The average annual percentage change is 1% or greater in the undesirable direction, and p <0.10.

Stacked column showing number of measures in each access area improving, not changing, and worsening Access Total (20 measures): Improving, 11, Not Changing, 5, Worsening, 4 Health Insurance (5 measures): Improving, 3, Not Changing, 0, Worsening, 2 Usual Source of Care (3 measures): Improving, 2, Not Changing, 1, Worsening, 0 Timely Access to Care (4 measures): Improving, 2, Not Changing, 2, Worsening, 0 Patient Perception of Need (8 measures): Improving, 4, Not Changing, 2, Worsening, 2

- Overall, 11 access measures were improving and 4 were worsening (Figure 1).
- Of the measures that showed improvement:
  ■ Three were measures of health insurance.
  ■ Two measures related to usual source of care.
  ■ Two were measures of timely access to care.
  ■ Four measures related to patient perception of need.
- Access measures that showed worsening trends include:
  ■ Two measures of health insurance.
  ■ Two measures of patient perception of need.

Table 1 Health Insurance Availability Measures

Measure Title (Data Source) | Trend Result
People under age 65 with health insurance (NHIS) | Improving
People under age 65 who were uninsured all year (MEPS) | Improving
People under age 65 with any period of uninsurance during the year (MEPS) | Improving
Adults age 65 and over with any private health insurance (NHIS)^i^ | Worsening
People under age 65 with any private health insurance (NHIS)^i^ | Worsening

Table 2 Usual Source of Care Measures

Measure Title (Data Source) | Trend Result
People with a specific source of ongoing care (NHIS) | Improving
People in fair or poor health with a specific source of ongoing care (NHIS) | Improving
People with a usual primary care provider (MEPS) | Not Changing

Table 3 Timely Access: Wait Time Measures

Measure Title (Data Source) | Trend Result
Adults who reported getting the help or advice they needed the same day they contacted their home health providers (HHCAHPS) | Not Changing

Table 4 Timely Access: Getting Appointments for Care Measures

Measure Title (Data Source) | Trend Result
Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed (MEPS) | Improving
Adults who needed care right away for an illness, injury, or condition in the last 12 months who sometimes or never got care as soon as needed (MEPS) | Improving
Adults who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed (MEPS) | Not Changing

Table 5 Patient Perception of Need Measures

Measure Title (Data Source) | Trend Result
Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment (MEPS) | Improving
People with a usual source of care who is somewhat to very difficult to contact during regular business hours over the telephone (MEPS) | Improving
People who were unable to get or delayed in getting needed dental care in the last 12 months (MEPS) | Improving
People who were unable to get or delayed in getting needed medical care in the last 12 months (MEPS) | Improving
People who were unable to get or delayed in getting needed prescription medicines in the last 12 months (MEPS) | Not Changing
People with a usual source of care, excluding hospital emergency rooms, who has office hours at night or on weekends (MEPS) | Not Changing
Children who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment (MEPS) | Worsening
Children who needed to see a specialist in the last 12 months who sometimes or never found it easy to see a specialist (MEPS) | Worsening

## Health Insurance

Increased health insurance coverage is associated with statistically significant and clinically relevant improvements for low-income adults, including access to care, use of preventive services, and self-reported health. Among those with chronic conditions, increased coverage is linked to improved medication adherence, more regular communication with physicians, and improved perceived health status.^4^

### Improving Measures

The three measures of health insurance that improved were:

- People under age 65 with health insurance.
- People under age 65 who were uninsured all year.
- People under age 65 with any period of uninsurance during the year.

Figure 2 People under age 65 with health insurance, 2000-2018

Line graph showing percentage of people with health 2000, 83 2001, 83.6 2002, 83.2 2003, 83.5 2004, 83.6 2005, 83.6 2006, 83 2007, 83.4 2008, 83.2 2009, 82.5 2010, 81.8 2011, 82.8 2012, 83.1 2013, 83.3 2014, 86.7 2015, 89.4 2016, 89.7 2017, 89.3 2018, 89

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2000-2018.

- From 2000 to 2018, the percentage of people under age 65 with health insurance increased from 83.0% to 89.0% (Figure 2).

Figure 3 People under age 65 who were uninsured all year, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing percentage of uninsured people 2002, 13.4 2003, 13.7 2004, 14.1 2005, 14.1 2006, 14.3 2007, 15.2 2008, 15.4 2009, 15.5 2010, 15.0 2011, 14.5 2012, 14.8 2013, 15.0 2014, 11.5 2015, 9.5 2016, 9.0 2017, 7.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, the percentage of people under age 65 who were uninsured all year decreased from 13.4% to 7.8% (Figure 3).

Figure 4 People under age 65 with any period of uninsurance during the year, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing percentage of people with any period of uninsurance 2002, 25.5 2003, 25.2 2004, 25.7 2005, 25.8 2006, 26.1 2007, 26.9 2008, 28.1 2009, 26.9 2010, 26 2011, 25.2 2012, 25.4 2013, 26.3 2014, 23.9 2015, 20.7 2016, 19.5 2017, 18.7

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, the percentage of people under age 65 with any period of uninsurance during the year decreased from 25.5% to 18.7% (Figure 4).

### Worsening Measures

The two measures of insurance that worsened were:

- Adults age 65 and over with any private health insurance (figure not included because of difficulty interpreting results).^ii^
- People under age 65 with any private health insurance.

Figure 5 People under age 65 with any private health insurance, 2000-2018

Line graph showing percentage of people with private insurance 2000, 71.5 2001, 71.2 2002, 69.4 2003, 68.9 2004, 68.8 2005, 68.2 2006,66.3 2007, 66.8 2008, 65.6 2009, 63.3 2010, 61.7 2011, 61.8 2012, 61.8 2013, 61.8 2014, 63.7 2015, 65.5 2016, 65.7 2017, 65.7 2018, 65.3

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2000-2018.

- From 2000 to 2018, the percentage of people under age 65 with any private health insurance decreased from 71.5% to 65.3% (Figure 5).

### Health Insurance Coverage: Early Release Program

In previous years, the NHQDR included the CDC’s National Center for Health Statistics (NCHS) National Health Interview Survey (NHIS) Early Release Program selected estimates of data regarding health and healthcare for the civilian noninstitutionalized U.S. population. The 2019 NHQDR includes estimates of health insurance coverage for the civilian noninstitutionalized U.S. population based on data from the January-June 2019 NHIS. These estimates are being published prior to final data editing and final weighting to provide access to the most recent information from NHIS. The 2019 NHIS has been redesigned, so comparisons between 2019 and prior data years are not being made.

The Early Release of Estimates From the National Health Interview Survey are not included in the summary analyses presented in this report. Final 2019 estimates will be included in the 2020 NHQDR. More information about the estimates are available on the NHIS website (https://www.cdc.gov/nchs/nhis.htm).

Figure 6 Adults ages 18-64 who were uninsured or had private or public coverage at the time of interview, 2019

Note: People were defined as uninsured if they did not have any private health insurance, Medicare, Medicaid, Children’s Health Insurance Program (CHIP), state-sponsored or other government plan, or military plan. People were also defined as uninsured if they had only Indian Health Service coverage or had only a private plan that paid for one type of service, such as accidents or dental care. Public coverage includes Medicaid, CHIP, state-sponsored or other government-sponsored health plan, Medicare, and military plans. Private coverage includes any comprehensive private insurance plan (including health maintenance and preferred provider organizations). These plans include those obtained through an employer, purchased directly, purchased through local or community programs, or purchased through the Health Insurance Marketplace or a state-based exchange. Private coverage excludes plans that pay for only one type of service, such as accidents or dental care. A small number of people were covered by both public and private plans and were included in both categories. Data are based on household interviews of a sample of the civilian noninstitutionalized population.

Bar chart shows that in 2019, among adults ages 18-64, 14.7% were uninsured, 20.4% had public coverage, and 66.8% had private health insurance coverage.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey Early Release Program, May 2020. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur202009-508.pdf.

- In 2019, 33.2 million people of all ages (10.3%) were uninsured at the time of interview (data not shown).
- In 2019, among adults ages 18-64, 14.7% were uninsured at the time of interview, 20.4% had public coverage, and 66.8% had private health insurance coverage (Figure 6).

Figure 7 Children ages 0-17 years who were uninsured or had private or public coverage at the time of interview, 2019

Note: People were defined as uninsured if they did not have any private health insurance, Medicare, Medicaid, Children’s Health Insurance Program (CHIP), state-sponsored or other government plan, or military plan. People were also defined as uninsured if they had only Indian Health Service coverage or had only a private plan that paid for one type of service, such as accidents or dental care. Public coverage includes Medicaid, CHIP, state-sponsored or other government-sponsored health plan, Medicare, and military plans. Private coverage includes any comprehensive private insurance plan (including health maintenance and preferred provider organizations). These plans include those obtained through an employer, purchased directly, purchased through local or community programs, or purchased through the Health Insurance Marketplace or a state-based exchange. Private coverage excludes plans that pay for only one type of service, such as accidents or dental care. A small number of people were covered by both public and private plans and were included in both categories. Data are based on household interviews of a sample of the civilian noninstitutionalized population.

Bar chart shows that in 2019, among children ages 0-17 years, 5.1% were uninsured, 41.4% had public coverage, and 55.2% had private health insurance coverage.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey Early Release Program, May 2020. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur202009-508.pdf.

- In 2019, among children ages 0-17 years, 5.1% were uninsured, 41.4% had public coverage, and 55.2% had private health insurance coverage (Figure 7).

Figure 8 Adults ages 18-64 who were uninsured at the time of interview, by poverty status, 2019

Note: For this measure, lower rates are better. Poverty categories are based on the ratio of the family’s income in the previous calendar year to the appropriate poverty threshold (given the family’s size and number of children), as defined by the U.S. Census Bureau for that year (Semega JL, Kollar MA, Creamer J, Mohanty A. Income and poverty in the United States: 2018. Current Population Reports, P60-266. 2019. https://www.census.gov/content/dam/Census/library/publications/2019/demo/p60-266.pdf). People categorized as “poor” have a ratio less than 1.0 (i.e., their family income is below the federal poverty level); “near poor” people have incomes of 100% to less than 200% of the federal poverty level; and “not poor” people have incomes that are 200% of the federal poverty level or greater. The percentage of respondents under age 65 with unknown poverty status in 2019 was 7.7%. People with unknown poverty status are not shown in this graph. Estimates may differ from estimates that are based on both reported and imputed income. People were defined as uninsured if they did not have any private health insurance, Medicare, Medicaid, Children’s Health Insurance Program (CHIP), state-sponsored or other government-sponsored health plan, or military plan. People were also defined as uninsured if they had only Indian Health Service coverage or had only a private plan that paid for one type of service, such as accidents or dental care.

Bar chart show that in 2019, the percentage adults ages 18-64 who were uninsured at the time of interview was higher among those who were poor (25.8%) and near poor (26.8%) compared with those who were not poor.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey Early Release Program, May 2020. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur202009-508.pdf.

- In 2019, among adults ages 18-64, the percentage who were uninsured at the time of interview was higher among those who were poor (25.8%) and near poor (26.8%) compared with those who were not poor (9.0%) (Figure 8).

Figure 9 Children ages 0-17 years who were uninsured at the time of interview, by poverty status, 2019

Note: For this measure, lower rates are better. Poverty categories are based on the ratio of the family’s income in the previous calendar year to the appropriate poverty threshold (given the family’s size and number of children), as defined by the U.S. Census Bureau for that year (Semega JL, Kollar MA, Creamer J, Mohanty A. Income and poverty in the United States: 2018. Current Population Reports, P60-266. 2019. https://www.census.gov/content/dam/Census/library/publications/2019/demo/p60-266.pdf). People categorized as “poor” have a ratio less than 1.0 (i.e., their family income is below the federal poverty level); “near poor” people have incomes of 100% to less than 200% of the federal poverty level; and “not poor” people have incomes that are 200% of the federal poverty level or greater. The percentage of respondents under age 65 with unknown poverty status in the first two quarters of 2019 was 7.7%. People with unknown poverty status are not shown in this graph. Estimates may differ from estimates that are based on both reported and imputed income. People were defined as uninsured if they did not have any private health insurance, Medicare, Medicaid, Children’s Health Insurance Program (CHIP), state-sponsored or other government-sponsored health plan, or military plan. People were also defined as uninsured if they had only Indian Health Service coverage or had only a private plan that paid for one type of service, such as accidents or dental care.

Year Poor Near Poor Not Poor 1997 22.4 22.8 6.1 2005 13 14.7 4.6 2010 10.2 12.6 4.6 2011 8.1 11.5 4 2012 7.5 10.1 4.5 2013 7.8 10.6 4 2014 5.9 8.6 3.6 2015 4.4 6.7 3.3 2016 6.5 6.9 3.5 2017 6 7.5 3.8 2018 6.4 6.3 4.2 Jan-Jun 2019 3.4 6.1 3.7

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey Early Release Program, May 2020. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur202009-508.pdf.

- In 2019, among children ages 0-17 years, 5.1% of those from poor households were uninsured, 6.5% of those from near-poor households were uninsured, and 4.3% of those from households that were not poor were uninsured (Figure 9).

Figure 10 Adults ages 18-64 who were uninsured at the time of interview, by race/ethnicity, 2019

Note: For this measure, lower rates are better. White, Black, and Asian are non-Hispanic. Hispanic includes all races. Data for Native Hawaiians/Pacific Islanders and American Indians and Alaska Natives are not available for this measure. People were defined as uninsured if they did not have any private health insurance, Medicare, Medicaid, Children’s Health Insurance Program (CHIP), state-sponsored or other government-sponsored health plan, or military plan. People were also defined as uninsured if they had only Indian Health Service coverage or had only a private plan that paid for one type of service, such as accidents or dental care.

LIne graph showing percentage of people uninsured at time of interview Year White Black Asian Hispanic 2010 16.4 27.2 19.5 43.2 2011 15.6 24.8 18.8 42.2 2012 15.1 23.6 19.1 41.3 2013 14.5 24.9 16.3 40.6 2014 11.6 17.7 12.5 33.7 2015 8.7 14.4 7.9 27.7 2016 8.6 15 7.5 25 2017 8.5 14.1 7.6 27.2 2018 9 15.2 8.1 26.7 Jan-Jun 2019 9.8 13.6 7.4 27.2

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey Early Release Program, May 2020. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur202009-508.pdf.

- In 2019, Hispanic adults were the most likely to lack health insurance coverage, while non-Hispanic White and non-Hispanic Asian adults were the least likely to be uninsured. Non-Hispanic Black adults were more likely than non-Hispanic White and non-Hispanic Asian adults to be uninsured (Figure 10).
- In 2019, 29.7% of Hispanic, 14.7% of non-Hispanic Black, 10.5% of non-Hispanic White, and 7.5% of non-Hispanic Asian adults ages 18-64 were uninsured at the time of interview.

Figure 11 Adults ages 18-64 who were uninsured at the time of interview, by state Medicaid expansion status, 2019

Note: For this measure, lower rates are better. People were defined as uninsured if they did not have any private health insurance, Medicare, Medicaid, Children’s Health Insurance Program (CHIP), state-sponsored or other government plan, or military plan. People were also defined as uninsured if they had only Indian Health Service coverage or had only a private plan that paid for one type of service, such as accidents or dental care. Under provisions of the Affordable Care Act of 2010 (P.L. 111-148, P.L. 111-152), states have the option to expand Medicaid eligibility to cover adults who have income up to and including 138% of the federal poverty level. There is no deadline for states to choose to implement the Medicaid expansion, and they may do so at any time. As of January 1, 2019, 33 states and the District of Columbia moved forward with Medicaid expansion.

Bar chart showing percentage of adults uninsured at time of interview Non-Medicaid Expansion States, 20.2 Medicaid Expansion States, 10

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey Early Release Program, May 2020. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur202009-508.pdf.

- In 2019, among adults ages 18-64, those living in non-Medicaid expansion states (21.2%) were twice as likely as those living in Medicaid expansion states (11.0%) to be uninsured at the time of interview (Figure 11).

### Dental Insurance

Dental caries, or tooth decay, is a common chronic disease that can cause pain, suffering, and diminished quality of life throughout one’s lifespan.^5^ Left untreated, tooth decay can progress and lead to infection, tooth loss, and more complex and expensive treatments. Untreated tooth decay can affect essential aspects of daily living, including eating, speaking, and performing at home, school, or work.^5^

Oral health issues can also affect other areas of health, and lack of access to dental care compounds the problem. For example, people without dental insurance are more likely to have heart disease, diabetes, and osteoporosis. People with dental insurance are more likely to visit a dental professional, take their children to a dental professional, receive recommended preventive screenings and treatments, and have better overall health.^6^

Figure 12 People under age 65 with any period of dental insurance during the year, 2006-2017

Line graph showing percentage of people with dental insurance 2006, 54 2007, 53 2008, 51.9 2009, 51.1 2010, 50.5 2011, 51.1 2012, 50.8 2013, 51 2014, 52.2 2015, 53.3 2016, 54 2017, 56.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2006-2017.

- From 2006 to 2017, overall, there was no significant change in the percentage of people with any period of dental insurance (Figure 12).
- From 2006 to 2017, the percentage of high-income people with any period of dental insurance increased from 74.6% to 78.8% (data not shown).

## Usual Source of Care

The AHRQ Medical Expenditure Panel Survey (MEPS) describes usual source of care (USC) as the particular medical professional, doctor’s office, clinic, health center, or other place where a person would usually go if sick or in need of advice about his or her health.

Having a USC is associated with reductions in inpatient admissions for physical health conditions and behavioral health conditions. Having a USC is also associated with decreased admissions for ambulatory care-sensitive conditions, readmissions, and spending.^7^

The two measures related to USC that improved were:

- People with a specific source of ongoing care.
- People in fair or poor health with a specific source of ongoing care.

Figure 13 People with a specific source of ongoing care, 2009-2018

Line graph showing percentage of people with a source of ongoing care 2009, 85.5 2010, 85.5 2011, 86.8 2012, 85.9 2013, 86.6 2014, 87.9 2015, 87.7 2016, 88.2 2017, 88.3 2018, 87.5

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2009-2018.

- From 2009 to 2018, the percentage of people with a specific source of ongoing care increased from 85.5% to 87.5% (Figure 13).

Figure 14 People in fair or poor health with a specific source of ongoing care, 2009-2018

Line graph showing people in fair or poor health with a source of ongoing care 2009, 87.5 2010, 87.9 2011, 87.8 2013, 88.3 2014, 90.5 2015, 89.8 2016, 90.5 2017, 89.5 2018, 89.8

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2009-2018.

- From 2009 to 2018, the percentage of people in fair or poor health with a specific source of ongoing care increased from 87.5% to 89.8% (Figure 14).

No measures related to USC showed a worsening trend.

## Timely Access to Care

A patient’s inability to obtain a timely healthcare appointment may result in various outcomes:

- The patient eventually seeing the desired healthcare providers,
- The patient obtaining healthcare elsewhere,
- The patient seeking an alternative form of care, or
- The patient not obtaining healthcare at all for the condition that led to the request for an appointment.

In any of these cases, the condition may worsen, improve (with or without treatment elsewhere), or continue until treated. Thus, long wait times may be associated with poorer health outcomes and financial burden from seeking non-network care and possibly more distant healthcare.^8^

The two measures related to timely care that improved were:

- Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed.
- Adults who needed care right away for an illness, injury, or condition in the last 12 months who sometimes or never got care as soon as needed.

Figure 15 Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing percentage of children who sometimes or never got an appointment for routine care when needed 2002, 10.2 2003, 8.7 2004, 7.0 2005, 7.1 2006, 7.0 2007, 7.3 2008, 6.5 2009, 5.5 2010, 5.5 2011, 6.0 2012, 5.2 2013, 5.5 2014, 5.3 2015, 5.2 2016, 5.8 2017, 6.0

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, the percentage of children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed decreased from 10.2% to 6.0% (Figure 15).

Figure 16 Adults who needed care right away for an illness, injury, or condition in the last 12 months who sometimes or never got care as soon as needed, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing percentage of adults who sometimes or never got urgent care when needed 2002, 15.3 2003, 14.3 2004, 14.2 2005, 15.1 2006, 15.3 2007, 13.9 2008, 15.4 2009, 14.7 2010, 14.4 2011, 13.6 2012, 14.7 2013, 14.6 2014, 12.4 2015, 11.9 2016, 11.0 2017, 13.0

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, the percentage of adults who needed care right away for an illness, injury, or condition in the last 12 months who sometimes or never got care as soon as needed decreased from 15.3% to 13.0% (Figure 16).

No measures related to timely care showed a worsening trend, overall, but disparities still exist. These are discussed in the Disparities portion of this Access section.

## Perception of Need

According to the World Health Organization, perceived health need is the need for health services as experienced by individuals and may or may not coincide with professionally defined or scientifically confirmed needs. The challenges that patients encounter in managing their care reflect an important aspect of medical care. These challenges relate more to clinical outcomes than to traditional measures of patient satisfaction. They emphasize barriers that keep patients from fully engaging in care rather than judgments about how pleasant the experience is. Still, they are more firmly rooted in the patient’s experience than are most clinical quality measures.^9^

The four measures of perception of need that improved were:

- Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment.^iii^
- People with a usual source of care who is somewhat to very difficult to contact during regular business hours over the telephone.
- People who were unable to get or delayed in getting needed dental care in the last 12 months.
- People who were unable to get or delayed in getting needed medical care in the last 12 months.

Figure 17 People with a usual source of care who is somewhat to very difficult to contact during regular business hours over the telephone, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing people show usual source of care is difficult to reach by telephone 2002, 19.1 2003, 17.7 2004, 16.1 2005, 16.1 2006, 16.6 2007, 15.3 2008, 14.1 2009, 14.6 2010, 13.0 2011, 13.4 2012, 12.3 2013, 14.9 2014, 14.3 2015, 14.9 2016, 14.0 2017, 13.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, the percentage of people with a usual source of care who is somewhat to very difficult to contact during regular business hours over the telephone decreased from 19.1% to 13.9% (Figure 17).

Figure 18 People who were unable to get or delayed in getting needed dental care in the last 12 months, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing people who were unable to get or delayed in getting dental care 2002, 5.5 2003, 6.1 2004, 5.9 2005, 6.4 2006, 6.3 2007, 5.5 2008, 5.6 2009, 6.5 2010, 5.8 2011, 5.9 2012, 5.7 2013, 6.4 2014, 5.7 2015, 5.5 2016, 4.9 2017, 4.6

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, the percentage of people who were unable to get or delayed in getting needed dental care in the last 12 months decreased from 5.5% to 4.6% (Figure 18).

Figure 19 People who were unable to get or delayed in getting needed medical care in the last 12 months, 2002-2017

Note: For this measure, lower rates are better.

Line graph showing percentage of people unable to get or delayed in getting needed medicare care 2002, 5.2 2003, 4.8 2004, 5.0 2005, 5.0 2006, 5.4 2007, 4.7 2008, 4.6 2009, 4.9 2010, 4.6 2011, 4.5 2012, 4.7 2013, 4.9 2014, 4.3 2015, 4.3 2016, 4.1 2017, 4.1

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2017.

- From 2002 to 2017, the percentage of people who were unable to get or delayed in getting needed medical care in the last 12 months decreased from 5.2% to 4.1% (Figure 19).

The two measures of perception of need that worsened were:

- Children who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment.
- Children who needed to see a specialist in the last 12 months who sometimes or never found it easy to see a specialist.

Figure 20 Children who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, 2008-2017

Note: For this measure, lower rates are better.

Line graph showing percentage of children sho sometimes or never found it easy to get care, tests, or treatment, 2008, 4.2 2009, 4.6 2010, 4.3 2011, 4.4 2012, 4.4 2013, 4.9 2014, 5.2 2015, 4.8 2016, 5.0 2017, 5.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2008-2017.

- From 2008 to 2017, the percentage of children who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment increased from 4.2% to 5.9% (Figure 20).

Figure 21 Children who needed to see a specialist in the last 12 months who sometimes or never found it easy to see a specialist

Note: For this measure, lower rates are better.

Line graph showing percentage of children who sometimes or never found it easy to see a specialist. 2008, 13.9 2009, 14.7 2010, 15.1 2011, 14.8 2012, 15.0 2013, 13.7 2014, 13.6 2015, 18.5 2016, 17.5 2017, 17.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2008-2017.

- From 2008 to 2017, the percentage of children who needed to see a specialist in the last 12 months who sometimes or never found it easy to see a specialist increased from 13.9% to 17.2% (Figure 21).

## Snapshot of Disparities in Access to Care

Figure 22 Number and percentage of access measures for which members of selected groups experienced better, same, or worse access to care compared with reference group, 2017 or 2018

Key: n = number of measures.

Stacked bar chart showing number of access measures for which groups had better, same, or worse care than reference group Poor vs. High Income (n=20), Better, 0, Same, 2, Worse, 18 Black vs. White (n=21), Better, 1, Same, 10, Worse, 10 Asian vs. White (n=19), Better, 7, Same, 6, Worse, 6 NHPI vs. White (n=4), Better, 0 Same, 3, Worse, 1 AI/AN vs. White (n=11), Better, 0, Same, 5, Worse, 6 Hispanic vs. non-Hispanic White (n=20), Better, 3, Same, 4, Worse, 13

- For the most recent year, people in poor households had worse access to care than people in high-income households for 90% of access measures (Figure 22).
- Blacks had worse access to care than Whites for 48% of access measures.
- Asians had worse access to care than Whites for 32% of access measures.
- Native Hawaiians/Pacific Islanders (NPHIs) had worse access to care than Whites for 25% of access measures.
- American Indians and Alaska Natives (AI/ANs) had worse access to care than Whites for 55% of access measures.
- Hispanics had worse access to care than non-Hispanic Whites for 65% of access measures.

Disparities varied among the different components of access to care:

- Of the 5 health insurance measures:
  ■ People in poor households had worse access to care for all the measures compared with people in high-income households.
  ■ AI/ANs and Hispanics had worse access to care for all the measures compared with Whites.
  ■ Blacks had worse access to care for 3 measures compared with Whites.
  ■ Asians had worse access to care for 1 measure compared with Whites.
- Of the 3 usual source of care measures:
  ■ People in poor households had worse access to care on all the measures compared with people in high-income households.
  ■ Blacks and Hispanics had worse access to care for 2 of 3 measures compared with Whites.
  ■ Asians, NHPIs, and AI/ANs had worse access to care for 1 of 3 measures compared with Whites.
- Of the 3 measures of timely access to care:
  ■ People in poor households had worse access to care for all the measures compared with people in high-income households.
  ■ Blacks and Hispanics had worse access to care for all the measures compared with Whites.
  ■ Asians had worse access to care for 2 of 3 measures compared with Whites.
- Of the 9 measures of patient perception of need:
  ■ People in poor households had worse access to care for 7 of 9 measures compared with people in high-income households.
  ■ Hispanics had worse access to care for 3 of 9 measures compared with Whites.
  ■ Blacks and Asians had worse access for 2 measures compared with Whites.

### Health Insurance

Health insurance coverage expansions significantly increase patients’ access to care and use of preventive care, primary care, chronic illness treatment, medications, and surgery. These increases appear to produce significant, multifaceted, and nuanced benefits to health. Some benefits may manifest in earlier detection of disease, some in better medication adherence and management of chronic conditions, and some in the psychological well-being born of knowing one can afford care when one gets sick.^10^

Healthcare access and insurance coverage are major factors that contribute to racial and ethnic disparities. Racial and ethnic disparities in access have been reduced significantly by expanded access to health insurance.^11^

Figure 23 People under age 65 with any private health insurance, by race, United States, 2018

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Bar chart showing percentage of people with private insurance Total, 65.3 White, 67.9 Black, 52 Asian, 74.8 NHPI, 50.1 AI/AN, 34.3 More Than One Race, 56.6

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2018.

- In 2018, AI/ANs (34.3%) under age 65 were less likely to have insurance compared with Whites (67.9%) (Figure 23).
- In 2018, Asians (74.8%) under age 65 were more likely than Whites (67.9%) to have health insurance.

Figure 24 People under age 65 with any private health insurance, stratified by ethnicity and income, 2018

Bar chart showing percentage of people with private insurance Income Non-Hispanic White Non-Hispanic Black Hispanic Poor 25 13.9 11.6 Low Income 42.4 38.5 28.1 Middle Income 75 68.6 62.2 High Income 91 88.2 85.1

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2018.

- In 2018, among all ethnic groups, people from poor, low-, and middle-income households were less likely to have any private insurance compared with people in high-income households (Figure 24).
- In 2018, high-income Hispanics and Blacks were less likely to have any private insurance compared with high-income Whites.

Figure 25 People under age 65 with any period of uninsurance during the year, by race, 2017

Key: AI/AN = American Indian or Alaska Native.

Bar chart showing percentage of people with any period of uninsurance Total, 18.7 White, 18.3 Black, 21.7 Asian, 15.1 AI/AN, 38.8 >1 Race, 18.1

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, AI/ANs under age 65 were twice as likely to have a period of uninsurance during the year compared with Whites (38.8% compared with 18.3%) (Figure 25).
- In 2017, Blacks under age 65 were more likely than Whites to have a period of uninsurance during the year (21.7% compared with 18.3%).
- In 2017, Asians under age 65 were less likely than Whites to have a period of uninsurance during the year (15.1% compared with 18.3%).

Figure 26 People under age 65 with any period of uninsurance during the year, stratified by race and income, 2017

Note: For this measure, lower rates are better. Data for AI/ANs and NHPIs do not meet the criteria for statistical reliability, data quality, or confidentiality.

Income White Black Asian >1 Race Poor 30.3 24.6 30 20.2 Low Income 28.8 28.3 22.8 31.8 Middle Income 20.4 22.9 21.3 15.1 High Income 10.1 12.1 8 11.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, among all racial groups, people from poor, low-, and middle-income households were more likely to report a period of uninsurance compared with people from high-income households (Figure 26).

#### Dental Insurance

Disparities by race or ethnicity, poverty, education, and smoking status persist. Among older adults who were non-Hispanic Black, Mexican American, poor, near poor, or current smokers, the prevalence of untreated decay was about 2 to 3 times that of those who were non-Hispanic White, not poor, or never smokers. The percentage of adults ages 21-64 years with any dental insurance has recently increased, largely driven by increased public dental insurance coverage.^12^

Figure 27 People under age 65 with any period of dental insurance during the year, by race, 2017

Key: AI/AN = American Indian or Alaska Native

Note: Data for NHPIs do not meet the criteria for statistical reliability, data quality, or confidentiality.

Bar chart showing percentage of people with any period of dental insurance Total, 56.2 White, 57.5 Black, 48.4 Asian, 62.6 AI/AN, 36.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, Blacks and AI/ANs were less likely than Whites to report having dental insurance (Figure 27).
- In 2017, Asians were more likely than Whites to report having dental insurance.

Figure 28 People under age 65 with any period of dental insurance during the year, by income, 2017

Bar chart showing percentage of people with any period of dental insurance Poor, 12.3 Low Income, 28.5 Middle Income, 59.5 High Income, 78.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, poor (12.3%), low-income (28.5%), and middle-income (59.5%) people were less likely than high-income (78.8%) people to report having dental insurance (Figure 28).

#### Medicare Advantage Insurance

The CMS Medicare Advantage (MA) program allows Medicare beneficiaries enrolled in both Part A and Part B to receive benefits from private plans rather than from the traditional fee-for-service (FFS) program. MA enrollees appear to be healthier than beneficiaries in traditional Medicare, according to measures of self-assessed health, functional status, and cognitive status.^13^

MA enrollees have less education than beneficiaries in traditional Medicare, on average, and are more likely to be in a low-to-middle-income group (per capita incomes between $20,000 and $40,000). They are less likely to have per capita incomes greater than $40,000, perhaps because higher income beneficiaries are more likely to have Medigap and retiree health benefits that supplement traditional Medicare.^13^

Hispanic beneficiaries are more likely to be in MA than traditional Medicare, partly owing to relatively high MA enrollment in parts of the country with large Hispanic populations, such as southern Florida. In contrast, beneficiaries living in rural areas, where MA has a smaller footprint, are more likely to be in traditional Medicare.^13^

Figure 29 Adults age 65 and over with Medicare Advantage plan, by race, 2018

Key: AI/AN = American Indian or Alaska Native.

Bar chart showing adults age 65 and over with Medicare Advantage Total, 25 White, 25.3 Black, 24 Asian, 25 AI/AN, 13.5 >1 Race, 18.7

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2018.

- In 2018, AI/ANs age 65 and over were less likely than Whites to have an MA plan (Figure 29).

Figure 30 Adults age 65 and over with Medicare Advantage plan, stratified by ethnicity and income, 2018

Bar chart showing percentage of adults age 65 and over with Medicare Advantage Non-Hispanic White, Poor, 15.3, Low Income, 28.5Middle Income, 27.3, High Income, 22 Hispanic Poor, 17.9, Low Income, 38.1, Middle Income, 33.9, High Income, 31

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2018.

- In 2018, high-income Hispanics (31.0%) were more likely than high-income non-Hispanic Whites (22.0%) to have Medicare Advantage (Figure 30).
- Low income Hispanics (38.1%) were more likely than low-income non-Hispanic Whites (28.5%) to have Medicare Advantage.

#### Dual-Eligible Beneficiaries

Dual-eligible beneficiaries are eligible for Medicare and Medicaid. Medicare is the primary payer for dual-eligible beneficiaries. Dual-eligible beneficiaries receive full Medicare coverage, including coverage of physician services, inpatient and outpatient acute care, and postacute skill-leveled care. Medicaid may cover additional services not covered under Medicare, as well as help with costs for Medicare premiums, deductibles, coinsurance, and copayments. Dual-eligible beneficiaries have low incomes that make it difficult to afford the premiums and cost sharing required by Medicare, as well as the cost of services not covered by the Medicare program.

More than half (56%) of individuals dually eligible for Medicare and Medicaid benefits in 2013 had at least one limitation in activities of daily living. A plurality (43%) did not graduate from high school. Compared with non-dual Medicare beneficiaries, more dual-eligible beneficiaries reported being in poor health (18% vs. 6%). Dual-eligible beneficiaries were also more likely than non-dual Medicare beneficiaries to live in an institution.^14^

Figure 31 Adults age 65 and over with dual-eligible insurance, by ethnicity, 2018

Bar chart showing percentage of adults over 65 with dual eligible insurance Total, 6.9 Non-Hispanic White, 3.6 Non-Hispanic Black, 14.2 Hispanic, 22.2

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2018.

- In 2018, Hispanics and Blacks age 65 and over were more likely to have dual-eligible insurance compared with Whites (22.2% and 14.2%, respectively, vs. 3.6%) (Figure 31).

### Usual Source of Care

Compared with White Americans, African Americans are less likely to use primary care as their usual source of care.^15^ Having a usual place and usual provider are associated with an increased likelihood of receiving preventive services and recommended screenings compared with having no usual source of care.^16^

Figure 32 People with a usual primary care provider, by race, 2017

Key: AI/AN = American Indian or Alaska Native

Note: Data for NHPI do not meet the criteria for statistical reliability, data quality, or confidentiality.

Bar chart showing percentage of people with a usual primary care provider Total, 76 White, 76.8 Black, 73.4 Asian, 70.1 AI/AN, 67.5 >1 Race, 78.4

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, Blacks (73.4%), Asians (70.1%), and AI/ANs (67.5%) were less likely than Whites (76.8%) to have a usual primary care provider (Figure 32).

Figure 33 People with a usual primary care provider, stratified by race and insurance, 2017

Note: Data do not meet the criteria for statistical reliability, data quality, or confidentiality for AI/ANs, NHPIs, and uninsured Asians.

Bar chart showing percentage of people with a usual primary care provider Race Any Private Public Only Uninsured Total 75.5 79.1 37.8 White 76.5 79.4 38.7 Black 72.5 78.1 35.7 Asian 68.1 76.7

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, among all racial groups, uninsured people were less likely than those with private insurance to have a usual primary care provider (Figure 33).
- In 2017, Blacks and Asians with private insurance were less likely than Whites with private insurance to have a usual primary care provider (72.5% and 68.1%, respectively, vs. 76.5%).

### Timely Access to Care

Having health insurance coverage is strongly associated with receiving timely and continuous care, and lack of it has been consistently found to be one of the main contributors to disparities in access to health services.^17^

Figure 34 Adults who needed care right away for an illness, injury, or condition in the last 12 months who sometimes or never got care as soon as needed, by ethnicity, 2017

Note: For this measure, lower rates are better.

Bar chart sowing percentage of adults who sometimes or never got urgent care as soon as needed Total, 13 Non-Hispanic White, 11.1 Non-Hispanic Black, 18.2 Hispanic, 18.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, non-Hispanic Blacks and Hispanics who needed care right away for an illness, injury, or condition were more likely than non-Hispanic Whites to report that they sometimes or never got care as soon as needed (18.2% and 18.3%, respectively, vs. 11.1%) (Figure 34).

Figure 35 Adults who needed care right away for an illness, injury, or condition in the last 12 months who sometimes or never got care as soon as needed, stratified by ethnicity and income, 2017

Note: For this measure, lower rates are better.

Bar chart showing percentage of adults who sometimes or never got urgent care as soon as needed Income Non-Hispanic White Non-Hispanic Black Hispanic Poor 19.9 22.7 24 Low Income 13.9 17.9 22 Middle Income 10.9 15.4 15.2 High Income 8.6 17.6 15.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, among non-Hispanic Whites who needed care right away for an illness, injury, or condition, people from poor and low-income households were more likely than people from high-income households to report that they sometimes or never got care as soon as needed (19.9% and 13.9%, respectively, vs. 8.6%) (Figure 35).
- In 2017, high-income Hispanics who needed care right away for an illness, injury, or condition were more likely than high-income Whites to report that they sometimes or never got care as soon as needed (15.8% vs. 8.6%).

Figure 36 Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, by ethnicity, 2017

Note: For this measure, lower rates are better.

Bar chart showing children who sometimes or never got an appointment for routine care when needed Total, 6.0 Non-Hispanic White, 4.5 Non-Hispanic Black, 8.8 Hispanic, 6.6

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, the percentage of children who had any appointments for routine healthcare who sometimes or never got an appointment for routine care as soon as needed was higher for non-Hispanic Blacks (8.8%) and Hispanics (6.6%) compared with non-Hispanic Whites (4.5%) (Figure 36).

Figure 37 Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, by income, 2017

Note: For this measure, lower rates are better.

Bar chart showing children who sometimes or never got an appointment for routine care when needed Total, 6.0 Poor, 8.9 Low Income, 8.9 Middle Income, 4.5 High Income, 4.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, the percentage of children who had any appointments for routine healthcare who sometimes or never got an appointment for routine care as soon as needed was higher for poor (8.9%) and low-income (8.9%) children compared with high-income children (4.2%) (Figure 37).

Figure 38 Adults who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, by ethnicity, 2017

Note: For this measure, lower rates are better.

Bar chart showing adults who sometimes or never got an appointment for routine care when needed Total, 16.4 Non-Hispanic White, 14.4 Non-Hispanic Black, 20.6 Hispanic, 19

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, non-Hispanic Blacks (20.6%) and Hispanics (19.0%) were more likely than non-Hispanic Whites (14.4%) to report that they sometimes or never got an appointment for routine care as soon as needed (Figure 38).

Figure 39 Adults who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, by ethnicity and income, 2017

Note: For this measure, lower rates are better.

Bar chart showing percentage of adults who sometimes or never got an appointment for routine care when needed Income Non-Hispanic White Non-Hispanic Black Hispanic Poor 18.6 19 16.2 Low Income 15.2 17.4 18.7 Middle Income 13.7 23.2 20.6 High Income 14 20.9 18.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, among non-Hispanic Whites, people from poor households were more likely than people from high-income households to report that they sometimes or never got an appointment for routine care as soon as needed (18.6% vs. 14%) (Figure 39).
- In 2017, high-income non-Hispanic Blacks and Hispanics were more likely than high-income Whites to report that they sometimes or never got an appointment for routine care as soon as needed (20.9% and 18.9%, respectively, vs. 14%).

### Perception of Need

Figure 40 Adults who needed to see a specialist in the last 12 months who sometimes or never found it easy to see a specialist, by race, 2017

Note: For this measure, lower rates are better. Data for AI/ANs and NHPIs do not meet the criteria for statistical reliability, data quality, or confidentiality.

Bar chart showing percentage of adults who sometimes or never found it easy to see a specialist Total, 15.4 White, 14.2 Black, 20.4 Asian, 24.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, Blacks (20.4%) and Asians (24.3%) who needed to see a specialist were more likely than Whites (14.2%) to report that they sometimes or never found it easy to get the appointment (Figure 40).

Figure 41 Adults who needed to see a specialist in the last 12 months who sometimes or never found it easy to see a specialist, by income, 2017

Note: For this measure, lower rates are better.

Bar chart showing percentage of adults who sometimes or never found it easy to see a specialist Total, 15.4 Poor, 19.7 Low Income, 15.6 Middle Income, 14.7 High Income, 15

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, poor adults (19.7%) who needed to see a specialist were more likely than high-income adults (15.0%) to report that they sometimes or never found it easy to get the appointment (Figure 41).

Figure 42 People with a usual source of care who is somewhat to very difficult to contact during regular business hours over the telephone, by ethnicity, 2017

Note: For this measure, lower rates are better.

Bar chart showing percentage of people who had trouble contacting their usual source of care by telephone Total, 13.9 Non-Hispanic White, 13.5 Non-Hispanic Black, 12.9 Hispanic, 15.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, Hispanics (15.8%) were more likely than non-Hispanic Whites (13.5%) to have a usual source of care who was somewhat to very difficult to contact during regular business hours over the telephone (Figure 42).

Figure 43 People with a usual source of care who is somewhat to very difficult to contact during regular business hours over the telephone, stratified by ethnicity and income, 2017

Note: For this measure, lower rates are better.

Income Non-Hispanic White Non-Hispanic Black Hispanic Poor 15.9 17.5 18.2 Low Income 15.6 14.5 17.6 Middle Income 12.8 11.2 14.2 High Income 12.9 9.7 14.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2017.

- In 2017, among non-Hispanic Blacks, poor and low-income people were more likely than high-income people to report that their usual source of care was somewhat to very difficult to contact during regular business hours over the telephone (17.5% and 14.5%, respectively, vs. 9.7%) (Figure 43).

i The figures in this section do not include this measure due to issues with interpretation. While the percentage of adults age 65 and over with any private insurance decreased, it is not “worsening,” per se, and might represent shifts in the insurance market. Some people might opt for Medicare Advantage.

ii The figure is not shown for adults age 651and over with any private insurance, because the decrease might represent a shift in the insurance market rather than gaps in access. Some people might have Medicare Advantage.

iii Updated data for this measure were not available, so a figure was not included. The most recent data for the measure are available at the NHQDR Data Query page (https://nhqrnet.ahrq.gov/inhqrdr/data/query).