# OVERVIEW OF U.S. HEALTHCARE SYSTEM LANDSCAPE

The Institute of Medicine defines healthcare quality as “the degree to which health care services for individuals and populations increase the likelihood of desired health outcomes and are consistent with current professional knowledge.” Many factors contribute to the quality of care in the United States, including access to timely care, affordability of care, and use of evidence-based guidelines to drive treatment.

This section of the report highlights utilization of healthcare services, healthcare workforce, healthcare expenditures, and major contributors to morbidity and mortality. These factors help to paint an overall picture of the U.S. healthcare system and particularly areas where improvements are needed. Quality measures show whether the healthcare system is adequately addressing risk factors, diseases, and conditions that place the greatest burden on the healthcare system and if change has occurred over time.

## Overview of the U.S. Healthcare System infrastructure

The NHQDR tracks care delivered by providers in many types of healthcare settings. The goal is to provide high-quality healthcare that is culturally and linguistically sensitive, patient centered, timely, affordable, well coordinated, and safe. The receipt of appropriate high-quality services and counseling about healthy lifestyles can facilitate the maintenance of well-being and functioning. In addition, social determinants of health, such as education, income, and residence location can affect access to care and quality of care.

Improving care requires facility administrators and providers to work together to expand access, enhance quality, and reduce disparities. It also requires coordination between the healthcare sector and other sectors for social welfare, education, and economic development. For example, Healthy People 2030 includes 5 domains (shown in the diagram below) and 78 social determinants of health objectives for federal programs and interventions.

Exhibit 1 Healthy People 2030 social determinants of health domains

Diagram showing individual in the center with five domains around him/her: health care access and quality, neighborhood and built environment, social and community context, economic stability, and education accesss and quality

Source: Healthy People 2030, Social Determinants of Health. https://health.gov/healthypeople/objectives-and-data/social-determinants-health.

The numbers of health service encounters and people working in health occupations illustrate the large scale and inherent complexity of the U.S. healthcare system. The tracking of healthcare quality measures in this report, notably in the Trends in Quality section, attempts to quantify progress made in improving quality and reducing disparities in the delivery of healthcare to the American people.

Figure 1 Number of healthcare service encounters, United States, 2015, 2016, 2018

Bar chart showing number of encounters in millions; data are provided in the text after the chart

Source: National Center for Health Statistics (NCHS), Health, United States, 2017 (https://www.cdc.gov/nchs/data/hus/hus17.pdf) (hospital visits and hospital days [Table 82]); National Ambulatory Medical Care Survey: 2016 National Summary Tables, Table 1 (https://www.cdc.gov/nchs/data/ahcd/namcs_summary/2016_namcs_web_tables.pdf); NCHS, Long-term care providers and services users in the United States: data from the National Study of Long-Term Care Providers, 2015-2016 (https://www.cdc.gov/nchs/data/series/sr_03/sr03_43-508.pdf) (nursing home days); Medicare Payment Advisory Commission (MedPAC), Health care spending and the Medicare Program: a data book, March 2020 (http://medpac.gov/docs/default-source/reports/mar19_medpac_entirereport_sec.pdf?sfvrsn=0) (home health [Table 9-3 and Table 9-7]) and hospice data [Table 12-4]).

- In 2016, there were 884 million physician office visits (Figure 1).
- During 2015-2016, residents spent 492 million days in nursing homes.
- In 2018, patients spent 139 million days in hospice.
- In 2018, there were 103 million home health visits.

## Overview of Disease Burden in the United States

The National Institutes of Health defines disease burden as the impact of a health problem, as measured by prevalence, incidence, mortality, morbidity, extent of disability, financial cost, or other indicators. The healthcare system aims to mitigate the effects of burden caused by the leading causes of morbidity and mortality.

This section of the report highlights two areas of disease burden that have major impact on the health system of the United States: years of potential life lost and leading causes of death. Measures of quality for most of these conditions are tracked in the NHQDR. Variation in access to care and care delivery across communities contributes to disparities related to race, ethnicity, sex, and socioeconomic status.

The concept of years of potential life lost (YPLL) involves estimating the average time a person would have lived had he or she not died prematurely. This measure is used to help quantify social and economic loss owing to premature death, and it has been promoted to emphasize specific causes of death affecting younger age groups. YPLL inherently incorporates age at death, and its calculation mathematically weights the total deaths by applying values to death at each age.^1^

Figure 2 Age-adjusted years of potential life lost before age 65, United States, 2018

Key: YPLL = years of potential life lost.

Note: The perinatal period occurs from 22 completed weeks (154 days) of gestation and ends 7 completed days after birth.^i^

Bar chart showing age-adjusted rate of YPLLs per 100,000 Cerebrovascular Disease, 76.8 Diabetes, 93.1 Liver Disease, 110.7 Congenital Anomalies, 156.3 Homicide, 213.6 Perinatal Period, 277.3 Suicide, 357.5 Heart Disease, 460.2 Cancer, 546.8 Unintentional Injury, 1008.5

Source: Centers for Disease Control and Prevention, National Center for Injury Prevention and Control (https://www.cdc.gov/injury), WISQARS Years of Potential Life Lost (YPLL) Report, 1981-2018. https://webappa.cdc.gov/sasweb/ncipc/ypll.html.

- From 2016 to 2018, there were no changes in the ranking of the top 10 leading diseases and injuries contributing to YPLL (Figure 2).
- The top category contributing to YPLL, unintentional injury, decreased from 1,020.8 per 100,000 population in 2016 to 1,008.5 per 100,000 population in 2018.
- In 2018, among females, unintentional injuries (593.4 per 100,000 population) were the leading contributing factor for YPLL, suicide (161.2 per 100,000 population) the 5th, and homicide (85.7 per 100,000 population) the 7th leading contributor (data not shown).
- In 2018, among males, unintentional injuries (1,417.8 per 100,000 population) were the leading contributor to YPLL, suicide (550.4 per 100,000 population) the 3rd, and homicide (338 per 100,000 population) the 5th leading contributor to YPLL (data not shown).

Figure 3 Leading causes of death for the total population, United States, 2018

Bar chart showing age-adjusted deaths per 100,000 population Kidney Disease, 2017, 13, 2018, 12.9 Suicide, 2017, 14, 2018, 14.2 Pneumonia and Flu, 2017, 14.3, 2018, 14.9 Diabetes, 2017, 21.5, 2018, 21.4 Alzheimer's Disease, 2017, 31, 2018, 30.5 Stroke, 2017, 37.6, 2018, 37.1 Chronic Lower Respiratory Diseases, 2017, 40.9, 2018, 39.7 Unintentional Injuries, 2017, 49.4, 2018, 48.0 Cancer, 2017, 152.5, 2018, 149.1 Heart Disease, 2017, 165, 2018, 163.6

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Mortality. Mortality in the United States, 2018. https://www.cdc.gov/nchs/products/databriefs/db355.htm.

- In 2018, heart disease, cancer, unintentional injuries, chronic lower respiratory diseases, stroke, Alzheimer’s disease, and diabetes were among the leading causes of death for the overall U.S. population (Figure 3).
- Overall, suicide was the 9th leading cause of death in 2018.

The years of potential life lost, years with disability, and leading causes of death illustrate the burden of disease experienced by the American people. Findings highlighted in the Trends in Quality section of this report attempt to quantify progress made in improving quality of care, reducing disparities in healthcare, and ultimately reducing disease burden.

## Overview of U.S. Community Hospitals

The United States has more than 6,000 hospitals. Figure 4 shows the number of different types of hospitals accessible by the general public (i.e., excludes prison hospitals or college infirmaries).

- Community hospitals are defined as all nonfederal, short-term general, and other special hospitals. They include academic medical centers or other teaching hospitals if they are nonfederal short-term hospitals. Special hospitals include obstetrics and gynecology; eye, ear, nose, and throat; long term acute care; rehabilitation; orthopedic; and other individually described specialty services.
- Other hospitals include nonfederal long-term care hospitals and hospital units within an institution such as a prison hospital or school infirmary. Long-term care hospitals may be defined by different methods; here they include hospitals with an average length of stay of 30 or more days.

Figure 4 U.S. hospitals, by type of hospital, 2018

Note: Community hospitals are defined as all nonfederal, short-term general, and other special hospitals. Other special hospitals include obstetrics and gynecology; eye, ear, nose, and throat; long term acute-care; rehabilitation; orthopedic; and other individually described specialty services. Community hospitals include academic medical centers or other teaching hospitals if they are nonfederal short-term hospitals. Excluded are hospitals not accessible by the general public, such as prison hospitals or college infirmaries. Other hospitals include nonfederal long-term care hospitals and hospital units within an institution, such as a prison hospital or school infirmary. Long-term care hospitals may be defined by different methods; here they include other hospitals with an average length of stay of 30 or more days.

Bar chart showing number of U.S. hospitals, by type Total U.S. Hospitals, 6,146 Total Community Hospitals, 5,198 Nongovernment Not-for-Profit Community Hospitals, 2,937 Investor-Owned (For-Profit) Community Hospitals, 1,296 State and Local Government Community Hospitals, 965 Federal Government Hospitals, 209 Nonfederal Psychiatric Hospitals, 616 Other Hospitals, 123

Source: American Hospital Association, Fast Facts on U.S. Hospitals, based on AHA Hospital Statistics, 2020 Edition. https://www.aha.org/system/files/media/file/2020/01/2020-aha-hospital-fast-facts-new-Jan-2020.pdf.

- In 2018, of the more than 6,000 hospitals in the United States, 85% were community hospitals (Figure 4).
- Most community hospitals (56.5%) were nongovernment, not-for-profit community hospitals.

Figure 5 Distribution of community hospitals in the United States, 2018

Map of the United States shows number of community hospitals in each state in 2018. The map is color-coded to show which states are in the 1st through 4th quartiles; read the text below for details.

Source: American Hospital Association, Fast Facts on U.S. Hospitals, based on AHA Hospital Statistics, 2020 Edition. https://www.aha.org/statistics/fast-facts-us-hospitals.

- In 2018, the states^ii^ with the most community hospitals in the United States tended to be the larger, more populated states. The top five states, Ohio (194), Pennsylvania (199), Florida (217), California (359), and Texas (523) account for nearly 30% of community hospitals (Figure 5).
- In 2018, there were 1,821 rural community hospitals and 3,377 urban community hospitals.

## U.S. Healthcare Workforce

Healthcare access and quality can be affected by workforce shortages, which can be an issue especially in rural areas. In addition, issues such as racial, ethnic, and gender concordance between providers and patients can affect communication, provider perspectives, and, ultimately, healthcare quality.

### Healthcare Workforce Shortages

Improving quality of care, increasing access to care, and controlling healthcare costs depend on the adequate availability of healthcare providers.^2^ Physician shortages currently exist in many states across the nation and will likely increase over the next 10 years and may influence the delivery of healthcare, negatively affecting patient outcomes.^2^

Figure 6 Number of people working in health occupations, United States, 2018

Key: EMT = emergency medical technician.

Note: Doctors of medicine also include doctors of osteopathic medicine. Other health practitioners include physician assistants, medical assistants, dental assistants, chiropractors, dietitians and nutritionists, optometrists, podiatrists, and audiologists, as well as massage therapists, medical equipment preparers, medical transcriptionists, pharmacy aides, veterinary assistants and laboratory animal caretakers, phlebotomists, and healthcare support workers. Aides include nursing, psychiatric, home health, occupational therapy, and physical therapy assistants and aides. Therapists include occupational therapists, physical therapists, radiation therapists, recreational therapists, respiratory therapists, speech-language pathologists, and exercise physiologists.

Bar chart showing number of people Dentists), 189,729 Advanced Practice Nurses, 250,331 Emergency Medical Technicians and Paramedics, 252,242 Pharmacists, 363,330 Therapists, 979,819 Doctors of Medicine), 1,045,995 Other Health Occupations, 1,424,344 Other Health Practitioners, 2,182,179 Health Technologists, 2,269,016 Aides, 2,644,019 Registered Nurses, 4,052,625

Source: American Community Survey, 2018, https://www.census.gov/programs-surveys/acs.

- In 2018, there were 1.05 million active medical doctors in the United States, which include doctors of medicine and doctors of osteopathy (Figure 6).
- In 2018, there were 190,000 dentists.
- In 2018, there were 4.1 million registered nurses, 2.3 million health technologists, and 2.6 million nursing and other aides.
- In 2018, 2.2 million other health practitioners provided care, including more than 142,000 physician assistants.

### Workforce Diversity

The number of full-time, year-round workers in healthcare occupations has almost doubled since 2000, increasing from 5 million to 9 million workers, according to the U.S. Census Bureau’s American Community Survey (https://www.census.gov/programs-surveys/acs.html).

A racially and ethnically diverse health workforce has been shown to promote better access and healthcare for underserved populations as well as to better meet the health needs of an increasingly diverse population. People of color, however, remain underrepresented in several health professions, despite longstanding efforts to increase the diversity of the healthcare field.^3^ Additional research has found that physicians from groups underrepresented in the health professions are more likely to serve minority and economically disadvantaged patients. It has also been found that Black and Hispanic physicians practice in areas with larger Black and Hispanic populations than other physicians do.^4^

Gender diversity is also important. Women currently account for three-quarters of full-time, year-round healthcare workers. Although the number of men who are dentists or veterinarians has decreased over the past two decades, men still make up more than half of dentists, optometrists, and emergency medical technicians/paramedics, as well as physicians and surgeons earning over $100,000.^5^

Women working as registered nurses, the most common healthcare occupation, earn on average $66,000. Women working as nursing, psychiatric, and home health aides, the second most common healthcare occupation, earn only $27,000.^5^

The impact of unequal gender distribution in the healthcare workforce is observed in the persistence of gender inequality in heart attack mortality. Most physicians are male, and some may not recognize differences in symptoms in female patients. The fact that gender concordance correlates with whether a patient survives a heart attack has implications for theory and practice. Medical practitioners should be aware of the possible challenges male providers face when treating female heart attack patients.^6^

#### Racial and Ethnic Diversity Among Physicians

Diversification of the physician workforce has been a goal for several years and could improve access to primary care for underserved populations and address health disparities. Family physicians’ race/ethnicity has become more diverse over time but still does not reflect the national racial/ethnic composition.^7^

Figure 7 Racial/ethnic distribution of all active physicians (left) and U.S. population racial/ethnic distribution (right), 2018

Note: White, Black, and Asian are non-Hispanic. Percentages do not add to 100 due to rounding and the exclusion of groups that together represented only about 1% of the total. Physicians (federal and nonfederal) who are licensed by a state are considered active, provided they are working at least 20 hours per week. Physicians who are retired, semiretired, temporarily not in practice, or not active for other reasons or who have not completed their graduate medical education are excluded. Active physicians include those working in direct patient care, administration, medical teaching, research, or other non-patient care activities. Active physicians include those with a doctor of medicine or a doctor of osteopathic medicine degree.

Pie chart showing percentage of each group among physicians White, 57% Black, 5% Asian, 17% Hispanic, 6% Unknown, 14%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Association of American Medical Colleges, Diversity in Medicine: Facts and Figures 2019. https://www.aamc.org/data-reports/workforce/interactive-data/figure-18-percentage-all-active-physicians-race/ethnicity-2018. Right chart: American Community Survey. ACS Demographic and Housing Estimates. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2018, Whites were 60% of the U.S. population and approximately 57% of physicians (Figure 7).
- Asians were about 6% of the U.S. population and approximately 17% of physicians.
- Blacks were 12% of the U.S. population but only 5% of physicians.
- Hispanics were 18% of the U.S. population but only 6% of physicians.
- People of more than race made up about 3% of the U.S. population but less than 1% of physicians.
- American Indians and Alaska Natives (AI/ANs) and Native Hawaiians/Pacific Islanders (NHPIs) accounted for 1% or less of the U.S. population and 1% or less of physicians (data not shown).

Physician–patient gender concordance can have a major impact on healthcare quality and outcome. Preventive care, including screenings, is key to reducing death and disability and improving health. Evidence has shown that patients with providers of the same gender have higher rates of breast, cervical, and colorectal cancer screenings.^8^

Figure 8 Physicians by race/ethnicity and sex, 2018

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Physicians (federal and nonfederal) who are licensed by a state are considered active, provided they are working at least 20 hours per week. Physicians who are retired, semiretired, temporarily not in practice, or not active for other reasons or who have not completed their graduate medical education are excluded. Active physicians include those working in direct patient care, administration, medical teaching, research, or other non-patient care activities. Active physicians include those with a doctor of medicine or a doctor of osteopathic medicine degree.

Bar chart showing percentage of males and females in each racial or ethnic group White, Male, 65.5, Female, 34.4 Black, Male, 46.9, Female, 53 Asian, Male, 55.7, Female, 43.9 AI/AN, Male, 60.1, Female, 39.8 NHPI, Male, 53, Female, 46.9 Hispanic, Male, 59.5, Female, 40.4 Other, Male, 63.4 36.4, Female, >1 Race, Male, 53.3, Female, 46.4

Source: Association of American Medical Colleges, Diversity in Medicine: Facts and Figures 2019. https://www.aamc.org/data-reports/workforce/interactive-data/figure-20-percentage-physicians-sex-and-race/ethnicity-2018.

- In 2018, among Black physicians, females (53.0%) constituted a larger percentage than males (47.0%) (Figure 8).
- All other groups had a greater percentage of males than females:
  ■ Among White physicians, 65.5% were male.
  ■ Among Asian physicians, 55.7% were male.
  ■ Among AI/AN physicians, 60.1% were male.
  ■ Among Hispanic physicians (alone or in combination with another race), 59.5% were male.

Figure 9 White physicians by age and sex, 2018

Note: Physicians (federal and nonfederal) who are licensed by a state are considered active, provided they are working at least 20 hours per week. Physicians who are retired, semiretired, temporarily not in practice, not active for other reasons or who have not completed their graduate medical education are excluded. Active physicians include those working in direct patient care, administration, medical teaching, research, or other non-patient care activities. Active physicians include those with a doctor of medicine or a doctor of osteopathic medicine degree.

Bar chart showing percentage of males and females in each age group <34, Male, 49.4, Female, 50.6 34-44, Male, 55, Female, 45 45-54, Male, 63.2, Female, 36.8 55-64, Male, 71.5, Female, 28.5 65+, Male, 79.3, Female, 20.7

Source: Association of American Medical Colleges, Diversity in Medicine: Facts and Figures 2019. https://www.aamc.org/data-reports/workforce/interactive-data/figure-25-white-physicians-age-and-sex-2018.

- In 2018, among White physicians, males were the vast majority of those age 65 years and over (79.3%) and of those ages 55-64 years (71.5%) (Figure 9).
- A little more than half of White physicians age 34 and younger were females (50.6%).
- Among White physicians age 35 and over, males made up a larger percentage of the workforce than females. This percentage increased with age.

Figure 10 Black physicians by age and sex, 2018

Note: Physicians (federal and nonfederal) who are licensed by a state are considered active, provided they are working at least 20 hours per week. Physicians who are retired, semiretired, temporarily not in practice, or not active for other reasons or who have not completed their graduate medical education are excluded. Active physicians include those working in direct patient care, administration, medical teaching, research, or other non-patient care activities. Active physicians include those with a doctor of medicine or a doctor of osteopathic medicine degree.

Bar chart showing percentage of males and females in each age group <34, Male, 32.8, Female, 67.2 34-44, Male, 36.5, Female, 63.5 45-54, Male, 46.3, Female, 53.7 55-64, Male, 55.8, Female, 44.2 65+, Male, 65.1, Female, 34.9

Source: Association of American Medical Colleges, Diversity in Medicine: Facts and Figures 2019. https://www.aamc.org/data-reports/workforce/interactive-data/figure-21-black-or-african-american-physicians-age-and-sex-2018.

- In 2018, among Black physicians under age 55, females made up a larger percentage of the workforce than males. This percentage decreased with increasing age (Figure 10).
- Females were 44.2% of Black physicians ages 55-64 and 34.9% of Black physicians age 65 and over.

Figure 11 Asian physicians by age and sex, 2018

Note: Physicians (federal and nonfederal) who are licensed by a state are considered active, provided they are working at least 20 hours per week. Physicians who are retired, semiretired, temporarily not in practice, not active for other reasons or who have not completed their graduate medical education are excluded. Active physicians include those working in direct patient care, administration, medical teaching, research, or other non-patient care activities. Active physicians include those with a doctor of medicine or a doctor of osteopathic medicine degree.

Bar chart showing percentage of males and females in each age group <34, Male, 48, Female, 52 34-44, Male, 51.6, Female, 48..4 45-54, Male, 57, Female, 43 55-64, Male, 66.3, Female, 33.7 65+, Male, 72.7, Female, 27.3

Source: Association of American Medical Colleges, Diversity in Medicine: Facts and Figures 2019. https://www.aamc.org/data-reports/workforce/interactive-data/figure-22-asian-physicians-age-and-sex-2018.

- In 2018, among Asian physicians, males were the vast majority of those age 65 years and over (72.7%) and of those ages 55-64 years (66.3%) (Figure 11).
- Among Asian physicians age 34 and younger, there were more females (52.0%) than males (48.0%).
- Among Asian physicians age 35 and over, males made up a larger percentage of the workforce than females. This percentage increased with age.

Figure 12 American Indian or Alaska Native physicians by age and sex, 2018

Note: Physicians (federal and nonfederal) who are licensed by a state are considered active, provided they are working at least 20 hours per week. Physicians who are retired, semiretired, temporarily not in practice, not active for other reasons or who have not completed their graduate medical education are excluded. Active physicians include those working in direct patient care, administration, medical teaching, research, or other non-patient care activities. Active physicians include those with a doctor of medicine or a doctor of osteopathic medicine degree.

Bar chart showing percentage of males and females in each age group <34, Male, 42.1, Female, 57.9 34-44, Male, 48.7, Female, 51.3 45-54, Male, 60.7, Female, 39.3 55-64, Male, 62.6, Female, 37.4 65+, Male, 73.2, Female, 26.8

Source: Association of American Medical Colleges, Diversity in Medicine: Facts and Figures 2019. https://www.aamc.org/data-reports/workforce/interactive-data/figure-23-american-indian-or-alaska-native-physicians-age-and-sex-2018.

- In 2018, among AI/AN physicians, males were the vast majority of those age 65 years and over (73.2%) and of those ages 55-64 years (62.6%) (Figure 12).
- Among AI/AN physicians age 34 and younger, there were more females (57.9%) than males (42.1%).
- Among AI/AN physicians age 35 and over, males made up a larger percentage of the workforce than females. This percentage increased with age.

Figure 13 Hispanic physicians by age and sex, 2018

Note: Physicians (federal and nonfederal) who are licensed by a state are considered active, provided they are working at least 20 hours per week. Physicians who are retired, semiretired, temporarily not in practice, not active for other reasons or who have not completed their graduate medical education are excluded. Active physicians include those working in direct patient care, administration, medical teaching, research, or other non-patient care activities. Active physicians include those with a doctor of medicine or a doctor of osteopathic medicine degree.

Bar chart showing percentage of males and females in each age group <34, Male, 44.7, Female, 55.3 34-44, Male, 51.2, Female, 48.8 45-54, Male, 60.8, Female, 39.2 55-64, Male, 67.5, Female, 32.5 65+, Male, 77.5, Female, 22.5

Source: Association of American Medical Colleges, Diversity in Medicine: Facts and Figures 2019. https://www.aamc.org/data-reports/workforce/interactive-data/figure-24-hispanic-or-latino-physicians-age-and-sex-2018.

- In 2018, most Hispanic physicians age 65 years and over (77.5%) and ages 55-64 years (67.5%) were males (Figure 13).
- Among Hispanic physicians age 34 and younger, there were more females (55.3%) compared with males (44.7%).
- Among Hispanic physicians age 35 and over, males made up a larger percentage of the workforce than females. This percentage increased with age.

#### Racial and Ethnic Diversity Among Dentists

The racial and ethnic diversity of the oral healthcare workforce is insufficient to meet the needs of a diverse population and to address persistent health disparities.^9^ Increased diversity among dentists may improve quality of care, particularly in the area of culturally and linguistically sensitive care.

Figure 14 Dentists by race (left) and U.S. population racial/ethnic distribution (right), 2018

Note: White, Black, and Asian are non-Hispanic. If estimates for certain racial/ethnic groups meet data suppression criteria, they are recategorized into Other. Percentages of the U.S. population do not add to 100 due to rounding and the exclusion of groups that together represented only about 1% of the total.

Pie chart showing percentage of each group among dentists White, 75% Black, 4% Asian, 18% Other, 3%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Health Resources and Services Administration, National Center for Health Workforce Analysis, 2019; U.S. Census Bureau, American Community Survey, 2018. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&hidePreview=false&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&vintage=2018. Right chart: American Community Survey. ACS Demographic and Housing Estimates. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2018, the vast majority of dentists (75%) were non-Hispanic White (Figure 14).
- In 2018, racial and ethnic minority groups accounted for 25% of dentists:
  ■ Asians, 18%,
  ■ Blacks, 4%, and
  ■ Other (more than one race, AI/ANs, NHPIs, and Hispanics), 3.0%.
- In 2018, the number of dentists for Hispanics did not meet the criteria for statistical reliability due to small sample size despite their being 18% of the U.S. population.

#### Racial and Ethnic Diversity Among Registered Nurses

Ensuring workforce diversity and leadership development opportunities for racial/ethnic minority nurses must remain a high priority in order to eliminate health disparities and, ultimately, achieve health equity.^10^

Figure 15 Registered nurses by race/ethnicity (left) and U.S. population racial/ethnic distribution (right), 2018

Note: White, Black, Asian, and >1 Race are non-Hispanic. Percentages of the U.S. population do not add to 100 due to rounding and the exclusion of groups that together represented only about 1% of the total.

Pie chart showing percentage of each group among registered nurses White, 73% Black, 8% Asian, 5% Hispanic, 10% Other, 4%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Health Resources and Services Administration, National Center for Health Workforce Analysis, 2019, Brief Summary Results From the 2018 National Sample Survey of Registered Nurses. Right chart: American Community Survey. ACS Demographic and Housing Estimates. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2018, the vast majority of RNs (73%) were non-Hispanic White (Figure 15).
- In 2018, racial and ethnic minority groups accounted for 27% of RNs:
  ■ Hispanics, 10%,
  ■ Blacks, 8%,
  ■ Asians, 5%, and
  ■ Other (more than one race, AI/ANs, and NHPIs), 3.5%.

#### Racial and Ethnic Diversity Among Pharmacists

Most healthcare diagnostic and treating occupations such as pharmacists, physicians, nurses, and dentists are primarily White while healthcare support roles such as dental assistants, medical assistants, and personal care aides are more diverse. To decrease disparities and enhance patient care, racial and ethnic diversity must be improved on all levels of the healthcare workforce, not just in support roles.^11^

Progress has been made toward increased racial and ethnic diversity but more work is needed. As Bush notes in an article on underrepresented minorities in pharmacy school, “If we are determined to reduce existing healthcare disparities among racial, ethnic, and socioeconomic groups, then we must be determined to diversify the healthcare workforce.”^12^

Figure 16 Pharmacists by race (left) and U.S. population racial/ethnic distribution (right), 2018

Note: White, Black, Asian, and >1 Race are non-Hispanic. Percentages of the U.S. population do not add to 100 due to rounding and the exclusion of groups that together represented only about 1% of the total.

Pie chart showing percentage of each group among pharmacists White, 70% Black, 5% Asian, 21% More than one race, 2% Other, 2%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Health Resources and Services Administration, National Center for Health Workforce Analysis, 2019. U.S. Census Bureau, American Community Survey, 2018. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&hidePreview=false&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&vintage=2018. Right chart: American Community Survey. ACS Demographic and Housing Estimates. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2018, the vast majority of pharmacists (70%) were non-Hispanic White (Figure 16).
- In 2018, racial and ethnic minority groups accounted for 30% of pharmacists:
  ■ Asians, 21%,
  ■ Blacks, 5%,
  ■ More than one race, 2%, and
  ■ Other (Hispanics, AI/ANs, and NHPIs), 2.0%.

#### Racial and Ethnic Diversity Among Therapists

Occupational therapists, physical therapists, radiation therapists, recreational therapists, and respiratory therapists are classified as health diagnosing and treating practitioners. Hispanics are significantly underrepresented in all of the occupations in the category of Health Diagnosing and Treating Practitioners. Among non-Hispanics, Blacks are underrepresented in most of these occupations.

Asians are underrepresented among speech–language pathologists, and AI/ANs are underrepresented in nearly all occupations. To the extent they can be reliably reported, data also show that NHPIs are underrepresented in all occupations in the Health Diagnosing and Treating Practitioners group.^11^

Therapists include occupational therapists, physical therapists, radiation therapists, recreational therapists, respiratory therapists, speech-language pathologists, exercise physiologists, and other therapists.

Figure 17 Therapists by race/ethnicity (left) and U.S. population racial/ethnic distribution (right), 2018

Note: White, Black, Asian, >1 Race, and Other are non-Hispanic. Percentages of the U.S. population do not add to 100 due to rounding and the exclusion of groups that together represented only about 1% of the total.

Pie chart showing percentage of each group among therapists White, 81% Black, 7% Asian, 7% Hispanic, 1% More than one race, 2% Other, 2%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Health Resources and Services Administration, National Center for Health Workforce Analysis, 2019. U.S. Census Bureau, American Community Survey, 2018. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&hidePreview=false&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&vintage=2018. Right chart: American Community Survey. ACS Demographic and Housing Estimates. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2018, the vast majority of therapists (81%) were non-Hispanic White (Figure 17).
- In 2018, racial and ethnic minority groups accounted for 19% therapists:
  ■ Blacks, 7%,
  ■ Asians, 7%,
  ■ More than one race, 2%,
  ■ Hispanics, 1%, and
  ■ Other (AI/ANs and NHPIs), 2%.

#### Racial and Ethnic Diversity Among Advanced Practice Registered Nurses

The adequacy and distribution of the primary care workforce to meet the current and future needs of Americans continue to be cause for concern. Advanced practice registered nurses are increasingly being used to fill this gap but may include clinicians in areas beyond primary care, such as clinical nurse specialists, nurse midwives, and nurse anesthetists.

Advanced practice registered nurses are registered nurses educated at the master’s or post-master’s level who serve in a specific role with a specific patient population. They include certified nurse practitioners, clinical nurse specialists, certified nurse anesthetists, and certified nurse-midwives.

Nurse practitioners, physicians, and physician assistants provide most of the primary care in the United States, with nurse practitioners accounting for 19% of the primary care workforce and physician assistants accounting for 7%.^13^

Nurse practitioners provide an extensive range of services that includes taking health histories and providing complete physical exams. They diagnose and treat acute and chronic illnesses, provide immunizations, prescribe and manage medications and other therapies, order and interpret lab tests and x rays, and provide health education and supportive counseling.

Nurse practitioners deliver primary care in practices of various sizes, types (e.g., private, public), and settings, such as clinics, schools, and workplaces. Nurse practitioners work independently and collaboratively. They often take the lead in providing care in innovative primary care arrangements, such as retail clinics.^14^

Figure 18 Advanced practice registered nurses by race (left) and U.S. population racial/ethnic distribution (right), 2018

Note: White, Black, Asian, >1 Race, and Other are non-Hispanic. Percentages of the U.S. population do not add to 100 due to rounding and the exclusion of groups that together represented only about 1% of the total.

Pie chart showing percentage of each group among advanced practice nurses White, 83% Black, 6% Asian, 7% Other, 4%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Health Resources and Services Administration, National Center for Health Workforce Analysis, 2019. U. S. Census Bureau, American Community Survey, 2018. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&hidePreview=false&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&vintage=2018. Right chart: American Community Survey. ACS Demographic and Housing Estimates. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2018, the vast majority of advanced practice registered nurses (83%) were non-Hispanic White (Figure 18).
- In 2018, racial and ethnic minority groups accounted for 17% of advanced practice registered nurses:
  ■ Asians, 7%,
  ■ Blacks, 6%, and
  ■ Other (Hispanics, more than one race, AI/ANs, and NHPIs), 4%.

#### Racial and Ethnic Diversity Among Emergency Professionals

Workforce diversity can reduce communication barriers and inequalities in healthcare delivery, especially in settings such as emergency departments where time pressure and incomplete information may worsen the effects of implicit biases. The racial and ethnic makeup of the paramedic and emergency medical technician workforce indicates that concerted efforts are needed to encourage students of diverse backgrounds to pursue emergency service careers.^15^

Figure 19 Emergency medical technicians and paramedics by race (left), and U.S. population racial/ethnic distribution (right), 2018

Note: White, Black, Asian, >1 Race, and Other are non-Hispanic. Percentages of the U.S. population do not add to 100 due to rounding and the exclusion of groups that together represented only about 1% of the total.

Pie chart showing percentage of each group among emergency medical technicians and paramedics White, 82% Black, 7% Asian, 3% More than one race, 3% Other, 5%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Health Resources and Services Administration, National Center for Health Workforce Analysis, 2019. U.S. Census Bureau, American Community Survey, 2018. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&hidePreview=false&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&vintage=2018. Right chart: American Community Survey. ACS Demographic and Housing Estimates. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2018, the vast majority of emergency medical technicians (EMTs) and paramedics (82%) were non-Hispanic White (Figure 19).
- In 2018, racial and ethnic minority groups accounted for 18% of EMTs and paramedics:
  ■ Blacks, 7%,
  ■ Asians, 3%,
  ■ More than one race, 3%,
  ■ Other (Hispanics, AI/ANs, and NHPIs), 5%.

#### Racial and Ethnic Diversity Among Other Health Practitioners

Other health practitioners include physician assistants, medical assistants, dental assistants, chiropractors, dietitians and nutritionists, optometrists, podiatrists, and audiologists, as well as massage therapists, medical equipment preparers, medical transcriptionists, pharmacy aides, veterinary assistants and laboratory animal caretakers, phlebotomists, and healthcare support workers.

Figure 20 Other health practitioners by race/ethnicity (left) and U.S. population racial/ethnic distribution (right), 2018

Key: AI/AN = American Indian or Alaska Native.

Note: White, Black, Asian, AI/AN, >1 Race, and Other are non-Hispanic. Percentages of the U.S. population do not add to 100 due to rounding and the exclusion of groups that together represented only about 1% of the total.

Pie chart showing percentage of each group among other health practitioners White, 72% Black, 11% Asian, 6% American Indian/Alaska Native, 1% Hispanic, 1% More than one race, 3% Other, 6%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Health Resources and Services Administration, National Center for Health Workforce Analysis, 2019. U.S. Census Bureau, American Community Survey, 2018. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&hidePreview=false&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&vintage=2018. Right chart: American Community Survey. ACS Demographic and Housing Estimates. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2018, the vast majority of other health practitioners (72%) were non-Hispanic White (Figure 20).
- In 2018, racial and ethnic minority groups accounted for 28% of other health practitioners:
  ■ Blacks, 11%,
  ■ Asians, 6%,
  ■ Other, 6%,
  ■ More than one race, 3%,
  ■ Hispanics, 1%, and
  ■ AI/ANs, 1%.

#### Racial and Ethnic Diversity Among Other Health Occupations

Other health occupations include veterinarians, acupuncturists, all other healthcare diagnosing or treating practitioners, dental hygienists, and licensed practical and licensed vocational nurses.

Figure 21 Other health occupations by race/ethnicity (left) and U.S. population racial/ethnic distribution (right), 2018

Key: AI/AN = American Indian or Alaska Native.

Note: White, Black, Asian, AI/AN, >1 Race, and Other are non-Hispanic. Percentages of the U.S. population do not add to 100 due to rounding and the exclusion of groups that together represented only about 1% of the total.

Pie chart showing percentage of each group among other health occupations White, 67% Black, 20% Asian, 5% American Indian/Alaska Native, 1% Hispanic, 2% More than one race, 2% Other, 3%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Health Resources and Services Administration, National Center for Health Workforce Analysis, 2019. U.S. Census Bureau, American Community Survey, 2018. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&hidePreview=false&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&vintage=2018. Right chart: American Community Survey. ACS Demographic and Housing Estimates. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2018, the vast majority of staff in other health occupations (67%) were non-Hispanic White (Figure 21).
- In 2018, racial and ethnic minority groups accounted for 33% of staff in other health occupations:
  ■ Blacks, 20%,
  ■ Asians, 5%,
  ■ Other, 3%,
  ■ More than one race, 2%,
  ■ Hispanics, 2%, and
  ■ AI/ANs, 1%.

#### Racial and Ethnic Diversity Among Health Technologists

Health technologists include clinical laboratory technologists and technicians, cardiovascular technologists and technicians, diagnostic medical sonographers, radiologic technologists and technicians, magnetic resonance imaging technologists, nuclear medicine technologists and medical dosimetrists, pharmacy technicians, surgical technologists, veterinary technologists and technicians, dietetic technicians and ophthalmic medical technicians, medical records specialists, and opticians (dispensing), miscellaneous health technologists and technicians, and technical occupations.

Figure 22 Health technologists by race/ethnicity (left) and U.S. population racial/ethnic distribution (right), 2018

Key: AI/AN = American Indian or Alaska Native.

Note: White, Black, Asian, AI/AN, >1 Race, and Other are non-Hispanic. Percentages of the U.S. population do not add to 100 due to rounding and the exclusion of groups that together represented only about 1% of the total.

Pie chart showing percentage of each group among health technologists White, 72% Black, 13% Asian, 7% American Indian/Alaska Native, 1% Hispanic, 1% More than one race, 3% Other, 3%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Health Resources and Services Administration, National Center for Health Workforce Analysis, 2019. U.S. Census Bureau, American Community Survey, 2018. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&hidePreview=false&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&vintage=2018. Right chart: American Community Survey. ACS Demographic and Housing Estimates. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2018, the vast majority of health technologists (72%) were non-Hispanic White (Figure 22).
- In 2018, racial and ethnic minority groups accounted for 28% of health technologists:
  ■ Blacks, 13%,
  ■ Asians, 7%,
  ■ Other, 3%,
  ■ More than one race, 3%,
  ■ Hispanics, 1%, and
  ■ AI/ANs, 1%.

#### Racial and Ethnic Diversity Among Healthcare Aides

Healthcare aides include nursing, psychiatric, home health, occupational therapy, and physical therapy assistants and aides.

Figure 23 Healthcare aides by race/ethnicity (left) and U.S. population racial/ethnic distribution (right), 2018

Key: AI/AN = American Indian or Alaska Native.

Note: White, Black, Asian, AI/AN, >1 Race, and Other are non-Hispanic. Percentages of the U.S. population do not add to 100 due to rounding and the exclusion of groups that together represented only about 1% of the total.

Pie chart showing percentage of each group among health aides White, 54%30 Black, 5% Asian, 5% American Indian/Alaska Native, 1% Hispanic, 2% More than one race, 3% Other, 5%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Health Resources and Services Administration, National Center for Health Workforce Analysis, 2019. U.S. Census Bureau, American Community Survey, 2018. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&hidePreview=false&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&vintage=2018. Right chart: American Community Survey. ACS Demographic and Housing Estimates. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2018, the majority of health aides (54%) were non-Hispanic White (Figure 23).
- In 2018, racial and ethnic minority groups accounted for 46% of health aides:
  ■ Blacks, 30%,
  ■ Asians, 5%,
  ■ Other, 5%,
  ■ More than one race, 3%,
  ■ Hispanics, 2%, and
  ■ AI/ANs, 1%.

#### Racial and Ethnic Diversity Among Psychologists

The United States has an inadequate workforce to meet the mental health needs of the population,^16,17,18^ and it is estimated that nearly 57% of the U.S. population with any mental illness does not receive needed treatment.^19^ This unmet need is even greater for racial and ethnic minority populations. Nearly three-quarters (73%) of Asians and Pacific Islanders,^iii^ 69% of African Americans, and 67% of Hispanics with a mental illness do not receive mental health treatment.^19,20,21,22^

These gaps in mental healthcare may be attributed to a number of reasons, including stigma, cultural attitudes and beliefs, lack of insurance, or lack of familiarity with the mental health system.^23,24,25^ However, a significant contributor to this treatment gap is the composition of the workforce.

The current mental health workforce lacks racial and ethnic diversity.^24,26^ Research has shown that racial/ethnic patient-provider concordance is correlated with patient engagement and retention in mental health treatment.^27^ In addition, racial and ethnic minority providers are more likely to serve patients of color than White providers.^24,26^

Among psychologists, a key practitioner group in the mental health workforce,^17,28^ minorities are significantly underrepresented. Psychologists in the United States are predominantly non-Hispanic White, while all racial/ethnic minorities represented only about one-sixth of all psychologists from 2011 to 2015.

Reducing the serious gaps in mental health care for racial and ethnic minority populations will require a significant shift in the workforce. Workforce recruitment, training, and education of more racially, ethnically, and culturally diverse practitioners will be essential to reduce these disparities.

Figure 24 Psychologists by race/ethnicity (left) and U.S. population racial/ethnic distribution (right), 2015

Key: API = Asian or Pacific Islander.

Note: White, Black, API, and >1 Race are non-Hispanic. Psychologist includes practitioners of general psychology, developmental and child psychology, clinical psychology, counseling psychology, school psychology, clinical child psychology, geropsychology, and health/medical psychology. Percentages of the U.S. population do not add to 100 due to rounding; in addition, the chart excludes groups that together represented only about 1% of the total.

Pie chart showing percentage of each group among psychologists White, 84% Black, 5% Asian, 3% Hispanic, 6% More than one race, 2%

Pie chart showing percentage of each group among the U.S. population White, 60% Black, 12% Asian, 6% Hispanic, 18% More than one race, 3%

Source: Left chart: Health Resources and Services Administration, Sex, Race, and Ethnic Diversity of U.S. Health Occupations (2011-2015), August 2017. https://bhw.hrsa.gov/sites/default/files/bhw/nchwa/diversityushealthoccupations.pdf. Right chart: American Community Survey. ACS Demographic and Housing Estimates, 2015 ACS 1-Year Estimates Data. https://data.census.gov/cedsci/table?q=Race%20and%20Ethnicity&t=Race%20and%20Ethnicity&tid=ACSDP1Y2018.DP05&hidePreview=false.

- In 2015, the vast majority of psychologists (84%) were non-Hispanic White (Figure 24).
- In 2018, racial and ethnic minority groups accounted for 16% of psychologists:
  ■ Hispanics, 6%,
  ■ Blacks, 5%,
  ■ APIs, 3%, and
  ■ More than one race, 2.0%.

## Overview of Healthcare Expenditures in the United States

- In 2018, national health expenditures totaled about $3.6 trillion, excluding administrative and investment costs.^29^
- Hospital expenditures grew 4.5% to $1,191.8 billion in 2018, slightly slower than the 4.7% growth in 2017.
- Physician and clinical services expenditures grew 4.1% to $725.6 billion in 2018, a slower growth than the 4.7% in 2017.
- Prescription drug spending increased 2.5% to $335.0 billion in 2018, faster than the 1.4% growth in 2017.
- In 2018, the federal government and households each accounted for 28% of healthcare spending (the largest shares), followed by private businesses (20%), state and local governments (17%), and other private revenues (7%). Federal government spending on health accelerated in 2018, increasing 5.6% after 2.8% growth in 2017.

### Personal Healthcare Expenditures

“Personal healthcare expenditures” measures the total amount spent to treat individuals with specific medical conditions. It comprises all of the medical goods and services used to treat or prevent a specific disease or condition in a specific person. These include hospital care; professional services; other health, residential, and personal care; home health care; nursing care facilities and continuing care retirement communities; and retail outlet sales of medical products.^30^

Figure 25 Distribution of personal healthcare expenditures by type of expenditure, 2018

Key: CCRCs = continuing care retirement communities.

Note: Percentages do not add to 100 due to rounding. Personal healthcare expenditures are outlays for goods and services related directly to patient care. These expenditures are total national health expenditures minus expenditures for investment, health insurance program administration and the net cost of insurance, and public health activities. Other Healthcare refers to other professional services, other health, residential, and personal care expenses, durable medical equipment, and non-durable medical products.

9Pie chart showing distribution of expenditures Hospital Care, 39% Physician and Clinical Services, 24% Prescription Drugs, 11% Nursing Care, 6% Other Health Care, 14% Dental Services, 4% Home Health Care, 3%

Source: Centers for Medicare & Medicaid Services, National Health Expenditures by type of service and source of funds, CY 1960-2018. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html.

- In 2018, hospital care expenditures were $1,191.8 billion, nearly 40% of personal healthcare expenditures (Figure 25).
- Expenditures for physician and clinical services were $725.6 billion, almost one-fourth of personal healthcare expenditures.
- Prescription drug expenditures were $335.0 billion, 11% of personal healthcare expenditures.
- Expenditures for dental services were $135.6 billion, 4% of personal healthcare expenditures.
- Nursing care facility expenditures were $168.5 billion and home health care expenditures were $102.2 billion, 6% and 3% of personal healthcare expenditures, respectively.

Figure 26 Personal healthcare expenditures (left) and prescription drug expenditures (right), by source of funds, 2018

Note: Data for both figures are available at https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html. Percentages may not add to 100 due to rounding. Personal healthcare expenditures are outlays for goods and services related directly to patient care. These expenditures are total national health expenditures minus expenditures for investment, health insurance program administration and the net cost of insurance, and public health activities. Other health insurance programs include Children’s Health Insurance Program (Titles XIX and XXI) and programs available through the Department of Defense and the Department of Veterans Affairs. Other third party payers may include worksite healthcare, other private venues, Indian Health Service, workers’ compensation, general assistance, maternal and child health programs, vocational rehabilitation programs, other federal programs, Substance Abuse and Mental Health Services Administration, other state and local programs, and school health programs.

Pie chart showing source of funds for healthcare expenditures Private, 35% Medicare, 23% Medicaid, 17% Out of Pocket, 12% Other Third Party, 8% Other Health Insurance Programs, 4% Pie chart showing source of funds for prescription drug expenditures Private, 40% Medicare, 32% Medicaid, 10% Out of Pocket, 14% Other Third Party, 1% Other Health Insurance Programs, 3%

Pie chart showing source of funds for prescription drugs Private Health Insurance, 42.0% Medicare, 30.3% Medicaid, 9.9% Out of Pocket, 14.0% Other Third Party Payers, 0.5% Other Health Insurance Programs, 3.3%

Source: Left chart: Centers for Medicare & Medicaid Services, National Health Expenditures by type of service and source of funds, CY 1960-2018; and NHE Tables 6, 7, 8, 12, 14, and 15. Right chart: Cnters for Medicare & Medicaid Services, NHE Table 16, Retail Prescription Drugs Expenditures; Levels, Percent Change, and Percent Distribution, by Source of Funds: Selected Calendar Years 1970-2018.

- In 2018, private insurance accounted for 35% of personal healthcare expenditures, followed by Medicare (23%), Medicaid (17%), and out of pocket (12%; Figure 26).
- Sources of funds varied by type of expenditure (data not shown):
  ■ Private insurance accounted for 40% of hospital, 43% of physician, 12% of home health, 10% of nursing home, 46% of dental, and 40% of prescription drug expenditures.
  ■ Medicare accounted for 25% of hospital, 23% of physician, 39% of home health, 23% of nursing home, 0.9% of dental, and 32% of prescription drug expenditures.
  ■ Medicaid accounted for 16% of hospital, 11% of physician, 35% of home health, 30% of nursing home, 9% of dental, and 10% of prescription drug expenditures.
  ■ Out-of-pocket payments accounted for 3% of hospital, 8% of physician, 10% of home health, 27% of nursing home, 40% of dental, and 14% of prescription drug expenditures.
- In 2018, retail prescription drug expenditures were $335.0 billion. Patients paid 14% of these expenses out of pocket, totaling $47.1 billion. All other health insurance entities, including private health insurance, Medicare, Medicaid, and other health insurance programs accounted for 85% of the total costs ($286.2 billion).
  ■ Private health insurance companies accounted for 40% of retail drug expenses ($134.3 billion in 2018).
  ■ Medicare accounted for 32.0% of retail drug expenses ($107.2 billion).
  ■ Medicaid accounted for 10.0% of retail drug expenses ($33.4 billion).
  ■ Other health insurance programs consisted of the Children’s Health Insurance Program (Titles XIX and XXI) and programs available through the Department of Defense and the Department of Veterans Affairs. These programs accounted for 3.4% of retail drug expenses ($11.3 billion).
  ■ Other third-party payers had the smallest percentage of costs (0.5%), which represented $1.8 billion in retail drug costs. These expenses were incurred by a variety of sources, including worksite healthcare, other private venues, Indian Health Service, workers’ compensation, general assistance, maternal and child health programs, vocational rehabilitation programs, other federal programs, Substance Abuse and Mental Health Services Administration, other state and local programs, and school health programs.

## Variation in Healthcare Quality

State-level data show that healthcare quality and disparities vary widely depending on state and region. Although a state may perform well in overall quality, the same state may face significant disparities in healthcare access or disparities within specific areas of quality.

Figure 27 Overall quality of care, by state, 2014-2018

Note: All state-level measures with data are used to compute an overall quality score for each state based on the number of quality measures above, at, or below the average across all states. States were ranked and quartiles are shown on the map. The states with the worst quality score are in the fourth quartile, and states with the best quality score are in the first quartile. Historically, the NHQDR has included state-specific estimates for selected AHRQ Quality Indicators (QIs) based on Healthcare Cost and Utilization Project (HCUP) data. The 2019 NHQDR does not include state-specific QI estimates based on 2017 HCUP data because the International Classification of Diseases, Tenth Revision, Clinical Modification/Procedure Coding System version of the QI software used did not include risk adjustment. State-specific QIs will be reported in future NHQDRs when the estimates can be risk adjusted.

Map of the United States shows quality of care by state. The map is color-coded to show which states are in the 1st through 4th quartiles; read the text below for details.

- Overall quality of care varied across the United States (Figure 27):
  ■ Some states in the Northeast (Delaware, Maine, Massachusetts, New Hampshire, Pennsylvania, and Rhode Island), some in the Midwest (Iowa, Minnesota, North Dakota, and Wisconsin), and Idaho and West Virginia had the highest overall quality scores. Scores were based on the number of measures that were better, same, or worse than the national average for each measure.
  ■ Some Southern and Southwestern states (District of Columbia,^iv^ New Mexico, and Texas), several Western states (Arizona, California, and Nevada), some Northwestern states (Montana, Oregon, Washington, and Wyoming), and Florida, New York, and Alaska had the lowest overall quality scores.
  ■ More information about healthcare quality in each state can be found on the NHQDR website, https://nhqrnet.ahrq.gov/inhqrdr/state/select.

i World Health Organization, Maternal and Perinatal Health. http://www.who.int/maternal_child_adolescent/topics/maternal/maternal_perinatal/en/.

ii For purposes of the NHQDR, the District of Columbia is treated as a state.

iii The National Survey on Drug Use and Health at the Substance Abuse and Mental Health Services Administration combines data for Asians and Pacific Islander populations, which includes Native Hawaiians.

iv For purposes of the NHQDR, the District of Columbia is treated as a state.