# EXECUTIVE SUMMARY

## Key Findings

- Access: From 2000 through 2016-2018, more than half (11 of 20) of access measures showed improvement, 25% (5 of 20) did not show improvement, and 20% (4 of 20) showed worsening. For example, there were significant gains in the percentage of people who reported having health insurance.
- Quality: Quality of healthcare improved overall from 2000 through 2018, but the pace of improvement varied by priority area:
  ■ Person-Centered Care: Almost half (14 of 29) of person-centered care measures were improving overall.
  ■ Patient Safety: Nearly half (12 of 26) of patient safety measures were improving overall.
  ■ Healthy Living: Almost 60% (41 of 70) of healthy living measures were improving overall.
  ■ Effective Treatment: More than 40% (15 of 36) of effective treatment measures were improving overall.
  ■ Care Coordination: Nearly 40% (3 of 8) of care coordination measures were improving overall.
  ■ Care Affordability: Forty percent (2 of 5) of affordable care measures were improving overall.
- Disparities: Overall, some disparities were getting smaller from 2000 through 2016-2018, but disparities persist and some even worsened, especially for poor^i^ and uninsured populations in all priority areas.
  ■ Racial and ethnic disparities vary by group:
    ♦ For about 40% of quality measures, Blacks (82 of 202) and American Indians and Alaska Natives (47 of 116) received worse care than Whites. For more than one-third of quality measures, Hispanics (61 of 177) received worse care than Whites.
    ♦ For nearly 30% of quality measures, Asians (52 of 185) received worse care than Whites, but Asians received better care than Whites for nearly one-third (56 of 185) of quality measures.
    ♦ For one-third of quality measures, Native Hawaiians/Pacific Islanders (24 of 72) received worse care than Whites.
  ■ Disparities vary by residence location:
    ♦ For nearly a quarter (24 of 102) of quality measures, residents of large central metropolitan areas received worse care than residents of large fringe metropolitan areas.
    ♦ For one-third of quality measures, residents of micropolitan and noncore areas received worse care than residents of large fringe metropolitan areas.
    ♦ For a little less than 20% of quality measures, medium and small metropolitan residents received worse care than residents of large fringe metropolitan areas.

## About the National Healthcare Quality and Disparities Report

For the 17th year in a row, AHRQ is reporting on healthcare quality and disparities. The annual National Healthcare Quality and Disparities Report (NHQDR) is mandated by Congress to provide a comprehensive overview of the quality of healthcare received by the general U.S. population and disparities in care experienced by different racial and socioeconomic groups.

The report assesses the performance of our healthcare system and identifies areas of strength and weakness, as well as disparities, for access to healthcare and quality of healthcare. Quality measures are grouped by priority areas, including person-centered care, patient safety, healthy living, effective treatment, care coordination, and affordable care.

More than 250 measures used in these reports span a wide range of structure, process, and outcome measures for which existing national data sources can be used. This report presents selected findings in each priority area and examples of large disparities, disparities worsening over time, and disparities showing improvement. A U.S. Department of Health and Human Services (HHS) Interagency Work Group (IWG)^ii^ that supports the reports selected the measures for tracking based on their importance, scientific soundness, and feasibility.

## Social Determinants of Health

Healthcare quality and delivery affect each person’s healthcare outcomes, but many other factors contribute to individual health. An integral part of delivering high-quality healthcare is understanding the social determinants of health (SDOH) of patients and of communities in which healthcare is provided. The World Health Organization defines SDOH as the conditions in which people are born, grow, live, work, and age.

SDOH can be discussed in the following contexts:

- Social context (e.g., demographics, social networks and supports; social cohesion; discrimination based on race, ethnicity, religion, sex, and gender identity; community safety; criminal justice climate; civic participation).
- Economic context (e.g., employment, income, poverty).
- Education (e.g., quality of daycare, schools, and adult education; literacy and high school graduation rates; English proficiency).
- Physical infrastructure (e.g., housing, transportation, workplace safety, food availability, parks and other recreational facilities, environmental conditions, sufficiency of social services).
- Healthcare context (e.g., access to high-quality, culturally and linguistically appropriate, and health-literate care; access to insurance; healthcare laws; health promotion initiatives; supply side of services; attitudes toward healthcare; and use of services).^1^

This report examines SDOH by highlighting disparities experienced by various subpopulations. Policymakers, researchers, providers, and other stakeholders can use this report’s analyses to understand the outcomes for racial and ethnic, insurance, income, and residence location groups.

## Reference

1 Agency for Healthcare Research and Quality. About SDOH in Healthcare. Content lLast reviewed February 2020. Agency for Healthcare Research and Quality, Rockville, MD. https://www.ahrq.gov/sdoh/about.html. Accessed September 14, 2020.

i Poor is defined as having family income below 100% of the federal poverty level (FPL).

ii Federal participants on IWG: AHRQ, Administration for Children and Families, Administration for Community Living, Assistant Secretary for Planning and Evaluation, Centers for Disease Control and Prevention, Centers for Medicare & Medicaid Services, Food and Drug Administration, Health Resources and Services Administration, Indian Health Service, National Institutes of Health, Office of the Assistant Secretary for Health, Substance Abuse and Mental Health Services Administration, and Veterans Health Administration.