# REFERENCES

1 Gardner JW, Sanborn JS. Years of potential life lost (YPLL)-what does it measure? Epidemiology 1990;1:322–9. https://www.ncbi.nlm.nih.gov/pubmed/2083312 [abstract]. Accessed August 5, 2019.2083312
2 Centers for Medicare & Medicaid Services. National Health Expenditures by Type of Service and Source of Funds, CY 1960-2017. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html. Accessed May 9, 2019.
3 Centers for Medicare & Medicaid Services. National Health Expenditures 2017 Highlights. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html. Accessed March 25, 2019.
4 Institute of Medicine. Crossing the Quality Chasm: A New Health System for the 21st Century. Washington, DC: National Academy Press; 2001. https://www.nap.edu/catalog/10027/crossing-the-quality-chasm-a-new-health-system-for-the. Accessed August 5, 2019.
5 Institute of Medicine. Envisioning the National Health Care Quality Report. Washington, DC: National Academy Press; 2001. https://www.nap.edu/catalog/10073/envisioning-the-national-health-care-quality-report. Accessed August 5, 2019.
6 DiMatteo MR. The role of the physician in the emerging health care environment. West J Med 1998;168(5):328–33. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1304975/. Accessed August 5, 2019.9614789
7 Stewart M, Brown JB, Donner A, . The impact of patient-centered care on outcomes. J Fam Pract 2000;49(9):796–804. https://www.ncbi.nlm.nih.gov/pubmed/11032203 [abstract]. Accessed August 5, 2019.11032203
8 Little P, Everitt H, Williamson I, . Observational study of effect of patient centredness and positive approach on outcomes of general practice consultations. BMJ 2001;323(7318):908–11. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC58543/. Accessed August 5, 2019.11668137
9 Anderson EB. Patient-centeredness: a new approach. Nephrol News Issues 2002;16(12):80–2. https://www.ncbi.nlm.nih.gov/pubmed/12452113 [abstract]. Accessed August 5, 2019.12452113
10 Beck RS, Daughtridge R, Sloane PD. Physician-patient communication in the primary care office: a systematic review. J Am Board Fam Pract 2002;15(1):25–38. https://www.jabfm.org/content/15/1/25.long. Accessed August 5, 2019.11841136
11 Rhoades DR, McFarland KF, Finch WH, . Speaking and interruptions during primary care office visits. Fam Med 2001;33(7):528–32. https://www.ncbi.nlm.nih.gov/pubmed/11456245 [abstract]. Accessed August 5, 2019.11456245
12 Weiner SJ, Schwartz A, Sharma G, . Patient-centered decision making and health care outcomes. Ann Intern Med 2013;158(8):573–9. https://www.ncbi.nlm.nih.gov/pubmed/23588745. Accessed August 5, 2019.23588745
13 Okunrintemi V, Spatz ES, Di Capua P, . Patient-provider communication and health outcomes among individuals with atherosclerotic cardiovascular disease in the United States: Medical Expenditure Panel Survey 2010 to 2013. Circ Cardiovasc Qual Outcomes 2017 Apr;10(4). https://www.ahajournals.org/doi/full/10.1161/CIRCOUTCOMES.117.003635?url_ver=Z39.88-2003&rfr_id=ori%3Arid%3Acrossref.org&rfr_dat=cr_pub%3Dpubmed. Accessed May 10, 2019.
14 National Academies of Sciences, Engineering, and Medicine. Improving Diagnosis in Health Care. Washington, DC: The National Academies Press; 2015. https://www.nap.edu/catalog/21794/improving-diagnosis-in-health-care. Accessed August 5, 2019.
15 Øvretveit, J. Do Changes to Patient-Provider Relationships Improve Quality and Save Money? A Review of the Evidence About Value Improvements Made by Changing Communication, Collaboration, and Support for Self-Care. London, UK: The Health Foundation; 2012. https://www.bl.uk/collection-items/do-changes-to-patientprovider-relationships-improve-quality-and-save-money-a-review-of-evidence-about-value-improvements-made-by-changing-communication-collaboration-and-support-for-selfcare. Accessed August 5, 2019.
16 Bertakis KD, Azari R. Patient-centered care is associated with decreased health care utilization. J Am Board Fam Med 2011 May–Jun;24(3):229–39. https://www.jabfm.org/content/24/3/229.long. Accessed August 5, 2019.21551394
17 Epstein RM, Franks P, Shields CG, . Patient-centered communication and diagnostic testing. Ann Fam Med 2005;3(5):415–21. http://www.annfammed.org/content/3/5/415.long. Accessed August 5, 2019.16189057
18 Posner KL, Severson J, Domino KB. The role of informed consent in patient complaints: reducing hidden health system costs and improving patient engagement through shared decision making (https://onlinelibrary.wiley.com/doi/10.1002/jhrm.21200). J Healthc Risk Manag 2015 Sep;35(2):38–45. https://www.ncbi.nlm.nih.gov/pubmed/26418139. Accessed August 5, 2019.26418139
19 Chou C. Time to start using evidence-based approaches to patient engagement. NEJM Catalyst 2018 Mar 28. https://catalyst.nejm.org/evidence-based-patient-provider-communication/. Accessed May 10, 2019.
20 Kohn LT, Corrigan JM, Donaldson MS, eds; Committee on Quality of Health Care in America, Institute of Medicine. To Err Is Human: Building a Safer Health System. Washington, DC: National Academy Press; 2000. http://www.nap.edu/catalog/9728.html. Accessed May 10, 2019.
21 Sunshine JE, Meo N, Kassebaum NJ, . Association of adverse effects of medical treatment with mortality in the United States: a secondary analysis of the Global Burden of Diseases, Injuries, and Risk Factors Study. JAMA Netw Open 2019;2(1):e187041. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6484545/. Accessed August 5, 2019.30657530
22 AHRQ National Scorecard on Hospital-Acquired Conditions: Updated Baseline Rates and Preliminary Results 2014-2017. https://www.ahrq.gov/sites/default/files/wysiwyg/professionals/quality-patient-safety/pfp/hacreport-2019.pdf. Accessed August 19, 2019.
23 Bailey MK, Weiss AJ, Barrett ML, . Characteristics of 30-day readmissions, 2010-2016. HCUP Statistical Brief #248. Rockville, MD: Agency for Healthcare Research and Quality; February 2019. www.hcup-us.ahrq.gov/reports/statbriefs/sb248-Hospital-Readmissions-2010-2016.pdf. Accessed August 19, 2019.
24 Fingar KR, Stocks C, Weiss AJ, . Most frequent operating room procedures performed in U.S. hospitals, 2003-2012. HCUP Statistical Brief #186. Rockville, MD: Agency for Healthcare Research and Quality; December 2014. https://www.hcup-us.ahrq.gov/reports/statbriefs/sb186-Operating-Room-Procedures-United-States-2012.jsp. Accessed July 12, 2019.
25 Gajic-Veljanoski O, Phua CW, Shah PS, . Effects of long-term low-molecular-weight heparin on fractures and bone density in non-pregnant adults: a systematic review with meta-analysis. J Gen Intern Med 2016 Aug;31(8):947–57. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4945546/. Accessed August 5, 2019.26895998
26 Bodenheimer T. Coordinating care—a perilous journey through the health care system. N Engl J Med 2008 Mar 6;358(10):1064–71. DOI:10.1056/NEJMhpr0706165. Accessed August 5, 2019.18322289
27 Shojania K, McDonald K, Wachter R, . Closing the Quality Gap: A Critical Analysis of Quality Improvement Strategies—Volume 7: Care Coordination. Rockville, MD: Agency for Healthcare Research and Quality; 2007. http://www.ahrq.gov/research/findings/evidence-based-reports/caregaptp.html. Accessed May 10, 2019.
28 Powell-Davies G, Williams AM, Larsen K, . Coordinating primary health care: an analysis of the outcomes of a systematic review. Med J Aust (https://www.ncbi.nlm.nih.gov/pubmed/18429740) 2008 Apr 21;188(8 Suppl):S65–8. https://www.ncbi.nlm.nih.gov/pubmed/18429740 [abstract]. Accessed August 5, 2019.18429740
29 Report to the Congress: Medicare Payment Policy. Chapter 9: Home health care services. Washington, DC: Medicare Payment Advisory Commission; March 2019. http://www.medpac.gov/docs/default-source/reports/mar19_medpac_ch9_sec.pdf?sfvrsn=0. Accessed May 10, 2019.
30 Coleman EA, Parry C, Chalmers S, . The care transitions intervention: results of a randomized controlled trial. Arch Intern Med 2006 Sep 25;166(17):1822–8. https://www.ncbi.nlm.nih.gov/pubmed/17000937. Accessed August 2, 2019.17000937
31 Whittington J, Cohen H. OSF Healthcare’s journey in patient safety. Qual Manag Health Care (https://www.ncbi.nlm.nih.gov/pubmed/?term=whittington+cohen+medication+reconciliation) 2004 Jan–Mar;13(1):53–9. https://www.ncbi.nlm.nih.gov/pubmed/14976907 [abstract]. Accessed August 5, 2019.14976907
32 Jencks SF, Williams MV, Coleman EA. Rehospitalizations among patients in the Medicare Fee-for-Service Program. N Engl J Med 2009;360:1418–28. https://www.nejm.org/doi/10.1056/NEJMsa0803563?url_ver=Z39.88-2003&rfr_id=ori:rid:crossref.org&rfr_dat=cr_pub%3dwww.ncbi.nlm.nih.gov. Accessed August 5, 2019.19339721
33 Demaerschalk BM, Hwang HM, Leung G. Cost analysis review of stroke centers, telestroke, and rt-PA. Am J Manag Care 2010 Jul;16(7):537–44. https://www.ncbi.nlm.nih.gov/pubmed/20645669. Accessed August 5, 2019.20645669
34 Fagan SC, Morgenstern LB, Petitta A, . Cost-effectiveness of tissue plasminogen activator for acute ischemic stroke. NINDS rt-PA Stroke Study Group. Neurology 1998;50:883–90. https://www.ncbi.nlm.nih.gov/pubmed/9566367. Accessed August 5, 2019.9566367
35 Johnston S. The economic case for new stroke thrombolytics. Stroke 2010 Oct;41(10 Suppl):S59–S62. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2955402/. Accessed August 5, 2019.20876507
36 Kenealy T, Arroll B. Antibiotics for the common cold and acute purulent rhinitis. Cochrane Database Syst Rev 2013 Jun 4;(6):CD000247. https://www.ncbi.nlm.nih.gov/pubmed/23733381. Accessed August 5, 2019.23733381
37 Choi JP, Park IJ, Lee BC, . Variability in the lymph node retrieval after resection of colon cancer: influence of operative period and process. Medicine (Baltimore) 2016 Aug;95(31):e4199. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4979778/. Accessed May 10, 2019.27495024
38 Scholl L, Seth P, Kariisa M, . Drug and opioid-involved overdose deaths — United States, 2013-2017. MMWR Morb Mortal Wkly Rep 2019;67:1419–27. 10.15585/mmwr.mm675152e1. Accessed May 10, 2019.
39 Center for Behavioral Health Statistics and Quality. Key Substance Use and Mental Health Indicators in the United States: Results From the 2016 National Survey on Drug Use and Health. NSDUH Series H-52. Rockville, MD: Substance Abuse and Mental Health Services Administration; 2017. HHS Publication No. SMA 17-5044. https://store.samhsa.gov/system/files/sma17-5044.pdf. Accessed May 20, 2019.
40 Hedegaard H, Curtin SC, Warner M. Suicide mortality in the United States, 1999-2017. NCHS Data Brief No. 330. Hyattsville, MD: National Center for Health Statistics; 2018. https://www.cdc.gov/nchs/data/databriefs/db330-h.pdf. Accessed July 26, 2019.
41 Stone DM, Simon TR, Fowler KA, . Vital Signs: Trends in state suicide rates — United States, 1999-2016 and circumstances contributing to suicide — 27 states, 2015. MMWR 2018 Jun 8;67(22);617–24. https://www.cdc.gov/mmwr/volumes/67/wr/mm6722a1.htm. Accessed May 10, 2019.29879094
42 Dabbagh A, Laws RL, Steulet C, . Progress toward regional measles elimination — worldwide, 2000-2017. MMWR Morb Mortal Wkly Rep 2018;67:1323–1329. 10.15585/mmwr.mm6747a6. Accessed August 5, 2019.30496160
43 Zhou F, Santoli J, Messonnier ML, . Economic evaluation of the 7-vaccine routine childhood immunization schedule in the United States, 2001. Arch Pediatr Adolesc Med (https://www.ncbi.nlm.nih.gov/pubmed/16330737) 2005 Dec;159(12):1136–44. https://www.ncbi.nlm.nih.gov/pubmed/16330737. Accessed August 5, 2019.16330737
44 Liang JL, Tiwari T, Moro P, . Prevention of pertussis, tetanus, and diphtheria with vaccines in the United States: recommendations of the Advisory Committee on Immunization Practices (ACIP). MMWR Recomm Rep (https://www.ncbi.nlm.nih.gov/pubmed/29702631) 2018 Apr 27;67(2):1–44. https://www.ncbi.nlm.nih.gov/pmc/articles/pmid/29702631/. Accessed May 10, 2019.
45 MacNeil JR, Rubin L, Folaranmi T. Use of serogroup B meningococcal vaccines in adolescents and young adults: recommendations of the Advisory Committee on Immunization Practices, 2015. MMWR Morb Mortal Wkly Rep (https://www.ncbi.nlm.nih.gov/pubmed/26492381) 2015 Oct 23;64(41):1171–6. https://www.cdc.gov/mmwr/preview/mmwrhtml/mm6441a3.htm. Accessed May 10, 2019.26492381
46 Grohskopf LA, Sokolow LZ, Broder KR, . Prevention and control of seasonal influenza with vaccines: recommendations of the Advisory Committee on Immunization Practices-United States, 2018-19 influenza season. MMWR Recomm Rep 2018 Aug 24;67(3):1–20. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6107316/. Accessed May 10, 2019.
47 Noone AM, Howlader N, Krapcho M, . SEER Cancer Statistics Review, 1975-2015. Bethesda, MD: National Cancer Institute; 2018. https://seer.cancer.gov/archive/csr/1975_2015/index.html. Accessed August 5, 2019.
48 Office of Disease Prevention and Health Promotion, U.S. Department of Health and Human Services. Healthy People 2020. https://www.healthypeople.gov/. Accessed May 14, 2019.
49 Orgera K, Artiga S. Issue Brief. Disparities in health and health care: five key questions and answers. Washington, DC: Henry J. Kaiser Family Foundation; August 2018. https://www.kff.org/disparities-policy/issue-brief/disparities-in-health-and-health-care-five-key-questions-and-answers/. Accessed May 14, 2019.
50 U.S. Department of Health and Human Services. Report of the Secretary’s Task Force on Black and Minority Health. Washington, DC: Government Printing Office; 1985. https://minorityhealth.hhs.gov/heckler30/. Accessed May 14, 2019.
51 Centers for Disease Control and Prevention. CDC health disparities and inequalities report — United States, 2013. MMWR 2013;62(Suppl 3):1–187. https://www.cdc.gov/minorityhealth/CHDIReport.html. Accessed May 14, 2019.
52 Office of Disease Prevention and Health Promotion, U.S. Department of Health and Human Services. Healthy People Foundation Health Measures. Disparities. https://www.healthypeople.gov/2020/about/foundation-health-measures/Disparities. Accessed May 14, 2019.
53 Centers for Disease Control and Prevention. HIV and African Americans. https://www.cdc.gov/hiv/group/racialethnic/africanamericans/index.html. Accessed May 14, 2019.
54 Office of Minority Health, U.S. Department of Health and Human Services. HIV/AIDS and African Americans. https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=4&lvlid=21. Accessed May 14, 2019.
55 Azar A. Ending the HIV Epidemic: A Plan for America. Washington, DC: U.S. Department of Health and Human Services; February 2019. https://www.hhs.gov/blog/2019/02/05/ending-the-hiv-epidemic-a-plan-for-america.html. Accessed May 14, 2019.
56 Heron M. Deaths: leading causes for 2016. Natl Vital Stat Rep 2018;67(6). Hyattsville, MD: National Center for Health Statistics. https://www.cdc.gov/nchs/data/nvsr/nvsr67/nvsr67_06.pdf. Accessed May 14, 2019.
57 U.S. Department of Health and Human Services. HIV Care and Treatment Activities. Last updated May 2017. https://www.hiv.gov/federal-response/federal-activities-agencies/hiv-care-and-treatment-activities. Accessed May 14, 2019.
58 Health Resources and Services Administration. Ryan White HIV/AIDS Program by the Numbers. https://hab.hrsa.gov/sites/default/files/hab/Publications/infographics/generalaudiencegraphic.pdf. Accessed May 14, 2019.
59 Asthma and Allergy Foundation of America. Asthma Facts and Figures. Medical review February 2018; updated June 2019. https://www.aafa.org/asthma-facts/. Accessed May 14, 2019.
60 Centers for Disease Control and Prevention. Most Recent National Asthma Data. Last updated May 2018. https://www.cdc.gov/asthma/most_recent_national_asthma_data.htm. Accessed May 14, 2019.
61 Centers for Disease Control and Prevention. CDC’s National Asthma Control Program. https://www.cdc.gov/asthma/nacp.htm. Accessed May 14, 2019.
62 Agency for Healthcare Research and Quality. Patient Safety Primer. Medication Errors and Adverse Drug Events. Last updated January 2019. https://psnet.ahrq.gov/primers/primer/23/Medication-Errors-and-Adverse-Drug-Events. Accessed May 14, 2019.
63 Office of Disease Prevention and Health Promotion. National Action Plan for Adverse Drug Event Prevention. Section 5. Anticoagulants. Washington, DC: U.S. Department of Health and Human Services; 2014. https://health.gov/hcq/pdfs/ADE-Action-Plan-Anticoagulants.pdf. Accessed May 14, 2019.
64 Agency for Healthcare Research and Quality. Examples of Home Health Care Quality Measures for Consumers. Last updated November 2018. https://www.ahrq.gov/talkingquality/measures/setting/long-term-care/home-health/examples.html. Accessed May 14, 2019.
65 Ngo-Metzger Q, Legedza AT, Phillips RS. Asian Americans’ reports of their health care experiences. Results of a national survey. J Gen Intern Med 2004 Feb;19(2):111–9. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1492145/. Accessed May 14, 2019.15009790
66 Ponce NA, Hays RD, Cunningham WE. Linguistic disparities in health care access and health status among older adults. J Gen Intern Med 2006 Jul;21(7):786–91. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1924691/. Accessed May 14, 2019.16808783
67 Zong J, Batalova J. Spotlight: The limited English proficient population in the United States. Migration Information Source 2015 Jul 8. http://www.migrationpolicy.org/article/limited-english-proficient-population-united-states/. Accessed May 14, 2019.
68 Institute of Medicine. Race, Ethnicity, and Language Data: Standardization for Health Care Quality Improvement. Washington, DC: The National Academies Press; 2009. 4. Defining language need and categories for collection. .https://www.ahrq.gov/research/findings/final-reports/iomracereport/reldata4.html. Accessed May 14, 2019.
69 Limited English Proficiency: A Federal Interagency Website. Frequently Asked Questions. https://www.lep.gov/faqs/faqs.html. Accessed May 14, 2019.
70 TeamSTEPPS^®^ Enhancing Safety for Patients With Limited English Proficiency Module. Rockville, MD: Agency for Healthcare Research and Quality; 2012. https://www.ahrq.gov/teamstepps/lep/index.html. Accessed May 14, 2019.
71 Centers for Disease Control and Prevention. Pneumococcal Vaccination: What Everyone Should Know. Last reviewed December 2017. https://www.cdc.gov/vaccines/vpd/pneumo/public/index.html. Accessed May 14, 2019.
72 Office for State, Tribal, Local, and Territorial Support. Menu of State Hospital Pneumococcal Vaccination Laws. Atlanta, GA; Centers for Disease Control and Prevention; November 2015. https://www.cdc.gov/phlp/docs/menu-shpneumovacclaws.pdf. Accessed May 14, 2019.
73 Centers for Disease Control and Prevention. Pneumococcal Vaccine Resources. Last reviewed December 2017. https://www.cdc.gov/vaccines/vpd/pneumo/hcp/references-resources.html. Accessed May 14, 2019.
74 Centers for Disease Control and Prevention. PneumoRecs VaxAdvisor Mobile App for Vaccine Providers. Last reviewed December 2018. https://www.cdc.gov/vaccines/vpd/pneumo/hcp/pneumoapp.html. Accessed May 14, 2019.
75 Hoover MA, Green HD Jr, Bogart LM, . Do people know I’m poz?: factors associated with knowledge of serostatus among HIV-positive African Americans’ social network members. AIDS Behav 2016 Jan;20(1):137–46. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4618789/. Accessed May 14, 2019.25903505
76 Wolitski R, Fecik N. Knowledge of HIV status is on the rise. Washington, DC: U.S. Department of Health and Human Services; August 2017. https://www.hiv.gov/blog/knowledge-hiv-status-rise. Accessed May 14, 2019.
77 Kutner M, Greenberg E, Jin Y, . The health literacy of America’s adults: results from the 2003 National Assessment of Adult Literacy. Washington, DC: U.S. Department of Education; 2006. Publication No. NCES 2006 483. https://nces.ed.gov/pubs2006/2006483_1.pdf. Accessed May 14, 2019.
78 Institute of Medicine. Health literacy: A prescription To End Confusion. Washington, DC: National Academies Press; 2004. https://www.nap.edu/catalog/10883/health-literacy-a-prescription-to-end-confusion. Accessed May 14, 2019.
79 Guide to Improving Patient Safety in Primary Care Settings by Engaging Patients and Families: Teach-Back. Rockville, MD: Agency for Healthcare Research and Quality; April 2018. www.ahrq.gov/professionals/quality-patient-safety/patient-family-engagement/pfeprimarycare/interventions/teach-back.html (https://www.ahrq.gov/professionals/quality-patient-safety/patient-family-engagement/pfeprimarycare/teachback.html). Accessed May 14, 2019.
80 Health Literacy Universal Precautions Toolkit, 2nd Edition: Use the Teach-Back Method: Tool #5. Rockville, MD: Agency for Healthcare Research and Quality; February 2015. www.ahrq.gov/professionals/quality-patient-safety/quality-resources/tools/literacy-toolkit/healthlittoolkit2-tool5.html. Accessed May 14, 2019.
81 Foo PK, Frankel RM, McGuire TG, . Patient and physician race and the allocation of time and patient engagement efforts to mental health discussions in primary care: an observational study of audiorecorded periodic health examinations. J Ambul Care Manage 2017 Jul–Sep;40(3):246–56. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5453836/. Accessed May 14, 2019.28350633
82 Centers for Disease Control and Prevention. Influenza (Flu). Last reviewed May 2019. https://www.cdc.gov/flu/index.htm. Accessed May 14, 2019.
83 CDC: Hospitals continue to lead field in health care worker flu vaccinations. Chicago, IL: American Hospital Association; September 2018. https://www.aha.org/news/headline/2018-09-27-cdc-hospitals-continue-lead-field-health-care-worker-flu-vaccinations. Accessed May 14, 2019.
84 Mulpuru S, Li L, Ye L, . Effectiveness of influenza vaccination on hospitalizations and risk factors for severe outcomes in hospitalized patients with COPD. Chest 2019 Jan;155(1):69078. https://journal.chestnet.org/article/S0012-3692(18)32725-9/fulltext. Accessed May 14, 2019.
85 National Institute of Diabetes and Digestive and Kidney Diseases. Diabetic Kidney Disease. https://www.niddk.nih.gov/health-information/diabetes/overview/preventing-problems/diabetic-kidney-disease. Accessed May 14, 2019.
86 Centers for Disease Control and Prevention. High Blood Pressure Facts. Last reviewed November 2016. https://www.cdc.gov/bloodpressure/facts.htm. Accessed May 14, 2019.
87 Centers for Disease Control and Prevention. High Blood Pressure Educational Materials. Last reviewed November 2018. https://www.cdc.gov/bloodpressure/educational_materials.htm. Accessed May 14, 2019.
88 Centers for Medicare & Medicaid Services. Dental Care. https://www.medicaid.gov/medicaid/benefits/dental/index.html. Accessed May 15, 2019.
89 National Institute of Diabetes and Digestive and Kidney Diseases. Weight Management. https://www.niddk.nih.gov/health-information/weight-management. Accessed July 24, 2019.
90 National Institute of Diabetes and Digestive and Kidney Diseases. Talking With Patients About Weight Loss: Tips for Primary Care Providers. https://www.niddk.nih.gov/health-information/weight-management/talking-adult-patients-tips-primary-care-clinicians. Accessed July 24, 2019.
91 Office of the Assistant Secretary for Planning and Evaluation, U.S. Department of Health and Human Services. U.S. Federal Poverty Guidelines Used To Determine Financial Eligibility for Certain Federal Programs. https://aspe.hhs.gov/poverty-guidelines. Accessed May 15, 2019.
92 Khullar D, Chokshi DA, Health, Income, & Poverty: Where We Are & What Could Help. Health Affairs 2018 Oct 4. https://www.healthaffairs.org/do/10.1377/hpb20180817.901935/full/. Accessed May 15, 2019.
93 Larrimore J. Does a higher income have positive health effects? Using the earned income tax credit to explore the income-health gradient. Milbank Q 2011 Dec;89(4):694–727. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3250638/. Accessed August 6, 2019.22188352
94 Shaw KM, Theis KA, Self-Brown S, . Chronic disease disparities by county economic status and metropolitan classification, Behavioral Risk Factor Surveillance System, 2013. Prev Chronic Dis 2016 Sep 1;13:E119. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5008860/. Accessed May 15, 2019.27584875
95 Bor J, Cohen GH, Galea S. Population health in an era of rising income inequality: USA, 1980-2015. Lancet 2017 Apr 8;389(10077):1475–90. 10.1016/S0140-6736(17)30571-8. Accessed August 6, 2019.28402829
96 Office on Women’s Health, U.S. Department of Health and Human Services. Pap and HPV Tests. Last reviewed January 2019. https://www.womenshealth.gov/a-z-topics/pap-hpv-tests. Accessed May 15, 2019.
97 U.S. Preventive Services Task Force. Cervical Cancer: Screening. Release Date: August 2018. https://www.uspreventiveservicestaskforce.org/Page/Document/UpdateSummaryFinal/cervical-cancer-screening2. Accessed May 15, 2019.
98 U.S. Preventive Services Task Force. Draft Recommendation Statement: Cervical Cancer: Screening. https://www.uspreventiveservicestaskforce.org/Page/Document/draft-recommendation-statement/cervical-cancer-screening2. Accessed July 24, 2019.
99 Henry J. Kaiser Family Foundation. Key Facts About the Uninsured Population. December 2018. https://www.kff.org/uninsured/fact-sheet/key-facts-about-the-uninsured-population/. Accessed May 15, 2019.
100 de Marco R, Pesce G, Marcon A, . The coexistence of asthma and chronic obstructive pulmonary disease (COPD): prevalence and risk factors in young, middle-aged, and elderly people from the general population. PLoS One 2013 May 10;8(5):e62985. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3651288/. Accessed May 15, 2019.23675448
101 Mayo Clinic. COPD: Overview. https://www.mayoclinic.org/diseases-conditions/copd/symptoms-causes/syc-20353679. Accessed May 15, 2019.
102 Centers for Disease Control and Prevention. National Diabetes Statistics Report, 2017: Estimates of Diabetes and Its Burden in the United States. Atlanta, GA: U.S. Department of Health and Human Services; 2017. https://www.cdc.gov/diabetes/pdfs/data/statistics/national-diabetes-statistics-report.pdf. Accessed May 15, 2019.
103 Sawyer B, McDermott D. How does the quality of the U.S. healthcare system compare to other countries? Slide 5: Hospital admissions for preventable diseases are more frequent in the U.S. than in comparable countries. Peterson-Kaiser Health System Tracker; March 28, 2019. https://www.healthsystemtracker.org/chart-collection/quality-u-s-healthcare-system-compare-countries/#item-hospital-admission-rate-for-asthma-heart-failure-hypertension-and-diabetes-2015. Accessed August 6, 2019.
104 MacDougall H. Dental disparities among low-income American adults: a social work perspective. Health Soc Work 2016 Aug;41(3):208–10. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4985883/. Accessed May 15, 2019.29206952
105 Centers for Disease Control and Prevention. Human Papillomavirus (HPV). Last reviewed April 2019. https://www.cdc.gov/hpv/parents/whatishpv.html. Accessed May 15, 2019.
106 Centers for Disease Control and Prevention. Human Papillomavirus (HPV): Vaccination Schedules & Recommendations. https://www.cdc.gov/hpv/hcp/schedules-recommendations.html. Accessed May 15, 2019.
107 U.S. Department of Health and Human Services. What Is the U.S. Opioid Epidemic? Last reviewed January 2019. https://www.hhs.gov/opioids/about-the-epidemic/index.html. Accessed May 15, 2019.
108 Hedegaard H, Miniño AM, Warner M. Drug overdose deaths in the United States, 1999-2017. NCHS Data Brief No. 329. Hyattsville, MD: National Center for Health Statistics. 2018. https://www.cdc.gov/nchs/data/databriefs/db329-h.pdf. Accessed July 26, 2019.
109 Centers for Disease Control and Prevention. Opioid Overdose: Understanding the Epidemic. Last reviewed December 2018. https://www.cdc.gov/drugoverdose/epidemic/index.html. Accessed May 15, 2019.
110 Joynt M, Train MK, Robbins BW, . The impact of neighborhood socioeconomic status and race on the prescribing of opioids in emergency departments throughout the United States. J Gen Intern Med 2013 Dec;28(12):1604–10. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3832731/. Accessed May 15, 2019.23797920
111 U.S. Department of Health and Human Services. 5-Point Strategy To Combat the Opioid Crisis. Last reviewed August 2018. https://www.hhs.gov/opioids/about-the-epidemic/hhs-response/index.html. Accessed May 15, 2019. [underlined: l]
112 Institute of Medicine Committee on the Consequences of Uninsurance. Care Without Coverage: Too Little, Too Late. Washington, DC: National Academies Press; 2002. 4, The Difference Coverage Could Make to the Health of Uninsured Adults. https://www.ncbi.nlm.nih.gov/books/NBK220633/. Accessed August 19, 2019.
113 Chartbook on Person- and Family-Centered Care. Rockville, MD: Agency for Healthcare Research and Quality; October 2016. Publication No. 16(17)-0015-9-EF. http://www.ahrq.gov/research/findings/nhqrdr/chartbooks/personcentered/index.html. Accessed May 15, 2019.
114 Bleser WK, Young SI, Miranda PY. Disparities in patient- and family-centered care during U.S. children’s health care encounters: a closer examination. Acad Pediatr 2017 Jan–Feb;17(1):17–26. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6333206/. Accessed May 15, 2019.27422496
115 Wolff JL, Boyd CM. A look at person- and family-centered care among older adults: results from a national survey [corrected]. J Gen Intern Med 2015 Oct;30(10):1497-504. Erratum in: J Gen Intern Med 2015 Oct;30(10):1567. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4579212/. Accessed May 15, 2019.26084973
116 Maurer M, Dardess P, Carman, KL, . Guide to Patient and Family Engagement: Environmental Scan Report. (Prepared by American Institutes for Research under Contract No. HHSA 290-200-600019). Rockville, MD: Agency for Healthcare Research and Quality; May 2012. AHRQ Publication No. 12-0042-EF. http://www.ahrq.gov/research/findings/final-reports/ptfamilyscan/index.html. Accessed May 15, 2019.
117 Johns Hopkins Medicine. Abdominal Aortic Aneurysm. https://www.hopkinsmedicine.org/health/conditions-and-diseases/abdominal-aortic-aneurysm. Accessed May 15, 2019.
118 Centers for Disease Control and Prevention. High Blood Pressure Fact Sheet. Last reviewed June 2016. https://www.cdc.gov/dhdsp/data_statistics/fact_sheets/fs_bloodpressure.htm. Accessed August 19, 2019.
119 Centers for Disease Control and Prevention. Influenza (Flu): Diabetes. Last reviewed February 2019. https://www.cdc.gov/flu/diabetes/index.htm. Accessed May 15, 2019.
120 Information Series for Adults: What You Need To Know About Diabetes and Adult Vaccines. Atlanta, GA: Centers for Disease Control and Prevention; August 2018. https://www.cdc.gov/vaccines/hcp/adults/downloads/fs-diabetes-vaccines.pdf. Accessed May 15, 2019.
121 Horvitz-Lennon M, Volya R, Garfield R, . Where you live matters: quality and racial/ethnic disparities in schizophrenia care in four state Medicaid programs. Health Serv Res 2015 Oct;50(5):1710–29. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4600368/. Accessed May 17, 2019.25759240
122 Lin YH, McLain AC, Probst JC, . Health-related quality of life among adults 65 years and older in the United States, 2011-2012: a multilevel small area estimation approach. Ann Epidemiol (https://www.ncbi.nlm.nih.gov/pubmed/27814940) 2017 Jan;27(1):52–58. https://www.ncbi.nlm.nih.gov/pubmed/27814940. Accessed May 17, 2019.27814940
123 Trivedi T, Liu J, Probst JC, . Obesity and obesity-related behaviors among rural and urban adults in the USA. Rural Remote Health 2015;15:3267. https://www.rrh.org.au/journal/article/3267. Accessed May 17, 2019.26458564
124 Andrilla CHA, Patterson DG, Garberson LA, . Geographic variation in the supply of selected behavioral health providers. Am J Prev Med 2018 Jun;54(6S3):S199–S207. https://www.ncbi.nlm.nih.gov/pubmed/29779543. Accessed May 17, 2019.29779543
125 Skinner AC, Slifkin RT. Rural/urban differences in barriers to and burden of care for children with special health care needs. J Rural Health (https://www.ncbi.nlm.nih.gov/pubmed/17397371) 2007 Spring;23(2):150–7. https://www.ncbi.nlm.nih.gov/pubmed/17397371. Accessed May 17, 2019.17397371
126 Hale N, Probst J, Robertson A. Rural area deprivation and hospitalizations among children for ambulatory care sensitive conditions. J Community Health 2016 Jun;41(3):451–60. https://www.ncbi.nlm.nih.gov/pubmed/26516019. Accessed May 17, 2019.26516019
127 Centers for Disease Control and Prevention. NCHS Urban-Rural Classification Scheme for Counties. Last reviewed June 2017. https://www.cdc.gov/nchs/data_access/urban_rural.htm. Accessed May 17, 2019.
128 Agency for Healthcare Research and Quality. National Healthcare Quality and Disparities Report State View. https://nhqrnet.ahrq.gov/inhqrdr/state/select. Accessed May 17, 2019.
129 U.S. Department of Health and Human Services. What is ‘Ending the HIV Epidemic: A Plan for America’? Last updated May 2019. https://www.hiv.gov/federal-response/ending-the-hiv-epidemic/overview. Accessed May 17, 2019.
130 U.S. Department of Health and Human Services. HIV Prevention Activities. https://www.hiv.gov/federal-response/federal-activities-agencies/hiv-prevention-activities. Accessed May 14, 2019.
131 Peterson-Kaiser Health System Tracker. 30-Day Mortality Following Certain Admissions. https://www.healthsystemtracker.org/indicator/quality/30-day-mortality-following-certain-admissions/. Accessed May 17, 2019.
132 Agency for Healthcare Research and Quality PSNet. Readmissions and Adverse Events After Discharge. https://psnet.ahrq.gov/primers/primer/11/Readmissions-and-Adverse-Events-After-Discharge. Accessed May 17, 2019.
133 March of Dimes. Low Birthweight. Last reviewed March 2018. https://www.marchofdimes.org/complications/low-birthweight.aspx. Accessed May 17, 2019.
134 Partridge S, Balayla J, Holcroft CA, . Inadequate prenatal care utilization and risks of infant mortality and poor birth outcome: a retrospective analysis of 28,729,765 U.S. deliveries over 8 years. Amer J Perinatol 2012;29:787–94. https://www.ncbi.nlm.nih.gov/pubmed/22836820. Accessed May 17, 2019.22836820
135 American Academy of Pediatrics. AAP Schedule of Well-Child Care Visits. Last updated October 2018. https://www.healthychildren.org/English/family-life/health-management/Pages/Well-Child-Care-A-Check-Up-for-Success.aspx. Accessed May 17, 2019.
136 Centers for Disease Control and Prevention. Healthy Weight: Child & Teen BMI Calculator. https://www.cdc.gov/healthyweight/bmi/calculator.html. Accessed May 17, 2019.
137 Johnson LH, Chambers P, Dexheimer JW. Asthma-related emergency department use: current perspectives. Open Access Emerg Med 2016;8:47–55. Published online 2016 Jul 13. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4950546/. Accessed August 6, 2019.
138 Jang H, Ozkaynak M, Ayer T, . Factors associated with first medication time for children treated in the emergency department for asthma. Pediatr Emerg Care 2018 Oct 2. [Epub ahead of print] https://www.ncbi.nlm.nih.gov/pubmed/30281550. Accessed May 17, 2019.
139 Bekmezian A, Fee C, Bekmezian S, . Emergency department crowding and younger age are associated with delayed corticosteroid administration to children with acute asthma. Pediatr Emerg Care 2013 Oct;29(10):1075–81. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3809097/. Accessed May 17, 2019.24076611
140 Zahran HS, Bailey CM, Damon SA, Garbe PL, Breysse PN. Vital Signs: Asthma in children — United States, 2001–2016. MMWR Morb Mortal Wkly Rep 2018;67:149–155. https://www.cdc.gov/mmwr/volumes/67/wr/mm6705e1.htm. Accessed August 19, 2019.29420459
141 Wall T, Nasseh K, Vujicic M. Majority of dental-related emergency department visits lack urgency and can be diverted to dental offices. Health Policy Institute Research Brief. Chicago, IL: American Dental Association; August 2014. https://www.ada.org/~/media/ADA/Science%20and%20Research/HPI/Files/HPIBrief_0814_1.ashx (https://www.ada.org/%7E/media/ADA/Science%20and%20Research/HPI/Files/HPIBrief_0814_1.ashx). Accessed May 17, 2019.
142 Centers for Disease Control and Prevention, National Center for Health Statistics. Emergency Department Visits. Last reviewed January 2017. https://www.cdc.gov/nchs/fastats/emergency-department.htm. Accessed May 17, 2019.
143 Brown JD, Harnett J, Chambers R, Sato R. The relative burden of community-acquired pneumonia hospitalizations in older adults: a retrospective observational study in the United States. BMC Geriatr 2018 Apr 16;18(1):92. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5902892/. Accessed May 17, 2019.29661135
144 Rozenbaum MH, Mangen MJ, Huijts SM, . Incidence, direct costs, and duration of hospitalization of patients hospitalized with community acquired pneumonia: a nationwide retrospective claims database analysis. Vaccine 2015 Jun 22;33(28):3193–9. https://www.ncbi.nlm.nih.gov/pubmed/25981488. Accessed May 17, 2019.25981488
145 Centers for Disease Control and Prevention. Pneumococcal Vaccination: Summary of Who and When To Vaccinate. https://www.cdc.gov/vaccines/vpd/pneumo/hcp/who-when-to-vaccinate.html. Accessed May 17, 2019.
146 Shanmugam VK, Fernandez SJ, Evans KK, . Postoperative wound dehiscence: predictors and associations. Wound Repair Regen 2015 Mar–Apr;23(2):184–90. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4587566/. Accessed May 17, 2019.25683272
147 Gachabayov M, You K, Sullivan R, . A retrospective cohort study to determine predictive factors for abdominal wound disruption following colorectal surgery. Ostomy Wound Manage (https://www.ncbi.nlm.nih.gov/pubmed/29718814) 2018 Apr;64(4):22–29. https://www.ncbi.nlm.nih.gov/pubmed/29718814. Accessed May 17, 2019.
148 Hsu DJ, McCarthy EP, Stevens JP, . Hospitalizations, costs, and outcomes associated with heroin and prescription opioid overdoses in the United States 2001-12. Addiction 2017 Sep;112(9):1558–64. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5544564/. Accessed May 16, 2019.28191702
149 National Cancer Institute. Surveillance, Epidemiology, and End Results Program. Cancer Stat Facts: Female Breast Cancer. https://seer.cancer.gov/statfacts/html/breast.html. Accessed June 3, 2019.
150 ASCO Guideline Update Recommends Tamoxifen for Up to 10 Years for Women With Non-Metastatic Hormone Receptor Positive Breast Cancer. Alexandria, VA: American Society of Clinical Oncology; May 27, 2014. https://www.asco.org/research-guidelines/quality-guidelines/guidelines/breast-cancer#/9816.
151 Burstein HJ, Temin S, Anderson H, . Adjuvant endocrine therapy for women with hormone receptor-positive breast cancer: American Society of Clinical Oncology Clinical Practice Guideline Focused Update. J Clin Oncol 2014 Jul 20;32(21):2255–69. Published online 2014 May 27. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4876310/. Accessed June 3, 2019.24868023
152 Breastcancer.org. Selective Estrogen Receptor Modulators (SERMs). Last reviewed August 2018. https://www.breastcancer.org/treatment/hormonal/serms. Accessed June 3, 2019.
153 National Cancer Institute. Hormone Therapy for Breast Cancer. Last reviewed February 2017. https://www.cancer.gov/types/breast/breast-hormone-therapy-fact-sheet. Accessed June 3, 2019.
154 John’s Hopkins Medicine, Triple Negative Breast Cancer. https://www.hopkinsmedicine.org/breast_center/breast_cancers_other_conditions/triple_negative_breast_cancer.html. Accessed August 19, 2019.
155 Waks AG, Winer EP. Breast cancer treatment: a review. JAMA 2019;321(3):288–300. https://www.ncbi.nlm.nih.gov/pubmed/30667505. Accessed June 3, 2019.30667505
156 Frasier LL, Holden S, Holden T, . Temporal trends in postmastectomy radiation therapy and breast reconstruction associated with changes in National Comprehensive Cancer Network guidelines. JAMA Oncol 2016;2(1):95–101. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4713236/. Accessed August 19, 2019.26539936
157 American Society of Clinical Oncology. ASCO Answers: Radiation Therapy. https://www.cancer.net/sites/cancer.net/files/asco_answers_radiation_therapy.pdf. Accessed June 3, 2019.
158 American Cancer Society. Cancer Facts & Figures 2018. https://www.cancer.org/content/dam/cancer-org/research/cancer-facts-and-statistics/annual-cancer-facts-and-figures/2018/cancer-facts-and-figures-2018.pdf. Accessed June 3, 2019.
159 Commission on Cancer. National Cancer Data Base. Cervix Measure Specifications: Cancer Programs Practice Profile Reports (CP^3^R). https://www.facs.org/~/media/files/quality%20programs/cancer/ncdb/measure%20specs%20cervix.ashx (https://www.facs.org/%7E/media/files/quality%20programs/cancer/ncdb/measure%20specs%20cervix.ashx). Accessed June 3, 2019.
160 Gill BS, Lin JF, Krivak TC, . National Cancer Data Base analysis of radiation therapy consolidation modality for cervical cancer: the impact of new technological advancements. Int J Radiat Oncol Biol Phys 2014 Dec 1;90(5):1083–90. Epub 2014 Sep 9. https://www.ncbi.nlm.nih.gov/pubmed/25216857. Accessed June 3, 2019.25216857
161 National Comprehensive Cancer Network^®^. NCCN Clinical Practice Guidelines in Oncology (NCCN Guidelines^®^). Cervical Cancer. Version 1.2015. https://www2.tri-kobe.org/nccn/guideline/archive/gynecological2015/english/cervical.pdf. Accessed August 2, 2019.
162 National Cancer Institute. Brachytherapy To Treat Cancer. Last reviewed January 2019. https://www.cancer.gov/about-cancer/treatment/types/radiation-therapy/brachytherapy. Accessed June 3, 2019.
163 University of New Mexico Health, Comprehensive Cancer Center. Radiation Therapy for Cervical Cancer. http://cancer.unm.edu/cancer/cancer-info/types-of-cancer/cervical-cancer/radiation-therapy-for-cervical-cancer/. Accessed June 3, 2019.
164 American Cancer Society. Key Statistics for Colorectal Cancer. https://www.cancer.org/cancer/colon-rectal-cancer/about/key-statistics.html. Accessed June 3, 2019.
165 Commission on Cancer. National Cancer Data Base. Colon Cancer Measure Specifications: Cancer Programs Practice Profile Reports (CP^3^R), Rapid Quality Reporting System (RQRS). https://www.facs.org/~/media/files/quality%20programs/cancer/ncdb/measure%20specs%20colon.ashx (https://www.facs.org/%7E/media/files/quality%20programs/cancer/ncdb/measure%20specs%20colon.ashx). Accessed June 3, 2019.
166 National Comprehensive Cancer Network^®^. NCCN Clinical Practice Guidelines in Oncology (NCCN Guidelines^®^). Colon Cancer. https://www.nccn.org/professionals/physician_gls/pdf/colon.pdf (requires account and login). Accessed August 19, 20199.
167 Cancer.Net. Understanding Chemotherapy. Approved by the Cancer.Net Editorial Board May 2019. https://www.cancer.net/navigating-cancer-care/how-cancer-treated/chemotherapy/understanding-chemotherapy. Accessed June 3, 2019.
168 National Institute on Aging. What Is Dementia? Last reviewed December 2017. https://www.nia.nih.gov/health/what-dementia. Accessed June 2, 2019.
169 Alzheimer’s Association report: 2019 Alzheimer’s disease facts and figures. Alzheimers Dement 2019 Mar;15(3):321–87. 10.1016/j.jalz.2019.01.010. Accessed August 2, 2019.
170 Dementia Management Quality Measurement Set Update. Chicago, IL: American Medical Association, American Academy of Neurology Institute, and American Psychiatric Association; 2016. https://www.aan.com/siteassets/home-page/policy-and-guidelines/quality/quality-measures/15dmmeasureset_pg.pdf. Accessed June 2, 2019.
171 Priority Setting for Healthcare Performance Measurement: Addressing Performance Measure Gaps for Dementia, Including Alzheimer’s Disease. Final Report. Washington, DC: National Quality Forum; October 2014. http://www.qualityforum.org/WorkArea/linkit.aspx?LinkIdentifier=id&ItemID=78039. Accessed June 2, 2019.
172 Sleeman KE, Perera G, Stewart R, . Predictors of emergency department attendance by people with dementia in their last year of life: retrospective cohort study using linked clinical and administrative data. Alzheimers Dement 2018 Jan;14(1):20–27. Epub 2017 Aug 22. https://www.ncbi.nlm.nih.gov/pubmed/28838779. Accessed June 2, 2019.28838779
173 Feng Z, Coots LA, Kaganova Y, . Hospital and ED use among Medicare beneficiaries with dementia varies by setting and proximity to death. Health Aff (Milwood) 2014 Apr;33(4):683–90. https://www.healthaffairs.org/doi/full/10.1377/hlthaff.2013.1179. Accessed June 2, 2019.
174 LaMantia MA, Stump TE, Messina FC, . Emergency department use among older adults with dementia. Alzheimer Dis Assoc Disord 2016; 30(1): 35–40. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4764430/. Accessed August 19, 2019.26523710
175 National Institute on Aging. Number of Alzheimer’s deaths found to be underreported. https://www.nia.nih.gov/news/number-alzheimers-deaths-found-be-underreported. Accessed June 2, 2019.
176 Weuve J, Hebert LE, Scherr PA, . Deaths in the United States among persons with Alzheimer’s disease (2010-2050). Alzheimers Dement 2014 March; 10(2):e40–e46. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3976898/. Accessed August 19, 2019.24698031
177 Racial and Ethnic Disparities in Alzheimer’s Disease: A Literature Review. Washington, DC: Office of the Assistant Secretary for Planning and Evaluation; February 1, 2014. https://aspe.hhs.gov/report/racial-and-ethnic-disparities-alzheimers-disease-literature-review. Accessed July 25, 2019.
178 Gilsanz P, Quesenberry CP Jr, Mayeda ER, . Stressors in midlife and risk of dementia: the role of race and education (https://www.ncbi.nlm.nih.gov/pubmed/31058684). Alzheimer Dis Assoc Disord 2019 May 1 [epub ahead of print]. https://www.ncbi.nlm.nih.gov/pubmed/31058684. Accessed July 25, 2019.
179 Spencer MR, Warner M, Bastian BA, . Drug overdose deaths involving fentanyl, 2011-2016. Natl Vital Stat Rep 2019;68(3). Hyattsville, MD: National Center for Health Statistics. https://www.cdc.gov/nchs/data/nvsr/nvsr68/nvsr68_03-508.pdf. Accessed July 26, 2019.
180 Adams MM, Alexander GR, Kirby RS, . Perinatal epidemiology for public health practice. New York, NY: Springer US; 2009.
181 World Health Organization, UNICEF, UNFPA, and the World Bank. Trends in Maternal Mortality: 1990 to 2010. Geneva, Switzerland: World Health Organization; 2012. https://www.who.int/reproductivehealth/publications/monitoring/9789241503631/en/. Accessed August 19, 2019.
182 Centers for Disease Control and Prevention. Pregnancy Mortality Surveillance System. Last reviewed August 2018. https://www.cdc.gov/reproductivehealth/maternalinfanthealth/pregnancy-mortality-surveillance-system.htm. Accessed May 31, 2019.
183 Petersen EE, Davis NL, Goodman D, . Vital Signs: Pregnancy-related deaths, United States, 2011-2015, and strategies for prevention, 13 states, 2013-2017. MMWR Morb Mortal Wkly Rep 2019;68:423–29. 10.15585/mmwr.mm6818e1. Accessed May 31, 2019.31071074
184 American College of Obstetricians and Gynecologists and the Society for Maternal–Fetal Medicine, Kilpatrick SK, Ecker JL. Severe maternal morbidity: screening and review. Am J Obstet Gynecol 2016;215(3):B17–B22. https://www.ajog.org/article/S0002-9378(16)30523-3/pdf. Accessed August 19, 2019.27560600
185 Agency for Healthcare Research and Quality. Patient Safety Primer: Maternal Safety. https://psnet.ahrq.gov/primers/primer/50/Maternal-Safety. Accessed July 25, 2019.
186 Riley W, Begun JW, Meredith L, . Integrated approach to reduce perinatal adverse events: standardized processes, interdisciplinary teamwork training, and performance feedback. Health Serv Res 2016 Dec;51 Suppl 3:2431–52. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5134347/. Accessed August 19, 2019.27807864
187 Riley W, Meredith L, Price R, . Decreasing malpractice claims by reducing preventable perinatal harm. Health Serv Res 2016 Dec;51 Suppl 3:2453–71. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5134345/. Accessed August 19, 2019.27549442
188 Burstein PD, Zalenski DM, Edwards J, . Changing labor and delivery practice: focus on achieving practice and documentation standardization with the goal of improving neonatal outcomes. Health Serv Res 2016 Dec;51 Suppl 3:2472–86. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5134346/. Accessed August 19, 2019.27766653
189 Kahwati LC, Sorensen AV, Teixeira-Poit S, . Impact of the Agency for Healthcare Research and Quality’s Safety Program for Perinatal Care. Jt Comm J Qual Pat Saf 2019 Apr;45(4):231–40. https://www.ncbi.nlm.nih.gov/pubmed/30638973. Accessed May 31, 2019.
190 Building U.S. Capacity To Review and Prevent Maternal Deaths. Report From Nine Maternal Mortality Review Committees. 2018. http://reviewtoaction.org/Report_from_Nine_MMRCs. Accessed May 31, 2019.
191 Geller SE, Rosenberg D, Cox SM, The continuum of maternal morbidity and mortality: factors associated with severity. Am J Obstetr Gynecol 2004;191(3):939–44. https://www.ncbi.nlm.nih.gov/pubmed/15467568. Accessed August 19, 2019.
192 Howell EA, Zeitlin J. Quality of care and disparities in obstetrics. Obstetr Gynecol Clin 2017;44(1):13–25. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5300700/. Accessed August 19, 2019.
193 Osterman MJK, Martin JA. Trends in low-risk cesarean delivery in the United States, 1990-2013. Natl Vital Stat Rep 2014;63(6). Hyattsville, MD: National Center for Health Statistics. https://www.cdc.gov/nchs/data/nvsr/nvsr63/nvsr63_06.pdf. Accessed August 19, 2019.
194 Xie RH, Gaudet L, Krewski D, . Higher cesarean delivery rates are associated with higher infant mortality rates in industrialized countries. Birth 2015 Mar;42(1):62–9. https://www.ncbi.nlm.nih.gov/pubmed/25597509. Accessed August 19, 2019.25597509
195 U.S. Department of Health and Human Services, Office of Disease Prevention and Health Promotion. Healthy People 2020. Maternal, Infant, and Child Health. https://www.healthypeople.gov/2020/topics-objectives/topic/maternal-infant-and-child-health/objectives. Accessed May 31, 2019.
196 Caughey AB, Cahill AG, Guise JM, , and American College of Obstetricians and Gynecologists. Safe prevention of the primary cesarean delivery. Am J Obstetr Gynecol 2014;210(3):179–93. https://www.ncbi.nlm.nih.gov/pubmed/24565430. Accessed August 19, 2019.
197 Bailit JL. Measuring the quality of inpatient obstetrical care. Obstetr Gynecol Surv 2007;62(3):207–13. https://www.ncbi.nlm.nih.gov/pubmed/17306043. Accessed August 19, 2019.
198 Srinivas SK, Fager C, Lorch SA. Evaluating risk-adjusted cesarean delivery rate as a measure of obstetric quality. Obstetr Gynecol 2010;115(5):1007–13. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4167363/. Accessed August 19, 2019.
199 U.S. Department of Health and Human Services. Secretary Priorities. Last reviewed July 2018. https://www.hhs.gov/about/leadership/secretary/priorities/index.html. Accessed May 17, 2019.
200 U.S. Department of Health and Human Services, Office of Minority Health. About Sickle Cell Disease. https://www.minorityhealth.hhs.gov/sicklecell/index.html. Accessed August 19, 2019.
201 Azar A. Remarks to the National Kidney Foundation. Washington, DC: U.S. Department of Health and Human Services; March 4, 2019. https://www.hhs.gov/about/leadership/secretary/speeches/2019-speeches/remarks-to-the-national-kidney-foundation.html. Accessed May 17, 2019.