# LOOKING FORWARD

The 2018 QDR has examined data across about 25 federal data sources to describe trends and disparities in access measures and quality measures across six domains. The report offers a comprehensive assessment of the best and worst performing quality and access measures over the past year. While trend data are limited in this year’s analysis, it is still clear that disparities exist by race, ethnicity, income, and residence location.

## Opportunities for Measurement

The QDR measure set is assessed annually to explore whether new clinical areas can be included to provide a more complete representation of the clinical, quality, and disparity issues across the United States. Recently, more data on opioids, dementia, maternal morbidity, and more refined measures for cancer care have been added. The QDR measure set will continue to be assessed for future reports to maintain its relevance to current quality measurement and quality improvement issues.

## HHS Research Priorities

In 2018-2019, the HHS Secretary identified four priorities for the Department: opioid use, health insurance reform, drug pricing, and value-based care.^199^ The Department has also identified gaps in research and data for HIV, sickle cell disease, and other conditions that warrant further exploration. In support of these aims, the QDR team will explore opportunities to include additional data relevant to these topics in future reports. This section elaborates on how the QDR’s activities remain relevant to the many ongoing HHS priorities.

### HIV Research

In 2019, the Administration established an initiative to end the HIV epidemic in the United States, with a goal of reducing new infections by 75% in 5 years and by 90% in 10 years. This initiative focuses on four strategies: diagnosing, treating, protecting, and responding to patients in the United States.^129^ The QDR currently tracks four unique HIV-related quality measures, one mortality measure, and five supplemental measures (not shown here).

The core measures in the QDR related to HIV include:

- New HIV cases per 100,000 population age 13 and over.
- People age 13 and over living with HIV who know their serostatus.
- People age 13 and over living with diagnosed HIV who had at least two CD4 or viral load tests performed at least 3 months apart during the last year, among reporting jurisdictions.
- People age 13 and over living with diagnosed HIV whose most recent viral load in the last 12 months was under 200 copies/mL.
- HIV infection deaths per 100,000 population.

Among these measures, this report has already highlighted the widening and narrowing disparities experienced by various racial and ethnic groups. These data are available through the online query tool at https://nhqrnet.ahrq.gov/inhqrdr/data/query. Moving forward, the QDR team will continue to track these measures with our data partners to understand how differences in quality measurement, disparities, and mortality are occurring over time.

### Sickle Cell Disease Research

In 2018, HHS furthered an initiative to focus on management and treatment of sickle cell disease, a genetic condition that affects the shape and composition of a person’s red blood cells. Patients with this disease are at higher risk for anemia, vascular conditions, and stroke.^200^ This condition adversely affects Blacks and other racial and ethnic minorities. Currently, no national data are available to include in the QDR related to sickle cell disease. These data will be added to the QDR once they are available.

### Kidney Disease Research

Patients who are managing kidney disease may have to undergo time-consuming, painful, and costly treatments to ensure their health. Among Medicare beneficiaries alone, CMS reported spending of $113 billion in 2016 for patients with kidney disease. In 2019, the Secretary of HHS delivered a presentation outlining a three-part strategy to support improved kidney health for all patients. This strategy includes “preventing, detecting, and slowing the progression of kidney disease; availing more treatment options; and lastly, increased organ transplantation as well as wearable and implantable artificial kidneys for patients.”^201^

Patients with kidney disease may require medication, dialysis, or a kidney transplant to ensure their well-being. The core measures in the QDR related to kidney disease and treatment include:

- End stage renal disease (ESRD) patients age 18 and over who saw a nephrologist at least 12 months prior to initiation of renal replacement therapy.
- Dialysis patients under age 70 who were registered on a waiting list for transplantation within a year of initiation.
- Patients with treated chronic kidney failure who received a transplant within 3 years of date of renal failure.
- Hemodialysis patients whose hemoglobin level is less than 10 g/dL.
- Adult hemodialysis patients who use arteriovenous fistulas as the primary mode of vascular access.
- Adult hemodialysis patients with adequate dialysis (Kt/V 1.2 or higher).

Among these measures, the data show that kidney disease affects populations disparately. These data are available through the online query tool at https://nhqrnet.ahrq.gov/inhqrdr/data/query. Moving forward, the QDR team will continue to track these measures with our data partners to understand how differences in quality measurement and disparities are occurring over time.

### Opioids

In 2017, the Department identified the opioid epidemic as an urgent national priority199 and outlined a five-point strategy to combat the epidemic,^111^ including:

- Improving access to treatment and recovery services,
- Promoting use of overdose-reversing drugs,
- Strengthening our understanding of the epidemic through better public health surveillance,
- Providing support for cutting-edge research on pain and addiction, and
- Advancing better practices for pain management.

The QDR team’s IWG subgroup on opioids examined opioid use by examining current work supported by the Department, including:

- Healthy People 2030 proposed objectives,
- HHS Data Council’s Opioid Data Work Group Opioid Metrics Recommendations,
- SAMHSA’s 2017 National Survey on Drug Use and Health,
- SAMHSA’s strategic plan, and
- CDC’s 2018 Surveillance Report of Drug-Related Risks and Outcomes.

This year’s QDR features new supplemental data for six opioid-related measures:

- Percentage and population estimates of past-year opioid (either prescription opioid or heroin) use disorder among people age 12 and over
- Number of people who died from drug overdoses involving opioids
- Number of people who died from drug overdose involving natural and semisynthetic opioids (e.g., oxycodone, hydrocodone, or morphine)
- Number of people who died from drug overdoses involving synthetic opioids other than methadone (e.g., prescription and illicit fentanyl, tramadol)
- Adults who filled an outpatient opioid prescription in the calendar year
- Adults who filled four or more outpatient opioid prescriptions in the calendar year

Gaps remain within available data and research.

## Future Research and Work

Readers can use the QDR to learn more about the nation’s progress in improving healthcare. The report helps identify opportunities to improve quality and reduce disparities. Ongoing disparities in care by race, ethnicity, income, residence location, and other socioeconomic factors underscore that while we have made important strides in quality and accessibility of healthcare, these outcomes are not equitably experienced across the United States and much work remains.