# NEW MEASURES IN THE 2018 QDR DATABASE

The 2018 QDR includes new measures in four topic areas: cancer care, dementia, opioid use, and maternal morbidity and mortality. These topics were based on a review of current literature and availability of quality measures and data as recommended by subject matter experts from the QDR Interagency Work Group and alignment with HHS priority areas.

These measures help fill in gaps in the care continuum and align with the priorities of effective treatment and care coordination. Measures in these topic areas are also categorized under prevention, treatment, management, or outcome categories.

This section presents the context for each topic area, its framework (where applicable), and how new measures may complement existing measures in these categories. All new measures are marked with an asterisk in the following sections and are not otherwise found in the summary analyses in the 2018 QDR. Disparities analyses for select measures are included. In future QDR publications, the measures described here will be considered for inclusion in the QDR annual analyses.

## Cancer Care

The continuum of cancer care includes risk assessment, primary prevention, screening, detection, diagnosis, treatment, survivorship, and end-of-life care. Movement across the stages of the cancer care continuum involves several types of needed care, as well as transitions between the types of care.

Type refers to the care delivered to accomplish a specific medical goal, such as detection, diagnosis, or treatment. Transition refers to the set of interactions needed to go from one type of care to another, such as from detection to diagnosis, which has implications for coordination of cancer care and patient navigation within the healthcare system. Each type and transition of care is subject to influences at multiple levels that can facilitate or impede appropriateness and quality of care, thus affecting successful achievement of medical goals and desired patient outcomes.

The exhibit below shows how types and transitions of care fit into the cancer care continuum and how new measures may complement existing measures for each stage of the cancer care continuum. The domains in the “Processes of Care Across the Cancer Care Continuum” align well with two priorities of the QDR (i.e., Effective Treatment and Care Coordination) and the categories (Prevention, Diagnosis and Treatment, Clinical Management, and Outcomes).

Mapping the measures to the stages in the cancer care continuum helps in assessing appropriateness and quality of care received by cancer patients by providing a framework to assess compliance with guidelines issued by reputable professional organizations such as the American Cancer Society, American Society of Clinical Oncology, and the US Preventive Services Task Force.

Exhibit 1 Opportunities to optimize cancer care

Diagram showing processees of care across the cancer care continuum Types of Care are risk assessment (age, family history, etc.), leading to primary prevention (lifestyle counseling, chemo prevention), leading to detection (screening--asymptomatic and appropriate testing--symptomatic), leading to diagnosis (imaging, biopsy, etc.), leading to cancer or precursor treatment (e.g., surgery, radiation), leading back and forth to post-treatment survivorship (e.g., testing, followup care, palliation), leading to end-of-life care (paliative care, bereavement, etc.), leading to process of care impacts (efficiency, equity, safety, effectiveness, timeliness, patient-centeredness), leading to patient outcomes (e.g., improved risk status, patient experience) and population outcomes (e.g., mortality, morbidity) Along the continuum are transitions of care at each point in the process. Processes

Source: National Cancer Institute. Multilevel Interventions Across the Cancer Care Continuum: Background Perspectives & Description of 2011 Conference and Journal Supplement. May 2010. https://cancercontrol.cancer.gov/mli/background-2011.pdf.

In earlier data cycles, the QDR featured measures for breast, cervical, colorectal, and lung cancers, along with select measures spanning these areas (from prevention to diagnosis and treatment, as well as outcomes, including mortality). The 2018 QDR database features six new treatment measures for breast, cervical, and colorectal cancers. Select measures are shown here and all measures can be accessed via the QDR’s Data Query Tool at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

### Breast Cancer Measures

Prevention Measures

- Women ages 50-74 who received a mammogram in the last 2 years (https://iqdnet.s-3.com/iqdnet/jsp/iqdnet.jsp?measure=Y&catId=705010&ReportYearCBId=0&msrId=70501011&)

Treatment Measures

- Tamoxifen or third generation aromatase inhibitor was recommended or administered within 1 year of diagnosis for women with AJCC T1cN0M0 or stage IB-III hormone receptor-positive breast cancer^*^
- Combination chemotherapy was recommended or administered within 4 months of diagnosis for women under 70 with AJCC T1cN0MO or Stage IB-III hormone receptor-negative breast cancer^*^
- Radiation therapy was recommended or administered following any mastectomy within 1 year of diagnosis of breast cancer for women with 4 positive regional lymph nodes^*^
- Women with clinical Stage I-IIb breast cancer who received axillary node dissection or sentinel lymph node biopsy (SLNB) at the time of surgery (lumpectomy or mastectomy)
- Women under age 70 treated for breast cancer with breast-conserving surgery who received radiation therapy to the breast within 1 year of diagnosis

Management Measures

- Breast cancer diagnosed at advanced stage (regional, distant stage, or local stage with tumor greater than 2 cm) per 100,000 women age 40 and over

Outcome Measures

- Female breast cancer deaths per 100,000 population

### Cervical Cancer Measures

Prevention Measures

- Women ages 21-65 who received a Pap smear in the last 3 years (https://iqdnet.s-3.com/iqdnet/jsp/iqdnet.jsp?measure=Y&catId=705010&ReportYearCBId=0&msrId=70501021&)
- Adolescent females ages 13-15 who received 3 or more doses of human papillomavirus (HPV) vaccine
- Adolescent females ages 16-17 who received 3 or more doses of HPV vaccine
- Adolescent males ages 13-15 who received 3 or more doses of HPV vaccine
- Adolescent males ages 16-17 who received 3 or more doses of HPV vaccine
- Adolescents ages 13-15 years who received 3 or more doses of HPV vaccine
- Adolescents ages 16-17 years who received 3 or more doses of HPV vaccine

Treatment Measures

- Use of brachytherapy in patients treated with primary radiation with curative intent in any stage of cervical cancer*
- Radiation therapy was completed within 60 days of initiation of radiation among women diagnosed with any stage of cervical cancer*

Management Measures

- Cervical cancer diagnosed at advanced stage (all invasive tumors) per 100,000 women age 20 and over

Outcome Measures

- No outcome measures are represented in available QDR data.

### Colorectal Cancer Measures

Prevention Measures

- Composite measure: Adults ages 50-75 who received any type of colorectal cancer screening (https://iqdnet.s-3.com/iqdnet/jsp/iqdnet.jsp?measure=Y&catId=705010&ReportYearCBId=0&msrId=70501031&)

Treatment Measures

- Adjuvant chemotherapy was recommended or administered within 4 months of diagnosis for patients under the age of 80 with AJCC Stage III lymph node-positive colon cancer*
- Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined
- Adults treated at a HRSA-supported health center with appropriate screening for colorectal cancer

Management Measures

- Colorectal cancer diagnosed at advanced stage (tumors diagnosed at regional or distant stage) per 100,000 population age 50 and over

Outcome Measures

- Colorectal cancer deaths per 100,000 population

### Lung Cancer Measures

Prevention, Treatment, and Management Measures

- No measures are represented in available QDR data.

Outcome Measures

- Lung cancer deaths per 100,000 population

### Other Cancer Measures

Prevention, Treatment, and Management Measures

- No measures are represented in available QDR data.

Outcome Measures

- Composite measure: Cancer deaths per 100,000 population per year for all cancers

### Breast Cancer

In 2016, the incidence rate of female breast cancer was 126.4 per 100,000 women per year and the death rate was 20.0 per 100,000 women per year.^149^ Among women, hormone receptor-positive (HR+) breast cancer is the most common type of breast cancer worldwide. About 60% to 75% of women with breast cancer have estrogen receptor-positive (ER+) breast cancer and 65% of these cancers are also progesterone receptor-positive (PgR+).^150^

Women diagnosed with HR+ breast cancer who are pre/peri menopausal should be offered adjuvant endocrine therapy with tamoxifen for 5 years, after which they should receive additional therapy based on menopausal status.^151^ Adjuvant endocrine therapy is highly effective and appropriate for nearly all women with ER+ or PgR+ tumors.

Aromatase inhibitors stop the production of estrogen in postmenopausal women. Aromatase inhibitors work by blocking the enzyme aromatase, which turns the hormone androgen into small amounts of estrogen in the body. Thus, less estrogen is available to stimulate the growth of HR+ breast cancer cells.

Tamoxifen is a selective estrogen receptor modulator (https://www.cancer.gov/Common/PopUps/popDefinition.aspx?id=CDR0000044229&version=Patient&language=English) (SERM), which binds to estrogen receptors (https://www.cancer.gov/Common/PopUps/popDefinition.aspx?id=CDR0000046409&version=Patient&language=English), preventing estrogen from binding. This process slows or stops the growth of hormone-sensitive tumors by blocking the body’s ability to produce hormones or by interfering with effects of hormones on breast cancer cells. Tumors that are hormone insensitive do not have hormone receptors (https://www.cancer.gov/Common/PopUps/popDefinition.aspx?id=CDR0000044359&version=Patient&language=English) and do not respond to hormone therapy.^152,153^

#### Use of Tamoxifen or Aromatase Inhibitor for Breast Cancer

Figure 142 Treatment: Tamoxifen or third-generation aromatase inhibitor was recommended or administered within 1 year of diagnosis for women with AJCC T1cN0M0 or stage IB-III hormone receptor-positive breast cancer, by race/ethnicity, 2005-2015

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander. AJCC T1cN0M0 – American Joint Committee on Cancer staging designation (https://www.cancer.org/cancer/breast-cancer/understanding-a-breast-cancer-diagnosis/stages-of-breast-cancer.html.

Note: White, Black, Asian, AI/AN, and NHPI are non-Hispanic. Hispanic includes all races.

Line graph showing percentage over time for total, White, Black, Asian, AI/AN, NHPI, and Hispanic 2015 achievable benchmark: 93% Total, 2005, 66.1, 2015, 86.6 White, 2005, 68.5, 2015, 87.7 Black, 2005, 57.9, 2015, 81.6 Asian, 2005, 62.3, 2015, 87 AI/AN, 2005, 64.7, 2015, 89 NHPI, 2005, 68.5, 2015, 89.1 Hispanic, 2005, 52.6, 2015, 82

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2015.

- From 2005 to 2015, the total percentage of women with AJCC T1cN0M0 or stage IB-III HR+ breast cancer for whom tamoxifen or third-generation aromatase inhibitor was recommended or administered within 1 year of diagnosis increased from 66.1% to 86.6% (Figure 142).
- The 2015 top 5 State achievable benchmark was 93%. Overall, the benchmark could be achieved in 3 years. AI/ANs, Asians, and NHPIs could achieve the benchmark in 2 years, Whites in 3 years, and Blacks and Hispanics in 4 years.
- The top 5 States that contributed to the achievable benchmark are Idaho, Iowa, Kentucky, Maine, and South Dakota.

#### Chemotherapy for Breast Cancer

Hormone receptor-negative breast cancer refers to the prognostic factors of breast cancers whose cells have tested negative for hormone epidermal growth factor receptor 2 (HER-2), estrogen receptors, and progesterone receptors. This type of cancer does not respond to hormonal therapy, such as tamoxifen or aromatase inhibitors, or other therapies that target HER-2.^154^

Chemotherapy is the use of drugs to destroy cancer cells. It works by keeping cancer cells from growing and dividing to make more cells. Because cancer cells usually grow and divide faster than normal cells, chemotherapy has a greater effect on cancer cells. However, the drugs used for chemotherapy are powerful and can damage healthy cells.

Chemotherapy can be used:

- Before surgery or radiation therapy to shrink tumors (neoadjuvant chemotherapy);
- After surgery or radiation therapy to kill any remaining cancer cells (adjuvant chemotherapy);
- As the only treatment for cancers of the blood or lymphatic system, such as leukemia and lymphoma; and
- For cancer that comes back after treatment (recurrent cancer).

Despite the associated short- and long-term risks, chemotherapy remains an essential treatment for preventing recurrence in many patients with stage I-III breast cancer.^155^

Figure 143 Combination chemotherapy was recommended or administered within 4 months of diagnosis for women under 70 with AJCC T1cN0M0 or Stage IB-III hormone receptor negative-breast cancer, by income, 2005-2015

Key: AJCC T1cN0M0 – American Joint Committee on Cancer staging designation (https://www.cancer.org/cancer/breast-cancer/understanding-a-breast-cancer-diagnosis/stages-of-breast-cancer.html).

Line graph showing percentage over time for income groups 2015 achievable benchmark: 98% Total, 2005, 75.3, 2015, 90.1 Poor, 2005, 68.5, 2015, 83.5 Low Income, 2005, 76.1, 2015, 90.1 Middle Income, 2005, 74.7, 2015, 91.4 High Income, 2005, 66.7, 2015, 86.1

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2015.

- From 2005 to 2015, the total percentage of women under age 70 with AJCC T1cN0M0 or Stage IB-III hormone receptor-negative breast cancer for whom combination chemotherapy was recommended or administered within 4 months of diagnosis increased from 75.3% to 90.1% (Figure 143). In 2005, 2012, and 2015, middle-income women with AJCC T1cN0M0 or Stage IB-III hormone receptor-negative breast cancer were more likely to be recommended or administered combination chemotherapy within 4 months of diagnosis than high-income women.
- The 2015 top 4 State achievable benchmark was 98%. Overall, the benchmark could be achieved in 5 years. Middle-income women could achieve the benchmark in 4 years, low-income women in 6 years, and high-income women in 7 years.
- The top 4 States that contributed to the achievable benchmark are Delaware, Massachusetts, Minnesota, and Oregon.

#### Radiation Therapy for Breast Cancer

The National Comprehensive Cancer Network recommends postmastectomy radiation therapy for patients with tumors >5 cm or 4 or more positive lymph nodes.^156^ Radiation therapy is the use of high-energy x rays or other particles to destroy cancer cells and slow tumor growth without harming nearby healthy tissue. It may be used along with other cancer treatments or as the main treatment. Sometimes radiation therapy is used to relieve symptoms, called palliative radiation therapy. More than half of all people with cancer receive some type of radiation therapy.^157^

Figure 144 Radiation therapy was recommended or administered following any mastectomy within 1 year of diagnosis of breast cancer for women with 4 positive regional lymph nodes, by insurance status, 2005-2015

Line graph showing percentage over time 2015 achievable benchmark: 97% Total, 2005,67.8, 2015, 86.1 Private Insurance, 2005, 72.6, 2015, 87.8 Public Insurance Only, 2005, 66, 2015, 80.9 Uninsured, 2005, 70.6, 2015, 82.5

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2015.

- From 2005 to 2015, the total percentage of women with 4 positive regional lymph nodes for whom radiation therapy was recommended or administered following any mastectomy within 1 year of diagnosis of breast cancer increased from 67.8% to 86.1% (Figure 144).
- From 2005 to 2015, the percentage of women for whom radiation therapy was recommended or administered increased from 72.6% to 87.8% for women with private insurance, from 66.0% to 80.9% for women with public insurance, and from 70.6% to 82.5% for uninsured women.
- In all years, women with public insurance were less likely than women with private insurance to be recommended or administered radiation therapy following any mastectomy within 1 year of diagnosis of breast cancer.
- In all years except 2005, uninsured women were less likely than privately insured women to be recommended or administered radiation therapy following any mastectomy within 1 year of diagnosis of breast cancer.
- The 2015 top 3 State achievable benchmark was 97%. Overall, the benchmark could be achieved in 5 years. Women with private insurance could achieve the benchmark in 4 years, publicly insured in 8 years, and uninsured in 10 years.
- The top 3 States that contributed to the achievable benchmark are Colorado, Kansas, and Massachusetts.

### Cervical Cancer

For 2018, the American Cancer Society estimated about 13,240 new cases of invasive cervical cancer in the United States.^158^ It is recommended that combinations of surgery, chemotherapy, and radiation therapy (including brachytherapy) be used for women with stage IB-IVA disease.^159^

While the research base is evolving, radiation oncologists are using intensity-modulated radiation therapy (IMRT) as a “replacement” for brachytherapy. Experts in cervical cancer routinely state that intracavitary brachytherapy for the treatment of locally advanced cervical cancer is perhaps the most important component of treatment and local disease control. Substituting IMRT for brachytherapy puts the patient at a higher risk of death.^160^

#### Brachytherapy for Cervical Cancer

Brachytherapy is a critical component of definitive therapy for all patients with primary cervical cancer who are not candidates for surgery.^161^ Brachytherapy is a type of internal radiation therapy in which seeds, ribbons, or capsules that contain a radiation source are placed in the body, in or near the tumor. Brachytherapy is a local treatment and treats only a specific part of the body. It is often used to treat cancers of the cervix.^162^

Figure 145 Treatment: Use of brachytherapy in patients treated with primary radiation with curative intent in any stage of cervical cancer, by insurance status, 2005-2015

Line graph showing percentage over time Total, 2005, 59.3, 2015, 70.4 Private Insurance, 2005, 69.1, 2015, 79.6 Public Insurance Only, 2005, 58.1, 2015, 69.8 Uninsured, 2005, 57.8, 2015, 62.8

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base.

- From 2005 to 2015, the total percentage of patients treated with primary radiation with curative intent in any stage of cervical cancer and brachytherapy increased from 59.3% to 70.4% (Figure 145).
- From 2005 to 2015, the percentage of patients treated with primary radiation with curative intent in any stage of cervical cancer and brachytherapy increased from 69.1% to 79.6% for women with private insurance and from 58.1% to 69.8% for women with public insurance. The percentage of uninsured women receiving this treatment increased from 2005 to 2014 (57.8% to 73.2%) and then decreased in 2015 to 62.8%.

#### Radiation Therapy for Cervical Cancer

Radiation therapy, or radiotherapy, is a common way to treat cervical cancer. During radiation therapy, high-energy x rays are used to kill cancer cells. Radiation therapy can be administered by a machine that aims x rays at the body (external beam radiation) or by placing small capsules of radioactive material directly into the cervix (internal or implant radiation or brachytherapy). Many patients receive both kinds of radiation therapy.

In stage I cervical cancer, radiation therapy may be used instead of surgery, or it may be used after surgery to destroy remaining cancer cells. In stage IB-IVA cervical cancer, radiation therapy is administered concurrently with chemotherapy.^163^

Figure 146 Radiation therapy was completed within 60 days of initiation of radiation among women diagnosed with any stage of cervical cancer, by geographic location, 2005-2015

Line graph showing percentage over time Total, 2005,73.2, 2015, 78.3 Large Metro, 2005, 70.5, 2015, 77.1 Small Metro, 2005, 75.3, 2015, 75.8 Micropolitan, 2005, 75.3, 2015, 86.2 Noncore, 2005, 78.8, 2015, 86.4

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2015.

- From 2005 to 2015, the total percentage of women diagnosed with any stage of cervical cancer for whom radiation therapy was completed within 60 days increased from 73.2% to 78.3% (Figure 146).
- The percentage of women who received this treatment increased from 70.5% to 77.1% in large metropolitan areas, from 75.3% to 86.2% in micropolitan areas, and from 78.8% to 86.4% in noncore areas.
- In 2005, 2006, 2011, and 2015, women in noncore areas were more likely to complete radiation therapy within 60 days of initiation than women in large metropolitan areas.

### Colorectal Cancer

Colorectal cancer is the third leading cause of cancer-related deaths in men and women in the United States. It is expected to cause about 51,000 deaths during 2019.164 Substantial data are available regarding underuse and wide variation in the use of chemotherapy with Stage III colon cancer.^165^

A diagnosis of stage III colon cancer means that the cancer has spread to nearby lymph nodes and the primary tumor has protruded into the bowel wall. When cancer cells are found in more than 3 lymph nodes, studies have shown a high risk of the disease returning, and intensive postsurgical therapy is standard in such cases.

For more than a decade, the standard of care for stage III cancer has been 6 months of postsurgical, or adjuvant, chemotherapy. Studies have shown that patients with resected colon cancer treated with adjuvant therapy have a survival advantage over those not treated with adjuvant therapy.^166^

Chemotherapy is the use of drugs to destroy cancer cells. It works by keeping the cancer cells from growing and dividing to make more cells. Because cancer cells usually grow and divide faster than normal cells, chemotherapy has a greater effect on cancer cells.^167^

#### Chemotherapy for Colon Cancer

Figure 147 Treatment: Adjuvant chemotherapy was recommended or administered within 4 months of diagnosis for patients under the age of 80 with AJCC Stage III lymph node-positive colon cancer, by income, 2005-2015

Line graph showing percentage over time 2015 achievable benchmark: 95% Total, 2005,81.7, 2015, 89.8 Poor, 2005, 72, 2015, 92.8 Low Income, 2005, 81.6, 2015, 89.6 Middle Income, 2005, 83.2, 2015, 90.1 High Income, 2005, 81.5, 2015, 95.7

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2015.

- From 2005 to 2015, the total percentage of patients under the age of 80 with AJCC Stage III lymph node-positive colon cancer for whom adjuvant chemotherapy was recommended or administered within 4 months of diagnosis increased from 81.7% to 89.8% (Figure 147).
- The 2015 top 5 state achievable benchmark was 95%. Overall, the benchmark could be achieved in 6 years. High-income patients have already achieved the benchmark. Poor patients could achieve the benchmark in 2 years and low- and middle-income patients could achieve the benchmark in 7 years.
- The top 5 States that contributed to the achievable benchmark are Kentucky, Maryland, Mississippi, Missouri, and Virginia.

## Dementia Among Older Adults

The population of older Americans is growing, and people are living longer. Aging tends to increase the prevalence of chronic diseases, including dementia. Dementia is the deterioration and eventual loss of memory and other cognitive and behavioral functions due to an abnormal and rapid loss of neurons, primarily in older adults (65 years and over).^168^

Dementia has multiple forms and some forms can progress into other conditions, most commonly, Alzheimer’s disease. In 2016, Alzheimer’s was the sixth leading cause of death in the United States and fifth leading cause among those 65 and over.^56^ In 2019, Medicare and Medicaid are expected to cover “$195 billion, or 67 percent of the total health care and long-term care payments for people with Alzheimer’s or other dementias.”^169^

Dementia has no cure or specific treatment plan. Patients with severe dementia often depend on others to provide care. Patients may go to the emergency department or be admitted to the hospital due to dementia or reasons related to dementia. During the course of their care, patients may also experience adverse events such as falls or pressure ulcers, thereby worsening their health.

Dementia and dementia care are difficult to measure, but several measure sets are available, such as the dementia management measure set from the American Medical Association, American Academy of Neurology, and American Psychiatric Association, updated in 2016.^170^ This measure set addresses areas such as diagnosis and safety (e.g., Disclosure of Dementia Diagnosis, Education and Support of Caregivers for Patients With Dementia, Safety Concern Screening and Follow-Up for Patients With Dementia). The Medicare Merit-based Incentive Payment System also includes dementia-related measures, such as screening for safety concerns. The National Quality Forum has also worked to identify measures of dementia care and outcomes.^171^

As dementia is a new focus for the QDR and measures are still being considered, the QDR team had limited data. Thus, two measures are presented here, one on management of dementia and the other on deaths from dementia. Measures may be added over time as understanding grows of how best to assess dementia care.

### Dementia Measures

Management Measures:

- Adults age 65 and over with and without dementia who had an emergency department visit^*^

Outcome Measures:

- Age-adjusted death rates for dementia^*^

### Emergency Department Visits With Dementia

People with dementia might be brought to the emergency department (ED) for a variety of reasons and the course of their care can lead to additional behavioral, cognitive, and physical health problems, including the increased likelihood of an adverse event.^172^

ED visits resulting from dementia can be challenging and costly for patients who may otherwise require a caregiver to support them. Furthermore, national data about people who experience dementia and Alzheimer’s disease remain limited. Providers, researchers, and policymakers have limited information to understand why patients with dementia come to the ED and how their care can be supported in the community to minimize their visits.^173^

Although ED visit rates are lower for older adults with dementia than for those without dementia, the consequences can be worse. Older adults with dementia have greater comorbidity, incur higher charges, are admitted to the hospital at higher rates, return to the ED at higher rates, and have higher mortality after an ED visit than patients without dementia.^174^

Figure 148 Management: Emergency department visits involving dementia among adults age 65 and over, 2016

Column chart showing rate per 100,000 population ED Visits Involving Dementia 65-69, 889.5 70-74, 2,068.5 75-79, 4,710.8 80-84, 9,784.0 85+, 19,817.0 ED Visits Not Involving Dementia 65-69, 39,071.4 70-74, 42,807.5 75-79, 51,401.3 80-84, 60,836.5 85+, 70,426.7

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample and Nationwide Emergency Department Sample, 2016.

- In 2016, the rate of emergency department visits involving dementia among adults was:
  ■ 889.5 per 100,000 for adults ages 65-69,
  ■ 2,068.5 per 100,000 for adults ages 70-74,
  ■ 4,710.8 per 100,000 for adults ages 75-79,
  ■ 9,784 per 100,000 for adults ages 80-84, and
  ■ 19,817 per 100,000 for adults ages 85 and over (Figure 148).

### Dementia Mortality

Alzheimer’s disease (AD) is currently ranked as the sixth leading cause of death in the United States, but recent estimates (https://www.nia.nih.gov/news/number-alzheimers-deaths-found-be-underreported) indicate that the disorder may rank third, just behind heart disease (https://www.nia.nih.gov/health/heart-health-and-aging#heart-disease) and cancer (https://www.nia.nih.gov/health/alzheimers-disease-common-medical-problems), as a cause of death for older people. Alzheimer’s is the most common cause of dementia among older adults.^175^

It is estimated that well over half a million deaths per year in the United States occur among older adults with AD. About two and a half times as many AD deaths will occur in 2050, absent a broadly applied intervention that prevents or delays AD onset.^176^

Two factors contribute to the substantial number of deaths. First, no one recovers from AD; it lasts until death. Second, most deaths in the United States occur in adults age 65 and over, the age of greatest risk for AD.^176^

AD may cause even more deaths than official sources recognize. It is difficult to determine how many deaths are caused by AD each year because of the way causes of death are recorded. The Centers for Disease Control and Prevention considers a person to have died from Alzheimer’s if the death certificate lists Alzheimer’s as the underlying cause of death, defined as “the disease or injury which initiated the train of events leading directly to death.” Therefore, conditions related to AD may be listed as the cause of death rather than AD itself.

For example, AD may damage areas of the brain that control swallowing, making it difficult to eat and drink. Individuals may swallow food into the windpipe instead of the esophagus, causing food particles to lodge in the lungs and cause infection. This type of infection is called aspiration pneumonia, a contributing cause of death among many people with AD.^169^

Consistent disparities remain among Blacks and Hispanics compared with non-Hispanic Whites in the:

- Prevalence and incidence of AD,
- Participation in clinical trials,
- Use of medications and other interventions,
- Use of long-term services and supports,
- Healthcare expenditures,
- Quality of care, and
- Caregiving.^177^

Problems related to scarce resources can affect brain health over the long term and may contribute to racial inequities in rates of dementia; however, education can help mitigate the risk.^178^

Figure 149 Outcome: Age-adjusted death rates for dementia per 100,000 population, by race/ethnicity, 2000-2017

Note: Age-adjusted rates are per 100,000 U.S. standard population. Rates are based on populations enumerated as of April 1 for census years and estimated as of July 1 for all other years. Race and Hispanic-origin categories are consistent with 1977 Office of Management and Budget standards. White and Black are non-Hispanic. Hispanic includes all races.

Line graph showing rate per 100,000 population over time All racial/ethnic group showed increases; data are in the text below the chart

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Mortality, 2000-2017.

- From 2000 to 2017, the age-adjusted death rate for dementia increased overall from 30.5 per 100,000 population to 66.7 per 100,000 population (Figure 149).
- From 2000 to 2017, the age-adjusted death rate for dementia increased from 32.0 per 100,000 population to 70.8 per 100,000 population for Whites, from 24.7 per 100,000 population to 65.0 per 100,000 population for Blacks, and from 17.2 per 100,000 population to 46.0 per 100,000 population for Hispanics.

Figure 150 Outcome: Age-adjusted death rates for dementia per 100,000 population, by sex, 2017

Note: Age-adjusted rates are per 100,000 U.S. standard population. Rates are based on populations enumerated as of April 1 for census years and estimated as of July 1 for all other years. Rates are age adjusted for all ages, under 65, and 65 and over.

Column chart showing rate per 100,000 population Male, 56.4 Female, 72.7

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Mortality, 2017.

- In 2017, the age adjusted death rate for dementia was 56.4 per 100,000 population for males and 72.7 per 100,000 for females (Figure 150).

## Opioid Use

The opioid crisis is a national and HHS priority. Many Departmental efforts are underway to better track the opioid crisis and understand the data, which are part of the HHS five-point opioid strategy.^111^ The QDR Interagency Work Group’s opioid subgroup considered the Department’s work to date when assessing which opioid measures would be best to track nationally.

Among the data gathered, most concerning is the increasing number of opioid overdose deaths in recent years. A record number of drug overdose deaths occurred in 2017: 70,237 deaths due to drug overdose, for an age-adjusted rate of 21.7 per 100,000 population.^108^

The QDR continues to track data on healthcare quality and disparities related to opioids. Select measures are shown here and all measures can be accessed via the QDR’s Data Query Tool at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

Inclusion of these measures will provide the foundation to understanding the number of drug overdose deaths involving opioids in the United States, in support of efforts to target specific subpopulations who most need healthcare services.

### Opioid Measures

Utilization Measures

- Adults ages 18-64 with four or more opioid prescriptions in the calendar year^*^
- Adults ages 18-64 with any opioid prescriptions in the calendar year^*^

Treatment Measures

- Hospital inpatient stays related to opioid use per 100,000 population
- Emergency department visits involving opioid-related diagnoses per 100,000 population

Prevalence Measures

- Adults age 18 and over with past-year opioid (either prescription opioid or heroin) use disorder^*^

Outcome Measures

- Drug overdose deaths involving any opioid per 100,000 resident population per year^*^
- Drug overdose deaths involving natural and semisynthetic opioids per 100,000 resident population per year^*^
- Drug overdose deaths involving synthetic opioids other than methadone per 100,000 resident population per year^*^

### Opioid Prescriptions

Increased availability and overuse of opioid medications (both prescription and nonprescription drugs) have contributed to adverse outcomes for patients, including increased risk of opioid use disorder, misuse of medication, and overdoses.^107^ The two measures on opioid prescriptions do not indicate healthcare quality; they show utilization instead. But awareness of prescription volume can inform efforts to prevent opioid misuse and abuse, such as diversion (selling one’s opioids) and overdose.

Figure 151 Utilization: Adults ages 18-64 who filled four or more outpatient opioid prescriptions in the calendar year, by insurance, 2013-2016

Line graph showing percentage Total, 2013, 4.6, 2014, 4.8, 2015, 4.3, 2016, 3.6 Private Insurance, 2013, 2.7, 2014, 2.9, 2015, 2.3, 2016, 1.7 Public Insurance Only, 2013, 12.9, 2014, 11.2, 2015, 10.2, 2016, 8.8 Uninsured, 2013, 2.7, 2014, 1.4, 2015, 1.9, 2016, 1.7

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2013-2016.

- From 2013 to 2016, overall, the percentage of adults under age 65 who filled four or more outpatient opioid prescriptions in the calendar year decreased from 4.6% to 3.6% (Figure 151).
- From 2013 to 2016, the percentage of adults with private insurance and those who were uninsured who filled four or more outpatient opioid prescriptions decreased from 2.7% to 1.7%. The percentage of publicly insured adults who filled four or more outpatient opioid prescriptions decreased from 12.9% to 8.8%.

Figure 152 Utilization: Adults ages 18-64 with any opioid prescriptions in the calendar year, by insurance, 2013-2016

Line graph showoing percentage Total, 2013, 15.3, 2014, 16, 2015, 15.5, 2016, 13 Private Insurance, 2013, 13.4, 2014, 13.7, 2015, 13.1, 2016, 10.8 Public Insurance Only, 2013, 27, 2014, 26.7, 2015, 24.6, 2016, 20.2 Uninsured, 2013, 8.8, 2014, 7, 2015, 7.2, 2016, 6.4

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2013-2016.

- From 2013 to 2016, overall, the percentage of adults under age 65 who filled any outpatient opioid prescriptions in the calendar year decreased from 15.3% to 13% (Figure 152).
- From 2013 to 2016, the percentage of adults with private insurance who filled any outpatient opioid prescriptions decreased from 13.4% to 10.8%. The percentage of publicly insured adults who filled any outpatient opioid prescriptions decreased from 27% to 20.2%. The percentage of uninsured adults who filled any outpatient opioid prescriptions decreased from 8.8% to 6.4%.

### Opioid Use Disorder

This measure provides insight into opioid use disorder as it relates to race/ethnicity and education. Much of the current data and information on the opioid crisis highlights the White population, and greater understanding of how it affects racial and ethnic minority populations is needed to effectively address disparities and the opioid crisis as a whole.

Disparities are also seen by education. It is important to examine these disparities, as educational level may affect one’s ability to understand and adhere to a treatment plan.

Figure 153 Prevalence: Adults with opioid (either prescription opioid or heroin) use disorder in the past year, by ethnicity, 2017

Note: For this measure, lower rates are better. White and Black are non-Hispanic. Hispanic includes all races.

Column chart showing percentage Total, 0.78 White, 0.94 Black, 0.64 Hispanic, 0.35

Source: Substance Abuse and Mental Health Services Administration, National Survey on Drug Use and Health, 2017.

- In 2017, Whites had the highest percentage of opioid use disorder (0.94%), followed by Blacks (0.64%) and Hispanics (0.35%) (Figure 153).

Figure 154 Prevalence: Adults with opioid (either prescription opioid or heroin) use disorder in the past year, by education, 2017

Note: For this measure, lower rates are better.

Column chart showing percent < High School, 1.27 High School Grad, 0.97 Any College, 0.63

Source: Substance Abuse and Mental Health Services Administration, National Survey on Drug Use and Health, 2017.

- In 2017, the percentage of adults with an opioid use disorder was 1.27% for adults with less than a high school education, 0.97% for high school graduates, and 0.63% for adults with any college education (Figure 154).

### Opioid-Related Mortality

In the past two decades, opioid overdose deaths have increased in the United States. This year, the QDR presents three measures of opioid mortality. Data for all three opioid mortality measures are based on International Classification of Diseases, Tenth Revision (ICD-10) codes and death certificates. For these three measures, state and local variation in the reporting of the specific drugs involved in the death must be considered.

The Centers for Disease Control and Prevention (CDC) opioid mortality data have not been analyzed for statistical significance in this report. Data were obtained from CDC’s WONDER database (https://wonder.cdc.gov/mcd.html).

#### Overdose Deaths Involving Any Opioid

The first mortality measure is drug overdose deaths involving any opioid per 100,000 resident population. These annual data collected by CDC show the largest category of overdose deaths involving opioids. It provides the foundation and starting point to understanding overdose deaths involving opioids. Other measures of overdose deaths involving opioids are more specific to the type of opioids. While the data can be stratified by race/ethnicity, sex, age, region, and urbanization, they do not specify the type of opioid involved in the overdose death.

Figure 155 Outcome: Drug overdose deaths involving any opioid per 100,000 population, by race, 1999-2017

Key: AI/AN = American Indian or Alaska Native; API = Asian or Pacific Islander.

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population, indicating increases in death rates for Whites, Blacks, APIs, and AI/ANs over time. Data are provided in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 1999-2017.

- From 2004 to 2016, overall, the rate of drug overdose deaths involving any opioid increased from 2.9 per 100,000 population to 14.9 per 100,000 population (Figure 155).
- From 1999 to 2017, the rate of drug overdose deaths involving any opioid increased:
  ■ From 3.0 per 100,000 population to 16.8 per 100,000 population for Whites,
  ■ From 3.4 per 100,000 population to 12.4 per 100,000 population for Blacks,
  ■ From 0.3 per 100,000 population to 1.6 per 100,000 population for APIs, and
  ■ From 2.6 per 100,000 population to 9.8 per 100,000 population for AI/ANs.
- Stratifications by race and gender show that males and females are both experiencing similar trends in opioid mortality across all subpopulations; however, males have much higher rates (data not shown).
  ■ For example, from 2004 to 2016, among males, the rate of drug overdose deaths involving any opioid increased from 7.0 per 100,000 population to 20.4 per 100,000 population for Whites, 4.4 per 100,000 population to 14.7 per 100,000 population for Blacks, 0.7 per 100,000 population to 2.3 per 100,000 population for APIs, and 6.2 per 100,000 population to 10.2 per 100,000 population for AI/ANs (data not shown).
  ■ Among females, from 2004 to 2016, the rate of drug overdose deaths involving any opioid increased from 3.5 per 100,000 population to 9.7 per 100,000 population for Whites, 2.0 per 100,000 population to 5.9 per 100,000 population for Blacks, 0.3 per 100,000 population to 0.8 per 100,000 population for APIs, and 3.3 per 100,000 population to 7.6 per 100,000 population for AI/ANs (data not shown).

Figure 156 Outcome: Drug overdose deaths involving any opioid per 100,000 population, by ethnicity, 1999-2017

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population, indicating increases for non-Hispanic Whites and Hispanics. Data are given in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 1999-2017.

- From 1999 to 2017, overall, the rate of drug overdose deaths involving any opioid increased:
  ■ From 2.8 per 100,000 population to 19.4 per 100,000 population for non-Hispanic Whites (Figure 156).
  ■ From 3.5 per 100,000 population to 6.8 per 100,000 population for Hispanics.
  ■ From 3.5 per 100,000 population to 12.9 per 100,000 population for non-Hispanic Blacks (data not shown).
  ■ From 0.3 per 100,000 population to 1.6 per 100,000 population for non-Hispanic APIs (data not shown).
  ■ From 2.9 per 100,000 population to 15.7 per 100,000 population for non-Hispanic AI/ANs (data not shown).

Figure 157 Outcome: Drug overdose deaths involving any opioid per 100,000 population, by age, 1999-2017

Note: For this measure, lower rates are better. The data for 1999-2000 for age 85 years and over are not included because the data do not meet the criteria for statistical reliability, data quality, or confidentiality.

Line graph showing rate per 100,000 population, indicating increases for all age groups. Data are given in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 1999-2017.

- From 1999 to 2017, overall, the rate of drug overdose deaths involving any opioid increased for most age groups (Figure 157); however, adults ages 25-34 years, 35-44 years, and 45-54 years have seen the largest increases in mortality rates:
  ■ 15-24 years: 1.6 per 100,000 population to 9.5 per 100,000 population.
  ■ 25-34 years: 4.1 per 100,000 population to 29.1 per 100,000 population.
  ■ 35-44 years: 7.2 per 100,000 population to 27.3 per 100,000 population.
  ■ 45-54 years: 5.4 per 100,000 population to 24.1 per 100,000 population.
  ■ 55-64 years: 1.5 per 100,000 population to 17.0 per 100,000 population.
  ■ 65-74 years: 0.5 per 100,000 population to 4.9 per 100,000 population.
  ■ 75-84 years: 0.4 per 100,000 population to 1.4 per 100,000 population.
- From 2001 to 2017, the mortality rate for adults age 85 years and over increased from 0.5 per 100,000 population to 1.2 per 100,000 population.

#### Overdose Deaths Involving Natural and Semisynthetic Opioids and Overdose Deaths Involving Synthetic Opioids Other Than Methadone

The second mortality measure is drug overdose deaths involving natural and semisynthetic opioids, and the third mortality measure is drug overdose deaths involving synthetic opioids other than methadone. These measures do not specify whether the overdose deaths from natural, semisynthetic, or synthetic opioids are due to legally prescribed medications or drugs that are illicitly manufactured or obtained.

Both of these annual measures provide more specific information than the first mortality measure by specifying the type of opioid involved in the overdose death. To understand the current opioid epidemic, it is critical to know which opioid drugs are contributing the most to overdose deaths involving opioids, and these two measures provide some insight.

The measure of drug overdose deaths involving natural and semisynthetic opioids describes individuals who have died from commonly prescribed opioids, including oxycodone, hydrocodone, and morphine. Oxycodone may be more commonly known by certain brand names, such as OxyContin and Percocet, and hydrocodone by the brand names Vicodin, Lortab, and Zohydro, among others.

The measure of drug overdose deaths involving synthetic opioids other than methadone describes individuals who have died from synthetic opioids such as fentanyl (illicit and prescription) and tramadol. Recent data have shown that fentanyl-related overdose deaths are heavily contributing to the opioid crisis. CDC reported that the age-adjusted rate for the number of drug overdose deaths involving fentanyl increased from 0.6 per 100,000 population in 2013 to 5.9 per 100,000 population in 2016.^179^

Although overdose death rates are higher for Whites and rates vary by gender within racial groups, Hispanics and Blacks are experiencing fast-rising rates of drug overdose deaths involving synthetic opioids other than methadone.^179^ Members of Black and Hispanic communities have expressed concern about availability of resources to address this problem and stigma related to opioid use.

Figure 158 Outcome: Drug overdose deaths involving natural and semisynthetic opioids per 100,000 population, by race, 1999-2017

Note: For this measure, lower rates are better. The 1999 data point for APIs is not included because it does not meet the criteria for statistical reliability, data quality, or confidentiality.

Line graph showing rate per 100,000 population, indicating increases for all racial groups. Data are given in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 1999-2017.

- From 1999 to 2017, overall, the rate of drug overdose deaths involving natural and semisynthetic opioids increased from 1.0 per 100,000 population to 4.4 per 100,000 population (Figure 158).
- From 1999 to 2017, the rate of drug overdose deaths involving natural and semisynthetic opioids increased for three racial groups:
  ■ Whites, 1.1 per 100,000 population to 5.1 per 100,000 population.
  ■ Blacks, 0.6 per 100,000 population to 2.8 per 100,000 population.
  ■ AI/ANs, 0.8 per 100,000 population to 3.6 per 100,000 population.
- From 2000 to 2017, the rate of drug overdose deaths involving natural and semisynthetic opioids increased for APIs from 0.2 per 100,000 population to 0.6 per 100,000 population.
- Stratifications by race and gender show that males and females are both experiencing similar trends in opioid mortality across all subpopulations; however, males have much higher rates. Also, Hispanic males show a slight decrease in rates over time while Hispanic females show an increase (data not shown):
  ■ From 1999 to 2016:
    ♦ The rate of drug overdose deaths increased from 1.4 per 100,000 population to 7.0 per 100,000 population for White males.
    ♦ The rate increased from 1.0 per 100,000 population to 3.3 per 100,000 population for Black males.
    ♦ The rate decreased from 2.3 per 100,000 population to 2.1 per 100,000 population for Hispanic males.
  ■ From 1999 to 2016:
    ♦ The rate of drug overdose deaths increased from 0.6 per 100,000 population to 4.9 per 100,000 population for White females.
    ♦ The rate increased from 0.3 per 100,000 population to 2.3 per 100,000 population for Black females.
    ♦ The rate decreased from 0.3 per 100,000 population to 1.2 per 100,000 population for Hispanic females.

Figure 159 Outcome: Drug overdose deaths involving natural and semisynthetic opioids per 100,000 population, by ethnicity, 1999-2017

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population, indicating increases for non-Hispanic Whites and Hispanics. Data are given in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 1999-2017.

- From 1999 to 2017, the rate of drug overdose deaths involving natural and semisynthetic opioids increased from 1.0 per 100,000 population to 5.9 per 100,000 population for non-Hispanic Whites and from 1.4 per 100,000 population to 1.8 per 100,000 population for Hispanics (Figure 159).
- From 1999 to 2017, the rate of drug overdose deaths involving natural and semisynthetic opioids increased from 0.6 per 100,000 population to 2.9 per 100,000 population for non-Hispanic Blacks and from 1.0 per 100,000 population to 5.7 per 100,000 population for non-Hispanic AI/ANs (data not shown).
- From 2002 to 2017, the rate increased from 0.2 per 100,000 population to 0.5 per 100,000 population for non-Hispanic APIs (data not shown).

Figure 160 Outcome: Drug overdose deaths involving natural and semisynthetic opioids per 100,000 population, by age, 1999-2017

Note: For this measure, lower rates are better. The data for 1999-2002 and 2004 for adults age 85 years and over and data in 2000 for ages 75-84 years are not included because they do not meet the criteria for statistical reliability, data quality, or confidentiality.

Line graph showing rate per 100,000 population, indicating increases for all age groups. Data are given in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 1999-2017.

- From 1999 to 2017, overall, the rate of drug overdose deaths involving natural and semisynthetic opioids increased for most age groups (Figure 160); however, adults ages 35-44 years, 45-54, and 55-64 years had the largest increases in mortality rates:
  ■ 15-24 years: 0.5 per 100,000 population to 2.1 per 100,000 population.
  ■ 25-34 years: 1.3 per 100,000 population to 6.3 per 100,000 population.
  ■ 35-44 years: 2.3 per 100,000 population to 7.7 per 100,000 population.
  ■ 45-54 years: 2.0 per 100,000 population to 8.6 per 100,000 population.
  ■ 55-64 years: 0.7 per 100,000 population to 7.1 per 100,000 population.
  ■ 65-74 years: 0.3 per 100,000 population to 2.5 per 100,000 population.
- From 1999 to 2017, the mortality rate for adults ages 75-84 years increased from 0.2 per 100,000 population to 1.0 per 100,000 population. Data are not available for 2000.
- From 2003 to 2017, the mortality rate for adults 85 years and over increased from 0.5 per 100,000 population to 0.9 per 100,000 population. Data are not available for 2004.

Figure 161 Outcome: Drug overdose deaths involving synthetic opioids other than methadone per 100,000 population, by race, 1999-2017

Key: AI/AN = American Indian or Alaska Native; API = Asian or Pacific Islander.

Note: For this measure, lower rates are better. The data for APIs (1999-2008, 2010, and 2012) and AI/ANs (1999-2003) are not included because they do not meet the criteria for statistical reliability, data quality, or confidentiality.

Line graph showing rate per 100,000 population, indicating increases for all racial groups and sharp increases from 2013 to 2017. Data are in the text below the graph.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 1999-2017.

- From 1999 to 2017, the overall rate of drug overdose deaths involving synthetic opioids other than methadone increased from 0.3 per 100,000 population to 9.0 per 100,000 population (Figure 161).
- From 1999 to 2017, the rate of drug overdose deaths involving synthetic opioids other than methadone increased from 0.3 per 100,000 population to 10.1 per 100,000 population for Whites and 0.1 per 100,000 population to 8.6 per 100,000 population for Blacks.
- From 2013 to 2017, Blacks (0.5 to 8.6 per 100,000 population) showed a 17.2-fold increase in mortality, while Whites (1.1 to 10.1 per 100,000 population) showed a 9.2-fold increase in mortality.
- For AI/ANs, the mortality rate increased from 0.7 per 100,000 population in 2004 to 3.9 per 100,000 population in 2017, a 5.6-fold increase.
- For APIs, the mortality rate increased from 0.1 per 100,000 population in 2009 to 0.9 per 100,000 population in 2017, a 9-fold increase.

Figure 162 Outcome: Drug overdose deaths involving synthetic opioids other than methadone per 100,000 population, by ethnicity, 1999-2017

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population, indicating increases for non-Hispanic Whites and Hispanics and sharp increases from 2013 to 2017. Data are in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 1999-2017.

- From 1999 to 2017, the rate of drug overdose deaths involving synthetic opioids other than methadone increased from 0.3 per 100,000 population to 11.9 per 100,000 population for non-Hispanic Whites; and from 0.1 per 100,000 population to 3.7 per 100,000 population for Hispanics (Figure 162).
- From 2013 to 2017, non-Hispanic Whites had a 9.2-fold increase and Hispanics had a 12.3-fold increase in mortality due to synthetic opioids other than methadone.
- From 1999 to 2017, the rate increased from 0.1 per 100,000 population to 9.0 per 100,000 population for non-Hispanic Blacks. From 2013 to 2017, non-Hispanic Blacks had an 18-fold increase in mortality due to synthetic opioids other than methadone (data not shown).
- From 2004 to 2017, the death rate for non-Hispanic AI/ANs increased from 0.9 per 100,000 population to 6.5 per 100,000 population (data not shown).
- From 2011 to 2017, the death rate for non-Hispanic APIs increased from 0.1 per 100,000 population to 0.8 per 100,000 population (data not shown).

Figure 163 Outcome: Drug overdose deaths involving synthetic opioids other than methadone per 100,000 population, by age, 1999-2017

Note: For this measure, lower rates are better. The data for age 85 years and over (1999-2017), ages 75-84 years (1999-2004, 2008, 2013), and ages 65-74 years (2000-2001) are not included because they do not meet the criteria for statistical reliability, data quality, or confidentiality.

Line graph showing rate per 100,000 population, indicating increases for all age groups and sharp increases for most age groups from 2013 to 2017. Data are in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 1999-2017.

- From 1999 to 2017, overall, the rate of drug overdose deaths involving synthetic opioids other than methadone increased for most age groups (Figure 163); however, adults ages 25-34 years, 35-44 years, and 45-54 years had the largest increases in mortality rates:
  ■ 15-24 years: 0.1 per 100,000 population to 6.1 per 100,000 population.
  ■ 25-34 years: 0.3 per 100,000 population to 19.5 per 100,000 population.
  ■ 35-44 years: 0.6 per 100,000 population to 17.3 per 100,000 population.
  ■ 45-54 years: 0.5 per 100,000 population to 13.6 per 100,000 population.
  ■ 55-64 years: 0.2 per 100,000 population to 8.3 per 100,000 population.
  ■ 65-74 years: 0.1 per 100,000 population to 1.9 per 100,000 population.
- From 2005 to 2017, the mortality rate for people ages 75-84 years increased from 0.2 per 100,000 population to 0.3 per 100,000 population.
- Mortality rates across most age groups had sharp increases from 2013 to 2017.

## Maternal Morbidity and Mortality

Maternal mortality, defined as the risk of dying from causes associated with childbirth, is considered a sentinel event in that it is a rare and negative maternal outcome.^180^ At a population level, it is also an indicator used to monitor maternal health and the quality of reproductive healthcare both internationally and nationally.^181^ Compared with other high-income industrialized countries, rates of maternal mortality in the United States are among the highest181 and more than doubled from 1987 to 2014 (from 7.2 per 100,000 live births to 18.0).^182^

Persistent racial and ethnic disparities in maternal mortality have also accompanied the rise in maternal deaths, with Black women having a pregnancy-related mortality ratio 3 times as high as that of non-Hispanic White women.^183^ Like maternal mortality, severe maternal morbidity, which encompasses unintended outcomes of labor and delivery that result in short-term or long-term health issues, has similarly increased in the United States in recent decades.^184^ The perinatal period presents unique patient safety challenges, including potential overuse and underuse of interventions, misdiagnosis, and emotional harm, which contribute to maternal morbidity and perinatal adverse events.^185^

Nationally, perinatal adverse events constitute some of the highest liability costs. Efforts to minimize and eliminate harm to mothers and babies have examined the use of maternal safety bundles, which involve standardized approaches to address obstetric emergencies in hospital settings.^186,187,188^ When these bundles have been implemented in hospitals with communication and resolution programs, hospitals, health systems, providers, and patients have observed lower rates of adverse events, lower costs, and improved patient outcomes.^186,187,189^

Most cases of maternal mortality and severe maternal morbidity are preventable, and prevention strategies include improving access to and coordination and delivery of quality care.^182,190,191^ Recognition is growing of the need to develop, monitor, and improve performance on quality measures in obstetrics care, particularly around disparities.^192^

Currently, the QDR tracks one preventive health measure related to maternal health (i.e., women who completed a pregnancy in the last 12 months who received early and adequate prenatal care). The 2018 report does not include any treatment and management measures but now includes two outcome measures related to maternal morbidity and mortality.

### Maternal Morbidity and Mortality Measures

- Cesarean deliveries among low-risk first births^*^
- In-hospital deaths per 100,000 delivery hospitalizations^*^

### Cesarean Deliveries Among Low-Risk First Births

Nearly one-third of all births in the United States are delivered by cesarean section (C section),193 which is higher than many other industrialized countries.^194^ Reducing the C-section rate continues to be an important focus of public health efforts nationwide, particularly for low-risk deliveries with no medical indication for the procedure.^195^

For low-risk pregnancies, C sections pose a greater risk for maternal morbidity and mortality than vaginal delivery. Risks include hemorrhage, infection, and blood clots, and these risks increase with subsequent C sections.^196^ Much of the increase in C-section rates is attributed to first births, which are amenable to intervention through quality improvement efforts.

Cesarean delivery of low-risk first births, also known as nulliparous term singleton vertex cesarean, relates to Healthy People 2020 Maternal, Infant, and Child Health Objective 7.1 (Reduce cesarean births among low risk women with no prior cesarean). This risk-adjusted measure has high face validity and easy measurability, controls for patient and fetal conditions before labor, and allows comparison between hospitals.^197,198^

This measure is also endorsed by multiple organizations, including the American College of Obstetricians and Gynecologists, the Joint Commission, the National Quality Forum, and the Centers for Medicare & Medicaid Services. However, this measure is not considered a measure of obstetric quality for higher risk women.

Figure 164 Outcome: Cesarean deliveries among low-risk first births, by race/ethnicity, 2007-2017

Key: AI/AN = American Indian or Alaska Native; API = Asian or Pacific Islander.

Note: For this measure, lower rates are better. White, Black, API, and AI/AN are non-Hispanic. Hispanic includes all races.

Line graph showing percentage over time. Data are given in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Natality, 2007-2017.

- In 2017, the percentage of women having cesarean deliveries for low-risk first birth was higher for Blacks (29.8%) than for Whites (25.1%; Figure 164).
- In 2017, there were no statistically significant differences in the percentage of cesarean deliveries among low-risk first births between:
  ■ Whites (25.1%) and American Indians and Alaska Natives (23.2%).
  ■ Whites (25.1%) and Asians and Pacific Islanders (APIs) (27.4%).
  ■ Non-Hispanic Whites (24.9%) and Hispanics (25.7%).

### In-Hospital Deaths per 100,000 Delivery Hospitalizations

Reports from 2011-2015 Pregnancy Mortality Surveillance System data show that 16.9% of pregnancy-related deaths occur on the day of delivery and 18.6% of pregnancy-related deaths occur 1 to 6 days postpartum.^182^ Thus, important insights can be gained from monitoring adverse maternal outcomes using hospital discharge surveillance data. Maternal deaths that occur during hospital stays may provide a window into both system and provider-level factors that can play a role in preventing maternal death.^182,189,190^

In-hospital deaths per 100,000 delivery hospitalizations provides a measure of intrapartum maternal mortality or those that occur during delivery through hospital discharge. This measure represents a small portion of the Centers for Disease Control and Prevention definition of pregnancy-related mortality and relates to Healthy People 2020 Maternal, Infant, and Child Health Objective 5 (Reduce the rate of maternal mortality).

This measure should be interpreted with caution as it is limited to in-hospital maternal deaths that occur during hospital stays. It does not include pregnancy-related deaths that occur outside hospital settings, those that occur prior to delivery, or those that occur after hospital discharge in the postpartum period.

Figure 165 Outcome: In-hospital deaths per 100,000 delivery hospitalizations, by race and ethnicity, 2016

Key: API = Asian or Pacific Islander.

Column chart showing rate per 100,000 deliveries Total, 5.9 White, 3.5 Black, 10.1 API, 7.5 Hispanic, 7.8

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Inpatient Databases, 2016, weighted to provide national estimates.

- In 2016, the rate of in-hospital deaths per 100,000 deliveries was 3.5 among Whites, 10.1 among Blacks, 7.5 among APIs, and 7.8 among Hispanics (Figure 164).

* The measures that are noted with an asterisk (*) are newly added to this year’s report.

* The measures that are noted with an asterisk (*) are newly added to this year’s report.

* The measures that are noted with an asterisk (*) are newly added to this year’s report.

* The measures that are noted with an asterisk (*) are newly added to this year’s report.