# QUALITY AND QUALITY DISPARITIES

Measures of healthcare quality tracked in the QDR encompass a broad array of services (prevention, acute treatment, and chronic disease management) and settings (doctors’ offices, emergency departments, dialysis centers, hospitals, nursing homes, hospices, and home health). Most QDR quality measures quantify processes that make up high-quality healthcare or outcomes related to receipt of high-quality healthcare. A few structural measures are included, such as the availability of health information technologies and workforce diversity.

Data used to generate QDR measures include results from more than three dozen datasets that provide estimates for various population subgroups and data years. Sources used to assess healthcare quality in the report include:

- Surveys of patients, patients’ families, and providers;
- Administrative data from healthcare facilities;
- Abstracts of clinical charts;
- Registry data; and
- Vital statistics.

Most data are reported annually and are generally available through 2016 or 2017.

Historically, quality of healthcare has varied based on race, ethnicity, socioeconomic status, age, sex, disability status, sexual orientation, and residence location. As specified in the Healthcare Research and Quality Act, this summary focuses on disparities related to race and socioeconomic status.

## TRENDS IN QUALITY

Quality of healthcare improved generally through 2017, but the pace of improvement varied by priority area.

Figure 33 Number and percentage of all quality measures that were improving, not changing, or worsening, total and by priority area, from 2000 through 2017

Key: n = number of measures.

Note: For most measures, trend data are available from 2001-2002 to 2017. For each measure with at least four estimates over time, weighted log-linear regression is used to calculate average annual percentage change and to assess statistical significance. Measures are aligned so that positive change indicates improved quality of care.

- Improving = Rates of change are positive at 1% per year or greater and statistically significant.
- No Change = Rate of change is less than 1% per year or not statistically significant.
- Worsening = Rates of change are negative at −1% per year or greater and statistically significant.

Stacked bar chart showing number of quality measures Total (n=147), Improving, 80, Not Changing, 59, Worsening, 8 Person-Centered Care (n=19), Improving, 13, Not Changing, 6, Worsening, 0 Patient Safety (n=21), Improving, 13, Not Changing, 7, Worsening, 1 Healthy Living (n=59), Improving, 35, Not Changing, 22, Worsening, 2 Effective Treatment (n=34), Improving, 16, Not Changing, 15, Worsening, 3 Care Coordination (n=9), Improving, 3, Not Changing, 4, Worsening, 2 Affordable Care (n=5), Improving, 0, Not Changing, 5, Worsening, 0

- Through 2017, across a broad spectrum of measures of healthcare quality, 54% showed improvement (Figure 33).
- Almost 70% of measures of Person-Centered Care improved.
- About 60% of measures of Patient Safety and Healthy Living improved.
- Almost half of measures of Effective Treatment improved.
- One-third of measures of Care Coordination improved.
- No Affordable Care measures changed overall.

Due to the nationwide conversion from the International Classification of Diseases, Ninth Revision (ICD-9) to the Tenth Revision (ICD-10) codes in the last quarter of 2015, at this time, we cannot trend the data for some AHRQ Quality Indicators that are based on nationwide Healthcare Cost and Utilization Project (HCUP) data. Measures that have been included in past reports are not always represented in this year’s report. Wherever this situation applies, this report includes a footnote.

### Trends in Person-Centered Care

The QDR addresses six priority areas, including person-centered care, defined as ensuring that each person and family is engaged as partners in their care. The rationale is that “[h]ealth care should give each individual patient and family an active role in their care. Care should adapt readily to individual and family circumstances, as well as differing cultures, languages, disabilities, health literacy levels, and social backgrounds.” Examples of person-centered care could be ensuring that patients’ feedback on their preferences, desired outcomes, and experiences of care is integrated into care delivery and enabling patients to effectively manage their care.

The Institute of Medicine identifies patient centeredness as a core component of quality healthcare.^4^ Patient centeredness is defined as:

[H]ealth care that establishes a partnership among practitioners, patients, and their families (when appropriate) to ensure that decisions respect patients’ wants, needs, and preferences and that patients have the education and support they need to make decisions and participate in their own care.^5^

Patient centeredness “encompasses qualities of compassion, empathy, and responsiveness to the needs, values, and expressed preferences of the individual patient.”^4^ In addition, translation and interpretation services, as well as auxiliary aids and services, facilitate communication between the provider and the patient and are often a legal requirement.^vii^ The patient-centered approach includes viewing the patient as a unique person, rather than focusing strictly on the illness, building a therapeutic alliance based on the patient’s and the provider’s perspectives.

Patient-centered care is supported by good provider-patient communication so that patients’ needs and wants are understood and addressed and patients understand and participate in their own care.^5^ This approach to care has been shown to improve patients’ health and healthcare.^6,7,8,9,10^

Unfortunately, many barriers exist to good communication. Providers differ in communication proficiency, including varied listening skills and different views from their patients of symptoms and treatment effectiveness.^11^ Additional factors influencing patient centeredness and provider-patient communication include:

- Language barriers.
- Racial and ethnic concordance between the patient and provider.
- Effects of disabilities on patients’ healthcare experiences.
- Providers’ cultural competency.

#### Importance of Person-Centered Care

##### Morbidity and Mortality

- Patient-centered decision making (when physicians take into account the needs and circumstances of a patient) for planning a patient’s care has been shown to improve healthcare outcomes.^12^
- Patient-centered approaches to care have been shown to improve patients’ health status. These approaches rely on building a provider-patient relationship, improving communication, fostering a positive atmosphere, and encouraging patients to actively participate in provider-patient interactions).^13^
- Patient-centered care can reduce the chance of misdiagnosis due to poor communication.^14^

##### Cost

- Poor communication, lack of collaboration, and lack of support for self-care are associated with suffering and waste in healthcare.^15^
- Patient centeredness has been shown to reduce overuse of medical care.^16^
- Patient centeredness can reduce the strain on system resources and save money by reducing the number of diagnostic tests and referrals.^17^
- Improving patient-provider communication during medical decision making can reduce costs.^18^

#### Findings on Person-Centered Care

The Person-Centered Care priority area includes measures of:

- Patient Experience of Care.
- Hospital Communication.
- Home Health Communication.
- Hospice Care.

Data for these measures can be found at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

Person-Centered Care improved quickly, but disparities were common, especially for uninsured and poor people.

No Person-Centered Care measure worsened.

Measures of patient-provider communication showed the greatest improvement:

- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never spent enough time with them
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say

Overall, effective communication leads to increased patient and clinician satisfaction, increased trust with the clinician, and functional and psychological well-being. Effective communication also leads to improved outcomes in specific diseases, including:

- A small but significant absolute risk reduction of mortality from coronary artery disease,
- Improved control of diabetes and hyperlipidemia,
- Better adherence to antihypertensives,
- Bereavement adjustment in caregivers of cancer patients, and
- Higher self-efficacy of adherence to HIV medications.^19^

##### Adequate Doctor’s Explanation

Figure 34 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand, 2002-2016

Note: For this measure, lower rates are better.

Line graph showing percentage 2002, 9.0 2003, 8.1 2004, 8.4 2005, 8.3 2006, 8.2 2007, 7.8 2008, 8.5 2009, 7.6 2010, 7.4 2011, 6.7 2012, 6.4 2013, 6.1 2014, 4.8 2015, 5.1 2016, 5.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- From 2002 to 2016, overall, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand decreased from 9.0% to 5.2% (Figure 34).

##### Adequate Time With the Patient

Figure 35 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never spent enough time with them, 2002-2016

Note: For this measure, lower rates are better.

Line graph showing percentage 2002, 15.3 2003, 13.9 2004, 13.4 2005, 13.9 2006, 13.9 2007, 13.3 2008, 13.2 2009, 12.8 2010, 11.2 2011, 11.6 2012, 10.9 2013, 10.4 2014, 9.2 2015, 9.6 2016, 9.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- From 2002 to 2016, overall, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never spent enough time with them decreased from 15.3% to 9.2% (Figure 35).

##### Respect From the Doctor

Figure 36 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say, 2002-2016

Note: For this measure, lower rates are better.

Line graph showing percentage 2002, 8.8 2003, 7.9 2004, 7.9 2005, 7.5 2006, 7.9 2007, 7.6 2008, 7.4 2009, 7.2 2010, 6.4 2011, 6.8 2012, 6.6 2013, 6.2 2014, 5.0 2015, 5.6 2016, 5.4

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- From 2002 to 2016, overall, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never showed respect for what they had to say decreased from 8.8% to 5.4% (Figure 36).

Efforts to promote person-centered care are underway within the Department of Health and Human Services (HHS). For example:

- The Office of Minority Health has developed Think Cultural Health (https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=1&lvlid=6), a set of cultural competency curriculum modules for providers.
- The HHS Office for Civil Rights’ (OCR) Medical School Curriculum Initiative (https://www.hhs.gov/civil-rights/for-individuals/special-topics/health-disparities/medical-school-curriculum-initiative/index.html) promotes a scenario-based curriculum on health disparities and cultural competency to educate student physicians, medical educators, and other healthcare providers on their civil rights obligations under Title VI of the Civil Rights Act of 1964. In 2019, OCR piloted a new presentation on effective communication requirements for individuals who are deaf or hard of hearing, per Section 504 of the Rehabilitation Act of 1973, Title II of the Americans With Disabilities Act, and Section 1557 of the Affordable Care Act.
- The 2013 Language Access Plan (https://www.hhs.gov/sites/default/files/open/pres-actions/2013-hhs-language-access-plan.pdf) (LAP) ensures access to HHS programs and activities for people with limited English proficiency. The covered programs and activities include Medicare, civil rights enforcement, and other HHS programs that provide benefits or services. The 2013 HHS LAP was developed by the HHS Language Access Steering Committee, which is led by the Director of the OCR on behalf of the Secretary.

### Trends in Patient Safety

The Institute of Medicine (IOM) defines patient safety as “freedom from accidental injury due to medical care or medical errors.”^20^ In 1999, the IOM published To Err Is Human: Building a Safer Health System,^viii^ which called for a national effort to reduce medical errors and improve patient safety.

#### Importance of Patient Safety

##### Mortality

Number of Americans who die in hospitals each year from medical errors (1999 est.) …………………………………………………………………………… 44,000-98,000^20^

Age-standardized mortality rate due to adverse effects of medical treatment ……………………………………………………. 1.15 per 100,000 population^21^

##### Prevalence

Number of hospital-acquired conditions in U.S. hospitals (2017) ………………. 2,550,000^22^

All-payer 30-day readmission rate (2016) …………………………………. 13.9% of admissions^23^

##### Cost

Additional hospital inpatient cost due to hospital-acquired conditions^22^:

- Central line-associated bloodstream infection ……………………………………… $48,108
- Ventilator-associated pneumonia ……………………………………………………….. $47,238
- Surgical site infection ………………………………………………………………………… $28,219
- Venous thromboembolism …………………………………………………………………. $17,367

#### Findings on Patient Safety

The Patient Safety priority area includes measures of:

- Healthcare-Associated Infections.
- Surgical Care.
- Other Complications of Hospital Care.
- Complications of Medication.
- Birth-Related Complications.
- Inappropriate Treatment.
- Supportive and Palliative Care.
- Home Health Communication.

Data for these measures can be found at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

Measures of Patient Safety improved, led by care that took place in a hospital setting, which represented nearly 70% of the measures that showed improvement.

The following three measures showed the most improvement:

- Inpatient adverse events in adults receiving knee replacement
- Inpatient adverse events in adults receiving hip joint replacement due to fracture or degenerative conditions
- Hospital patients with an anticoagulant-related adverse drug event to low-molecular-weight heparin (LMWH) and factor Xa

One measure was worsening:

- Adults who reported a home health provider asking to see all the prescription and over-the-counter medicines they were taking when they first started getting home health care

##### Adverse Events With Knee Replacement

Total knee arthroplasty is the most common inpatient surgery performed annually in the United States. At least 700,000 knee replacements are performed each year in the United States.^24^ While these procedures are generally successful, approximately 8% of patients develop infections, mechanical loosening, or implant failure postoperatively and require revision surgery.

Figure 37 Inpatient adverse events in adults receiving knee replacement, 2009-2016

Note: For this measure, lower rates are better.

2009, 3.3 2010, 4.9 2011, 4.8 2012, 3.6 2013, 2.3 2014, 2.6 2015, 1.7 2016, 2.0

Source: Agency for Healthcare Research and Quality and Centers for Medicare & Medicaid Services, Medicare Patient Safety Monitoring System, 2009-2016.

- From 2009 to 2016, overall, the percentage of inpatient adverse events in adults receiving knee replacement decreased from 3.3% to 2.0% (Figure 37).

##### Adverse Events With Hip Replacement

More than 300,000 total hip arthroplasty (THA) surgeries are performed annually, making it one of the most common surgeries in the United States. THA predictably results in tremendous improvements in quality of life for patients with osteoarthritis and other hip pathologies, such as osteonecrosis, rheumatoid arthritis, and posttraumatic arthritis. Unfortunately, complications are not infrequent after THA, inflicting considerable physical, mental, and financial burden on patients and their families and caregivers, as well as on the healthcare system.

Figure 38 Inpatient adverse events in adults receiving hip joint replacement due to fracture or degenerative conditions, 2009-2016

Note: For this measure, lower rates are better.

Line graph showing percentage 2009, 7.5 2010, 7.8 2011, 7.7 2012, 6.5 2013, 4.9 2014, 4.5 2015, 4.0 2016, 4.9

Source: Agency for Healthcare Research and Quality and Centers for Medicare & Medicaid Services, Medicare Patient Safety Monitoring System, 2009-2016.

- From 2009 to 2016, overall, the percentage of inpatient adverse events in adults receiving hip joint replacement due to fracture or degenerative conditions decreased from 7.5% to 4.9% (Figure 38).

##### Adverse Drug Events With Heparin and Factor Xa

Adverse drug events (ADEs) include medication errors and adverse drug reactions, representing a major source of harm among hospitalized patients. Anticoagulant drugs, including warfarin, unfractionated heparin, and low-molecular-weight heparin, are among the most commonly implicated medications that cause ADEs in hospitalized patients. Low-molecular-weight heparin is used to prevent venous thromboembolic disease on acute or elective admission to the hospital and to treat deep vein thrombosis and pulmonary embolism.^25^

Figure 39 Adult inpatients with an anticoagulant-related adverse drug event to low-molecular-weight heparin (LMWH) and factor Xa, United States, 2009-2016

Note: For this measure, lower rates are better.

Line graph showing percentage 2009, 5.6 2010, 4.8 2011, 4.8 2012, 4.6 2013, 3.4 2014, 3.5 2015, 3.0 2016, 2.2

Source: Agency for Healthcare Research and Quality and Centers for Medicare & Medicaid Services, Medicare Patient Safety Monitoring System, 2009-2016.

- From 2009 to 2016, overall, the percentage of adult inpatients with an anticoagulant-related adverse drug event to low-molecular-weight heparin (LMWH) and factor Xa decreased from 5.6% to 2.2% (Figure 39).

##### Home Health Provider Checking Medication

Figure 40 Adults who reported a home health provider asking to see all the prescription and over-the-counter medicines they were taking when they first started getting home health care, 2012-2017

Note: Benchmarks can include data from both states and territories.

Line graph showing percentage 2015 Achievable Benchmark: 86% 2012, 78.8 2013, 78.9 2014, 78.3 2015, 77.8 2016, 77.6 2017, 77.1

Source: Centers for Medicare & Medicaid Services, Home Health Consumer Assessment of Healthcare Providers and Systems, 2012-2017.

- From 2012 to 2017, overall, the percentage of adults who reported a home health provider asking to see all the prescription and over-the-counter medicines they were taking when they first started getting home health care decreased from 78.8% to 77.1% (Figure 40).
- The 2015 top 5 state achievable benchmark was 86%. There is no evidence of progress toward the benchmark.
- The top 5 states and territories that contributed to the achievable benchmark are Louisiana, Mississippi, Northern Mariana Islands, Puerto Rico, and Virgin Islands.

Efforts to promote patient safety are underway within HHS. For example:

- The Comprehensive Unit-based Safety Program (https://www.ahrq.gov/professionals/education/curriculum-tools/cusptoolkit/index.html) is a patient safety model that includes training tools to make care safer by improving the foundation for how physicians, nurses, and other clinical team members work together. It builds the capacity to address safety issues by combining clinical best practices and the science of safety.
- Team Strategies and Tools To Enhance Performance and Patient Safety (TeamSTEPPS (https://www.ahrq.gov/teamstepps)) is an evidence-based set of teamwork tools aimed at optimizing patient outcomes by improving communication and teamwork skills among healthcare professionals.

### Trends in Care Coordination

Healthcare in the United States is often fragmented. Clinical services are frequently organized around small groups of providers who function autonomously and specialize in specific symptoms or organ systems. Therefore, many patients receive attention only for individual health conditions rather than receiving coordinated care. For example, the typical Medicare beneficiary sees two primary care providers and five specialists each year.^26^ Communication of important information among providers and between providers and patients may entail delays or inaccuracies or may fail to occur.

Care coordination is a conscious effort to ensure that all key information needed to make care decisions is available to patients and providers. It is defined as the deliberate organization of patient care activities between two or more participants involved in a patient’s care to facilitate appropriate delivery of healthcare services.^27^ Care coordination is multidimensional and essential to preventing adverse events, ensuring efficiency, and making care patient centered.^28^

Patients in greatest need of care coordination include those with multiple chronic medical conditions, concurrent care from several health professionals, many medications, extensive diagnostic workups, or transitions from one care setting to another. Effective care coordination requires well-defined multidisciplinary teamwork based on the principle that all who interact with a patient must work together to ensure the delivery of safe, high-quality care.

The National Quality Strategy says the goal of care coordination is to enable healthcare providers, patients, and caregivers to all work together to “ensure that the patient gets the care and support he needs and wants, when and how he needs and wants it.” While measurement of care coordination is at an early stage of development, key goals include coordinating transitions of care, reducing hospital readmissions, communicating medication information, and reducing preventable emergency department visits.

#### Importance of Care Coordination

##### Morbidity and Mortality

Care coordination interventions have been shown to:

- Reduce mortality among patients with heart failure;
- Reduce mortality and dependency among patients with stroke;
- Reduce symptoms among patients with depression and at the end of life; and
- Improve glycemic control among patients with diabetes.^27^

##### Cost

Care coordination interventions have been shown to:

- Reduce hospitalizations among patients with heart failure;
- Reduce readmissions among patients with mental health conditions; and
- Be cost-effective when applied to treatment of depression.^27^

#### Findings on Care Coordination

The Care Coordination priority area includes measures of:

- Transitions of Care.
- Medication Information.
- Preventable Emergency Department Visits.
- Preventable Hospitalizations.
- Preventable Hospitalizations Among Home Health Patients.
- Potentially Harmful Services Without Benefit.
- Supportive and Palliative Care.
- Potentially Avoidable Admissions.

Data for these measures can be found at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

Progress in Care Coordination has been slow, with little improvement and two measures getting worse.

Only three measures showed improvement overall:

- Home health patients who had timely initiation of care
- Adult hospital patients who did not receive good communication about discharge information
- People with a usual source of care who usually asks about prescription medications and treatments from other doctors

Two measures were worsening:

- Home health care patients who had an emergency department visit and were then hospitalized
- Home health care patients who had an emergency department visit without a hospitalization

##### Initiation of Home Health Care

The demand for home health care services is increasing due to the growing aging population, rising rates of chronic conditions, and advances in the provision of health-related services in patients’ homes. In 2017, 11,844 home health agencies served 3.4 million Medicare beneficiaries at a cost of $17.7 billion.^29^

Figure 41 Home health patients who had timely initiation of care, 2013-2016

Line graph showing percentage 2015 Achievable Benchmark: 95% 2013, 91.3 2014, 91.4 2015, 92.1 2016, 93.3

Source: Centers for Medicare & Medicaid Services, Outcome and Assessment Information Set, 2013-2016.

- From 2013 to 2016, overall, the percentage of home health patients who had timely initiation of care increased from 91.3% to 93.3% (Figure 41).
- The 2015 top 5 state achievable benchmark was 95%. There is no evidence of progress toward the benchmark.
- The top 5 states that contributed to the achievable benchmark are Alabama, Louisiana, Nebraska, South Dakota, and West Virginia.

##### Communication About Discharge Information

Effective care coordination begins with ensuring that accurate clinical information is available to support medical decisions by patients and providers. A common transition of care is discharge from the hospital. Giving patients and caregivers self-management support after discharge has been shown to reduce readmissions to the hospital and lower costs.^30^

Figure 42 Adult hospital patients who did not receive good communication about discharge information, 2009-2017

Note: For this measure, lower rates are better.

Line graph showing percentage 2015 Achievable Benchmark: 8% 2009, 15.8 2010, 14.6 2011, 13.7 2012, 12.9 2013, 11.8 2014, 11.3 2015, 10.9 2016, 10.5 2017, 10.4

Source: Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems, 2009-2017.

- From 2009 to 2017, overall, the percentage of hospital patients who did not receive good communication about discharge information decreased from 15.8% to 10.4% (Figure 42).
- The 2015 top 5 state achievable benchmark was 8%. At the current rate of decrease, overall, the benchmark could be achieved in 4 years.
- The top 5 states that contributed to the achievable benchmark are Colorado, Nebraska, New Hampshire, South Dakota, and Utah.

##### Communication About Treatment From Other Doctors

Different providers may prescribe medications for the same patient. Patients are responsible for keeping track of all their medications, but medication information can be confusing, especially for patients on multiple medications. When care is not well coordinated and some providers do not know about all of a patient’s medications, patients are at greater risk for adverse events related to drug interactions, overdosing, or underdosing.

In addition, providers need to periodically review all of a patient’s medications to ensure that they are taking what is needed and only what is needed. Medication reconciliation has been shown to reduce both medication errors and adverse drug events.^31^

Figure 43 People with a usual source of care who usually asks about prescription medications and treatments from other doctors, 2002-2016

Line graph showing percentage 2002, 75.1 2003, 76.4 2004, 77.8 2005, 77.7 2006, 79 2007, 80.1 2008, 80.5 2009, 79.3 2010, 82.8 2011, 81.7 2012, 82.7 2013, 79.9 2014, 80 2015, 81 2016, 80.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- From 2002 to 2016, overall, the percentage of people with a usual source of care who usually asks about prescription medications and treatments from other doctors increased from 75.1% to 80.9% ((Figure 43).

##### Hospitalization of Home Health Patients

Acute care hospitalization is the hospital admission rate for Medicare beneficiaries receiving skilled home health benefits, and its reduction is seen as a way to improve quality and reduce healthcare costs. Nearly 20% of all Medicare beneficiaries discharged from hospitals are rehospitalized within 30 days and 34% are rehospitalized within 90 days.^32^

Figure 44 Home health care patients who had an emergency department visit and were then hospitalized, 2013-2016

Note: For this measure, lower rates are better. Benchmarks can include data from both states and territories.

Line graph showing percentage 2015 Achievable Benchmark: 14% 2013, 17.5 2014, 17.9 2015, 18.9 2016, 19.3

Source: Centers for Medicare & Medicaid Services, Outcome and Assessment Information Set, 2013-2016.

- From 2013 to 2016, overall, the percentage of home health care patients who had an emergency department visit and were then hospitalized increased from 17.5% to 19.3% (Figure 44).
- The 2015 top 5 state achievable benchmark was 14%. There is no evidence of progress toward the benchmark.
- The top 5 states and territories that contributed to the achievable benchmark are Colorado, Montana, South Dakota, Utah, and Virgin Islands.

##### Emergency Department Visits of Home Health Patients

Figure 45 Home health care patients who had an emergency department visit without a hospitalization, 2013-2016

Note: For this measure, lower rates are better. Benchmarks can include data from both states and territories.

Line graph showing percentage 2015 Achievable Benchmark: 3% 2013, 3.6 2014, 3.7 2015, 3.8 2016, 3.8

Source: Centers for Medicare & Medicaid Services, Outcome and Assessment Information Set, 2013-2016.

- From 2013 to 2016, overall, the percentage of home health care patients who had an emergency department visit without a hospitalization increased from 3.6% to 3.8% (Figure 45).
- The 2015 top 5 state achievable benchmark was 3%. There is no evidence of progress toward the benchmark.
- The top 5 states and territories that contributed to the achievable benchmark are District of Columbia, Florida, New Jersey, Puerto Rico, and Texas.

Efforts to promote care coordination are underway within HHS. For example:

- [underlined: The] Care Coordination Measures Atlas Update (https://www.ahrq.gov/professionals/prevention-chronic-care/improve/coordination/atlas2014/index.html) expands on the atlas first published in 2011. The updated compendium of care coordination measures offers new measures with a focus on those that reflect coordination efforts within the primary care setting and includes a section on emerging trends in care coordination measurement.
- Care Coordination Accountability Measures for Primary Care Practice (https://www.ahrq.gov/research/findings/final-reports/pcpaccountability/index.html) presents measures selected systematically from the Care Coordination Measures Atlas that are well suited for use by health plans and insurers to assess the quality of coordination in primary care practices and by primary care practices themselves to assess their own performance.
- [underlined: The] Care Coordination Quality Measure for Primary Care (https://www.ahrq.gov/professionals/prevention-chronic-care/improve/coordination/ccqmpc/index.html) (CCQM-PC) is a survey of adult patients’ experiences with care coordination in primary care settings. It was developed to comprehensively assess patient perceptions of the quality of their care coordination experiences. The CCQM-PC is designed to be used in primary care research and evaluation, with potential applications to primary care quality improvement. Guidance regarding the fielding of the survey is provided in addition to the full survey, which is in the public domain and may be used without additional permission.
- [underlined: The] Clinical-Community Relationships Measures Atlas (https://www.ahrq.gov/professionals/prevention-chronic-care/resources/clinical-community-relationships-measures-atlas/index.html) was developed to identify ways to further define, measure, and evaluate programs based on clinical-community relationships for the delivery of clinical preventive services. This atlas provides a measurement framework and lists existing measures of clinical-community relationships and is intended to support research and evaluation in the field.
- [underlined: The] Clinical-Community Relationships Evaluation Roadmap (https://www.ahrq.gov/professionals/prevention-chronic-care/resources/clinical-community-relationships-eval-roadmap/index.html)addresses clinical-community resource relationships for selected clinical preventive services, but the principles and questions offered may also apply to other clinical and nonclinical services. The roadmap also may apply to those interested in effective relationships and coordination between clinics and community organizations, such as schools or social service providers.

### Trends in Effective Treatment

As better understanding of health and sickness has led to superior ways of preventing, diagnosing, and treating diseases, the health of most Americans has improved dramatically. However, many Americans do not receive the full benefits of high-quality care.

#### Findings on Effective Treatment

The Effective Treatment priority area includes measures of the following:

- Cancer
  ■ Breast Cancer
  ■ Colorectal Cancer
  ■ Other Cancers
- Cardiovascular Disease
  ■ Prevention of Heart Disease
  ■ Treatment of Heart Attack
  ■ Treatment of Heart Failure
  ■ Surgery for Heart and Vascular Disease
  ■ Stroke
- Chronic Kidney Disease
  ■ Care of End Stage Renal Disease
- Diabetes
  ■ Management of Diabetes
  ■ Control of Diabetes
  ■ Hospitalizations for Diabetes
- HIV/AIDS
  ■ Management of HIV/AIDS
- Mental Health and Substance Abuse
  ■ Treatment of Depression
  ■ Treatment of Substance Abuse
- Musculoskeletal Disease
- Respiratory Diseases
  ■ Treatment of Respiratory Infections
  ■ Management of Asthma

Measures cover preventive care, treatment of illness, chronic disease management, and outcomes of care. Data for these measures can be found at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

Almost half of measures of Effective Treatment improved, nearly half did not change, and three got worse.

The three measures of Effective Treatment that showed the greatest improvement were measures related to the treatment of illness:

- Acute stroke patients for whom IV thrombolytic therapy was initiated at the hospital within 3 hours of time last known well
- Doctor’s office, emergency department, and outpatient department visits where antibiotics were prescribed for a diagnosis of common cold per 10,000 population
- Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined

The measures that worsened over time were related to mental health and substance abuse:

- Emergency department visits involving opioid-related diagnoses per 100,000 population
- Hospital inpatient stays involving opioid-related diagnoses per 100,000 population
- Suicide deaths among people age 12 and over per 100,000 population

##### Initiation of Thrombolytic Therapy for Stroke

Stroke is one of the most costly health problems affecting Americans and a leading cause of serious long-term disability in the United States.^33^ Multiple analyses have shown that treatment with tissue plasminogen activator (tPA) is cost-effective when administered within the first 3 hours after symptom onset.^34^ It is estimated that tPA treatment within 3 hours of symptom onset adds 0.75 quality-adjusted life years and saves $6,000 per patient treated.^35^

Figure 46 Acute stroke patients for whom IV thrombolytic therapy was initiated at the hospital within 3 hours of time last known well, 2013-2016

Line graph showing percentage 2015 achievable benchmark: 93% 2013, 68.5 2014, 79.9 2015, 85.5 2016, 87.9

Source: Centers for Medicare & Medicaid Services Clinical Data Warehouse, 2013-2016

- From 2013 to 2016, overall, the percentage of acute stroke patients for whom IV thrombolytic therapy was initiated at the hospital within 3 hours (less than or equal to 180 minutes) of time last known well increased from 68.5% to 87.9% (Figure 46).
- The 2015 top 5 state achievable benchmark was 93%. At the current rate of increase, overall, the benchmark could be achieved in 1 year.
- The top 5 states that contributed to the achievable benchmark are Colorado, Florida, Hawaii, Minnesota, and North Dakota.

##### Antibiotics for Common Cold

Most people around the world will have one or more common cold episodes every year. Except in low-income countries, the common cold is one of the most cited reasons for people to use antibiotics, even more so if the mucus from their nose is colored (acute purulent rhinitis). However, common colds are caused by viruses, which do not respond to antibiotics, and antibiotics can cause side effects, especially diarrhea. Overuse of antibiotics leads to bacteria becoming resistant to antibiotics.^36^

Figure 47 Doctor’s office, emergency department, and outpatient department visits where antibiotics were prescribed for a diagnosis of common cold per 10,000 population, 2010-2014

Note: For this measure, lower rates are better.

Line graph showing rate per 10,000 population 2010-2011, 108.8 2011-2012, 106 2012-2013, 72.4 2013-2014, 72.1

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Ambulatory Medical Care Survey and National Hospital Ambulatory Medical Care Survey, 2010-2014.

- From 2010 to 2014, overall, the rate of doctor’s office and emergency department visits where antibiotics were prescribed for a diagnosis of common cold per 10,000 population decreased from 108.8 to 72.1 per 10,000 population (Figure 47).

##### Surgical Resection of Colon Cancer

Approximately 75% of patients with colorectal cancer will present with potentially curable disease by surgical resection. In the absence of a distant metastasis, the regional lymph node (LN) status is the most important pathologic predictor of long-term survival in patients with colon cancer.

The number of LNs retrieved from a patient with colon cancer has been identified as a potentially important measure of the quality of cancer care by many organizations, including the American College of Surgeons, the American Society of Clinical Oncology, the National Comprehensive Cancer Network, and various health insurance providers. A minimum of 12 examined LNs at curative resection is now advocated as a quality measure and is recommended for proper staging.^37^

Figure 48 Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined, 2005-2015

Line graph showing percentage 2015 achievable benchmark: 95% 2005, 59.9 2006, 66.8 2007, 76.7 2008, 80.5 2009, 83.5 2010, 85.1 2011, 86.4 2012, 87.9 2013, 89.7 2014, 90.7 2015, 91.6

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2015.

- From 2005 to 2015, overall, the percentage of patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined increased from 59.9% to 91.6% (Figure 48).
- The 2015 top 5 state achievable benchmark was 95%. At the current rate of increase, overall, the benchmark could be achieved in 1 year.
- The top 5 states that contributed to the achievable benchmark are Iowa, Maine, Massachusetts, New York, and Wisconsin.

##### Emergency Department Visits Involving Opioids

The U.S. opioid overdose epidemic continues to evolve. In 2016, 66.4% of the 63,632 drug overdose deaths involved an opioid. In 2017, among 70,237 drug overdose deaths, 47,600 (67.8%) involved opioids, with increases across age groups, racial/ethnic groups, county urbanization levels, and multiple states. From 2013 to 2017, synthetic opioids contributed to increases in drug overdose death rates in several states. From 2016 to 2017, synthetic opioid-involved overdose death rates increased 45.2%.^38^

Figure 49 Emergency department visits involving opioid-related diagnoses per 100,000 population, 2005-2016

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population 2015 achievable benchmark: 62 per 100,000 population 2005, 89.1 2006, 91.8 2007, 82.6 2008, 94.1 2009, 107.4 2010, 117.5 2011, 131.2 2012, 146.8 2013, 166.2 2014, 177.7 2015, 210 2016, 243.5

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample and Nationwide Emergency Department Sample, 2005-2016.

- From 2005 to 2016, overall, the rate of emergency department visits related to opioid use per 100,000 population increased from 89.1 to 243.5 per 100,000 population (Figure 49).
- The 2015 top 3 state achievable benchmark was 62 per 100,000 population. There is no evidence of progress toward the benchmark.
- The top 3 states that contributed to the achievable benchmark are Iowa, Nebraska, and South Dakota.

##### Hospital Stays Involving Opioids

The National Survey on Drug Use and Health shows that in 2016, nearly 12 million people age 12 and over misused opioids in the past year.^39^

Figure 50 Hospital inpatient stays involving opioid-related diagnoses per 100,000 population

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population 2015 achievable benchmark: 103 per 100,000 population 2005, 136.8 2006, 164.2 2007, 159 2008, 165.7 2009, 181.4 2010, 197.1 2011, 207.8 2012, 210.4 2013, 213.7 2014, 224.6 2015, 252.5 2016, 296.9

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample and Nationwide Emergency Department Sample, 2005-2016.

- From 2005 to 2016, overall, the rate of hospital inpatient stays related to opioid use increased from 136.8 to 296.9 per 100,000 population (Figure 50).
- The 2015 top 5 state achievable benchmark was 103 per 100,000 population. There is no evidence of progress toward the benchmark.
- The top 5 states that contributed to the achievable benchmark are Georgia, Iowa, Nebraska, Texas, and Wyoming.

##### Suicide Deaths

Preventing suicide is a leading public health and research priority, but despite policy and clinical initiatives aimed at reducing suicide, the rate of suicide in the United States has increased.^40^ From 1999 to 2016, suicide rates increased significantly in 44 states, and 25 states experienced increases above 30%.41

Figure 51 Suicide deaths among people age 12 and over per 100,000 population, 2000-2016

Line graph showing rate per 100,000 population 2000, 10.4 2001, 10.7 2002, 10.9 2003, 10.8 2004, 13.2 2005, 13.2 2006, 10.9 2007, 11.3 2008, 14 2009, 14.2 2010, 14.6 2011, 14.9 2012, 15.2 2013, 15.2 2014, 15.7 2015, 16 2016, 16.3

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 2000-2016.

- From 2000 to 2016, overall, the rate of suicide increased from 10.4 per 100,000 population to 16.3 per 100,000 population (Figure 51).

Efforts to promote effective treatment are underway within HHS. For example:

- Six Building Blocks: A Team-Based Approach to Improving Opioid Management in Primary Care (https://www.ahrq.gov/professionals/prevention-chronic-care/improve/six-building-blocks.html). An AHRQ grantee developed a structured systems-based approach for primary care providers and their staff members to improve management of patients on chronic opioid therapy.
- The Academy: Integrating Behavioral Health and Primary Care (https://integrationacademy.ahrq.gov/). The Academy works to expand the integration of behavioral healthcare and primary care. It also supports those who are implementing medication-assisted treatment (MAT) in primary care settings by:
  ■ Providing technical assistance and support to the grantees funded by AHRQ’s Increasing Access to Medication-Assisted Treatment in Rural Primary Care Practices initiative.
  ■ Developing and disseminating resources and information to the broader audience of providers implementing MAT in rural primary care practices.
  The Academy site compiles links to websites, videos, and webinars that address opioids, including:
  ■ Search and Rescue (https://searchandrescueusa.org/) Link to Exit Disclaimer (https://www.ahrq.gov/externaldisclaimer.html), a website from the Partnership for Drug-Free Kids with tools and resources about prescription drug misuse to support healthcare providers and their patients.
  ■ Remaining Optimistic When Treating OUD Can Be Challenging (https://pcssnow.org/education-training/training-courses/how-to-remain-optimistic-when-treating-addiction/) Link to Exit Disclaimer (https://www.ahrq.gov/externaldisclaimer.html), a video from the Providers Clinical Support System that discusses the importance of provider optimism when providing substance use treatment.
  ■ Addressing Clinicians’ Concerns About Adding OUD Treatment (https://www.youtube.com/watch?v=xeMFKWaNm-E), a video from the Providers Clinical Support System that addresses providers’ concerns and hesitation to offer MAT for opioid use disorder.
  ■ The Opioid Crisis: Treating Addiction and Saving Lives (https://www.nihcm.org/topics/population-health/the-opioid-crisis-treating-addiction-and-saving-lives) Link to Exit Disclaimer (https://www.ahrq.gov/externaldisclaimer.html), a webinar from the National Institute for Health Care Management Foundation that examines ways to expand access to evidence-based treatment for opioid use disorder.
  ■ The Opioid Crisis: Understanding Pain and Preventing Opioid Misuse (https://www.nihcm.org/topics/population-health/the-opioid-crisis-understanding-pain-and-preventing-opioid-misuse) Link to Exit Disclaimer (https://www.ahrq.gov/externaldisclaimer.html), a webinar from the National Institute for Health Care Management Foundation that describes strategies to prevent opioid use disorder, including prescribing guidelines, collaborative partnerships, pain management alternatives, and education.
- Civil Rights and the Opioid Crisis (https://www.hhs.gov/civil-rights/for-individuals/special-topics/opioids/index.html), a public education campaign implemented by the HHS OCR to improve access to evidence-based opioid use disorder treatment and recovery services, such as MAT, by ensuring that covered entities know their obligations under federal nondiscrimination laws, including laws prohibiting discrimination on the basis of disability or limited English proficiency. The campaign includes a video by OCR Director Roger Severino, fact sheets, digital postcards, and a newsletter.
- How To Help Someone Thinking of Suicide (https://healthreach.nlm.nih.gov/document/117/How-to-Help-Someone-Thinking-of-Suicide), a one-page handout available in 10 languages that teaches people how to help someone thinking of suicide. It identifies signs, symptoms, and behaviors of someone who may be thinking of suicide. It also provides a list of actions people can take to assist a person in crisis. Finally, the handout provides the phone number and web link for the Suicide Prevention Lifeline.
- Preventing Suicide: A Technical Package of Policy, Programs, and Practices (https://www.cdc.gov/violenceprevention/pdf/suicidetechnicalpackage.pdf), a select group of strategies based on the best available evidence to help communities and states sharpen their focus on prevention activities with the greatest potential to prevent suicide. These strategies include strengthening economic supports; strengthening access and delivery of suicide care; creating protective environments; promoting connectedness; teaching coping and problem-solving skills; identifying and supporting people at risk; and lessening harms and preventing future risk.

### Trends in Healthy Living

Many illnesses associated with chronic conditions are related to unhealthy behaviors, environmental hazards, and poor social supports and can be prevented by increasing access to effective clinical preventive services and promoting community interventions that advance public and population health. Working with communities is critical to ensure that immunizations and early detection and prevention services reach everyone who needs them and to build healthy neighborhoods and support networks.

Promoting healthy lifestyles that prevent disease and disability is better for people and more efficient than treating conditions after organ damage has been done.

#### Importance of Healthy Living

##### Morbidity and Mortality

Advances in medical science protect children against more diseases than ever before. Some diseases that once injured or killed thousands of children have been eliminated completely and others are close to eradication, primarily due to safe and effective vaccines. Polio is one example of the great impact that vaccines have had in the United States. Polio was once America’s most feared disease, causing death and paralysis across the country, but today, thanks to vaccination, there are no reports of polio in the United States.

Measles vaccination has prevented an estimated 21 million deaths worldwide since 2000. Despite these substantial gains, global elimination goals have not been met, and previous strides are now threatened by a 31% increase in the number of measles cases reported globally between 2016 and 2017.^42^ According to the Centers for Disease Control and Prevention (CDC), from January 1 to July 3, 2019, 1,109 individual cases of measles were confirmed in 28 states.^ix^ This is the greatest number of cases reported in the United States since 1994 and since measles was declared eliminated in 2000.

##### Cost

It is much cheaper to prevent a disease using immunization than to treat it. In a 2005 study on the economic impact of routine childhood immunization in the United States, researchers estimated that for every dollar spent, the vaccination program saved more than $5 in direct costs and approximately $11 in additional costs to society.^43^

#### Findings on Healthy Living

The Healthy Living priority area includes measures of:

- Maternal and Child Health.
- Lifestyle Modification.
- Functional Status Preservation and Rehabilitation.
- Supportive and Palliative Care.
- Clinical Preventive Services.

Data for these measures can be found at https://nhqrnet.ahrq.gov/inhqrdr/data/query.

Most Healthy Living measures improved, and only two were getting worse.

The top Healthy Living measures that showed improvement over time were vaccination measures:

- Adolescents ages 13-15 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of 10 years
- Adolescents ages 16-17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of 10 years
- Adolescents ages 16-17 who received 1 or more doses of meningococcal conjugate vaccine
- Hospital patients who received influenza vaccination

Two Healthy Living measures worsened over time and both were cancer screening measures:

- Women ages 21-65 who received a Pap test in the last 3 years
- Women ages 50-74 who received a mammogram in the last 2 years

##### Adolescent Tdap Vaccination

CDC’s Advisory Committee on Immunization Practices (ACIP) recommends routine vaccination for tetanus, diphtheria, and pertussis. Infants and young children are recommended to receive a 5-dose series of diphtheria and tetanus toxoids and acellular pertussis (DTaP) vaccines, with one adolescent booster dose of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) vaccine. CDC found that the cost per quality-adjusted life-year saved ranged from $30,946 to $62,716 and cost per case averted ranged from $1,966 to $3,263.^44^

Figure 52A Adolescents ages 13-15 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of 10 years, 2008-2016

Line graph showing percentage 2015 achievable benchmark: 96% 2008, 46.7 2009, 62.2 2010, 74.2 2011, 80.5 2012, 85.3 2013, 87.5 2014, 88.3 2015, 87.1 2016, 88

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2016.

Figure 52B Adolescents ages 16-17 who received 1 or more doses of tetanus toxoid, reduced diphtheria toxoid, and acellular pertussis (Tdap) since the age of 10 years, 2008-2016

Line graph showing percentage 2015 achievable benchmark: 96% 2008, 31.9 2009, 45.3 2010, 60.2 2011, 74.8 2012, 83.6 2013, 83.7 2014, 86.6 2015, 85.3 2016, 88

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2016.

- From 2008 to 2016, overall, the percentage of adolescents ages 13-15 years who received 1 or more doses of Tdap vaccine increased from 46.7% to 88.0% (Figure 52A).
- From 2008 to 2016, overall, the percentage of adolescents ages 16-17 years who received 1 or more doses of Tdap vaccine increased from 31.9% to 88.0% (Figure 52B).
- The 2015 top 5 state achievable benchmark was 96%. At the current rate of increase, overall, the benchmark could be achieved in 1 year.
- The top 5 states that contributed to the achievable benchmark are Alabama, Georgia, Missouri, Rhode Island, and Vermont.

##### Adolescent Meningococcal Vaccine

ACIP recommends that adolescents and young adults ages 16-23 years be vaccinated with a serogroup B meningococcal (MenB) vaccine to provide short-term protection against most strains of this disease.^45^

Figure 53 Adolescents ages 16-17 years who received 1 or more doses of meningococcal conjugate vaccine, 2008-2016

Line graph showing percentage 2015 achievable benchmark: 96% 2008, 38.6 2009, 51.8 2010, 59.5 2011, 69 2012, 74.4 2013, 77.3 2014, 79.1 2015, 81.9 2016, 82.9

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2016.

- From 2008 to 2016, overall, the percentage of adolescents ages 16-17 years who received 1 or more doses of meningococcal conjugate vaccine increased from 38.6% to 82.9% (Figure 53).
- The 2015 top 5 state achievable benchmark was 96%. At the current rate of increase, overall, the benchmark could be achieved in 3 years.
- The top 5 states that contributed to the achievable benchmark are Indiana, Michigan, New Jersey, Pennsylvania, and Rhode Island.

##### Influenza Vaccination

Influenza vaccination is the primary method for preventing the illness and its severe complications, and annual vaccination is recommended for everyone age 6 months and over.^46^ All healthcare contacts, including hospitalizations, provide excellent opportunities for vaccination, particularly for people at the highest risk for complications and death from influenza.

ACIP recommends that eligible hospitalized patients receive the influenza vaccine before discharge.^46^ This preventive strategy is measured in quality metrics of inpatient immunization by the Joint Commission and the Centers for Medicare & Medicaid Services.

Figure 54 Hospital patients who received influenza vaccination, 2012-2016

Line graph showing percentage 2015 achievable benchmark: 97% 2012, 87.2 2013, 92.2 2014, 93.8 2015, 94.1 2016, 93.5

Source: Centers for Medicare & Medicaid Services Clinical Data Warehouse, 2012-2016.

- From 2012 to 2016, overall, the percentage of hospital patients who received influenza vaccination increased from 87.2% to 93.5% (Figure 54).
- The 2015 top 5 state achievable benchmark was 97%. There is no significant progress toward the benchmark.
- The top 5 states that contributed to the achievable benchmark are Florida, Indiana, Maryland, North Carolina, and South Carolina.

##### Receipt of Pap Test

The United States Preventive Services Task Force recommends cervical cancer screening as part of routine health maintenance for women ages 21 through 65. Cervical cancer incidence and mortality rates have declined since the introduction of the Pap test in the mid-20th century, and rates continue to decline to this day.^47^

Figure 55 Women ages 21-65 who received a Pap test in the last 3 years, 2000-2015

Note: NHIS cancer supplement is not administered annually.

Line graph showing percentage 2015 achievable benchmark: 87% 2000, 87.5 2005, 85.3 2008, 84.5 2010, 82.8 2013, 80.7 2015, 81.2

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2000-2015.

- From 2000 to 2015, overall, the percentage of women ages 21-65 who received a Pap test in the last 3 years decreased from 87.5% to 81.2% (Figure 55).
- The 2014 top 5 state achievable benchmark was 87%. There is no evidence of progress toward the benchmark.
- The top 5 states that contributed to the achievable benchmark are Connecticut, Delaware, Maryland, Massachusetts, and Wisconsin.

##### Receipt of Mammogram

Breast cancer screening is used to identify women with asymptomatic cancer with the goal of enabling women to undergo less invasive treatments that lead to better outcomes, ideally at earlier stages and before the cancer progresses.

Figure 56 Women ages 50-74 who received a mammogram in the last 2 years, 2000-2015

Note: NHIS cancer supplement is not administered annually.

Line graph showing percentage 2014 achievable benchmark: 85% 2000, 77.2 2003, 75.7 2005, 72 2008, 73.7 2010, 72.4 2013, 72.6 2015, 71.6

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2000-2015.

- From 2000 to 2015, overall, the percentage of women ages 50-74 who received a mammogram in the last 2 years decreased from 77.2% to 71.6% (Figure 56).
- The 2014 top 5 state achievable benchmark was 85%. There is no evidence of progress toward the benchmark.
- The top 5 states that contributed to the achievable benchmark are Connecticut, Delaware, Maryland, Massachusetts, and Rhode Island.

Efforts to promote healthy living treatment are underway within HHS. For example:

■ Strategy 6R: Reminder Systems for Immunizations and Preventive Services (https://www.ahrq.gov/cahps/quality-improvement/improvement-guide/6-strategies-for-improving/health-promotion-education/strategy6r-reminder-systems.html) includes reminder systems for patients and reminder systems for clinicians.

## DISPARITIES IN HEALTHCARE

Healthcare is not experienced equitably by all populations. A healthcare disparity is a difference between population groups in the way they access, experience, and receive healthcare. Factors that influence healthcare disparities include social, economic, environmental, and other disadvantages,^48,49^ some of which are explored in this report.

In 2001, the National Academies of Medicine identified disparities in its publication Crossing the Quality Chasm: A New Health System for the 21st Century.^4^ As depicted in the exhibit below, in addition to a quality chasm, a disparities chasm exists and this gap widens for many specific populations. To improve healthcare delivery, access, and overall quality, a holistic and person-centered understanding of the barriers and limitations for each population is needed.

Exhibit Linking the Disparities and Quality Chasms

Diagram showing the gap between care for disadvantaged people and advantaged people. Factors contributing to disparities include inequitable access, insurance, poverty, language, culture, and bias. Disadvantaged people receive care that is ineffective, unsafe, not timely, not patient centered, and inefficient. There is a larger quality chasm for disadvantaged people due to poor quality and disparities.

Source: Based on Institute of Medicine. Crossing the Quality Chasm: A New Health System for the 21st Century. Washington, DC: The National Academies Press; 2001. 10.17226/10027 .

The Disparities in Healthcare section of the 2018 QDR examines the best and worst performing quality measures among the measures used in the report. These quality measures are analyzed in this section of the report by race and ethnicity, income, insurance status, and residence location. While these categories are broad, each section begins with key definitions to orient readers and includes analyses showing quality measure performance in the latest data year and analyses showing whether disparities were widening or narrowing over time.

To learn more about the measures included in this section of the report, refer to Appendix A. Readers interested in stratifying QDR data by other variables such as education, sex, age, and more may use the QDR Data Query Tool to access the data directly (https://nhqrnet.ahrq.gov/inhqrdr/data/query).

### Racial and Ethnic Disparities

Researchers, patients, providers, and policymakers have worked to identify, understand, and eliminate the disparities experienced by different racial and ethnic groups across the healthcare system. In 1985, the Department of Health and Human Services published the Report of the Secretary’s Task Force on Black and Minority Health (Heckler Report), which marked the first comprehensive study of racial and minority health by the U.S. government.^50^ Since then, the Department, along with other stakeholders, has continued this work, including throughout the QDR. The growing evidence base shows that patients of different racial and ethnic groups experience quality of care inequitably and disparately.^51,52^

Racial and ethnic groups are defined according to Standards for the Classification of Federal Data on Race and Ethnicity, issued by the Office of Management and Budget (available at https://www.gpo.gov/fdsys/granule/FR-1997-10-30/97-28653).

The basic racial and ethnic categories for federal statistics and program administrative reporting are defined as follows:

1. American Indian or Alaska Native (AI/AN). A person having origins in any of the original peoples of North and South America (including Central America) and who maintains tribal affiliation or community attachment.
2. Asian. A person having origins in any of the original peoples of the Far East, Southeast Asia, or the Indian subcontinent, including, for example, Cambodia, China, India, Japan, Korea, Malaysia, Pakistan, the Philippine Islands, Thailand, and Vietnam.
3. Black or African American. A person having origins in any of the black racial groups of Africa. Terms such as “Haitian” can be used in addition to “Black or African American.”
4. Hispanic or Latino. A person of Cuban, Mexican, Puerto Rican, Central or South American, or other Spanish culture or origin, regardless of race. The term “Spanish origin” can be used in addition to “Hispanic or Latino.”
5. Native Hawaiian/Pacific Islander (NHPI). A person having origins in any of the original peoples of Hawaii, Guam, Samoa, or other Pacific Islands.
6. White. A person having origins in any of the original peoples of Europe, the Middle East, or North Africa.

This section presents three types of findings related to disparities for each population:

1. Largest disparities for a single data year, focusing on the most recent data year.
2. Trends in quality of care (number of measures improving, not changing, and worsening) for the population group.
3. Comparison with the reference group, focusing on the change in the gap between the two groups.

### Overview of Racial and Ethnic Disparities

Figure 57 Number and percentage of quality measures for which members of selected groups experienced better, same, or worse quality of care compared with reference group (White), 2013, 2015, 2016, or 2017

Key: n = number of measures; NHPI = Native Hawaiian/Pacific Islander; AI/AN = American Indian or Alaska Native.

Note: The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from NIDDK USRDS is 2013 and from AHRQ HCUP is 2016.

Stacked bar chart showing number of quality measures Black (n=190), Better, 28, Same, 86, Worse, 76 Asian (n=172), Better, 48, Same, 77, Worse, 47 AI/AN (n=106), Better, 14, Same, 50, Worse, 42 NHPI (n=57), Better, 8, Same, 26, Worse, 23 Hispanic, All Races (n=167), Better, 39, Same, 70, Worse, 58

- Figure 57 features quality measures that show whether Black, Asian, AI/AN, NHPI, and Hispanic populations were performing better, same, or worse than White populations in the latest data year.
- Data for the most recent year show that quality measures were worse for Blacks than Whites for 40% of quality measures. Whites also performed better on quality measures compared with Asians (27%), AI/ANs (40%), NHPIs (40%), and Hispanics (35%).
- Asians performed better than Whites on 28% of quality measures; however, most populations had lower percentages. Blacks, AI/ANs, and NHPIs performed better on less than 15% of all measures. Hispanics performed better than Whites on 23% of all reported quality measures.

Figure 58 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, 2000 through 2013, 2014, 2015, 2016, or 2017

Key: n = number of measures; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: There were no worsening disparities over time observed for Blacks, AI/ANs, and NHPIs in this year’s analysis.

Stacked bar chart showing number of quality measures Black (n=56), Improving, 4, Not Changing, 52, Worsening, 0 Asian (n=32), Improving, 2, Not Changing, 29, Worsening, 1 AI/AN (n=33), Improving, 2, Not Changing, 31, Worsening, 0 NHPI (n=12), Improving, 1, Not Changing, 11, Worsening, 0 Hispanic, All Races (n=49), Improving, 5, Not Changing, 42, Worsening, 2

Quality measures with disparities at baseline were analyzed to see if disparities related to race and ethnicity were narrowing (improving), widening (worsening), or not changing:

- In this year’s analyses, only one quality measure for Asians (“Home health care patients whose management of oral medications improved”) and two quality measures for Hispanics showed a worsening disparity over time (“Home health patients who had improvement in upper body dressing” and “Home health care patients whose ability to walk or move around improved”) (Figure 58).
- Fewer quality measures are available for select subpopulations, overall. The percentage of quality measures with disparities at baseline that improved over time was 10% for Hispanics, 8% for NHPIs, 7% for Blacks, 6% for Asians, and 6% for AI/ANs.

Due to the nationwide conversion from the International Classification of Diseases, Ninth Revision (ICD-9) to the Tenth Revision (ICD-10) codes in the last quarter of 2015, at this time, we cannot trend the data for some AHRQ Quality Indicators that are based on nationwide Healthcare Cost and Utilization Project (HCUP) data. Measures that have been included in past reports are not always represented in this year’s report. Wherever this situation applies, this report includes a footnote.

### Disparities for Blacks

In 2016, Blacks were more than seven times as likely as Whites to die from an HIV infection.

Figure 59 Number and percentage of quality measures for which Blacks experienced better, same, or worse quality of care compared with reference group (White), 2013, 2015, 2016, or 2017

Key: n = number of measures.

Note: The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from NIDDK USRDS is 2013 and from AHRQ HCUP is 2016.

Stacked bar chart showing number of quality measures Total (n=190), Better, 28, Same, 86, Worse, 76 Person-Centered Care (n=27), Better, 3, Same, 13, Worse, 11 Patient Safety (n=31), Better, 8, Same, 15, Worse, 8 Healthy Living (n=60), Better, 5, Same, 29, Worse, 26 Effective Treatment (n=42), Better, 8, Same, 19, Worse, 15 Care Coordination (n=25),Better, 3, Same, 6, Worse, 16 Affordable Care (n=5), Better, 1, Same, 4, Worse, 0

- Data for the most recent year show that quality was better for Whites than for Blacks on 40% of all quality measures and that quality was better for Blacks than for Whites on 15% of all quality measures (Figure 59).

#### Largest Disparities

The measures with the largest disparities for Blacks include:

- New HIV cases per 100,000 population age 13 and over.
- HIV infection deaths per 100,000 population.
- Hospital admissions for asthma per 100,000 population, children ages 2-17.

##### New HIV Cases

According to CDC research, in 2017, Blacks accounted for 13% of the nation’s population and represented 43% of all new HIV cases. Most of these cases affect Black male adolescents and adults.^53^ The Office of Minority Health reports that in 2016, for every one White male, an estimated 7.8 African American males received a new HIV diagnosis.^54^

Figure 60 New HIV cases per 100,000 population age 13 and over, 2015

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population 2015 achievable benchmark: 4.2 per 100,000 population Total, 14.8 Non-Hispanic Black, 53.1 Non-Hispanic White, 6.1

Source: Centers for Disease Control and Prevention, HIV AIDS Surveillance System, 2015.

- In 2015, non-Hispanic Blacks reported 53.1 new HIV cases per 100,000 population for people age 13 and over compared with 6.1 per 100,000 cases for non-Hispanic Whites (Figure 60).
- The 2015 top 5 state achievable benchmark was 4.2 per 100,000 population. There is no evidence of progress toward the benchmark.
- The top 5 states that contributed to the achievable benchmark are Idaho, Iowa, Maine, West Virginia, and Wisconsin.

In 2019, the administration announced a Presidential initiative to end the HIV epidemic in the United States. The Department of Health and Human Services has committed to “reducing new infections by 75 percent in the next five years and by 90 percent in the next ten years.”^55^ The Department’s website www.hiv.gov also outlines key resources for patients, provides data, and details programs supporting a federal response to the epidemic.

##### HIV Infection Deaths

HIV mortality disproportionately affects some racial and ethnic groups more than others. According to CDC data, in 2016, HIV was the sixth leading cause of death for Black men ages 25-34 and fifth for Black women ages 35-44.^56^

Figure 61 HIV infection deaths per 100,000 population, 2016

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population 2016 achievable benchmark: 0.75 per 100,000 population Total, 1.8 Non-Hispanic Black, 7.2 Non-Hispanic White, 1

Source: Centers for Disease Control and Prevention, National7 Vital Statistics System-Mortality, 2016.

- In 2016, Blacks had 7.2 HIV infection deaths per 100,000 population compared with 1.0 per 100,000 cases for Whites (Figure 61). These cases represent mortality for which HIV was the leading cause of death.
- The 2016 top 5 state achievable benchmark was 0.75 per 100,000 population. There is no evidence of progress toward the benchmark.
- The states that contributed to the achievable benchmark are Colorado, Massachusetts, Michigan, Minnesota, Missouri, Oregon, Washington, and Wisconsin (more than 5 states contributed to the benchmark due to ties).

Federal efforts to reduce mortality include the promotion of treatment therapies, such as antiretroviral therapy, pre-exposure prophylaxis, and postexposure prophylaxis.^57^ Several HHS agencies provide a federal response to the HIV epidemic, including HRSA’s HIV/AIDS Bureau, which administers the Ryan White HIV/AIDS Program (RWHAP). This is the largest federal program focused exclusively on providing HIV care and treatment to patients with inadequate or no insurance. Through RWHAP’s partnerships, more than 512,000 people receive care annually.^58^

##### Hospital Admissions for Asthma

Asthma is the most common chronic lung condition among children under 17 years in the United States. Asthma has no cure and without treatment, patients can die.^59^ CDC research shows that from 2001 to 2016, 8% fewer children experienced one or more asthma attacks. Nonetheless, in 2016, one in 12 children ages 0-17 had asthma and among them, asthma disproportionately affected males, non-Hispanic Black children, and children from low-income households.^60^

Figure 62 Hospital admissions for asthma per 100,000 population, children ages 2-17, 2016

Note: For this measure, lower rates are better.

Columns showing rate per 100,000 population Total, 86.1 Non-Hispanic Black, 220.8 Non-Hispanic White, 45.9

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2016.

- In 2016, non-Hispanic Blacks reported 220.8 children (ages 2-17) per 100,000 population were admitted to the hospital for asthma compared with 45.9 per 100,000 cases for non-Hispanic Whites (Figure 62).

Federal resources to reduce asthma prevalence include CDC’s National Asthma Control Program. This program funds states, schools, and nonprofits to support improved asthma surveillance, training, and education activities.^61^ In 1989, the National Heart, Lung, and Blood Institute of the National Institutes of Health established the National Asthma Education and Prevention Program (https://www.nhlbi.nih.gov/science/national-asthma-education-and-prevention-program-naepp) (NAEPP). NAEPP oversees the development of asthma guidelines, creates tools and materials to put guidelines into practice, coordinates federal asthma-related activities, and builds partnerships.

#### Trends in Quality of Care for Blacks

Figure 63 Number and percentage of all quality measures that were improving, not changing, or worsening, total for Blacks and by priority area, 2000 through 2013, 2015, 2016, or 2017

Key: n = number of measures.

- Improving = Quality is going in a positive direction at an average annual rate greater than 1% per year.
- Not changing = Quality is not changing or is changing at an average annual rate of 1% or less per year.
- Worsening = Quality is going in a negative direction at an average annual rate greater than 1% per year.

Stacked bar chart showing number of quality measures Total (n=139), Improving, 76, Not Changing, 53, Worsening, 10 Person-Centered Care (n=19), Improving, 11, Not Changing, 7, Worsening, 1 Patient Safety (n=15), Improving, 7, Not Changing, 7, Worsening, 1 Healthy Living (n=59), Improving, 34, Not Changing, 24, Worsening, 1 Effective Treatment (n=32), Improving, 18, Not Changing, 11, Worsening, 3 Care Coordination (n=9), Improving, 5, Not Changing, 1, Worsening, 3 Affordable Care (n=5), Improving, 1, Not Changing, 3, Worsening, 1

- Across the 139 measures of healthcare quality tracked in the report for Blacks, 55% showed improvement, 38% remained unchanged, and 7% were getting worse from 2000 to 2017 (Figure 63).^x^
- Affordable Care showed the least improvement (20% of measures).

#### Changes in Disparities for Blacks

Figure 64 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, total for Blacks and by priority area, 2000 through 2013, 2014, 2015, 2016, or 2017

Key: n = number of measures.

Stacked bar chart showing number of quality measures Total (n=56), Improving, 4, Not Changing, 52, Worsening, 0 Person-Centered Care (n=6), Improving, 0, Not Changing, 6, Worsening, 0 Patient Safety (n=2), Improving, 0, Not Changing, 2, Worsening, 0 Healthy Living (n=26), Improving, 0, Not Changing, 26, Worsening, 0 Effective Treatment (n=16), Improving, 4, Not Changing, 12, Worsening, 0 Care Coordination (n=5), Improving, 0, Not Changing, 5, Worsening, 0 Affordable Care (n=1), Improving, 0, Not Changing, 1, Worsening, 0

- From 2000 to 2017, few disparities in quality of care faced by Blacks were getting smaller (Figure 64). Of 56 quality measures for which a disparity existed at baseline, only 4 showed a narrowing disparity:
  ■ New HIV cases per 100,000 population age 13 and over.
  ■ HIV infection deaths per 100,000 population.
  ■ Hospital patients with heart attack given fibrinolytic medication within 30 minutes of arrival.
  ■ Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population.
- Most disparities were not changing, and none were widening.

##### New HIV Cases

Figure 65 New HIV cases per 100,000 population age 13 and over, 2008-2015

Note: For this measure, lower rates are better.

Line graph showing the rate per 100,000 population going from 74.8 for Blacks and 7.6 for Whites to 53.1 for Blacks and 6.1 for Whites 2015 achievable benchmark: 4.2 per 100,000 population

Source: Centers for Disease Control and Prevention, HIV-AIDS Surveillance System, 2008-2015.

- Data from 2008 to 2015 show that the disparity between Blacks and Whites is narrowing, but Blacks are still experiencing a much higher rate of new HIV cases (53.1 per 100,000 population in 2015) compared with Whites (6.1 per 100,000 population in 2015; Figure 65) and other racial and ethnic groups (data not shown).
- The 2015 top 5 state achievable benchmark was 4.2 per 100,000 population. At the current rate of increase, overall, the benchmark could be achieved in 16 years.
- The top 5 states that contributed to the achievable benchmark are Idaho, Iowa, Maine, West Virginia, and Wisconsin.

##### HIV Infection Deaths

Figure 66 HIV infection deaths per 100,000 population, 2000-2016

Note: For this measure, lower rates are better.

Line graph showing the rate per 100,000 population going from 23.3 for Blacks and 2.8 for Whites to 7.2 for Blacks and 1 for Whites 2015 achievable benchmark: 0.75 per 100,000 population

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 2000-2016.

- Data from 2000 to 2016 show that the disparity between Blacks and Whites is narrowing, but Blacks are still experiencing a much higher rate of HIV infection deaths (7.2 per 100,000 population in 2016) compared with Whites (1.0 per 100,000 population in 2016; Figure 66) and other racial and ethnic groups (data not shown).
- The 2015 top 5 state achievable benchmark was 0.75 per 100,000 population. At current rates of improvement, Whites could reach the benchmark in 2 years and Blacks in 6 years.
- The top 5 states that contributed to the achievable benchmark are Colorado, Minnesota, Oregon, Washington, and Wisconsin.

##### Fibrinolytic Medication for Heart Attack

Figure 67 Hospital patients with heart attack given fibrinolytic medication within 30 minutes of arrival, 2005-2015

Note: Data for Blacks in 2014 and 2015 do not meet the criteria for statistical reliability, data quality, or confidentiality.

Line graph showing percentage as 27.7 for Blacks and 38.7 for Whites in 2005 and 51.4 for Blacks and 55.9 for Whites in 2013. Data for Whites are also shown for 2014 (60.5) and 2015 (57.1).

Source: Centers for Medicare & Medicaid Services Clinical Data Warehouse for Hospital Inpatient Quality Reporting Program, 2005-2015.

- Data from 2005 to 2013 show that the disparity between Blacks and Whites is narrowing, but Blacks are still experiencing a lower percentage of patients with heart attack getting timely fibrinolytic medication (Figure 67).

Figure 68 Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population, 2001-2016

Note: For this measure, lower rates are better.

Line graph showing rate per million population going from 525.7 for Blacks and 133.3 for Whites in 2001 to 391.3 for Blacks and 144.9 for Whites in 2016

Source: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases, U.S. Renal Data System, 2001-2016.

- Data from 2001 to 2016 show that the disparity between Blacks and Whites is narrowing, but Blacks are still experiencing a higher rate of ESRD due to diabetes (Figure 68).

### Disparities for Asians

From 2000 to 2015, more Asians became aware of their HIV serostatus (70.5% to 80.4%).

Figure 69 Number and percentage of quality measures for which Asians experienced better, same, or worse quality of care compared with reference group (White) in 2013, 2015, 2016, or 2017

Key: n = number of measures.

Note: The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from NIDDK USRDS is 2013 and from AHRQ HCUP is 2016.

Stacked bar chart showing number of quality measures Total (n=172), Better, 48, Same, 77, Worse, 47 Person-Centered Care (n=29), Better, 1, Same, 10, Worse, 18 Patient Safety (n=28), Better, 8, Same, 12, Worse, 9 Healthy Living (n=52), Better, 13, Same, 30, Worse, 9 Effective Treatment (n=36), Better, 9, Same, 30, Worse, 7 Care Coordination (n=24),Better, 16, Same, 4, Worse, 4 Affordable Care (n=3), Better, 1, Same, 2, Worse, 0

- Data for the most recent year show that quality was better for Whites than for Asians on 27% of all quality measures and that quality was better for Asians than for Whites on 28% of all quality measures (Figure 69). This sample includes the latest data year for all HCUP measures.

#### Largest Disparities

The measures with the largest disparities for Asians include:

- Hospital patients with an anticoagulant-related adverse drug event to low-molecular-weight heparin (LMWH) and factor Xa.
- Adults who reported that home health providers always treated them with courtesy and respect in the last 2 months of care.
- Adults with limited English proficiency and a usual source of care (USC) whose USC had language assistance.

##### Anticoagulant-Related Adverse Drug Events

Thromboembolic disorders such as venous thromboembolism, deep vein thrombosis, and pulmonary embolism are examples of preventable adverse events that hospital patients may experience during the course of their inpatient care. Medications such as LMWH thrombosis inhibitors and factor Xa inhibitors help patients treat and prevent these disorders. Nonetheless, sometimes adverse events related to these medications may occur. Heparin is among the highest risk medications and incorrect prescribing or administration of this medicine may result in an adverse event.^62^

Figure 70 Hospital patients with an anticoagulant-related adverse drug event to low-molecular-weight heparin (LMWH) and factor Xa, 2015

Note: For this measure, lower rates are better.

Column chart showing percentage Total, 3.0 Asian, 11.4 White, 2.7

Source: Centers for Medicare & Medicaid Services and Agency for Healthcare Research and Quality, Medicare Patient Safety Monitoring System, 2015.

- In 2015, 11.4% of Asian hospital patients experienced an adverse drug event related to LMWH and factor Xa compared with 2.7% of White patients (Figure 70).

The HHS National Action Plan for Adverse Drug Event Prevention outlines specific strategies to reduce ADEs associated with anticoagulant drugs and therapies.^63^

##### Treatment by Home Health Providers

Home health providers are committed to delivering high-quality and compassionate care and services to patients in a manner that supports each patient’s respect and dignity. Home health performance is examined through several types of quality measures that look at areas such as efficiency, patient safety, and patient-centered care. Evaluation of patient experience of care is conducted with the Consumer Assessment of Healthcare Providers and Systems Home Health Care Survey.^64^

Figure 71 Adults who reported that home health providers always treated them with courtesy and respect in the last 2 months of care, 2017

Column chart showing percentage 2017 achievable benchmark: 95% Total, 93.5 Asian, 84.3 White, 94.2

Source: Agency for Healthcare Research and Quality, Home Health Consumer Assessment of Healthcare Providers and Systems, 2017.

- In 2017, fewer Asian adults (84.3%) reported that home health providers always treated them with courtesy and respect in the last 2 months compared with 94.2% of White adults (Figure 71).
- The 2017 top 5 state achievable benchmark was 95%. There is no evidence of progress toward the benchmark.
- The top states that contributed to the achievable benchmark are Alabama, Kentucky, Louisiana, Mississippi, South Carolina, and West Virginia (more than 5 states contributed to the benchmark due to ties).

##### Providers With Language Assistance

Current research shows that Asians continue to experience health disparities in several quality areas, including patient-centered care and satisfaction.^65^ Adults who have limited English proficiency may experience disparities in their care and gaps in communication with their healthcare team.^66^

According to the Migration Policy Institute, in 2013, an estimated 25.1 million individuals living in the United States reported having limited English proficiency.^67^ “More than one in four people aged 5 and over with LEP are born in the U.S.”^68^ Language assistance such as access to translation services, health education materials written in a known language, and other resources are required by law, but not all patients have access to these services at their usual source of care.^69^

Figure 72 Adults with limited English proficiency and usual source of care (USC) whose USC had language assistance, 2016

Column chart showing percentage Total, 94.1 Asian, 89.2 White, 95.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, 89.2% of Asian adults with limited English proficiency had a usual source of care that offered language assistance compared with 95.9% of White adults (Figure 72).

The Limited English Proficiency website69 offers a repository of resources collated by the Department of Justice to support improved communication with patients. AHRQ has also established a Limited English Proficiency module as part of its TeamSTEPPS® training that shows the importance of language assistance services in keeping patients safe and avoiding adverse events.^70^

#### Trends in Quality of Care for Asians

Figure 73 Number and percentage of all quality measures that were improving, not changing, or worsening, total for Asians and by priority area, from 2000 through 2011, 2013, 2014, 2015, 2016, or 2017

Key: n = number of measures.

- Improving = Quality is going in a positive direction at an average annual rate greater than 1% per year.
- Not changing = Quality is not changing or is changing at an average annual rate of 1% or less per year.
- Worsening = Quality is going in a negative direction at an average annual rate greater than 1% per year.

Stacked bar chart showing number of quality measures Total (n=113), Improving, 64, Not Changing, 43, Worsening, 6 Person-Centered Care (n=19), Improving, 13, Not Changing, 6, Worsening, 0 Patient Safety (n=9), Improving, 2, Not Changing, 6, Worsening, 1 Healthy Living (n=50), Improving, 34, Not Changing, 16, Worsening, 1 Effective Treatment (n=24), Improving, 13, Not Changing, 10, Worsening, 1 Care Coordination (n=8), Improving, 3, Not Changing, 3, Worsening, 2 Affordable Care (n=3), Improving, 0, Not Changing, 2, Worsening, 1

- Across the 113 measures of healthcare quality tracked in the report for Asians, 57% were improving, 38% were not changing, and 5% were getting worse from 2000 to 2017 (Figure 73).^xi^
- Affordable Care (no measures) and Patient Safety (22% of measures) showed the least improvement.

#### Changes in Disparities for Asians

Figure 74 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, total for Asians and by priority area, 2000 through 2013, 2015, 2016, or 2017

Key: n = number of measures.

Stacked bar chart showing number of quality measures Total (n=32), Improving, 2, Not Changing, 29, Worsening, 1 Person-Centered Care (n=13), Improving, 0, Not Changing, 13, Worsening, 0 Patient Safety (n=1), Improving, 0, Not Changing, 0, Worsening, 1 Healthy Living (n=13), Improving, 1, Not Changing, 12, Worsening, 0 Effective Treatment (n=3), Improving, 1, Not Changing, 2, Worsening, 0 Care Coordination (n=2), Improving, 0, Not Changing, 2, Worsening, 0 Affordable Care (n=0)

- From 2000 through 2017, disparities in quality of care between Asians and Whites remained the same for most measures. Of 32 quality measures with a disparity at baseline, disparities were not changing for 29 (91%) (Figure 74).
- Two measures showed narrowing disparities: Hospital patients who received pneumococcal immunization and People age 13 and over living with HIV who know their serostatus.
- One measure showed a widening disparity: Home health patients whose management of oral medications improved.

##### Pneumococcal Immunization

Two kinds of pneumococcal vaccines are available in the United States:

- Pneumococcal conjugate vaccine (for children under 2 years, adults over 65 years of age, and adults with certain health conditions) and
- Pneumococcal polysaccharide vaccine (for people ages 2-64 with certain medical conditions, adults ages 19-64 who smoke cigarettes, and adults age 65 years and over).^71^

Providers can help determine if vaccination is right for their patients, especially during a hospital visit. The impact of doing so can prevent patients from acquiring pneumonia. States have varying laws for pneumococcal immunization in hospitals and administration will vary based on a patient’s demographics and medical history.^72^

Figure 75 Hospital patients who received pneumococcal immunization, 2012-2015

Line graph showing percentage 2015 achievable benchmark: 97.2% 2012, Asian, 85.7, White, 90.0 2013, Asian, 90.5, White, 92.8 2014, Asian, 91.2, White, 90.0 2015, Asian, 94.9, White, 88.4

Source: Centers for Medicare & Medicaid Services, Quality Improvement Organization Program, 2012-2015.

- Data from 2012 to 2015 show that the disparity between Asians and Whites is narrowing due to an increase in Asian hospital patients receiving pneumococcal immunizations (85.7% to 94.9%) while Whites showed no statistically significant change in this measure (90.0% to 88.4%) (Figure 75). The trend was changing in 2015 with Asians performing better than Whites for this measure.
- The 2015 top 5 state achievable benchmark was 97.2%. At the current rate of increase, overall, the benchmark could be achieved in 1 year.
- The top 5 states that contributed to the achievable benchmark are Hawaii, Maine, New Hampshire, South Carolina, and Wisconsin.

CDC has produced several patient and provider educational resources to inform patients about the importance of vaccination, the impact of pneumonia, and who is best suited for the vaccine.^73^ Among these resources is CDC’s PneumoRecs VaxAdvisor mobile app, which helps providers determine their patient’s vaccination needs based on current clinical guidelines.^74^

##### Knowledge of HIV Serostatus

Stigmatization of HIV hinders patients from seeking testing, which may delay treatment and affect a patient’s health and quality of life.^75^ According to CDC, people ages 13-24 are less likely to know their HIV serostatus.^76^ Accurate estimates of new HIV infection rates are crucial for preventing the spread of the disease.

Figure 76 People age 13 and over living with HIV who know their serostatus, 2010-2015

Line graph showing percentage 2015 achievable benchmark: 91.9% 2010, Asian, 70.5, White, 86.4 2011, Asian, 72.0, White, 86.8 2012, Asian, 73.8, White, 87.1 2013, Asian, 75.4, White, 87.5 2014, Asian, 77.8, White, 87.9 2015, Asian, 80.4, White, 88.1

Source: Centers for Disease Control and Prevention, HIV-AIDS Surveillance System, 2010-2015.

- Data from 2000 to 2015 show that the disparity between Asians and Whites is narrowing due to an increase in the percentage of Asians (70.5% to 80.4%) and Whites (86.4% to 88.1%) who are living with HIV and aware of their serostatus (Figure 76).
- The 2015 top 5 state achievable benchmark was 91.9%. At the current rate of increase, overall, the benchmark could be achieved in 6 years.
- The top 5 states that contributed to the achievable benchmark are Idaho, New Jersey, Pennsylvania, South Dakota, and Vermont.

### Disparities for American Indians and Alaska Natives

American Indians and Alaska Natives performed worse on almost 55% of Person-Centered Care quality measures.

Figure 77 Number and percentage of quality measures for which American Indians and Alaska Natives experienced better, same, or worse quality of care compared with reference group (White), 2013, 2015, 2016, or 2017

Key: n = number of measures.

Note: The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from NIDDK USRDS is 2013 and from AHRQ HCUP is 2016.

Stacked bar chart showing number of quality measures Total (n=106), Better, 14, Same, 50, Worse, 42 Person-Centered Care (n=22), Better, 1, Same, 9, Worse, 12 Patient Safety (n=7), Better, 1, Same, 6, Worse, 0 Healthy Living (n=44), Better, 5, Same, 23, Worse, 16 Effective Treatment (n=24), Better, 7, Same, 8, Worse, 9 Care Coordination (n=8), Better, 0, Same, 3, Worse, 5 Affordable Care (n=1), Better, 0, Same, 1, Worse, 0

- Data for the most recent year show that quality was better for Whites than for AI/ANs on about 40% of all quality measures and that quality was better for AI/ANs than for Whites on 13% of all quality measures (Figure 77). This sample includes the latest data year for all HCUP measures.

#### Largest Disparities

The measures with the largest disparities for AI/ANs include:

- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never spent enough time with them.
- Hospital patients who received influenza vaccination.

##### Adequate Doctor’s Explanation

Many patients leave their healthcare visit unsure of what their provider asked them to do or what was discussed. Nationwide, only 12% of adults have proficient health literacy.^77^ That means almost 9 out of 10 Americans find it challenging “to obtain, process, and understand basic health information and services needed to make appropriate health decisions.”^78^

Figure 78 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand, 2016

Note: For this measure, lower rates are better.

Column chart showing percentage Total, 5.2 AI/AN, 19.1 White, 4.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, 19.1% of AI/AN adults who had a doctor’s office or clinic visit in the past 12 months reported that their health providers sometimes or never explained their health information in a way they could understand, compared with 4.8% of Whites (Figure 78).

AHRQ has developed several resources to improve provider-patient communication and to support improved understanding of a patient’s care plan. These resources include the Guide to Improving Patient Safety in Primary Care Settings by Engaging Patients and Families (https://www.ahrq.gov/professionals/quality-patient-safety/patient-family-engagement/pfeprimarycare/index.html), which features a teach-back intervention. This intervention focuses on primary care providers discussing the patients’ care plan with them and having patients explain it back to them in their own words to ensure their understanding.^79^

Another resource is the AHRQ Health Literacy Universal Precautions Toolkit (www.ahrq.gov/literacy),80 which helps primary care practices promote greater understanding for all patients by using strategies such as teach-back (https://www.ahrq.gov/professionals/quality-patient-safety/quality-resources/tools/literacy-toolkit/healthlittoolkit2-tool5.html).

##### Adequate Time With Doctor

Both providers and patients report not having enough time during patient appointments and this challenge continues to affect the quality of healthcare services. Research by Foo, et. al., demonstrates that patient and provider race both have an impact on how long discussions regarding mental/behavioral health concerns are discussed vs. other biomedical concerns.^81^

Figure 79 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never spent enough time with them, 2016

Note: For this measure, lower rates are better.

Column chart showing percentage Total, 9.2 AI/AN, 28 White, 8.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, 28% of AI/AN adults who had a doctor’s office or clinic visit in the past 12 months reported that their health providers sometimes or never spent enough time with them, compared with 8.5% of Whites (Figure 79).

##### Influenza Vaccination

CDC estimates that there were 21,500 to 35,500 flu-related deaths from October 1, 2018, through March 9, 2019.82 In 2017, approximately 92% of hospital employees reported receiving an influenza vaccination in the 2017-2018 season according to CDC and the American Hospital Association.^83^ While long-debated as an issue of personal choice, influenza vaccination among healthcare providers can efficiently limit the spread of disease. Moreover, current research shows that influenza vaccination provided to hospital patients also limits the spread of the flu and is even effective in patients with COPD.^84^

Figure 80 Hospital patients who received influenza vaccination, 2016

Column chart showing percentage 2016 achievable benchmark: 97% Total, 93.5 AI/AN, 82.5 White, 94.1

Source: Centers for Medicare & Medicaid Services, Quality Improvement Organization Program, 2016.

- In 2016, the percentage of hospital patients who received the influenza vaccination was lower for AI/ANs (82.5%) compared with Whites (94.1%; Figure 80).
- The 2016 top 5 state achievable benchmark was 97%. Overall, there was no progress toward the benchmark.
- The top states that contributed to the achievable benchmark are Florida, Indiana, Maine, Massachusetts, New Jersey, Tennessee, Virginia, and Utah (more than 5 states contributed to the benchmark due to ties).

While current clinical guidelines show that people who are 6 months or older should receive an annual flu vaccine, not all patients can access vaccines or treatment if they become ill. CDC details preventive strategies (https://www.cdc.gov/flu/prevent/index.html) to protect against the flu.

#### Trends in Quality of Care for American Indians and Alaska Natives

Figure 81 Number and percentage of all quality measures that were improving, not changing, or worsening, total for American Indians and Alaska Natives and by priority area, from 2000 through 2013, 2014, 2015, 2016, or 2017

Key: n = number of measures.

- Improving = Quality is going in a positive direction at an average annual rate greater than 1% per year.
- Not changing = Quality is not changing or is changing at an average annual rate of 1% or less per year.
- Worsening = Quality is going in a negative direction at an average annual rate greater than 1% per year.

Stacked bar chart showing number of quality measures Total (n=93), Improving, 38, Not Changing, 51, Worsening, 4 Person-Centered Care (n=15), Improving, 3, Not Changing, 11, Worsening, 1 Patient Safety (n=7), Improving, 2, Not Changing, 4, Worsening, 1 Healthy Living (n=43), Improving, 20, Not Changing, 23, Worsening, 0 Effective Treatment (n=19), Improving, 12, Not Changing, 6, Worsening, 1 Care Coordination (n=8), Improving, 1, Not Changing, 6, Worsening, 1 Affordable Care (n=1), Improving, 0, Not Changing, 1, Worsening, 0

- Among the 93 quality measures with data for AI/ANs, 38 (41%) were improving, 51 (55%) were not changing, and 4 (4%) were getting worse from 2000 through 2017 (Figure 81).
- Effective Treatment showed the most improvement (63% of measures) and Affordable Care, Care Coordination, and Person-Centered Care showed less improvement.^xii^

#### Changes in Disparities for American Indians and Alaska Natives

Figure 82 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, total for American Indians and Alaska Natives and by priority area, from 2000 through 2013, 2015, 2016, or 2017

Key: n = number of measures.

Stacked bar chart showing number of quality measures Total (n=33), Improving, 2, Not Changing, 31, Worsening, 0 Person-Centered Care (n=11), Improving, 0, Not Changing, 11, Worsening, 0 Patient Safety (n=0) Healthy Living (n=14), Improving, 1, Not Changing, 13, Worsening, 0 Effective Treatment (n=4), Improving, 1, Not Changing, 3, Worsening, 0 Care Coordination (n=4), Improving, 0, Not Changing, 4, Worsening, 0 Affordable Care (n=0)

- Disparities between AI/ANs and Whites did not change for most of the quality measures from 2000 through 2017. Of 33 quality measures with a disparity at baseline, 31 (94%) were not changing (Figure 82).
- Only two measures showed narrowing disparities, and one of these was also the most improving measure in 2017: Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population.

##### End Stage Renal Disease Due to Diabetes

Diabetes is the leading cause of kidney disease in the United States. According to the National Institute of Diabetes and Digestive and Kidney Diseases, Whites experience diabetes and kidney disease at a lower rate than other racial and ethnic groups.^85^

Figure 83 Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population, 2001-2016

Note: For this measure, lower rates are better.

Line graph showing rate per million population AI/AN, 2001, 526.0, 2002, 494.3, 2003, 469.6, 2004, 478.2, 2005, 430.0, 2006, 367.7, 2007, 379.6, 2008, 390.0, 2009, 382.6, 2010, 347.6, 2011, 321.3, 2012, 322.6, 2013, 298.6, 2014, 288.6, 2015, 275.8, 2016, 285.9 White, 2001, 133.3, 2002, 131.9, 2003, 132.3, 2004, 134.3, 2005, 135.0, 2006, 139.6, 2007, 136.2, 2008, 133.9, 2009, 135.0, 2010, 134.3, 2011, 129.2, 2012, 129.7, 2013, 132.5, 2014, 133.6, 2015, 139.8, 2016, 144.9

Source: National Institute of Diabetes and Digestive and Kidney Diseases, United States Renal Data System, 2001-2016.

- From 2001 to 2016, the disparity between AI/ANs and Whites decreased for the adjusted incident rate of end stage renal disease due to diabetes. For AI/ANs, the rate decreased from 526 per million population to 285.9 per million, and for Whites, there were no statistically significant changes (from 133.3 per million to 144.9 per million; Figure 83).

### Disparities for Native Hawaiians and Pacific Islanders

Ninety-two percent of all quality measures for Native Hawaiians and Pacific Islanders did not change over time.

Figure 84 Number and percentage of quality measures for which Native Hawaiians/Pacific Islanders experienced better, same, or worse quality of care compared with reference group (White), 2015, 2016, or 2017

Key: n = number of measures.

Note: The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from NIDDK USRDS is 2013 and from AHRQ HCUP is 2016.

Stacked bar chart showing number of quality measures Total (n=57), Better, 8, Same, 26, Worse, 23 Person-Centered Care (n=16), Better, 1, Same, 6, Worse, 9 Patient Safety (n=7), Better, 1, Same, 5, Worse, 1 Healthy Living (n=17), Better, 2, Same, 10, Worse, 5 Effective Treatment (n=10), Better, 2, Same, 4, Worse, 4 Care Coordination (n=7), Better, 2, Same, 1, Worse, 4 Affordable Care (n=0)

- Data for the most recent year show that quality was better for Whites than for NHPIs on 40% of all quality measures and quality was better for NHPIs than for Whites on 14% of all quality measures (Figure 84). This sample includes the latest data year for all HCUP measures.

#### Largest Disparities

The measures with the largest disparities for NHPIs include:

- Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high.
- New HIV cases per 100,000 population age 13 and over.
- Adults who reported that home health providers always treated them with courtesy and respect in the last 2 months of care.

##### Blood Pressure Measurement

Patients with hypertension or high blood pressure may also experience other chronic diseases such as heart disease or stroke, and they may have difficulty managing their care. According to CDC, one-third of adults in the United States have hypertension, but about 20% of adults with hypertension do not know they have it.^86^

Figure 85 Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high, 2017

Column chart showing percentage Total, 92.8 NHPI, 77 White, 92.8

Source: Centers for Disease Control and Prevention, National Health Interview Survey, 2017.

- In 2017, the percentage of adults who received a blood pressure measurement in the last 2 years and could state whether their blood pressure was normal or high was lower for NHPIs (77%) than for Whites (92.8%; Figure 85).

CDC offers several educational resources for patients, providers, and communications professionals to learn more about high blood pressure and its treatment.^87^

##### New HIV Cases

Figure 86 New HIV cases per 100,000 population age 13 and over, 2015

Note: For this measure, lower rates are better.

Line chart showing percentage 2015 achievable benchmark: 4.2 per 100,000 population Total, 14.8 Non-Hispanic NHPI, 17.8 Non-Hispanic White, 6.1

Source: Centers for Disease Control and Prevention, HIV-AIDS Surveillance System, 2015.

- NHPIs age 13 and over had 17.8 new HIV cases per 100,000 population compared with Whites (6.1 per 100,000 population; Figure 86).
- The 2015 top 5 state achievable benchmark was 4.2 per 100,000 population.
- The top 5 states that contributed to the achievable benchmark are Idaho, Iowa, Maine, West Virginia, and Wisconsin.

##### Treatment by Home Health Providers

Figure 87 Adults who reported that home health providers always treated them with courtesy and respect in the last 2 months of care, 2017

Column chart showing percentage 2017 achievable benchmark: 95% Total, 93.5 NHPI, 88.5 White, 94.2

Source: Agency for Healthcare Research and Quality, Home Health Consumer Assessment of Healthcare Providers and Systems, 2017.

- In 2017, the percentage of adults who reported that home health providers always treated them with courtesy and respect in the last 2 months was lower for NHPIs (88.5%) compared with Whites (94.2%; Figure 87).
- The 2017 top 5 state achievable benchmark was 95%. Overall, there was no progress toward the benchmark.
- The top states that contributed to the achievable benchmark are Alabama, Kentucky, Louisiana, Mississippi, South Carolina, and West Virginia (more than 5 states contributed to the benchmark due to ties).

#### Trends in Quality of Care for Native Hawaiians/Pacific Islanders

Most quality measures for NHPIs showed no statistically significant changes from 2008 to 2015, 2016, or 2017.

Figure 88 Number and percentage of all quality measures that were improving, not changing, or worsening, total for Native Hawaiians/Pacific Islanders and by priority area, from 2008 through 2012, 2013, 2014, 2015, 2016, or 2017

Key: n = number of measures.

- Improving = Quality is going in a positive direction at an average annual rate greater than 1% per year.
- Not changing = Quality is not changing or is changing at an average annual rate of 1% or less per year.
- Worsening = Quality is going in a negative direction at an average annual rate greater than 1% per year.

Stacked bar chart showing number of quality measures Total (n=48), Improving, 14, Not Changing, 32, Worsening, 2 Person-Centered Care (n=10), Improving, 2, Not Changing, 8, Worsening, 0 Patient Safety (n=7), Improving, 1, Not Changing, 5, Worsening, 1 Healthy Living (n=15), Improving, 7, Not Changing, 8, Worsening, 0 Effective Treatment (n=8), Improving, 3, Not Changing, 5, Worsening, 0 Care Coordination (n=8), Improving, 1, Not Changing, 6, Worsening, 1 Affordable Care (n=0)

- Among the 48 quality measures with data for NHPIs, 14 (29%) were improving, 32 (67%) were not changing, and 2 (4%) were getting worse from 2008 through 2017 (Figure 88).^xiii^

#### Changes in Disparities for Native Hawaiians/Pacific Islanders

Figure 89 Number and percentage of all quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, total for Native Hawaiians/Pacific Islanders and by priority area, from 2008 through 2015, 2016, or 2017

Key: n = number of measures.

Stacked bar chart showing number of quality measures Total (n=12), Improving, 1, Not Changing, 11, Worsening, 0 Person-Centered Care (n=5), Improving, 0, Not Changing, 5, Worsening, 0 Patient Safety (n=0) Healthy Living (n=2), Improving, 0, Not Changing, 2, Worsening, 0 Effective Treatment (n=2), Improving, 1, Not Changing, 1, Worsening, 0 Care Coordination (n=3), Improving, 0, Not Changing, 3, Worsening, 0 Affordable Care (n=0)

- Disparities between NHPIs and Whites did not change for most of the quality measures from 2008 through 2017. Of the 12 quality measures with a disparity at baseline, disparities were not changing for 11 measures (92%) (Figure 89).
- No measures showed widening disparities, and only one measure showed a narrowing disparity: People age 13 and over living with HIV who know their serostatus.

##### Knowledge of HIV Serostatus

Figure 90 People age 13 and over living with HIV who know their serostatus, 2010-2015

Line graph showing percentage 2015 achievable benchmark: 91.9% NHPI, 2010, 74.0, 2011, 75.6, 2012, 77.3, 2013, 79.3, 2014, 80.1, 2015, 82.2 White, 2010, 86.4, 2011, 86.8, 2012, 87.1, 2013, 87.5, 2014, 87.9, 2015, 88.1

Source: Centers for Disease Control and Prevention, HIV AIDS Surveillance System, 2010-2015.

- Data from 2010 to 2015 show that the disparity between NHPIs and Whites was narrowing due to a larger increase in the percentage of NHPIs (74% to 82.2%) than Whites (86.4% to 88.1%) who are living with HIV and aware of their serostatus (Figure 90).
- The 2015 top 5 state achievable benchmark was 91.9%. At the current rate of increase, overall, the benchmark could be achieved in 6 years.
- The top 5 states that contributed to the achievable benchmark are Idaho, New Jersey, Pennsylvania, South Dakota, and Vermont.

### Disparities for Hispanics

Hispanics performed worse than non-Hispanic Whites on almost 59% of Person-Centered Care quality measures and 37% of Healthy Living measures.

Figure 91 Number and percentage of quality measures for which Hispanics experienced better, same, or worse quality of care compared with reference group (non-Hispanic White), 2013, 2015, 2016, or 2017

Key: n = number of measures.

Note: The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from NIDDK USRDS is 2013 and from AHRQ HCUP is 2016.

Stacked bar chart showing number of quality measures Total (n=167), Better, 39, Same, 70, Worse, 58 Person-Centered Care (n=17), Better, 2, Same, 5, Worse, 10 Patient Safety (n=23), Better, 10, Same, 11, Worse, 2 Healthy Living (n=58), Better, 9, Same, 27, Worse, 22 Effective Treatment (n=42), Better, 9, Same, 18, Worse, 15 Care Coordination (n=22), Better, 8, Same, 8, Worse, 6 Affordable Care (n=5), Better, 1, Same, 1, Worse, 3

- Data for the most recent year show that quality was better for non-Hispanic Whites than for Hispanics on 35% of all quality measures and quality was better for Hispanics than for non-Hispanic Whites on 23% of all quality measures (Figure 91). This sample includes the latest data year for all HCUP measures.

#### Largest Disparities

The measures with some of the largest disparities for Hispanics include:

- New HIV cases per 100,000 population age 13 and over.
- Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population.
- People without a usual source of care who indicated a financial or insurance reason for not having a source of care.

##### New HIV Cases

Figure 92 New HIV cases per 100,000 population age 13 and over, 2015

Note: For this measure, lower rates are better.

Column chart showing rate per 100,000 population 2015 achievable benchmark: 4.2 per 100,000 population Total, 14.8 Hispanic, 22.5 Non-Hispanic White, 6.1

Source: Centers for Disease Control and Prevention, HIV-AIDS Surveillance System, 2015.

- In 2015, the rate of new HIV cases per 100,000 population age 13 and over was higher for Hispanics (22.5) compared with non-Hispanic Whites (6.1; Figure 92).
- The 2015 top 5 state achievable benchmark was 4.2 per 100,000 population. At the current rate of increase, overall, the benchmark could not be achieved for 20 years.
- The top 5 states that contributed to the achievable benchmark are Idaho, Iowa, Maine, West Virginia, and Wisconsin.

##### End Stage Renal Disease Due to Diabetes

Figure 93 Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population, 2016

Note: For this measure, lower rates are better.

Column chart showing rate per million population Total, 169 Hispanic, 300.9 Non-Hispanic White, 122

Source: National Institute of Diabetes and Digestive and Kidney Diseases, United States Renal Data System, 2016.

- In 2016, the rate of end stage renal disease due to diabetes was higher for Hispanics (300.9 per million population) compared with non-Hispanic Whites (122 per million population; Figure 93).

##### Financial or Insurance Barriers to Usual Sources of Care

Figure 94 People without a usual source of care who indicated a financial or insurance reason for not having a source of care, 2016

Note: For this measure, lower rates are better.

Column chart showing percentage Total, 13.8 Hispanic, 21.7 Non-Hispanic White, 10.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, the percentage of people without a usual source of care who indicated a financial or insurance reason for not having a source of care was lower for non-Hispanic Whites (10.3%) than for Hispanics (21.7%; Figure 94).

#### Changes in Quality of Care for Hispanics

Figure 95 Number and percentage of all quality measures that were improving, not changing, or worsening, total for Hispanics and by priority area, from 2000 through 2013, 2014, 2015, 2016, or 2017

Key: n = number of measures.

- Improving = Quality is going in a positive direction at an average annual rate greater than 1% per year.
- Not changing = Quality is not changing or is changing at an average annual rate of 1% or less per year.
- Worsening = Quality is going in a negative direction at an average annual rate greater than 1% per year.

Stacked bar chart showing number of quality measures Total (n=127), Improving, 69, Not Changing, 47, Worsening, 11 Person-Centered Care (n=19), Improving, 10, Not Changing, 8, Worsening, 1 Patient Safety (n=12), Improving, 4, Not Changing, 7, Worsening, 1 Healthy Living (n=54), Improving, 36, Not Changing, 16, Worsening, 2 Effective Treatment (n=28), Improving, 16, Not Changing, 10, Worsening, 2 Care Coordination (n=9), Improving, 2, Not Changing, 3, Worsening, 4 Affordable Care (n=5), Improving, 1, Not Changing, 3, Worsening, 1

- Of the 127 quality measures with data for Hispanics, 54% were improving, 37% were not changing, and 9% were getting worse from 2000 through 2017 (Figure 95).^xiv^
- Hispanics are improving in Healthy Living and Effective Treatment and worsening or not changing on Care Coordination and Affordable Care.

#### Changes in Disparities for Hispanics

Figure 96 Number and percentage of all quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, total for Hispanics and by priority area, from 2000 through 2013, 2014, 2015, 2016, or 2017

Key: n = number of measures.

Stacked bar chart showing number of quality measures Total (n=49), Improving, 5, Not Changing, 42, Worsening, 2 Person-Centered Care (n=7), Improving, 0, Not Changing, 7, Worsening, 0 Patient Safety (n=3), Improving, 0, Not Changing, 3, Worsening, 0 Healthy Living (n=24), Improving, 4, Not Changing, 18, Worsening, 2 Effective Treatment (n=12), Improving, 1, Not Changing, 11, Worsening, 0 Care Coordination (n=0) Affordable Care (n=3), Improving, 0, Not Changing, 3, Worsening, 0

- Of the 49 quality measures with a disparity at baseline, disparities between Hispanics and non-Hispanic Whites did not change for 42 (86%) from 2000 through 2017 (Figure 96).
- Five measures showed narrowing disparities—one Effective Treatment measure and four Healthy Living measures.
- The measure that showed the most improvement is an Effective Treatment measure: Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population. The other four measures are in Healthy Living.
- The second most improving measure is Home health care patients whose shortness of breath decreased.
- The other improving measures are:
  ■ Children ages 2-17 who had a preventive dental service in the calendar year,
  ■ Children ages 2-17 who had a dental visit in the calendar year, and
  ■ Adults with obesity who ever received advice from a health professional about eating fewer high-fat or high-cholesterol foods.
- Two measures showed widening disparities: Home health patients who had improvement in upper body dressing and Home health patients whose ability to walk or move around improved.

##### End Stage Renal Disease

Diabetes is the leading cause of kidney disease in the United States. According to the National Institute of Diabetes and Digestive and Kidney Diseases, non-Hispanic Whites experience diabetes and kidney disease at a lower rate than other racial and ethnic groups.^85^

Figure 97 Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population, 2001-2016

Note: For this measure, lower rates are better.

Line graph showing rate per million population 2001 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Hispanic 410.0 411.0 412.1 398.9 378.5 376.8 366.6 366.6 358.9 355.2 346.5 323.2 316.7 299.8 302.6 300.9 2001 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Non-Hispanic White 133.3 131.9 132.3 134.3 135.0 139.6 136.2 133.9 135.0 134.3 129.2 129.7 132.5 133.6 139.8 144.9

Source: National Institute of Diabetes and Digestive and Kidney Diseases, United States Renal Data System, 2001-2016.

- Data from 2001 to 2016 show that the disparity between Hispanics and non-Hispanic Whites was narrowing; however, the narrowing disparity was due to the rate for Whites increasing over time (Figure 97).
- Hispanics showed a decreasing rate of ESRD (410 to 300.9 per million population) but still had higher rates than non-Hispanic Whites (133.3 to 144.9 per million population).

##### Pediatric Preventive Dental Care

Children in the United States can access dental insurance coverage through Medicaid or the Children’s Health Insurance Program, which enables affordable access for most children ages 2-17.^88^

Figure 98 Children ages 2-17 who had a preventive dental service in the calendar year, 2002-2016

Line graph showing percentage 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Hispanic 24.8 27.3 29.6 28.9 30.5 33.1 34.6 32.7 34.9 35.8 36.9 41.8 39.7 42.7 42.5 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Non-Hispanic White 48.1 50.5 50.0 50.1 51.8 51.2 46.0 49.0 48.5 48.0 51.2 51.4 51.3 51.2 50.1

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- Data from 2002 to 2016 show that the disparity between Hispanics and Whites was narrowing over time. Hispanics showed an improvement (24.8% to 42.5%) but Whites still have higher rates of performance for this measure and have not shown statistically significant differences over time (48.1% to 50.1%) (Figure 98).

Figure 99 Children ages 2-17 who had a dental visit in the calendar year, 2002-2016

Line graph showing percentage 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Hispanic 33.8 36.7 38.3 38.4 38.6 42.1 42.8 41.9 42.3 43.9 45.5 49.0 48.1 50.1 50.7 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Non-Hispanic White 57.6 59.6 59.0 58.5 59.7 58.6 54.1 57.2 55.9 56.1 59.0 59.3 59.7 59.3 59.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- Data from 2002 to 2016 show that the disparity between Hispanics and Whites was narrowing. Hispanics showed improvement (33.8% to 50.7%) but Whites still have higher rates of performance for this measure and have not shown statistically significant differences over time (50.7% to 59.8%) (Figure 99).

##### Obesity

The prevalence of obesity is continuing to rise in the United States. More than one-third of adults are overweight or affected by obesity.^89^

Figure 100 Adults with obesity who ever received advice from a health professional about eating fewer high-fat or high-cholesterol foods, 2002-2016

Line graph showing percentage 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Hispanic 38.8 44.5 41.3 40.6 45.6 48.2 53.3 56.5 53.6 51.2 50.2 52.2 51.2 55.0 51.9 2002 2003 2004 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Non-Hispanic White 49.5 49.8 49.9 51.0 50.0 50.1 49.0 50.5 50.1 50.4 49.5 51.5 50.4 50.7 46.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- Data from 2002 to 2016 show that the disparity between Hispanics and non-Hispanic Whites was narrowing; however, Hispanics showed improvement (38.8% to 51.9%), while Whites showed declining rates of performance for this measure (49.5% to 46.3%) (Figure 100).

The National Institutes of Diabetes and Digestive and Kidney Diseases (NIDDK) has outlined several strategies for healthcare providers to use to speak with their patients in a respectful manner about healthy eating habits.^90^

### Disparities by Income

The QDR tracks disparities data for income and insurance categories. Income groups are based on the Federal Poverty Level (FPL) for a family of four:

- Poor: Less than 100% of FPL
- Low income: 100% to less than 200% of FPL
- Middle income: 200% to less than 400% of FPL
- High income: 400% or more of FPL

The poverty guidelines are issued annually in the Federal Register by the Department of Health and Human Services, Assistant Secretary for Planning and Evaluation. The guidelines vary by family size and there are different family income criteria for the contiguous 48 states, Alaska, and Hawaii. Criteria for U.S. territories are unavailable.^91^

The relationship between income and healthcare outcomes has been studied for many years, and researchers have shown the positive relationship between more income and better health outcomes.^92,93,94,95^ Income is not the same as wealth, which can include assets other than income. Wealth is disproportionately dispersed among higher income categories, and research also shows a positive association between greater wealth and better health outcomes.^92^

This section shows quality measures with the largest income disparities and trends in disparities.

High-income groups performed better than other income groups on more than half of all quality measures.

Figure 101 Number and percentage of quality measures for which income groups experienced better, same, or worse quality of care compared with reference group (high income), 2015, 2016, or-2017

Key: n = number of measures.

Note: The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from AHRQ HCUP is 2016.

Stacked bar chart showing number of quality measures Total (n=363), Better, 24, Same, 135, Worse, 204 Poor (n=121), Better, 11, Same, 37, Worse, 73 Low Income (n=121), Better, 7, Same, 43, Worse, 71 Middle Income (n=121), Better, 6, Same, 55, Worse, 60

- Data for the most recent year show that high-income groups performed better than other income groups on almost 60% of all quality measures (Figure 101).
- Performance was better for high-income groups than for low-income groups on almost 60% of the measures. Compared with middle-income groups, high-income groups performed better on about half the measures.

This sample includes the latest data year for all Healthcare Cost and Utilization Project (HCUP) measures.

#### Largest Disparities

The measure with the largest income disparities is “People without a usual source of care who indicated a financial or insurance reason for not having a source of care.”

Measures with the largest income disparities include:

- People without a usual source of care who indicated a financial or insurance reason for not having a source of care (all income groups).
- Women ages 21-65 who received a Pap smear in the last 3 years (middle income, low income).
- People under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income (middle income).
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand (low income).
- Hospital admissions for chronic obstructive pulmonary disease or asthma per 100,000 population age 40 and over (poor).
- Hospital admissions for short-term complications of diabetes per 100,000 population, adults (poor).

##### Difficulty Accessing a Usual Source of Care

People with lower incomes may experience difficulty accessing affordable care and are less likely to have a usual source of care that is readily accessible.^94^ People who are unwell and have low incomes are also more likely to experience poverty.^92^

Figure 102 People without a usual source of care who indicated a financial or insurance reason for not having a source of care, 2016

Note: For this measure, lower rates are better.

Column chart showing percentage Total, 13.8 Poor, 22.9 Low Income, 19.9 Middle Income, 13.4 High Income, 6.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, the measure with the largest income disparities was people without a usual source of care who indicated a financial or insurance reason for not having a source of care. The percentages were 22.9% for poor people, 19.9% for low-income people, 13.4% for middle-income people, and 6.8% for high-income people (Figure 102).

##### Receipt of Pap Test

A Pap test is a cervical screening test to detect potentially cancerous or precancerous abnormalities in females.^96^ In 2018, the United States Preventive Services Task Force (USPSTF) recommended all women ages 21-65 receive screening every 3 years and specified screening tests for different age brackets. Women ages 21-29 years are recommended to receive a cervical cytology test only, and women ages 30-65 are recommended to receive cytology tests every 3 years, high-risk HPV (hrHPV) testing every 5 years, or a combination of cytology and hrHPV testing every 5 years.^97^

The 2018 guidelines are different than the guidelines available in 2015. The 2015 USPSTF guidelines indicated that clinical considerations for alternative screening strategies are considered for women 30 years and over.^98^ The latest guidelines from 2018 include women 21 years and over. In addition, the latest criteria for women ages 30-65 years are more specific than earlier recommendations.^97^

Figure 103 Women ages 21-65 who received a Pap smear in the last 3 years, 2015

Column chart showing percentage 2014 achievable benchmark: 86.9% Total, 81.2 Low Income, 74.5 Middle Income, 79.3 High Income, 88

Source: Centers for Disease Control and Prevention, National Health Interview Survey, 2015.

- In 2015, the percentage of women ages 21-65 years who received a Pap Test in the last 3 years was lower for low-income women (74.5%) and middle-income women (79.3%) compared with high-income women (88.0%; Figure 103).
- The 2014 top 5 state achievable benchmark was 86.9%. Women in low-income and middle-income households made no progress toward the benchmark. Women in high-income households met the benchmark.
- The top 5 states that contributed to the achievable benchmark are Connecticut, Delaware, Maryland, Massachusetts, and Wisconsin.

##### High Family Medical Expenditures

The most prominent barriers to health coverage include affordability, eligibility for public coverage in a person’s state, immigration status, and lack of familiarity with signup procedures.^99^ Poor health may require a family to spend more on healthcare, resulting in less income. Costs will vary based on each person or family’s needs and may inhibit a family’s ability to reach other goals.^92^

Figure 104 People under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income, 2016

Note: For this measure, lower rates are better.

Column chart showing percentage Total, 17.1 Middle Income, 21 High Income, 10.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, the percentage of people under age 65 whose family’ health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income was higher for middle-income people (21%) than high-income people (10.9%; Figure 104).

##### Adequate Explanation by Doctor

Many patients leave their healthcare visit unsure of what their provider asked them to do or what was discussed. Nationwide, only 12% of adults have proficient health literacy.^77^ That means almost 9 out of 10 Americans find it challenging “to obtain, process, and understand basic health information and services needed to make appropriate health decisions.”^77^

Figure 105 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand, 2016

Note: For this measure, lower rates are better.

Column chart showing percentage Total, 5.2 Low Income, 8.9 High Income, 3.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand was higher for low-income adults (8.9%) than for high-income adults (3.5%; Figure 105).

Efforts are underway within HHS to improve provider-patient communication. Examples include:

- AHRQ’s Guide to Improving Patient Safety in Primary Care Settings by Engaging Patients and Families (https://www.ahrq.gov/professionals/quality-patient-safety/patient-family-engagement/pfeprimarycare/index.html), which features a teach-back intervention. This intervention focuses on primary care providers discussing patients’ care plans with them and having patients explain the plan back in their own words to ensure their understanding.^79^
- AHRQ’s Health Literacy Universal Precautions Toolkit (www.ahrq.gov/literacy),80 which helps primary care practices promote greater understanding for all patients by using various strategies, including teach-back (https://www.ahrq.gov/professionals/quality-patient-safety/quality-resources/tools/literacy-toolkit/healthlittoolkit2-tool5.html).

##### Hospital Admissions for Chronic Obstructive Pulmonary Disease or Asthma

Asthma and chronic obstructive pulmonary disease (COPD) are severe respiratory conditions that may co-occur in some patients.^100^ COPD is the third leading cause of death in the United States and may present in the form of respiratory disease such as bronchitis. COPD develops slowly over years, so most people are at least 40 years old when symptoms begin.^101^

Figure 106 Hospital admissions for chronic obstructive pulmonary disease or asthma per 100,000 population, adults age 40 and over, 2016

Note: For this measure, lower rates are better.

Column chart showing rate per 100,000 population Total, 464.5 Poor, 754.3 High Income, 246.1

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2016.

- In 2016, the rate of hospital admissions for COPD or asthma among adults age 40 years and over was three times as high for poor people (754.3 per 100,000 population) compared with high-income people (246.1 per 100,000 population; Figure 106).

##### Hospital Admissions for Diabetes Complications

More than 100 million people living in the United States have diabetes or are at risk for diabetes.^102^ Compared with other countries, the rate of hospital admissions for short-term complications of diabetes is higher in the United States.^103^ Such complications may be related to kidney disease, hypertension, vision problems, pain, or other problems.

Figure 107 Hospital admissions for short-term complications of diabetes per 100,000 population, adults, 2016

Note: For this measure, lower rates are better.

Column chart showing rate per 100,000 population Total, 53.3 Poor, 83.6 High Income, 27.7

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2016.

- In 2016, the rate of hospital admissions for short-term complications of diabetes was three times as high for poor adults (83.6 per 100,000 population) compared with high-income adults (27.7 per 100,000 population; Figure 107).

#### Trends in Quality of Care for Income Groups

Figure 108 Number and percentage of all quality measures that were improving, not changing, or worsening, total and by income group, from 2000 through 2014, 2015, 2016, or 2017

Key: n = number of measures.

- Improving = Quality is going in a positive direction at an average annual rate greater than 1% per year.
- Not changing = Quality is not changing or is changing at an average annual rate of 1% or less per year.
- Worsening = Quality is going in a negative direction at an average annual rate greater than 1% per year.

Stacked bar chart showing number of quality measures Total (n=311), Improving, 165, Not Changing, 121, Worsening, 25 Poor (n=78), Improving, 44, Not Changing, 29, Worsening, 5 Low Income (n=78), Improving, 44, Not Changing, 29, Worsening, 5 Middle Income (n=78), Improving, 41, Not Changing, 30, Worsening, 7 High Income (n=77), Improving, 36, Not Changing, 33, Worsening, 8

- Across all 311 measures of healthcare quality tracked in the report, poor people and low-income people had a higher percentage of improving measures and a lower percentage of worsening measures compared with high-income and middle-income groups (Figure 108).

#### Changes in Income Disparities

Most disparities by income show no statistically significant changes over time.

Figure 109 Number and percentage of quality measures with disparity at baseline for which disparities related to income were improving, not changing, or worsening, 2000 through 2014, 2015, 2016, or 2017

Key: n = number of measures.

Stacked bar chart showing number of quality measures Total (n=160), Improving, 13, Not Changing, 142, Worsening, 5 Poor (n=55), Improving, 8, Not Changing, 45, Worsening, 2 Low Income (n=55), Improving, 5, Not Changing, 48, Worsening, 2 Middle Income (n=50), Improving, 0, Not Changing, 49, Worsening, 1

- Disparities by income remain unchanged for almost 90% of quality measures (Figure 109).
- Only 13 measures showed narrowing disparities and 5 measures showed widening disparities.
- Among the largest improvements observed in this report’s analysis, four unique measures were also tracked and reported in the 2017 report. They are:
  ■ Children ages 2-17 who had a preventive dental service in the calendar year.
  ■ People unable to get or delayed in getting needed dental care due to financial or insurance reasons.
  ■ People unable to get or delayed in getting needed medical care due to financial or insurance reasons.
  ■ Adolescents females ages 13-15 who received 3 or more doses of human papillomavirus vaccine.

Among the largest improvements observed, two measures were new to this report:

- Emergency department visits involving opioid-related diagnoses per 100,000 population.
- Hospital inpatient stays involving opioid-related diagnoses per 100,000 population.

##### Children Who Had a Preventive Dental Service

Children in the United States can access dental insurance coverage through Medicaid or CHIP, which enables affordable access for most children ages 2-17.^88^

Figure 110 Children ages 2-17 who had a preventive dental service in the calendar year, 2002-2016

Line graph showing percentage, with low income increasing over time and high income remaining steady 2002, low income, 27.6, high income, 56.3; 2016, low income, 40.9, high income, 56

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- In 2002, 27.6% of children in low-income households had preventive dental appointments and the percentage increased to 40.9% in 2016 (Figure 110).
- Data from 2002 to 2016 show that the disparities between high-income and low-income people were narrowing over time.

Efforts are underway within HHS to improve children’s access to dental care, including the Health Resources and Services Administration (HRSA) initiative Integration of Oral Health and Primary Care Practice. HRSA published a report on the initiative that summarized recommendations for improving preventive oral healthcare (https://www.hrsa.gov/sites/default/files/hrsa/oralhealth/integrationoforalhealth.pdf).

##### Financial Barriers to Dental Care

The most prominent barriers to health coverage include affordability, eligibility for public coverage in a person’s state, immigration status, and lack of familiarity with signup procedures.^99^ Research shows that lack of access to oral healthcare also worsens physical and mental health.^104^

Figure 111 People unable to get or delayed in getting needed dental care due to financial or insurance reasons, 2002-2016

Line graph showing percentage, with low income decreasing over time 2002, poor, 82.9, high income, 48.5; 2016, poor, 73.7, high income, 56.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- In 2002, 82.9% of poor people were unable to get or delayed in getting needed dental care due to financial or insurance reasons. The percentage decreased to 73.7% in 2016 (Figure 111).
- Data from 2002 to 2016 show that disparities between high-income and poor people were narrowing over time.

##### Financial Barriers to Medical Care

The most prominent barriers to health coverage include affordability, eligibility for public coverage in a person’s state, immigration status, and lack of familiarity with signup procedures.^99^ Uninsured patients may delay visiting a provider until their health concern becomes unbearable or skip preventive visits if they feel healthy.^99^

Figure 112 People unable to get or delayed in getting needed medical care due to financial or insurance reasons, 2002-2016

Line graph showing percentage, with poor decreasing over time and high income remaining steady 2002, poor, 67.9, high income, 32.7; 2016, poor, 45.6, high income, 32.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- In 2002, 67.9% of poor people were unable to get or delayed in getting needed medical care due to financial or insurance reasons (Figure 112). In 2016, the percentage had dropped to 45.6%.
- The percentage of high-income people who were unable to get or delayed in getting medical care due to financial or insurance reasons changed little from 2002 to 2016 (32.7% to 32.3%). Thus, the gap between poor people and high-income people was narrowing, indicating considerable improvement in access to medical care for poor people.

##### Adolescent Vaccination

According to CDC, 33,700 women and men are diagnosed with a cancer caused by human papillomavirus (HPV) infection annually and HPV vaccination could prevent more than 90% of these cancers.^105^ Children should begin receiving the HPV vaccine at ages 11-12 years.^106^

Figure 113 Adolescent females ages 13-15 who received 3 or more doses of human papillomavirus vaccine, 2008-2016

Line graph showing percentage 2008 2009 2010 2011 2012 2013 2014 2015 2016 Poor 12.7 24.2 27.3 34.3 36.1 36.3 38.9 40.9 42.1 2008 2009 2010 2011 2012 2013 2014 2015 2016 High Income 22.7 27.3 31.7 31.5 26.3 33.7 34.9 35.1 39.8

Source: Centers for Disease Control and Prevention, National Immunization Survey-Teen, 2008-2016.

- In 2008, 12.7% of poor adolescent females ages 13-15 received 3 or more doses of HPV vaccine, and by 2016, the percentage had increased to 42.1% (Figure 113). From 2008 to 2016, the percentage of high-income adolescent females who received 3 or more doses of HPV vaccine increased from 22.7% to 39.8%.
- Data from 2008 to 2016 show that disparities between high-income and poor adolescents were narrowing over time and both populations are improving.

##### Emergency Department Visits Involving Opioids

Increased availability and overuse of opioid medications (both prescription and nonprescription drugs) have contributed to adverse outcomes for patients, including increased risk of opioid use disorder, misuse of medications, and overdoses.^107^ Overdoses involving opioids killed more than 47,600 people in 2017.^108^

Prescription and nonprescription opioid access and use vary by state, age group, sex, and race/ethnicity, and research to understand and manage disparities continues to grow.^109^ Current research shows differences in care delivery for patients who are prescribed opioid medications. People who live in areas with lower socioeconomic resources are less likely to receive opioids for pain management in emergency departments than people with higher incomes and resources.^110^

Figure 114 Emergency department visits involving opioid-related diagnoses per 100,000 population, 2005-2016

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population, indicating increases in rates for poor, low-income, and high-income people over time. Rates increased faster for poor and low income than for high income.

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2005-2016.

- In 2005, the rate of emergency department visits involving opioid-related diagnoses was 104.9 per 100,000 population for poor people, and in 2016, the rate increased to 314.3 per 100,000 population (Figure 114).
- From 2005 to 2016, the rate of emergency visits involving opioid-related diagnoses increased from 90.2 per 100,000 population to 255.3 per 100,000 population for low-income people.
- From 2005 to 2016, the rate of emergency visits involving opioid-related diagnoses increased from 65.5 per 100,000 population to 169.8 per 100,000 population for high-income people.
- Data from 2005 to 2016 show that disparities were widening over time between high-income and low-income people and high income and poor people.

##### Hospital Inpatient Stays Involving Opioids

Figure 115 Hospital inpatient stays involving opioid-related diagnoses per 100,000 population, 2005-2016

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population, indicating increases in rates for poor, low-income, middle-income, and high-income people over time. Rates increased faster for poor, low income, and middle income than for high income.

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2005-2016.

- In 2005, the rate of inpatient hospital stays involving opioid-related diagnoses was 179.6 per 100,000 population for poor people, and in 2016, the rate increased to 386.9 per 100,000 population (Figure 115).
- From 2005 to 2016, the rate of inpatient hospital stays involving opioid-related diagnoses increased from 125.5 per 100,000 population to 303.8 per 100,000 population for low-income people.
- From 2005 to 2016, the rate of emergency visits involving opioid-related diagnoses increased from 117.2 per 100,000 population to 260.9 per 100,000 population for middle-income people.
- From 2005 to 2016, the rate of emergency visits involving opioid-related diagnoses increased from 98.1 per 100,000 population to 205.4 per 100,000 population for high-income people.
- Data from 2005 to 2016 show that disparities between high-income and middle-income people were widening over time. The gap was greater between high-income and low-income people and widest between high-income and poor people.

In 2017, HHS launched a departmentwide initiative with a five-point strategy to combat the opioid epidemic. Many agencies supported this initiative by establishing specific research opportunities, resources, and data to support providers, patients, and researchers.^111^ More information is available at https://www.hhs.gov/opioids/.

### Disparities by Insurance Status

This section examines trends and disparities among quality measures by insurance status. Insurance categories differ for ages 0-64 years and for adults’ age 65 years and over. Insurance categories for people ages 0-64 years follow:

- Private Insurance: Person has access to insurance from a private insurer.
- Public Insurance: Person receives insurance from one or more government-sponsored sources, including Medicaid, State Children’s Health Insurance Program, state-sponsored or other government-sponsored health plans, Medicare, and military plans.
- Uninsured: Person does not have any health insurance.

Quality measures that examine health insurance status for adults age 65 and over include a distinction for access to Medicare:

- Private Insurance: Person has access to insurance from a private insurer and Medicare.
- Public Insurance: Person receives insurance from Medicare only. Person may also receive insurance from Medicare and other government-sponsored sources, including Medicaid, state-sponsored or other government-sponsored health plans, and military plans.

Adults 65 years or over usually have Medicare coverage at a minimum.^112^ In addition, the Indian Health Service (IHS) offers public coverage to and is considered a comprehensive healthcare delivery system for AI/ANs. Currently, IHS serves 2.6 million AI/ANs who belong to 573 federally recognized tribes in 37 states. IHS is not described as a health plan in this report. Non-IHS data sources, including CDC’s National Center for Health Statistics, also track disparities for AI/AN populations.

The bar chart below summarizes 142 quality measures, including 73 measures with data for people with public insurance and 69 measures with data for people who are uninsured. All measures compared these groups with adults with private insurance.

Figure 116 Number and percentage of quality measures for which insurance groups experienced better, same, or worse quality of care compared with reference group (privately insured), 2015, 2016, or 2017

Key: n = number of measures.

Note: The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from AHRQ HCUP is 2016.

Stacked bar chart showing number of quality measures Total (n=142), better, 21, same, 44, worse, 77 Public (n=73), better, 12, same, 28, worse, 33 Uninsured (n=69), better, 9, same, 16, worse, 44

- Data for the most recent year show that compared with people with private insurance, people with public insurance experienced better quality for 16% of measures and uninsured people performed better on 13% of quality measures (Figure 116).
- Uninsured people performed worse on 64% of quality measures, and people with public insurance performed worse on 45% of quality measures.

This sample includes the latest data year for all HCUP measures.

#### Largest Disparities for People With Public Insurance

The three quality measures with the largest disparities between people with public insurance and people with private insurance are person- and family-centered care measures. Person- and family-centered care focuses on improving the patient and family’s experience of care through clear, easy-to-understand communication.

Delivering care that is person and family centered empowers patients and families to navigate, coordinate, and manage their care appropriately and effectively. Person-centered care means defining success not just by the resolution of clinical symptoms but also by whether a patient has achieved his or her desired outcomes and goals.

Examples of person-centered care include ensuring that patients’ preferences, desired outcomes, and experiences of care are integrated into care delivery; integrating patient-generated data in electronic health records; and finding additional ways to involve patients and families in managing their care effectively.^113^ Gaps in care can yield adverse events, improper management of care, poor health outcomes, and lower quality of life.^114,115,116^

The person- and family-centered care measures with the largest disparities are:

- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand.
- Rating of health care 0-6 on a scale from 0 to 10 (best grade) by adults who had a doctor´s office or clinic visit in the last 12 months.
- Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never listened carefully to them.

##### Adequate Explanation by Health Providers

Figure 117 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand, 2016

Note: For this measure, lower rates are better.

Column chart showing percentage Total, 5.2 Public Insurance Only, 9.8 Private Insurance, 4.0

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never explained things in a way they could understand was more than twice as high for adults with public insurance (9.8%) compared with adults with private insurance (4.0%; Figure 117).

##### Rating of Healthcare

Figure 118 Rating of healthcare 0-6 on a scale from 0 to 10 (best grade) by adults who had a doctor’s office or clinic visit in the last 12 months, 2016

Note: For this measure, lower rates are better.

Column chart showing percentage Total, 10.2 Public Insurance Only, 20.2 Private Insurance, 8.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months and gave their healthcare a rating of 0-6 on a scale of 0 to 10 was more than twice as high for people with public insurance (20.2%) compared with people with private insurance (8.5%; Figure 118). Ratings of 0 indicate the worst healthcare possible and 10 indicates the best healthcare possible.

##### Providers Who Listened to Patients

Figure 119 Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never listened carefully to them, 2016

Note: For this measure, lower rates are better.

Column chart showing percentage Total, 6.6 Public Insurance Only, 12.6 Private Insurance, 5.6

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never listened carefully to them was more than twice as high for people with public insurance (12.6%) compared with people with private insurance (5.6%; Figure 119).

AHRQ has developed several resources to improve provider-patient communication and to support improved understanding of a patient’s care plan, including:

- Guide to Improving Patient Safety in Primary Care Settings by Engaging Patients and Families (https://www.ahrq.gov/professionals/quality-patient-safety/patient-family-engagement/pfeprimarycare/index.html), which features a teach-back intervention. This intervention focuses on primary care providers discussing the patients’ care plan with them and having patients explain it back to them in their own words to ensure their understanding.^79^
- Health Literacy Universal Precautions Toolkit (www.ahrq.gov/literacy),80 which helps primary care practices promote greater understanding for all patients by using strategies such as teach-back (https://www.ahrq.gov/professionals/quality-patient-safety/quality-resources/tools/literacy-toolkit/healthlittoolkit2-tool5.html).
- TeamSTEPPS® Limited English Proficiency module that shows the importance of language assistance services in keeping patients safe and avoiding adverse events.^70^

#### Largest Disparities for Uninsured People

The three quality measures with the largest disparities between uninsured people and people with private insurance are person- and family-centered care measures:

- People without a usual source of care who indicated a financial or insurance reason for not having a source of care
- Deaths per 1,000 adult hospital admissions with abdominal aortic aneurysm repair
- Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high

##### Difficulty Accessing a Usual Source of Care

People with lower incomes may experience difficulty accessing affordable care and are less likely to have a usual source of care that is readily accessible.^94^ In addition, poor health contributes to low income, creating a cycle sometimes referred to as the health-poverty trap.^92^

Figure 120 People without a usual source of care who indicated a financial or insurance reason for not having a source of care, 2016

Note: For this measure, lower rates are better.

Column chart showing percentage Total, 13.8 Uninsured, 36.1 Private Insurance, 7.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, the percentage of adults without a usual source of care who indicated a financial or insurance reason for not having a source of care was five times as high for uninsured people (36.1%) compared with people with private insurance (7.2%; Figure 120).

##### Abdominal Aortic Aneurysm Mortality

Abdominal aortic aneurysm (AAA, or triple A) occurs mostly in adults over 60 years of age. The aorta can rupture due to an aneurysm (a weakened section of an artery wall). This type of aneurysm occurs more frequently in the part of the aorta that is within the abdomen. Several risk factors may contribute to this disease, including hypertension, diabetes, obesity, smoking, and high cholesterol.^117^

Figure 121 Deaths per 1,000 adult hospital admissions with abdominal aortic aneurysm repair, 2016

Note: For this measure, lower rates are better.

Column chart showing deaths per 1,000 admissions Total, 36.8 Uninsured, 109.8 Private Insurance, 27.2

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2016.

- In 2016, the AAA mortality rate was four times as high for uninsured adults (109.8 per 1,000 hospital admissions) compared with adults with private insurance (27.2 per 1,000 hospital admissions; Figure 121).

##### Blood Pressure Management

High blood pressure is a risk factor for heart disease and stroke. Maintaining healthy blood pressure requires patients to take prescription medication, consume healthier diets, and incorporate exercise into their routine. One-third of Americans have high blood pressure and another third are considered prehypertensive.^118^

Figure 122 Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high, 2017

Column chart showing percentage Total, 92.8 Uninsured, 78.4 Private Insurance, 94.3

Source: Centers for Disease Control and Prevention, National Health Interview Survey, 2017.

- In 2017, the percentage of adults who received a blood pressure measurement in the last 2 years and could state whether their blood pressure was normal or high was higher for people with private insurance (94.3%) compared with uninsured people (78.4%; Figure 122).

#### Changes in Quality of Care by Insurance Status

Figure 123 Number and percentage of all quality measures that were improving, not changing, or worsening, total and by insurance status, from 2000 through 2013, 2014, 2015, 2016, or 2017

Key: n = number of measures.

- Improving = Quality is going in a positive direction at an average annual rate greater than 1% per year.
- Not changing = Quality is not changing or is changing at an average annual rate of 1% or less per year.
- Worsening = Quality is going in a negative direction at an average annual rate greater than 1% per year.

Stacked bar chart showing number of quality measures Total (n=149), Improving, 70, Not Changing, 69, Worsening, 10 Uninsured (n=49), Improving, 18, Not Changing, 28, Worsening, 3 Public Only (n=50), Improving, 28, Not Changing, 20, Worsening, 2 Any Private (n=50), Improving, 24, Not Changing, 21, Worsening, 5

- From 2000 through 2017, across 149 measures of healthcare quality with data by insurance status, a higher percentage of measures was improving for people with public insurance (56%) compared with uninsured people (37%) and people with private insurance (48%) (Figure 123).
- The percentage of worsening measures was lower for people with public insurance (4%) compared with uninsured people (6%) and people with private insurance (10%).

#### Changes in Disparities by Insurance

Figure 124 Number and percentage of quality measures with disparity at baseline for which disparities related to insurance were improving, not changing, or worsening, 2000 through 2014, 2015, 2016, or 2017

Key: n = number of measures.

Stacked bar chart showing number of quality measures Total (n=58), Improving, 1, Not Changing, 56, Worsening, 1 Uninsured (n=35), Improving, 1, Not Changing, 33, Worsening, 1 Public Insurance Only (n=23), Improving, 0, Not Changing, 23, Worsening, 0

- Disparities by insurance status were not changing for most quality measures. These measures encompass Person-Centered Care, Affordable Care, Healthy Living, and Effective Treatment (Figure 124).
- One measure showed improvement over time in disparities between uninsured people and people with private insurance: Adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year.
- One measure showed a widening disparity between uninsured people and people with private insurance: People without a usual source of care who indicated a financial or insurance reason for not having a source of care.

##### Receipt of Flu Vaccine by Patients with Diabetes

Some patients are at higher risk of contracting the flu. These include children, older adults, and people with diabetes. The flu also has a greater likelihood of exacerbating diabetes in affected patients.^119^

Figure 125 Adults age 40 and over with diagnosed diabetes who received a flu vaccination in the calendar year, 2008-2016

Line graph showing percentage, indicating an increase over time for uninsured adults. Adults with insurance showed no statistically significant changes: uninsured, 2008, 36.7, 2016, 49.7; public insurance only, 2008, 52.5, 2016, 62.4; private insurance, 2008, 60.6, 2016, 59.7

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2008-2016.

- From 2008 to 2016, the disparity between adults with private insurance and uninsured adults narrowed in the percentage of adults age 40 and over with diabetes who received a flu vaccine. This percentage increased from 36.7% in 2008 to 49.7% in 2016 for uninsured adults. There were no statistically significant changes over time for people with private insurance in the percentage with diabetes who got a flu vaccine (Figure 125).

CDC has prepared several patient and provider resources, including fact sheets for adults about diabetes and adult vaccines.^120^

##### Financial or Insurance Barriers to Care

As noted earlier, people with lower incomes may have difficulty accessing a usual source of care.^94^

Figure 126 People without a usual source of care who indicated a financial or insurance reason for not having a source of care, 2002-2016

Line graph showing percentage, indicating an increase over time for uninsured adults. Adults with private insurance showed no statistically significant changes: uninsured, 2008, 28.0, 2016, 36.1; public insurance only, 2008, 18.5, 2016, 13.5; private insurance, 2008, 8.9, 2016, 7.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- From 2002 to 2016, the disparity between adults with private insurance and uninsured adults widened in the percentage of people without a usual source of care who indicated a financial or insurance reason for not having a source of care. The estimate for uninsured people without a usual source of care increased from 28% in 2002 to 36.1% in 2016, and there were no statistically significant changes for people with private insurance (Figure 126).

### Disparities by Residence Location

Where people live affects their access to healthcare and the quality of their healthcare. Current research shows that disparities by residence location affect both adults and children.^121,122,123,124,125,126^

#### Residence Location Groups

This report uses the 2013 National Center for Health Statistics (NCHS) classification for analyzing healthcare quality and disparities by residence location, replacing the previously used 2006 classification scheme.

The 2013 scheme includes six urbanization categories, including:

- Four metropolitan county designations:
  ■ Large Central Metropolitan: Large central metropolitan counties in a metropolitan statistical area (MSA) of 1 million or more population:
    1. That contain the entire population of the largest principal city of the MSA, or
    2. Whose entire population is contained within the largest principal city of the MSA, or
    3. That contain at least 250,000 residents of any principal city in the MSA.
  ■ Large Fringe Metropolitan: Counties in MSAs of 1 million or more population that do not qualify as large central.^xv^ Large Fringe Metropolitan areas are also described as suburban areas. This category is the reference group that all other residence locations are compared with in this report.
  ■ Medium Metropolitan: Counties in MSAs of 250,000 to 999,999 population.
  ■ Small Metropolitan: Counties in MSAs of less than 250,000 population.
- Two nonmetropolitan county designations:
  ■ Micropolitan: Counties in a micropolitan statistical area.
  ■ Noncore: Nonmetropolitan counties that are not in a micropolitan statistical area.

The key differences between the 2006 and the 2013 NCHS Urban-Rural Classification schemes are noted in the description of small metropolitan, micropolitan, and noncore areas. The 2013 classification broadens the inclusion criteria for each residence location. All other definitions are unchanged (Table 1).^127^

Table 1 NCHS Urban-Rural Classification Scheme, 2006 vs. 2013

Areas | 2006 Classification | 2013 Classification
Small Metropolitan | Counties in MSAs of 50,000 to 249,999 population | Counties in MSAs of less than 250,000 population.
Micropolitan | Urban cluster population of 10,000-49,999 individuals. | Counties in a micropolitan statistical area.
Noncore | Nonmetropolitan counties that did not qualify as micropolitan. | Nonmetropolitan counties that are not in a micropolitan statistical area.

Figure 127 shows a map of U.S. county classifications according to the 2013 NCHS Urban-Rural Classification system. Counties across the United States are listed below the map to show examples of the corresponding areas.

Figure 127 Map showing 2013 NCHS Urban-Rural County Classifications in the United States

Map of United States showing county grouping, which are described in the text after the map

- Metropolitan Areas:
  ■ Large Central Metropolitan Areas: Denver County, Colorado; Washington, DC; Cook County, Illinois.
  ■ Large Fringe Metropolitan Areas: San Bernardino County, California; Broward County, Florida; Bergen County, New Jersey.
  ■ Medium Metropolitan Areas: Scott County, Kentucky; York County, Maine; Douglas County, Nebraska.
  ■ Small Metropolitan Areas: Baldwin County, Alabama; Wayne County, North Carolina; Allen County, Ohio.
- Nonmetropolitan Areas:
  ■ Micropolitan Areas: Woodward County, Oklahoma; Cherokee County, South Carolina; Harrison County, West Virginia.
  ■ Noncore Areas: Wallowa County, Oregon; Bedford County, Pennsylvania; Crane County, Texas.

The QDR uses the NCHS classification to analyze performance of quality measures that have data available by residence location. In addition to the annual report, data on state-based performance metrics are available through the QDR State Snapshots.^128^

With the State Snapshots tool, users can explore the quality of their state’s healthcare and compare their state’s data with national data or data from the best performing states. Users can access a state dashboard showing performance compared with benchmarks for more than 80 measures. Some of these measures are also stratified by subpopulations to show disparities.

#### Overview of Disparities by Residence Location

Nonmetropolitan areas had worse performance on one-third of all quality measures compared with suburban areas in the latest data year.

Figure 128 Number and percentage of quality measures for which members of selected groups experienced better, same, or worse quality of care compared with reference group (large fringe metropolitan) in 2015, 2016, or 2017, by residence location

Key: n = number of measures.

Note: The measures represented in this chart are available in Appendix A. Definitions of residence locations are available at https://www.cdc.gov/nchs/data_access/urban_rural.htm (refer to Appendix B). The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from AHRQ HCUP is 2016.

Stacked bar chart showing number of quality measures Total Measures (n=508), Better, 40, Same, 359, Worse, 109 Large Central Metro (n=106), Better, 5, Same, 80, Worse, 21 Medium Metro (n=103), Better, 6, Same, 87, Worse, 10 Small Metro (n=102), Better, 9, Same, 81, Worse, 12 Micropolitan (n=102), Better, 10, Same, 60, Worse, 32 Noncore (n=95), Better, 10, Same, 51, Worse, 34

- Both nonmetropolitan areas, noncore (10.5%) and micropolitan (9.8%) had the highest percentage of quality measures for which performance was better than in large fringe metropolitan areas (Figure 128).
- Nonmetropolitan areas also had the highest percentage of measures for which performance was worse than in large fringe metropolitan areas: Noncore, 35.8%; Micropolitan, 31.4%; Large Central Metropolitan, 19.8%; Small Metropolitan, 11.8%; and Medium Metropolitan, 9.7%.

#### Largest Disparities

Measures with the largest disparities for residence location can be grouped into four categories:

- Mortality measures:
  ■ HIV infection deaths per 100,000 population (large central metropolitan, medium metropolitan)
  ■ Deaths per 1,000 hospital admissions with expected low-mortality (noncore)
  ■ Infant mortality per 1,000 live births, birth weight 2,500 grams or more (small metropolitan)
- Pediatric measures:
  ■ Children ages 0-17 with a wellness checkup in the past 12 months (medium metropolitan, small metropolitan, micropolitan)
  ■ Children who had their height and weight measured by a health provider within the past 2 years (micropolitan)
  ■ Emergency department encounters for asthma, children ages 2-17 (large central metropolitan)
  ■ Hospital admissions for asthma per 100,000 population, children ages 2-17 (large central metropolitan)
- Care Coordination measures:
  ■ Emergency department visits with a principal diagnosis related to dental conditions (micropolitan)
  ■ Hospital admissions for community-acquired pneumonia per 100,000 population, adults age 18 and over (noncore)
- Patient Safety measures:
  ■ Reclosure of postoperative abdominal wound dehiscence per 1,000 abdominopelvic surgery admissions of length 2 or more days, adults (medium metropolitan, small metropolitan, noncore)

##### Mortality Measure: HIV Infection Deaths

HIV mortality disproportionately affects some racial and ethnic groups more than others. According to CDC data, in 2016, HIV was the sixth leading cause of death for Black men ages 25-34 and fifth for Black women ages 35-44.^56^

Figure 129 HIV infection deaths per 100,000 population, 2016

Note: For this measure, lower rates are better.

Column chart showing rate per 100,000 population 2015 achievable benchmark: 0.75 per 100,000 population Total, 1.8 Large Central Metro, 2.9 Medium Metro, 1.6 Large Fringe Metro, 1.2

Source: Centers for Disease Control and Prevention, National Vital Statistics Survey - Mortality, 2016.

- In 2016, the death rate from HIV infections was higher in large central metro areas (2.9 per 100,000 population) and medium metro areas (1.6 per 100,000 population) compared with the rate in large fringe metro areas (1.2 per 100,000 population; Figure 129).
- The 2015 top 5 state achievable benchmark was 0.75 per 100,000 population. At the current rate of increase, overall, the benchmark could be achieved in 5 years for large central metropolitan and medium metropolitan areas and in 3 years for large fringe metropolitan areas.
- The top 5 states that contributed to the achievable benchmark are Kansas, Kentucky, Minnesota, Missouri, and Washington. In 2016, Colorado, Minnesota, Oregon, Washington, and Wisconsin reached the benchmark.

An HHS initiative to eliminate new HIV infections is underway. The goal is “to reduce new HIV infections in the United States by 75 percent in five years and by 90 percent by 2030.”^129^ Federal efforts to reduce HIV-related mortality include the promotion of treatment therapies such as antiretroviral therapy, as well as pre-exposure prophylaxis and postexposure prophylaxis.^130^

Several HHS agencies provide a federal response to the HIV epidemic, including HRSA’s HIV/AIDS Bureau, which administers the Ryan White HIV/AIDS Program (RWHAP). RWHAP is the largest federal program focused exclusively on providing HIV care and treatment to patients with inadequate or no insurance. Through RWHAP’s partnerships, more than 512,000 people receive care annually.^58^

##### Mortality Measure: Unexpected Deaths After Hospital Admission

Death within 30 days of a hospital discharge may indicate that patients did not receive appropriate care during their hospital admission.^131^ Factors contributing to death include noncontinuous care or treatment and inadequate communication with the care team.^132^

Figure 130 Deaths per 1,000 hospital admissions with expected low mortality, 2016

Note: For this measure, lower rates are better.

Column chart showing deaths per 1,000 hospital admissions Total, 0.22 Noncore, 0.43 Large Fringe Metro, 0.21

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2016.

- In 2016, the death rate for conditions with expected low mortality was higher in noncore areas (0.43 per 100,000 population) than in large fringe metro areas (0.21 per 100,000 population; Figure 130).

##### Mortality Measure: Infant Mortality

Low birth weight can be a predictor of developmental delays and mortality among infants.^133^ Infant mortality and low birth weight can decline when pregnant women receive adequate prenatal care.^134^

Figure 131 Infant mortality per 1,000 live births, birth weight 2,500 grams or more, 2016

Note: For this measure, lower rates are better.

Column chart showing deaths per 1,000 live births Total, 2.1 Small Metro, 2.6 Large Fringe Metro, 1.7

Source: Centers for Disease Control and Prevention, National Vital Statistics Survey – Linked Birth and Infant Death Data, 2016.

- In 2016, the mortality rate among infants with a birth weight of 2,500 grams or more was higher in small metro areas (2.6 per 1,000 live births) compared with large fringe metro areas (1.7 per 1,000 live births; Figure 131).

##### Pediatric Measure: Wellness Visits

Wellness visits for children offer preventive care, allow tracking of growth and development, identify concerns, and establish a team-based model of care for the provider, the child, and his or her parents or caregivers. The American Academy of Pediatrics has provided an online schedule for wellness visits.^135^

Figure 132 Children ages 0-17 with a wellness checkup in the past 12 months, 2017

Column chart showing percentage Total, 84 Medium Metro, 84.2 Small Metro, 82.6 Micropolitan, 78.0 Large Fringe Metro, 88.7

Source: Centers for Disease Control and Prevention, National Health Interview Survey, 2017.

- In 2017, the percentage of children ages 0-17 who had a wellness checkup in the past year was lower in medium metro (84.2%), small metro (82.6%), and micropolitan areas (78.0%) than in large fringe metro areas (88.7%; Figure 132).

##### Pediatric Measure: Height and Weight Measurement

During children’s wellness visits, it is standard practice to measure their height and weight. This practice allows providers to assess children’s body mass index (BMI) and development to see if there is any cause for concern. The Centers for Disease Control and Prevention has created a BMI calculator for children ages 2-19 years old.^136^

Although it is standard practice to measure height and weight, findings in this report show variation does exist by residence location.

Figure 133 Children who had their height and weight measured by a health provider within the past 2 years, 2016

Column chart showing percentage Total, 93.4 Micropolitan, 91.0 Large Fringe Metro, 95.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, the percentage of children who had their height and weight measured by a health provider within the past 2 years was lower in micropolitan areas (91.0%) than in large fringe metro areas (95.3%; Figure 133).

##### Pediatric Measure: Emergency Department Visits for Asthma

Asthma is one of the most common chronic pediatric diseases, and acute asthma exacerbation is a leading cause of emergency department (ED) visits for children.^137^ Given the severity of asthma, timely treatment is crucial. Current research shows that ED overcrowding, acuity, and age affect treatment time for children visiting the ED.^138,139^

Figure 134 Emergency department encounters for asthma, children ages 2-17, 2016

Note: For this measure, lower rates are better.

Column chart showing rate per 100,000 population Total, 730.7 Large Central Metro, 1,058.8 Large Fringe Metro, 606.9

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2016.

- In 2016, the rate of children ages 2-17 who with ED visits for asthma was almost twice as high in large central metro areas (1,058.8 per 100,000 population) as it was in large fringe metro areas (606.9 per 100,000 population; Figure 134).

##### Pediatric Measure: Hospital Admissions for Asthma

Asthma is the most common chronic lung condition among children under 17 years in the United States.^140^ Asthma has no cure and without treatment, patients can die. CDC research shows that from 2001 to 2016, 8% fewer children experienced one or more asthma attacks. Nonetheless, in 2017, about 1 in 12 children ages 0-17 had asthma and among them, asthma disproportionately affected males, non-Hispanic Black children, and children from low-income households.^60^

Figure 135 Hospital admissions for asthma per 100,000 population, children ages 2-17, 2016

Note: For this measure, lower rates are better.

Column chart showing rate per 100,000 population Total, 86.1 Large Central Metro, 127.3 Large Fringe Metro, 73.9

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2016.

- In 2016, the rate of hospital admissions for children ages 2-17 with asthma was almost twice as high in large central metro areas (127.3 per 100,000 population) as in large fringe metro areas (73.9 per 100,000 population; Figure 135).

##### Care Coordination Measure: Emergency Department Visits for Dental Conditions

More people across the United States are using the ED for dental complaints.^141^ In 2016, the rate of ED visits for dental complaints was 45.8 visits per 100 people.^142^ Research shows that many of these visits could be prevented through appropriate preventive care.^141^

Figure 136 Emergency department visits with a principal diagnosis related to dental conditions, 2016

Note: For this measure, lower rates are better.

Column chart showing rate per 100,000 population Total, 312.3 Micropolitan, 482.9 Large Fringe Metro, 221.6

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2016.

- In 2016, the rate of ED visits related to dental conditions in micropolitan areas (482.9 per 1,000 encounters) was more than twice the rate in large fringe metro areas (221.6 per 1,000 encounters; Figure 136).

##### Care Coordination Measure: Hospital Admissions for Pneumonia

Pneumonia is a devastating and life-threatening condition that can strike anyone, but older adults have increased susceptibility for community-acquired pneumonia (CAP).^143,144^ The costs associated with CAP can be mitigated by preventive efforts, including vaccinations.^144^ CDC recommends pneumococcal vaccination for all adults 65 years and over, as well as adults ages 19-64 years who have certain medical conditions (e.g., HIV, leukemia) or who smoke.^145^

Figure 137 Hospital admissions for community-acquired pneumonia per 100,000 population, adults age 18 and over, 2016

Column chart showing rate per 100,000 population Total, 227 Noncore, 481.9 Large Fringe Metro, 223.9

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2016.

- In 2016, the rate of hospital admissions for CAP was more than twice as high in noncore areas (481.9 per 100,000 population) compared with large fringe metro areas (223.9 per 100,000 population; Figure 137).

##### Patient Safety Measure: Surgical Complications

Wound dehiscence is when an incision breaks open and does not heal properly after surgery, often within 10 days.^146^ This postoperative complication can result in increased morbidity and mortality for patients who have had abdominopelvic surgeries.^147^

Figure 138 Reclosure of postoperative abdominal wound dehiscence per 1,000 abdominopelvic surgery admissions of length 2 or more days, adults, 2016

Note: For this measure, lower rates are better.

Column chart showing rate per 1,000 surgery admissions Total, 0.66 Medium Metro, 0.78 Small Metro, 0.81 Noncore, 1.05 Large Fringe Metro, 0.55

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2016.

- In 2016, the rate of adults who had a wound reclosed after abdominopelvic surgery was worse in three metro areas compared with large fringe metro areas (0.55 per 100,000 surgery admissions; Figure 138). Noncore areas had the worst rate (1.05 per 100,000 surgery admissions), followed by small metro (0.81 per 100,000 surgery admissions) and medium metro areas (0.78 per 100,000 surgery admissions).

#### Changes in Quality of Care by Residence Location

Figure 139 Number and percentage of all quality measures that were improving, not changing, or worsening, total and by residence location, from 2002 through 2011, 2015, 2016, or 2017

Key: n = number of measures.

- Improving = Quality is going in a positive direction at an average annual rate greater than 1% per year.
- Not changing = Quality is not changing or is changing at an average annual rate of 1% or less per year.
- Worsening = Quality is going in a negative direction at an average annual rate greater than 1% per year.

Stacked bar chart showing number of quality measures Total (n=344), Improving, 156, Not Changing, 155, Worsening, 33 Large Central Metro (n=57), Improving, 27, Not Changing, 25, Worsening, 5 Large Fringe Metro (n=57), Improving, 28, Not Changing, 23, Worsening, 6 Medium Metro (n=57), Improving, 25, Not Changing, 27, Worsening, 5 Small Metro (n=59), Improving, 27, Not Changing, 25, Worsening, 7 Micropolitan (n=58), Improving, 29, Not Changing, 25, Worsening, 4 Noncore (n=56), Improving, 20, Not Changing, 30, Worsening, 6

- Across 344 quality measures, 45% are improving, 45% are not changing, and 10% are worsening (Figure 139).
- Noncore areas have fewer improving measures and more measures not changing compared with other areas.

#### Changes in Disparities by Residence Location

Figure 140 Number and percentage of quality measures with disparity at baseline for which disparities related to residence location were improving or not changing, 2002 through 2011, 2014, 2015, 2016, or 2017

Key: n = number of measures.

Stacked bar chart showing number of quality measures Reference group is large fringe metro--no disparities were worsening (widening) Total (n=73), Improving, 4, Not Changing, 69 Large Central Metro (n=21), Improving, 1, Not Changing, 20 Medium Metro (n=9), Improving, 1, Not Changing, 8 Small Metro (n=10), Improving, 2, Not Changing, 8 Micropolitan (n=15), Improving, 0, Not Changing, 15 Noncore (n=18), Improving, 0, Not Changing, 18

- Disparities by residence location remained unchanged for most quality measures (Figure 140). These measures encompass Person- and Family-Centered Care, Care Affordability, Healthy Living, and Effective Treatment.
- The 2017 report did not show widening or narrowing disparities by residence location.^xvi^ This year’s report also shows no widening disparities. Of the four measures that showed narrowing disparities, the largest improvement over time was for Hospital inpatient stays involving opioid-related diagnoses per 100,000 population (large central metro).
- Both nonmetropolitan areas (noncore and micropolitan) showed no statistically significant differences over time for any measures.

##### Inpatient Stays Due to Opioid Use

Increased availability and overuse of opioid medications (both prescription and nonprescription drugs) have contributed to adverse outcomes for patients, including increased risk of opioid use disorder, misuse of medications, and potential overdoses.^107^

The rapid and ongoing rise in both numbers of hospitalizations and their costs suggests that the burden of prescription opioid overdoses may threaten the infrastructure and finances of U.S. hospitals.^148^

Figure 141 Hospital inpatient stays involving opioid-related diagnoses per 100,000 population, 2005-2016

Note: For this measure, lower rates are better.

Line graph showing rate per 100,000 population 2015 achievable benchmark: 102.9 per 100,000 population 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Large Central Metro 195.8 257.8 206.4 192.0 239.0 244.7 266.0 250.2 243.9 250.5 276.9 311.2 2005 2006 2007 2008 2009 2010 2011 2012 2013 2014 2015 2016 Large Fringe Metro 111.5 142.8 132.4 157.5 143.5 170.5 202.8 202.0 206.1 213.6 239.2 284.8

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2005-2016.

- From 2005 to 2016, the gap between people in large fringe metro areas and those in large central metro areas in opioid-related hospital stays has narrowed. In 2005, the rate was 111.5 per 100,000 population in large fringe metro areas vs. 195.8 per 100,000 population in large central metro areas. In 2016, both rates had risen, to 284.8 in large fringe metro areas and 311.2 in large central metro areas (Figure 141).
- Although the gap has narrowed over time, a disparity still exists and the rates for both populations are worsening.
- The 2015 top 5 state achievable benchmark was 102.9 per 100,000 population. Neither the large central metropolitan population nor the large fringe metro population has made progress toward the benchmark.
- The top 5 states that contributed to the achievable benchmark are Georgia, Iowa, Nebraska, Texas, and Wyoming. In 2016, Georgia, Iowa, Nebraska, South Carolina, South Dakota, Texas, and Wyoming reached the benchmark.

In 2017, HHS launched a departmentwide initiative with a five-point strategy to combat the opioid epidemic. Many agencies supported this initiative by establishing specific research opportunities, resources, and data to support providers, patients and researchers.^111^

vii For example, Section 1557 of the Affordable Care Act (ACA), 42 U.S.C. 18116, and Title VI of the Civil Rights Act of 1964, 42 U.S.C. 2000d, require the practitioner or hospital to take reasonable steps to ensure meaningful access to individuals with limited English proficiency, such as providing language interpreters and translating vital documents. Section 1557 of the ACA and Section 504 of the Rehabilitation Act of 1973, 29 U.S.C. 794, require the practitioner or hospital to take appropriate steps to ensure effective communication with individuals with disabilities, such as by providing sign language interpreters, materials in Braille, and/or accessible electronic formats.

viii To Err Is Human: Building a Safer Health System is a landmark report on patient safety, and AHRQ still considers it the gold standard for medical error research.

ix Data on measles cases are available on CDC’s website at https://www.cdc.gov/measles/cases-outbreaks.html.

x Due to the nationwide conversion from the International Classification of Diseases, Ninth Revision (ICD-9) to the Tenth Revision (ICD-10) codes in the last quarter of 2015, at this time, we cannot trend the data for some AHRQ Quality Indicators that are based on nationwide Healthcare Cost and Utilization Project (HCUP) data. Measures that have been included in past reports are not always represented in this year’s report. Wherever this situation applies, this report includes a footnote.

xi Due to the nationwide conversion from the International Classification of Diseases, Ninth Revision (ICD-9) to the Tenth Revision (ICD-10) codes in the last quarter of 2015, at this time, we cannot trend the data for some AHRQ Quality Indicators that are based on nationwide Healthcare Cost and Utilization Project (HCUP) data. Measures that have been included in past reports are not always represented in this year’s report. Wherever this situation applies, this report includes a footnote.

xii Due to the nationwide conversion from the International Classification of Diseases, Ninth Revision (ICD-9) to the Tenth Revision (ICD-10) codes in the last quarter of 2015, at this time, we cannot trend the data for some AHRQ Quality Indicators that are based on nationwide Healthcare Cost and Utilization Project (HCUP) data. Measures that have been included in past reports are not always represented in this year’s report. Wherever this situation applies, this report includes a footnote.

xiii Due to the nationwide conversion from the International Classification of Diseases, Ninth Revision (ICD-9) to the Tenth Revision (ICD-10) codes in the last quarter of 2015, at this time, we cannot trend the data for some AHRQ Quality Indicators that are based on nationwide Healthcare Cost and Utilization Project (HCUP) data. Measures that have been included in past reports are not always represented in this year’s report. Wherever this situation applies, this report includes a footnote.

xiv Due to the nationwide conversion from the International Classification of Diseases, Ninth Revision (ICD-9) to the Tenth Revision (ICD-10) codes in the last quarter of 2015, at this time, we cannot trend the data for some AHRQ Quality Indicators that are based on nationwide Healthcare Cost and Utilization Project (HCUP) data. Measures that have been included in past reports are not always represented in this year’s report. Wherever this situation applies, this report includes a footnote.

xv For comparisons across residence locations, large fringe MSAs (large city suburbs) are used as the reference group since these counties have the lowest levels of poverty and typically have the best quality and access to healthcare.

xvi Due to the nationwide conversion from the International Classification of Diseases, Ninth Revision (ICD-9) to the Tenth Revision (ICD-10) codes in the last quarter of 2015, at this time, we cannot trend the data for some AHRQ Quality Indicators that are based on nationwide Healthcare Cost and Utilization Project (HCUP) data. Measures that have been included in past reports are not always represented in this year’s report. Wherever this situation applies, this report includes a footnote.