# ACCESS TO HEALTHCARE AND DISPARITIES IN ACCESS

To obtain high-quality care, Americans must first gain entry into the healthcare system. Measures of access to care tracked in the QDR include having health insurance, having a usual source of care, encountering difficulties when seeking care, and receiving care as soon as wanted.

Historically, Americans have experienced variable access to care based on race, ethnicity, socioeconomic status, age, sex, disability status, sexual orientation, gender identity, and residential location. This report discusses findings that showed the largest statistically significant disparities related to some of these variables where data are available.

## Overall Trends in Access

Figure 11 Number and percentage of access measures for which measures were improving, not changing, or worsening, 2000 through 2016 or 2017

Key: n = number of measures.

Note: The measures represented in this chart are available in Appendix A.

Stacked column showing number of access measures Improving, 11, Not Changing, 7, Worsening, 3 Total = 21

Overall, 11 access measures were improving (Figure 11). Some of the largest improvements in access include:

- Children who had any appointments for routine healthcare in the last 12 months who sometimes or never^iv^ got an appointment for routine care as soon as needed.
- People who were in fair or poor health with a specific source of ongoing care.
- People with a specific source of ongoing care.

Three measures were worsening, including:

- Children who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment.

Figure 12 Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, 2002-2016

Note: For this measure, lower rates are better.

Line graph showing percentage 2002, 10.2 2003, 8.7 2004, 7 2005, 7.1 2006, 7 2007, 7.3 2008, 6.5 2009, 5.5 2010, 5.5 2011, 6 2012, 5.2 2013, 5.5 2014, 5.3 2015, 5.2 2016, 5.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- From 2002 to 2016, the percentage of children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed decreased from 10.2% to 5.8% (Figure 12).

Figure 13 People who were in fair or poor health with a specific source of ongoing care, 2009-2017

Line graph showing percentage 2009, 87.5 2010, 87.9 2011, 87.8 2012, 86.3 2013, 88.3 2014, 90.5 2015, 89.8 2016, 90.5 2017, 89.5

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2009-2017.

- From 2009 to 2017, the percentage of people in fair or poor health with a specific source of ongoing care increased from 87.5% to 89.5% (Figure 13).

Figure 14 People with a specific source of ongoing care, 2009-2017

Line graph showing percentage 2009, 85.5 2010, 85.5 2011, 86.8 2012, 85.9 2013, 86.6 2014, 87.9 2015, 87.7 2016, 88.2 2017, 88.3

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2009-2017.

- From 2009 to 2017, the percentage of people with a specific source of ongoing care increased from 85.5% to 88.3% (Figure 14).

Figure 15 Children who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, 2008-2016

Note: For this measure, lower rates are better.

Line graph showing percentage 2008, 4.2 2009, 4.6 2010, 4.3 2011, 4.4 2012, 4.4 2013, 4.9 2014, 5.2 2015, 4.8 2016, 5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2008-2016.

- The percentage of children who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment increased from 4.2% in 2008 to 5.0% in 2016 (Figure 15).

## Trends in Access Disparities

Most disparities in access to care showed no statistically significant changes, with a few exceptions. The following access measures showed that disparities over time narrowed (the difference between the comparison group and reference group decreased) from the baseline data year to the most recent data year.^v^

Figure 16 Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, 2008-2016

Note: For this measure, lower rates are better.

Line graph showing percentage for uninsured and any private insurance Uninsured 2008, 29.7 2009, 28.9 2010, 26.1 2011, 26.4 2012, 25.1 2013, 27.3 2014, 22.4 2015, 18.5 2016, 20.2 Any Private 2008, 7.5 2009, 7.1 2010, 6.3 2011, 7.1 2012, 6.6 2013, 6.3 2014, 7.0 2015, 6.9 2016, 7.4

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2008-2016.

- From 2008 to 2016, the gap between uninsured adults and adults with private insurance in the percentage of adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment decreased (Figure 16).
- In 2008, 7.5% of adults with private insurance and 29.7% of uninsured adults sometimes or never found it easy to get care, tests, or treatment. In 2016, 7.4% of adults with private insurance and 20.2% of uninsured adults sometimes or never found it easy to get care, tests, or treatment.

## Trends in Health Insurance Coverage

The Early Release Program of the National Health Interview Survey (NHIS) provides timely data on health insurance coverage in the United States. Since these are the latest data published, these data are not included in the summary analyses conducted for this report. However, it is important to note the status of health insurance coverage with the most recent data available at the time this report was released.

Below are findings from Health Insurance Coverage: Early Release of Estimates From the National Health Interview Survey, 2018 Report. More information about the estimates are available on the NHIS website at https://www.cdc.gov/nchs/nhis.htm.

Figure 17 Adults ages 18-64 who were uninsured or had private or public coverage at the time of interview, 1997-2018

Note: A small number of people were covered by both public and private plans and were included in both categories.

Line graph showing percentage for uninsured, public insurance, and private insurance 1997, Uninsured,18.9, Public, 10.2, Private, 72.8 2005, Uninsured, 18.9, Public, 11.5, Private, 70.9 2010, Uninsured, 22.3, Public, 15, Private, 64.1 2011, Uninsured, 21.3, Public, 15.9, Private, 64.2 2012, Uninsured, 20.9, Public, 16.4, Private, 64.1 2013, Uninsured, 20.4, Public, 16.7, Private, 64.2 2014, Uninsured, 16.3, Public, 17.7, Private, 67.3 2015, Uninsured, 12.8, Public, 18.9, Private, 69.7 2016, Uninsured, 12.4, Public, 20, Private, 69.2 2017, Uninsured, 12.8, Public, 19.3, Private, 69.3 2018, Uninsured,13.3, Public, 19.4, Private, 68.9

Source: National Center for Health Statistics, National Health Interview Survey Early Release Program, May 2019. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur201905.pdf.

- In 2018, among adults ages 18-64, 68.9% (136.6 million) had private health insurance, 19.4% (39 million) had public coverage, and 13.3% (26.3 million) were uninsured at the time of interview (Figure 17).
- After generally increasing, more recently, the percentage of adults ages 18-64 who were uninsured at the time of interview decreased and then leveled off. Between 2015 and 2018, the increase among uninsured adults ages 18-64 (from 12.8% to 13.3%) was not statistically significant.
- The percentage of adults ages 18-64 with private or public coverage generally increased. However, more recently the percentages with private or public coverage have leveled off.

Figure 18 Children ages 0-17 years who were uninsured or had private or public coverage at the time of interview, 1997-2018

Note: A small number of people were covered by both public and private plans and were included in both categories.

Line graph showing percentage for uninsured, public insurance, and private insurance 1997, Uninsured,12.9, Public, 21.4, Private, 66.2 2005, Uninsured, 8.9, Public, 29.9, Private, 62.4 2010, Uninsured, 7.8, Public, 39.8, Private, 53.8 2011, Uninsured, 7, Public, 41, Private, 53.3 2012, Uninsured, 6.6, Public, 42.1, Private, 52.8 2013, Uninsured, 6.5, Public, 42.2, Private, 52.6 2014, Uninsured, 5.5, Public, 42.2, Private, 53.7 2015, Uninsured, 4.5, Public, 42.2, Private, 54.7 2016, Uninsured, 5.1, Public, 43, Private, 53.8 2017, Uninsured, 5, Public, 41.3, Private, 55 2018, Uninsured,5.2, Public, 41.8, Private, 54.7

Source: National Center for Health Statistics, National Health Interview Survey Early Release Program, May 2019. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur201905.pdf

- In 2018, among children ages 0-17 years, 54.7% had private health insurance, 41.8% had public coverage, and 5.2% were uninsured (Figure 18).
- The percentage of children who were uninsured generally decreased over time. However, more recently, the percentage of children who were uninsured has leveled off.
- While the percentage of children with private health insurance coverage has decreased and public coverage has increased over time, more recently, the percentage of children with public or private coverage has leveled off.

Figure 19 Adults ages 18-64 who were uninsured at the time of interview, by poverty status, 1997-2018

Note: For this measure, lower rates are better. Poverty categories are based on the ratio of the family’s income in the previous calendar year to the appropriate poverty threshold (given the family’s size and number of children), as defined by the U.S. Census Bureau for that year. People categorized as “poor” have a ratio less than 1.0 (i.e., their family income is below the poverty threshold); “near poor” people have incomes of 100% to less than 200% of the poverty threshold; and “not poor” people have incomes that are 200% of the poverty threshold or greater.

Line graph showing percentage for poor, near poor, not poor Year Poor Near Poor Not Poor 1997 40.2 34.9 9.9 2005 38.5 36.6 10.7 2010 42.2 43 12.6 2011 40.1 40.1 12 2012 40.1 39.2 11.4 2013 39.3 38.5 11.4 2014 32.3 30.9 8.9 2015 25.2 24.1 7.6 2016 26.2 23.2 7.2 2017 24.4 23.8 8.2 2018 27.4 25.1 8.3

Source: National Center for Health Statistics, National Health Interview Survey Early Release Program, May 2019. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur201905.pdf.

- In 2018, among adults ages 18-64, 27.4% of those who were poor, 25.1% of those who were near poor, and 8.3% of those who were not poor lacked health insurance coverage at the time of interview (Figure 19).
- The percentage of uninsured adults decreased between 2010 and 2018 among all three poverty status groups. However, the greatest decreases in the uninsured rate since 2013 were among adults who were poor or near poor.
- More recently, among adults ages 18-64 who were not poor, the percentage who were uninsured increased between 2015 and 2018. However, the observed increases between 2015 and 2018 in the percentage uninsured among those who were poor and near poor were not statistically significant.

Figure 20 Children ages 0-17 years who were uninsured at the time of interview, by poverty status, 1997-2018

Note: For this measure, lower rates are better. Poverty categories are based on the ratio of the family’s income in the previous calendar year to the appropriate poverty threshold (given the family’s size and number of children), as defined by the U.S. Census Bureau for that year. People categorized as “poor” have a ratio less than 1.0 (i.e., their family income is below the poverty threshold); “near poor” people have incomes of 100% to less than 200% of the poverty threshold; and “not poor” people have incomes that are 200% of the poverty threshold or greater.

Line graph showing percentage for poor, near poor, and not poor Year Poor Near Poor Not Poor 1997 22.4 22.8 6.1 2005 13 14.7 4.6 2010 10.2 12.6 4.6 2011 8.1 11.5 4 2012 7.5 10.1 4.5 2013 7.8 10.6 4 2014 5.9 8.6 3.6 2015 4.4 6.7 3.3 2016 6.5 6.9 3.5 2017 6 7.5 3.8 2018 6.4 6.3 4.2

Source: National Center for Health Statistics, National Health Interview Survey Early Release Program, May 2019. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur201905.pdf.

- In 2018, among children ages 0-17 years, 6.4% of those who were poor, 6.3% of those who were near poor, and 4.2% of those who were not poor lacked health insurance coverage at the time of interview (Figure 20).
- The percentage of uninsured children decreased among all three groups between 2010 and 2015.
- Among children who were not poor, the percentage who were uninsured increased from 3.3% in 2015 to 4.2% in 2018.
- From 2015 through 2018, among children who were near poor, there were no statistically significant changes in the percentage who were uninsured.
- Among poor children, the percentage who were uninsured increased from 4.4% in 2015 to 6.5% in 2016 and has stayed relatively stable between 2016 and 2018.

Figure 21 Adults ages 18-64 who were uninsured at the time of interview, by race/ethnicity, 2010-2018

Note: For this measure, lower rates are better. White, Black, and Asian are non-Hispanic. Hispanic includes all races. Data for Native Hawaiians/Pacific Islanders and American Indians and Alaska Natives are not available for this measure.

Line graph showing percentage for White, Black, Asian, and Hispanic Year White Black Asian Hispanic 2010 16.4 27.2 19.5 43.2 2011 15.6 24.8 18.8 42.2 2012 15.1 23.6 19.1 41.3 2013 14.5 24.9 16.3 40.6 2014 11.6 17.7 12.5 33.7 2015 8.7 14.4 7.9 27.7 2016 8.6 15 7.5 25 2017 8.5 14.1 7.6 27.2 2018 9 15.2 8.1 26.7

Source: National Center for Health Statistics, National Health Interview Survey Early Release Program, May 2019. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur201905.pdf.

- In 2018, among adults ages 18-64, 9.0% of Whites, 15.2% of Blacks, 8.1% of Asians, and 26.7% of Hispanics lacked health insurance coverage at the time of interview (Figure 21).
- Significant decreases in the percentage of uninsured adults were observed from 2013 through 2018 for all four racial/ethnic groups.
- Hispanic adults had the greatest percentage point decrease in the uninsured rate from 2013 (40.6%) through 2018 (26.7%).

## Snapshot of Disparities in Access

Figure 22 Number and percentage of access measures for which members of selected groups experienced better, same, or worse access to care compared with reference group, 2016 or 2017

Key: n = number of measures; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: The measures represented in this chart are available in Appendix A. The number of measures is based on the measures that have data for each population group.

Stacked columns showing number of access measures Poor vs. High Income (n=20), 1 same, 19 worse Black vs. White (n=21), 1 better, 11 same, 9 worse Asian vs. White (n=19), 6 better, 6 same, 7 worse AI/AN vs. White (n=11), 6 same, 5 worse NHPI vs. White (n=4), 4 same Hispanic vs. Non-Hispanic White (n=20), 3 better, 2 same, 15 worse

For the most recent data year (2016 or 2017), findings show that many disparities persist in access to care. Selected findings below show the largest disparities for each population group.

### Poor People

Poor people (at or below 100% of the Federal Poverty Level [FPL) experienced worse access to care compared with high-income people (400% or more of FPL) for 19 of 20 access measures (Figure 22; see Appendix A). Across the QDR measure set for the most recent data year, health insurance measures showed the largest disparities between poor people and high-income people.

Figure 23 People under age 65 with health insurance, 2017

Bar chart showing percentage Total, 89.3, Poor, 82.1, High Income, 96.1

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2017.

- In 2017, 82.1% of poor individuals under age 65 had health insurance compared with 96.1% of high-income individuals (Figure 23).

Figure 24 People under age 65 with any private health insurance, 2017

Columns showing percentage Total, 65.7, Poor, 20.8. Low Income, 36.7, Middle Income, 70.5, High Income, 91

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2017.

- In 2017, 20.8% of poor individuals under age 65 had private health insurance compared with 91.0% of high-income individuals (Figure 24).

### Blacks

Blacks experienced worse access to care compared with Whites for 43% of the measures and the same access to care for 52% of the measures (Figure 22; see Appendix A). Access measures related to timely access to care showed the largest disparities between Blacks and Whites.

Figure 25 Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, 2016

Note: For this measure, lower rates are better. Routine care includes healthcare at a doctor’s office or clinic when care is not needed right away

Columns showing percentage Total, 5.8 Black, 8.3 White, 4.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, 8.3% of Black children who had any appointments for routine healthcare in the last 12 months sometimes or never got an appointment for routine care as soon as needed compared with 4.9% of White children (Figure 25).

Figure 26 Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, 2016

Note: For this measure, lower rates are better.

Columns showing percentage Total, 7.8 Black, 12.3 White, 6.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, 12.3% of Black adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment sometimes or never found it easy to get the care, tests, or treatment compared with 6.8% of White adults (Figure 26).

### Asians

Asians experienced worse access to care compared with Whites for 37% of the measures, the same access for 32% of the measures, and better access for 32% of the measures (Figure 22; see Appendix A). Access measures that showed the largest disparities between Asians and Whites include measures related to timely access to care.

Figure 27 Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, 2016

Note: For this measure, lower rates are better.

Columns showing percentage Total, 5.8 Asian, 10.4 White, 4.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, 10.4% of Asian children who had any appointments for routine healthcare in the last 12 months sometimes or never got an appointment for routine care as soon as needed compared with 4.9% of White children (Figure 27).

Figure 28 Adults who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, 2016

Note: For this measure, lower rates are better.

Columns showing percentage Total, 14 Asian, 25.8 White, 12.6

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, 25.8% of Asian adults who had any appointments for routine healthcare in the last 12 months sometimes or never got an appointment for routine care as soon as needed compared with 12.6% of White adults (Figure 28).

### American Indians/Alaska Natives

Among the 11 measures in the QDR measure set that had data for AI/ANs for the most recent data year, 5 showed worse care for AI/ANs compared with Whites, and 6 showed the same access to care for AI/ANs (Figure 22; see Appendix A). Access measures that showed the largest disparities between AI/ANs and Whites include health insurance measures.^vi^

Figure 29 People under age 65 who were uninsured all year, 2016

Note: For this measure, lower rates are better.

Columns showing percentage Total, 9.0 AI/AN, 27.3 White, 9.1

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, 27.3% of AI/ANs under age 65 were uninsured all year compared with 9.1% of Whites (Figure 29).

Figure 30 People under age 65 with health insurance, 2017

Columns showing percentage Total, 89.3 AI/AN, 73.1 White, 89.4

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2017.

- In 2017, 73.1% of AI/ANs under age 65 had health insurance compared with 89.4% of Whites (Figure 30).

### Native Hawaiians/Pacific Islanders

Among the 4 measures in the QDR measure set that had data for NHPIs for the most recent data year, all 4 showed the same access to care for NHPIs compared with Whites ((Figure 22; see Appendix A). Access measures include 2 health insurance measures, 1 measure for usual source of care, and 1 measure of patient’s perception of getting needed care.

### Hispanics

Hispanics experienced worse access to care compared with non-Hispanic Whites for 75% of the measures for the most recent data year, the same access for 10% of the measures, and better access for 15% of the measures (Figure 22; see Appendix A). Access measures that showed the largest disparities between Hispanics and non-Hispanic Whites include health insurance measures.

Figure 31 People under age 65 who were uninsured all year, 2016

Note: For this measure, lower rates are better.

Columns showing percentage Total, 9.0 Hispanic, 18.3 Non-Hispanic White, 6.0

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- In 2016, 18.3% of Hispanics under age 65 were uninsured all year compared with 6.0% of Whites (Figure 31).

Figure 32 People under age 65 with health insurance, 2017

Columns showing percentage Total, 89.3 Hispanic, 79.4 Non-Hispanic White, 92.6

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2017.

- In 2017, 79.4% of Hispanics under age 65 had health insurance compared with 92.6% of non-Hispanic Whites (Figure 32).

iv The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

v Trends in disparities are defined as a change in the difference between a comparison group and reference group from the baseline data year to the most recent data year. The change in disparities is the absolute difference in annual percentage of change between the comparison group and reference group. The annual percentage of change is estimated using unweighted linear regression. For more information, see Introduction and Methods.

vi The Indian Health Service (IHS) offers public coverage to and is considered a comprehensive healthcare delivery system for AI/ANs. Currently, IHS serves 2.6 million AI/ANs who belong to 573 federally recognized tribes in 37 states. IHS is not described as a health plan in this report.