# OVERVIEW OF U.S. HEALTHCARE SYSTEM LANDSCAPE

The Institute of Medicine defines healthcare quality as “the degree to which health care services for individuals and populations increase the likelihood of desired health outcomes and are consistent with current professional knowledge.” Many factors contribute to the quality of care in the United States, including access to timely care, affordability of care, and use of evidence-based guidelines to drive treatment.

This section of the report highlights utilization of healthcare services, healthcare workforce, healthcare expenditures, and major contributors to morbidity and mortality. These factors help to paint an overall picture of the U.S. healthcare system and particularly areas where improvements are needed. Quality measures show whether the healthcare system is adequately addressing risk factors, diseases, and conditions that place the greatest burden on the healthcare system and if change has occurred over time.

## Overview of the U.S. Healthcare System infrastructure

Healthcare in the United States is complex. The healthcare industry employs millions of workers providing billions of services each year. In 2016, there were 626 health systems in the United States. About 12% of systems offer a Medicare Advantage plan (Figure 1). Nearly one-third of Medicare beneficiaries are covered by private insurers through the Medicare Advantage program.

Figure 1 Variation in systems offering a Medicare Advantage plan, by number of physicians in the system

Key: HMO = health maintenance organization; PACE = Programs of All-Inclusive Care for the Elderly.

Note: The hospital figures represent all nonfederal general acute care hospitals in the United States. A health system is an organization that includes at least one hospital and at least one group of physicians that provides comprehensive care (including primary and specialty care) and is connected with each other and with the hospital through common ownership or joint management.

Bar graph showing plans offered 50-149 physicians (205 systems): Any, 2%, HMO, 2%, PACE, 1%, Other, 0.5% 150-449 physicians (215 systems): Any, 10%, HMO, 5%, PACE, 4%, Other, 2% 500+ physicians (206 systems): Any, 23%, HMO, 17%, PACE, 7%, Other, 8%

Source: Agency for Healthcare Research and Quality, Snapshot of U.S. Health Systems, 2016 Data Highlight No.1 (https://www.ahrq.gov/sites/default/files/wysiwyg/snapshot-of-us-health-systems-2016v2.pdf).

The QDR tracks care delivered by providers in many types of healthcare settings. The goal is to provide high-quality healthcare that is culturally and linguistically sensitive, patient centered, timely, affordable, well coordinated, and safe. The receipt of appropriate high-quality services and counseling about healthy lifestyles can facilitate the maintenance of well-being and functioning. In addition, social determinants of health, such as education, income, and residence location, can affect access to care and quality of care.

Improving care requires facility administrators and providers to work together to expand access, enhance quality, and reduce disparities. It also requires coordination between the healthcare sector and other sectors for social welfare, education, and economic development. For example, Healthy People 2020 includes 33 social determinants of health objectives for federal programs and interventions.^ii^

The numbers of health service encounters and people working in health occupations illustrate the large scale and inherent complexity of the U.S. healthcare system. The tracking of healthcare quality measures in this report, notably in the Trends in Quality section, attempts to quantify progress made in improving quality and reducing disparities in the delivery of healthcare to the American people.

Figure 2 Number of healthcare service encounters, United States, 2015, 2016, 2017

Bar chart showing number of encounters in millions; data are provided in the text after the chart

Source: National Center for Health Statistics (NCHS), Health, United States, 2017 (physician [Table 76] and hospital visits [Table 82]) (https://www.cdc.gov/nchs/data/hus/hus17.pdf); NCHS, Long-term care providers and services users in the United States: data from the National Study of Long-Term Care Providers, 2015-2016 (https://www.cdc.gov/nchs/data/series/sr_03/sr03_43-508.pdf) (nursing home days); Medicare Payment Advisory Commission (MedPAC), Health care spending and the Medicare Program: a data book, March 2019 (http://medpac.gov/docs/default-source/reports/mar19_medpac_entirereport_sec.pdf?sfvrsn=0) (home health [Table 9-1]) and hospice data [Table 12-4]).

- In 2015, there were 991 million physician office visits, including visits to physicians in health centers (Figure 2).
- In 2015, there were 832 million hospital outpatient visits.
- In 2016, residents spent 492 million days in nursing homes.
- In 2015, patients spent 214 million days in hospitals.
- In 2017, patients spent 132 million days in hospice.
- In 2017, there were 105 million home health visits.

Figure 3 Number of people working in health occupations, United States, 2017 (unless otherwise noted)

Note: Doctors of Medicine also include Doctors of Osteopathic Medicine. Other health practitioners include physician assistants, medical assistants, dental assistants, chiropractors, dietitians and nutritionists, optometrists, podiatrists, and audiologists, as well as massage therapists, medical equipment preparers, medical transcriptionists, pharmacy aides, veterinary assistants and laboratory animal caretakers, phlebotomists, and healthcare support workers. Aides include nursing, psychiatric, home health, occupational therapy, and physical therapy assistants and aides. Therapists include occupational therapists, physical therapists, radiation therapists, recreational therapists, respiratory therapists, speech-language pathologists, and exercise physiologists.

Bar chart showing number of people Dentists (2016), 196,000 Advanced Practice Nurses, 215,450 Emergency Medical Technicians and Paramedics, 252,000 Pharmacists, 309,000 Other Health Practitioners, 370,100 Therapists, 676,140 Doctors of Medicine (2019), 1,005,000 Other Health Occupations, 1,531,200 Health Technologists, 2,451,250 Aides, 2,581,880 Registered Nurses, 2,907,000

Source: National Center for Health Statistics, Health, United States, 2017 (https://www.cdc.gov/nchs/hus/index.htm) (dentists); The Henry J. Kaiser Family Foundation, State Health Facts, Provider and Service Use, 2019 (https://www.kff.org/other/state-indicator/total-active-physicians/?currentTimeframe=0&sortModel=%7B%22colId%22:%22Location%22,%22sort%22:%22asc%22%7D (https://www.kff.org/other/state-indicator/total-active-physicians/?currentTimeframe=0&sortModel=%7B%22colld%22:%22Location%22,%22sort%22:%22asc%22%7D)) (doctors); and Bureau of Labor Statistics Occupational Employment Statistics (https://www.bls.gov/oes/), 2017 (all other occupations).

- In 2019, there were 1,005,000 active medical doctors in the United States, which include doctors of medicine and doctors of osteopathy (Figure 3).
- In 2016, there were 196,000 dentists.
- In 2017, there were 2.9 million registered nurses, 2.5 million health technologists, and 2.6 million nursing and other aides.
- In 2017, 370,000 other health practitioners provided care, including more than 109,000 physician assistants.

## Overview of Disease Burden in the United States

The National Institutes of Health defines disease burden as the impact of a health problem, as measured by prevalence, incidence, mortality, morbidity, extent of disability, financial cost, or other indicators. The healthcare system aims to mitigate the effects of burden caused by the leading causes of morbidity and mortality.

This section of the report highlights three areas of disease burden that have major impact on the health system of the United States, and measures of quality for most of these conditions are tracked in the QDR. Variation in access to care and care delivery across communities contributes to disparities related to race, ethnicity, sex, and socioeconomic status.

The concept of years of potential life lost (YPLL) involves estimating the average time a person would have lived had he or she not died prematurely. This measure is used to help quantify social and economic loss owing to premature death, and it has been promoted to emphasize specific causes of death affecting younger age groups. YPLL inherently incorporates age at death, and its calculation mathematically weights the total deaths by applying values to death at each age.^1^

Figure 4 Years of potential life lost before age 65, United States, 2017

Key: YPLL = years of potential life lost.

Note: The perinatal period occurs from 22 completed weeks (154 days) of gestation and ends 7 completed days after birth.^iii^

Bar chart showing age-adjusted rate of YPLLs per 100,000 Cerebrovascular Disease, 79.4 Diabetes, 91.1 Liver Disease, 108.6 Congenital Anomalies, 159.1 Homicide, 223.6 Perinatal Period, 285.8 Suicide, 354.4 Heart Disease, 460.8 Cancer, 559 Unintentional Injury, 1062.1

Source: Centers for Disease Control and Prevention, National Center for Injury Prevention and Control (https://www.cdc.gov/injury), Years of Potential Life Lost (YPLL) Reports, 1999-2017. https://webappa.cdc.gov/sasweb/ncipc/ypll10.html.

- From 2016 to 2017, there were no changes in the ranking of the top 10 leading diseases and injuries contributing to YPLL (Figure 4).
- The top category contributing to YPLL, unintentional injury, increased from 1,020.8 per 100,000 population in 2016 to 1,062.1 per 100,000 population in 2017.
- In 2017, among females, unintentional injuries were the second leading contributing factor for YPLL, suicide the 5^th^, and homicide the 7^th^ leading contributor. Among males, unintentional injuries were the second leading contributor to YPLL, suicide the 4^th^, and homicide the 5^th^ leading contributor to YPLL (data not shown).

A disability-adjusted life year (DALY) is a measure of burden of disease that takes into account years of life lost due to premature death and years of productive life lost to poor health or disability. For a given population, DALYs are calculated by summing the years of life lost prematurely and weighted years lived with disability. Improvements in the United States’ age-standardized DALY rate since 1995 have largely come from improvements in premature death (years of life lost), as opposed to improvements in the years lived with disability.

Figure 5 Age standardized disability-adjusted life year rate per 100,000 population, both sexes, by disease, 2017

Bar graph showing rate per 100,000 population of disability-adjusted life years Skin Diseases, 884 Diabetes, 1,173 Chronic Respiratory Diseases, 1,226 Nervous System Disorders, 1,574 Substance Use Disorders, 2,002 Mental Disorders, 2,133 Musculoskeletal Disorders, 2,287 Injuries, 2,836 Cancers and Tumors (Neoplasms), 2,942 Cardiovascular Diseases, 3,030

Source: Kaiser Family Foundation analysis of data from Institute for Health Metrics and Evaluation. Global Burden of Disease Study 2016 (GBD 2016) Data Downloads (http://ghdx.healthdata.org/gbd-results-tool?params=gbd-api-2017-permalink/800072f595f5c8beaf8722067f58572f).

- In 2017, cardiovascular diseases (3,030 per 100,000 population) and cancer (2,942 per 100,000 population) accounted for most DALYs (Figure 5).

Figure 6 Leading causes of death for the total population, United States, 2017

Bar chart showing age-adjusted deaths per 100,000 population Kidney Disease, 13 Suicide, 14 Pneumonia and Flu, 14.3 Diabetes, 21.5 Alzheimer's Disease, 31 Stroke, 37.6 Chronic Lower Respiratory Diseases, 40.9 Unintentional Injuries, 49.4 Cancer, 152.5 Heart Disease, 165

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Mortality. Mortality in the United States, 2017. https://www.cdc.gov/nchs/data/databriefs/db328-h.pdf.

- In 2017, heart disease, cancer, unintentional injuries, chronic lower respiratory diseases, stroke, Alzheimer’s disease, and diabetes were among the leading causes of death for the overall U.S. population (Figure 6).
- Overall, suicide was the 9^th^ leading cause of death in 2017, the 8^th^ leading cause among men, and the 14^th^ among females (data by sex not shown).
- From 2016 to 2017, age-adjusted death rates increased for pneumonia and flu, suicide, stroke, chronic lower respiratory diseases, Alzheimer’s disease, diabetes, and unintentional injuries (data not shown).
- From 2016 to 2017, cancer showed a significant decrease (data not shown).
- In 2017, unintentional injuries was the third leading cause of death among males and sixth among females (data not shown).

The years of potential life lost, years with disability, and leading causes of death illustrate the burden of disease experienced by the American people. Findings highlighted in the Trends in Quality section of this report attempt to quantify progress made in improving quality of care, reducing disparities in healthcare, and ultimately reducing disease burden.

## Overview of Healthcare Costs in the United States

- In 2017, national health expenditures totaled about $3 trillion, excluding administrative and investment costs.^2^
- The rate of growth in hospital spending decreased in 2017. Spending rose 4.6 percent to $1.1 trillion compared with 5.6 percent growth in 2016. The slower growth for 2017 reflected slower growth in use and intensity of services. Growth in outpatient visits slowed while growth in inpatient days increased at about the same rate in both 2016 and 2017.
- Physician and clinical services spending increased 4.2 percent to $694.3 billion in 2017. This increase followed more rapid growth of 5.6 percent in 2016 and 6.0 percent in 2015. Less growth in total spending for physician and clinical services in 2017 was a result of slower growth in use and intensity of physician and clinical services.
- Retail prescription drug spending slowed in 2017, increasing 0.4 percent to $333.4 billion. This slower rate of growth followed 2.3 percent growth in 2016, which was much slower than in 2014, when spending grew 12.4 percent, and in 2015, when spending grew 8.9 percent. These higher rates of growth in 2014 and 2015 were primarily the result of the introduction of new, innovative medicines and faster growth in prices for existing brand-name drugs.
  Retail prescription drug spending growth slowed in 2017 primarily due to slower growth in the number of prescriptions dispensed, a continued shift to lower cost generic drugs, slower growth in the volume of some high-cost drugs, declines in generic drug prices, and lower price increases for existing brand-name drugs.^3^
- Expenditures from multiple sources channeled to both the public and private care sectors make it challenging to control growth in healthcare costs. New delivery system models such as the patient-centered medical home have been developed to coordinate fragmented care across public and private sectors and may promote more efficient healthcare spending.

Figure 7 Distribution of personal healthcare expenditures by type of expenditure, 2017

Note: Personal healthcare expenditures are outlays for goods and services related directly to patient care. These expenditures are total national health expenditures minus expenditures for investment, health insurance program administration and the net cost of insurance, and public health activities. More detailed information is available at https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/Downloads/DSM-16.pdf.

Pie chart showing distribution of expenditures Hospital Care, 38.2% Physician and Clinical Services, 23.5% Prescription Drugs, 11.6% Nursing Care, 5.7% Other Health Care, 13.4% Dental Services, 4.4% Home Health Care, 3.3%

Source: Centers for Medicare & Medicaid Services, National Health Expenditures by type of service and source of funds, CY 1960-2017. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html.

- In 2017, hospital care expenditures were $1.1 trillion, nearly 40% of personal healthcare expenditures (Figure 7).
- Expenditures for physician and clinical services were $694.3 billion, almost one-fourth of personal healthcare expenditures
- Prescription drug expenditures were $333.4 billion, 12% of personal healthcare expenditures.
- Expenditures for dental services were $129.1 billion, 4% of personal healthcare expenditures.
- Nursing care facility expenditures were $166.3 billion and home health care expenditures were $97 billion, 6% and 3% of personal healthcare expenditures, respectively.

Figure 8 Personal healthcare expenditures and prescription drug expenditures, by source of funds, 2017

Note: Data for both figures are available at https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html. Percentages may not add to 100 due to rounding. Personal healthcare expenditures are outlays for goods and services related directly to patient care. These expenditures are total national health expenditures minus expenditures for investment, health insurance program administration and the net cost of insurance, and public health activities. Other health insurance programs include Children’s Health Insurance Program (Titles XIX and XXI) and programs available through the Department of Defense and the Department of Veterans Affairs. Other third party payers may include worksite healthcare, other private venues, Indian Health Service, workers’ compensation, general assistance, maternal and child health programs, vocational rehabilitation programs, other federal programs, Substance Abuse and Mental Health Services Administration, other state and local programs, and school health programs.

Pie chart showing source of funds for healthcare expenditures Private, 35.1% Medicare, 22.3% Medicaid , 17.6% Out of Pocket, 12.3% Other Third Party, 8.4% Other Health Insurance Programs, 4.3%

Source: Centers for Medicare & Medicaid Services, National Health Expenditures by type of service and source of funds, CY 1960-2017; and NHE Tables 6, 7, 8, 12, 14, and 15.

Pie chart showing source of funds for prescription drugs Private Health Insurance, 42.0% Medicare , 30.3% Medicaid , 9.9% Out of Pocket, 14.0% Other Third Party Payers, 0.5% Other Health Insurance Programs, 3.3% Source: Centers for Medicare & Medicaid Services, NHE Table 16, Retail Prescription Drugs Expenditures; Levels, Percent Change, and Percent Distribution, by Source of Funds: Selected Calendar Years 1970-2017.

Source: Centers for Medicare & Medicaid Services, NHE Table 16, Retail Prescription Drugs Expenditures; Levels, Percent Change, and Percent Distribution, by Source of Funds: Selected Calendar Years 1970-2017.

- In 2017, private insurance accounted for 35% of personal healthcare expenditures, followed by Medicare, Medicaid, and out of pocket (Figure 8).
- Sources of funds varied by type of expenditure (data not shown):
  ■ Private insurance accounted for 40% of hospital, 43% of physician, 11% of home health, 10% of nursing home, 45% of dental, and 42% of prescription drug expenditures.
  ■ Medicare accounted for 25% of hospital, 23% of physician, 40% of home health, 23% of nursing home, 0.7% of dental, and 30% of prescription drug expenditures.
  ■ Medicaid accounted for 17% of hospital, 11% of physician, 36% of home health, 30% of nursing home, 10% of dental, and 10% of prescription drug expenditures.
  ■ Out-of-pocket payments accounted for 3% of hospital, 9% of physician, 9% of home health, 27% of nursing home, 41% of dental, and 14% of prescription drug expenditures.
- In 2017, retail prescription drug expenditures were $333.4 billion. Patients paid 14% of these expenses out of pocket, totaling $46.7 billion. All other health insurance entities, including private health insurance, Medicare, Medicaid, and other health insurance programs accounted for 85.5% of the total costs ($285 billion).
  ■ Private health insurance companies accounted for 42% of retail drug expenses ($140.1 billion in 2017).
  ■ Medicare accounted for 30.3% of retail drug expenses ($100.9 billion).
  ■ Medicaid accounted for 9.9% of retail drug expenses ($33 billion).
  ■ Other health insurance programs consisted of the Children’s Health Insurance Program (Titles XIX and XXI) and programs available through the Department of Defense and the Department of Veterans Affairs. These program accounted for 3.3% of retail drug expenses ($11 billion).
  ■ Other third-party payers had the smallest percentage of costs (0.5%), which represented $1.8 billion in retail drug costs. These expenses were incurred by a variety of sources, including worksite healthcare, other private venues, Indian Health Service, workers’ compensation, general assistance, maternal and child health programs, vocational rehabilitation programs, other federal programs, Substance Abuse and Mental Health Services Administration, other state and local programs, and school health programs.

## Variation in Healthcare Quality and Disparities

State-level data show that healthcare quality and disparities vary widely depending on state and region. Although a state may perform well in overall quality, the same state may face significant disparities in healthcare access or disparities within specific areas of quality.

Figure 9 Overall quality of care, by state, 2015-2017

Note: All state-level measures with data are used to compute an overall quality score for each state based on the number of quality measures above, at, or below the average across all states. States were ranked and quartiles are shown on the map. The states with the worst quality score are in the fourth quartile, and states with the best quality score are in the first quartile. Historically, the QDR has included state-specific estimates for selected AHRQ Quality Indicators (QIs) based on Healthcare Cost and Utilization Project (HCUP) data. The 2018 QDR does not include state-specific QI estimates based on 2016 HCUP data because the International Classification of Diseases, Tenth Revision, Clinical Modification/Procedure Coding System version of the QI software used did not include risk adjustment. State-specific QIs will be reported in future QDRs when the estimates can be risk adjusted.

Map of United States showing quality by quartile. First quartile is best (highest) and fourth quartile is worst (lowest): Quartile 4: Alaska, California, Oregon, Nevada, Arizona, New Mexico, Montana, Wyoming, Oklahoma, Texas, Louisiana, DC, New York Quartile 3: Hawaii, Washington, Kansas, Arkansas, Mississippi, Florida, Georgia, Tennessee, Virginia, Illinois, Indiana, Michigan, Vermont Quartile 2: Idaho, Utah, South Dakota, Nebraska, Iowa, Missouri, Alabama, Kentucky, Ohio, South Carolina, North Carolina, Maryland, Connecticut Quartile 1: Colorado, North Dakota, Minnesota, Wisconsin, West Virginia, Pennsylvania, New Jersey, Delaware, Rhode Island, Massachusetts, New Hampshire, Maine

- Overall quality of care varied across the United States (Figure 9):
  ■ Some states in the Northeast (Delaware, Maine, Massachusetts, New Hampshire, Pennsylvania, New Jersey and Rhode Island), some in the Midwest (Minnesota, North Dakota, and Wisconsin), and Colorado and West Virginia had the highest overall quality scores. Scores were based on the number of measures that were better, same, or worse than the national average for each measure.
  ■ Some Southern and Southwestern states (District of Columbia, Louisiana, New Mexico, Oklahoma, and Texas), several Western states (Arizona, California, and Nevada), some Northwestern states (Montana, Oregon, and Wyoming), and New York and Alaska had the lowest overall quality scores.

Figure 10 Average differences in quality of care for Blacks, Hispanics, and Asians compared with Whites, by state, 2015-2017

Note: All measures in this report that had state-level data to assess racial and ethnic disparities were used. Separate quality scores were computed for Whites, Blacks, Hispanics, and Asians. For each state, the average of the Black, Hispanic, and Asian scores was divided by the White score. State-level AI/AN data were not available for analysis. States were ranked on this ratio, and quartiles are shown on the map. The states with the worst disparity score are in the fourth quartile, and states with the best disparity score are in the first quartile. Disparity scores were not risk adjusted for population characteristics in each state, so these findings do not take into account population differences between states. Historically, the QDR has included state-specific estimates for selected AHRQ Quality Indicators (QIs) based on Healthcare Cost and Utilization Project (HCUP) data. The 2018 QDR does not include state-specific QI estimates based on 2016 HCUP data because the International Classification of Diseases, Tenth Revision, Clinical Modification/Procedure Coding System version of the QI software used did not include risk adjustment. State-specific QIs will be reported in future QDRs when the estimates can be risk adjusted.

Map of United States showing disparities by quartile. Fourth quartile is worst (highest) and first quartile is best (lowest). Fourth quartile: California, Texas, Minnesota, Wisconsin, Illinois, Ohio, South Carolina, Pennsylvania, New Jersey, New York, Connecticut, Massachusetts Third quartile: Nevada, Oklahoma, Missouri, Louisiana, Mississippi, Alabama, Georgia, Florida, Tennessee, North Carolina, Indiana, DC, Delaware Second quartile: Alaska, Hawaii, Washington, Arizona, Colorado, Wyoming, Nebraska, Kansas, Iowa, Arkansas, Michigan, Virginia, Rhode Island First quartile, Oregon, Idaho, Utah, New Mexico, Montana, North Dakota, South Dakota, Kentucky, West Virginia, Maryland, New Hampshire, Maine Missing: Vermont

- Racial and ethnic disparities varied across the United States (Figure 10):
  ■ Some Western and Midwestern states (Idaho, Montana, New Mexico, North Dakota, Oregon, South Dakota, and Utah), several Southern states (Kentucky, Maryland, and West Virginia), and Maine and New Hampshire had the fewest racial and ethnic disparities overall.
  ■ Several Northeastern states (Connecticut, Massachusetts, New Jersey, New York, and Pennsylvania), several Midwestern states (Illinois, Minnesota, Ohio, and Wisconsin), and California, South Carolina, and Texas had the most racial and ethnic disparities overall.

ii For more information, refer to Healthy People 2020 midcourse review. Chapter IV: Leading Health Indicators. Hyattsville, MD: National Center for Health Statistics; 2016. https://www.cdc.gov/nchs/data/hpdata2020/HP2020MCR-B04-LHI.pdf. Also refer to Chapter 39: Social Determinants of Health (SDOH). https://www.cdc.gov/nchs/data/hpdata2020/HP2020MCR-C39-SDOH.pdf.

iii World Health Organization, Maternal and Perinatal Health. http://www.who.int/maternal_child_adolescent/topics/maternal/maternal_perinatal/en/.