# APPENDIX B DEFINITIONS AND ABBREVIATIONS USED IN 2018 REPORT

## Definitions

### Racial and Ethnic Groups

Racial and ethnic groups are defined according to Standards for the Classification of Federal Data on Race and Ethnicity, issued by the Office of Management and Budget (available at https://www.gpo.gov/fdsys/granule/FR-1997-10-30/97-28653).

The basic racial and ethnic categories for federal statistics and program administrative reporting are defined as follows:

1. American Indian or Alaska Native (AI/AN). A person having origins in any of the original peoples of North and South America (including Central America) and who maintains tribal affiliation or community attachment.
2. Asian. A person having origins in any of the original peoples of the Far East, Southeast Asia, or the Indian subcontinent, including, for example, Cambodia, China, India, Japan, Korea, Malaysia, Pakistan, the Philippine Islands, Thailand, and Vietnam.
3. Black or African American. A person having origins in any of the black racial groups of Africa. Terms such as “Haitian” can be used in addition to “Black or African American.”
4. Hispanic or Latino. A person of Cuban, Mexican, Puerto Rican, Central or South American, or other Spanish culture or origin, regardless of race. The term “Spanish origin” can be used in addition to “Hispanic or Latino.”
5. Native Hawaiian/Pacific Islander (NHPI). A person having origins in any of the original peoples of Hawaii, Guam, Samoa, or other Pacific Islands.
6. White. A person having origins in any of the original peoples of Europe, the Middle East, or North Africa.

### Income

Income groups are based on the Federal Poverty Level (FPL) for a family of four:

- Poor: Less than 100% of FPL
- Low income: 100% to less than 200% of FPL
- Middle income: 200% to less than 400% of FPL
- High income: 400% or more of FPL

The poverty guidelines are available at https://aspe.hhs.gov/poverty-guidelines.

### Urban-Rural Areas

Urban and rural areas are defined based on the National Center for Health Statistics 2013 Urban-Rural Classification Scheme.

Figure B-1 Map Showing 2013 NCHS Urban-Rural County Classifications in the United States

Map shows 2013 NCHS urban-rural classifications in the US

- Metropolitan counties:
  ■ Large central metro counties in metropolitan statistical area (MSA) of 1 million or more population that: (1) contain the entire population of the largest principal city of the MSA, or (2) are completely contained within the largest principal city of the MSA, or (3) contain at least 250,000 residents of any principal city in the MSA
  ■ Large fringe metro counties in MSA of 1 million or more population that do not qualify as large central.
  ■ Medium metro counties in MSA of 250,000-999,999 population.
  ■ Small metro counties in MSAs of less than 250,000 population.
- Nonmetropolitan counties:
  ■ Micropolitan: Counties in a micropolitan statistical area.
  ■ Noncore: Nonmetropolitan counties that are not in a micropolitan statistical area.

More information is available at https://www.cdc.gov/nchs/data_access/urban_rural.htm.

### Activity Limitations

Activity limitations are classified as basic, complex, and neither:

- Basic activity limitations include problems with mobility, self-care (activities of daily living), domestic life (instrumental activities of daily living), and activities that depend on sensory functioning (limited to people who are blind or deaf).
- Complex activity limitations include limitations experienced in work and in community, social, and civic life. For the purpose of the QDR, adults with disabilities are those with physical, sensory, and/or mental health conditions that can be associated with a decrease in functioning in such day-to-day activities as bathing, walking, doing everyday chores, and engaging in work or social activities.

The paired measure is intended to be consistent with statutory definitions of disability, such as the first criterion of the 1990 Americans With Disabilities Act and other federal program definitions of disability. The category “neither” refers to individuals with neither basic nor complex activity limitations, as defined here.

## Abbreviations Used in the QDR

- AAA: abdominal aortic aneurysm
- ACS NSQIP: American College of Surgeons National Surgical Quality Improvement Program
- AD: Alzheimer’s disease
- ADE: adverse drug event
- AI/AN: American Indian or Alaska Native
- AJCC: American Joint Committee on Cancer
- API: Asian and Pacific Islander
- BMI: body mass index
- CAP: community-acquired pneumonia
- CCQM-PC: Care Coordination Quality Measure for Primary Care
- COPD: chronic obstructive pulmonary disease
- DALY: disability-adjusted life year
- ED: emergency department
- FPL: Federal Poverty Level
- HCUP: Healthcare Cost & Utilization Project
- HHCAHPS: Home Health Consumer Assessment of Healthcare Providers and Systems
- HPV: human papillomavirus
- ICD-9: International Classification of Diseases, Ninth Revision
- ICD-10: International Classification of Diseases, Tenth Revision
- IMRT: intensity-modulated radiation therapy
- IOM: Institute of Medicine
- IWG: Interagency Work Group
- LAP: Language Access Plan
- LEP: limited English proficiency
- LN: lymph node
- LMWH: low-molecular-weight heparin
- MedPAC: Medicare Payment Advisory Commission
- MEPS: Medical Expenditure Panel Survey
- MPSMS: Medicare Patient Safety Monitoring System
- MSA: metropolitan statistical area
- NCDB: National Cancer Data Base
- NEDS: National Emergency Department Sample
- NHANES: National Health and Nutrition Examination Survey
- NHIS: National Health Interview Survey
- NHSS: National HIV/AIDS Surveillance System
- NHPI: Native Hawaiian/Pacific Islander
- NIS: National Immunization Survey
- NVSS: National Vital Statistics System
- OCR: Office for Civil Rights
- QDR: National Healthcare Quality and Disparities Report
- SID: State Inpatient Databases
- THA: total hip arthroplasty
- UM-KECC: University of Michigan Kidney Epidemiology and Cost Center
- USC: usual source of care
- USRDS: U.S. Renal Data System
- YPLL: years of potential life lost

### Agencies and Offices in the U.S. Department of Health and Human Services

- AHRQ: Agency for Healthcare Research and Quality
  ■ CDOM: Center for Delivery, Organization, and Markets
  ■ CFACT: Center for Financing, Access, and Cost Trends
  ■ CQuIPS: Center for Quality Improvement and Patient Safety
  ■ OC: Office of Communications
  ■ OEREP: Office of Extramural Research, Education, and Priority Populations
- ACL: Administration for Community Living
- ASPE: Office of the Assistant Secretary for Planning and Evaluation
- CDC: Centers for Disease Control and Prevention
  ■ ACIP: Advisory Committee on Immunization Practices
  ■ NCHHSTP DHAP: National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, Division of HIV/AIDS Prevention
  ■ NCHS: National Center for Health Statistics
  ■ NCIRD: National Center for Immunizations and Respiratory Diseases
  ■ NPCR: National Program of Cancer Registries
  ■ NCCDPHP-ONDIEH: National Center for Chronic Disease Prevention and Health Promotion, Office of Noncommunicable Diseases, Injury and Environmental Health
- CMS: Centers for Medicare & Medicaid Services
  ■ QIO: Quality Improvement Organization Program
- FDA: Food and Drug Administration
- HRSA: Health Resources and Services Administration
  ■ RWHAP: Ryan White HIV/AIDS Program
- IHS: Indian Health Service
- NIH: National Institutes of Health
  ■ NCI: National Cancer Institute
  ■ NHLBI: National Heart, Lung, and Blood Institute
  ■ NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases
  ■ NIMHD: National Institute on Minority Health and Health Disparities
  ■ OD/ORWH: Office of the Director/Office of Research on Women’s Health
- OASH: Office of the Assistant Secretary for Health
- SAMHSA: Substance Abuse and Mental Health Services Administration

### Other Federal Agencies

- VHA: Veterans Health Administration