# APPENDIX A LIST OF MEASURES AND SUMMARY OF RESULTS FOR FIGURES

## A.1 Access to Care

Measures Included in Figure 11: Number and percentage of access measures for which measures were improving, not changing, or worsening, 2000 through 2016 or 2017

Measures included in Figure 22: Number and percentage of access measures for which members of selected groups experienced better, same, or worse access to care compared with reference group, 2016 or 2017

## A.2 Quality Trends

Measures included in Figure 33: Number and percentage of all quality measures that were improving, not changing, or worsening, total and by priority area, from 2000 through 2012, 2014, 2016, or 2017

## A.3 Disparities: Race and Ethnicity

Measures included in Figure 57: Number and percentage of quality measures for which members of selected groups experience better, same, or worse quality of care compared with reference group (White), 2013, 2015, 2016, or 2017

Measures Included in Figure 58: Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, 2000 through 2013, 2014, 2015, 2016, or 2017

Measures Included in Figure 59: Number and percentage of quality measures for which Blacks experienced better, same, or worse quality of care compared with reference group (White), 2013, 2015, 2016, or 2017

Measures included in Figure 63: Number and percentage of all quality measures that were improving, not changing, or worsening, total for Blacks and by priority area, 2000 through 2013, 2014, 2015, 2016, or 2017

Measures Included in Figure 64: Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, total for Blacks and by priority area, 2000 through 20…

Measures Included in Figure 69: Number and percentage of quality measures for which Asians experienced better, same, or worse quality of care compared with reference group (White), 2013, 2015, 2016, or 2017

Measures Included in Figure 73: Number and percentage of all quality measures that were improving, not changing, or worsening, total for Asians and by priority area, 2000 through 2011, 2013, 2014, 2015, 2016, or 2017

Measures Included in Figure 74: Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, total for Asians and by priority area, 2000 through 20…

Measures Included in Figure 77: Number and percentage of quality measures for which American Indians and Alaska Natives experienced better, same, or worse quality of care compared with reference group (White), 2013, 2015, 2016, or 2017

Measures included in Figure 81: Number and percentage of all quality measures that were improving, not changing, or worsening, total for American Indians and Alaska Natives and by priority area, from 2000 through 2013, 2014, 2015, 2016, or 2017

Measures Included in Figure 82: Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, total for American Indians and Alaska Natives and by p…

Measures Included in Figure 84: Number and percentage of quality measures for which Native Hawaiians/Pacific Islanders experienced better, same, or worse quality of care compared with reference group (White), 2015, 2016, or 2017

Measures included in Figure 88: Number and percentage of all quality measures that were improving, not changing, or worsening, total for Native Hawaiians/Pacific Islanders and by priority area, 2001 through 2012, 2013, 2014, 2015, 2016, or 2017

Measures included in Figure 89: Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, total for Native Hawaiians/Pacific Islanders and by priority area, 2008 thr…

Measures Included in Figure 91: Number and percentage of quality measures for which Hispanics experienced better, same, or worse quality of care compared with reference group (White), 2013, 2015, 2016, or 2017

Measures included in Figure 95: Number and percentage of all quality measures that were improving, not changing, or worsening, total for Hispanics and by priority area, from 2000 through 2013, 2014, 2015, 2016, or 2017

Measures Included in Figure 96: Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, total for Hispanics and by priority area, 2000 through…

## A.4 Disparities: Income

Measures included in Figure 101: Number and percentage of quality measures for which income groups experienced better, same, or worse quality of care compared with reference group (high income), 2015, 2016, or 2017

Measures included in Figure 108: Number and percentage of all quality measures that were improving, not changing, or worsening, by income group, from 2000 through 2014, 2015, 2016, or 2017

Measures included in Figure 109: Number and percentage of quality measures with disparity at baseline for which disparities related to income were improving, not changing, or worsening, 2000 through 2014, 2015, 2016, or 2017

## A.5 Disparities: Insurance Status

Measures included in Figure 116: Number and percentage of quality measures for which insurance groups experienced better, same, or worse quality of care compared with reference group (privately insured), 2015, 2016, or 2017

Measures included in Figure 123: Number and percentage of all quality measures that were improving, not changing, or worsening, by insurance status, from 2000 through 2013, 2014, 2015, 2016, or 2017

Measures Included in Figure 124: Number and percentage of quality measures with disparity at baseline for which disparities related to insurance were improving, not changing, or worsening, 2000 through 2014, 2015, 2016, or 2017

## A.6 Disparities: Residence Location

Measures included in Figure 128. Number and percentage of quality measures for which members of selected groups experienced better, same, or worse quality of care compared with reference group in 2015, 2016, or 2017, by residence location

Measures included in Figure 139. Number and percentage of all quality measures that were improving, not changing, or worsening, by residence location, from 2002 through 2011, 2014, 2015, 2016, or 2017

Measures Included in Figure 140. Number and percentage of quality measures with disparity at baseline for which disparities related to residence location were improving, not changing, or worsening, 2002 through 2011, 2014, 2015, 2016, or 2017