# REFERENCES

Banthin JS, Bernard DM. Changes in financial burdens for health care: national estimates for the population younger than 65 years, 1996 to 2003. JAMA 2006;296(22):2712–9. https://www.ncbi.nlm.nih.gov/pubmed/17164457. Accessed June 25, 2018.17164457
Carney Moore JM, Dolansky M, Hudak C, . Care coordination between convenient care clinics and healthcare homes. J Am Assoc Nurse Pract 2015 May;27(5):262–9. https://www.ncbi.nlm.nih.gov/pubmed/25284043 [abstract only]. Accessed June 25, 2018.25284043
Centers for Medicare & Medicaid Services. National Health Expenditures 2015 Highlights. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html. Accessed June 25, 2018.
Gardner JW, Sanborn JS. Years of potential life lost (YPLL)—what does it measure? Epidemiology 1990;1:322–9. https://www.ncbi.nlm.nih.gov/pubmed/2083312 [abstract only]. Accessed June 25, 2018.2083312
Health Resources and Services Administration, Office of Health Equity. Health Equity Report 2017. Rockville, MD: U.S. Department of Health and Human Services; 2018. https://www.hrsa.gov/sites/default/files/hrsa/health-equity/2017-HRSA-health-equity-report-PRINTER.pdf. Accessed June 25, 2018.
Henrikson NB, Change E, Ulrich K, . Communication with physicians about health care costs: survey of an insured population. Perm J 2017:21:16–070. https://www.thepermanentejournal.org/issues/2017/spring/6377-communication-with-physicians.html. Accessed June 25, 2018.
Ingram DD, Franco SJ. NCHS urban-rural classification scheme for counties. National Center for Health Statistics. Vital Health Stat 2012;2(154). https://www.cdc.gov/nchs/data/series/sr_02/sr02_154.pdf. Accessed June 25, 2018.
Key substance use and mental health indicators in the United States: results from the 2016 National Survey on Drug Use and Health. NSDUH Series H-52. Rockville, MD:, Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality; 2017. HHS Publication No. SMA 17-5044. https://www.samhsa.gov/data/sites/default/files/2016_ffr_1_slideshow_v5.pdf. Accessed June 25, 2018.
Kohn L, Corrigan J, Donaldson M, eds. To err is human: building a safer health system. Institute of Medicine, Committee on Quality of Health Care in America. Washington, DC: National Academy Press; 2000. https://www.nap.edu/catalog/9728/to-err-is-human-building-a-safer-health-system. Accessed June 25, 2018.
Reed M, Graetz I, Wang H, . Consumer-directed health plans with health savings accounts: whose skin is in the game and how do costs affect care seeking? Med Care 2012 Jul;50(7):585–90. https://www.ncbi.nlm.nih.gov/pubmed/22322099 [abstract only]. Accessed June 25, 2018.22322099
Shojania K, McDonald K, Wachter R, . Closing the quality gap: a critical analysis of quality improvement strategies—Volume 7: Care coordination. Rockville, MD: Agency for Healthcare Research and Quality; 2007. https://www.ahrq.gov/research/findings/evidence-based-reports/caregaptp.html (https://archive.ahrq.gov/research/findings/evidence-based-reports/caregaptp.html). Accessed June 25, 2018.
U.S. Department of Health and Human Services. The Opioid Epidemic by the Numbers. Updated January 2018. https://www.hhs.gov/opioids/sites/default/files/2018-01/opioids-infographic.pdf. Accessed June 25, 2018.
Zimmerman C. Families with chronic conditions in high-deductible health plans facing substantial financial burden. Find Brief 2011 Mar;14(1):1–3. https://www.ncbi.nlm.nih.gov/pubmed/21560795 [abstract only]. Accessed June 25, 2018.