# ACKNOWLEDGMENTS

The National Healthcare Quality and Disparities Report (QDR) is the product of collaboration among agencies from the U.S. Department of Health and Human Services (HHS), other federal departments, and the private sector. Many individuals guided and contributed to this effort. Without their magnanimous support, the report would not have been possible.

Specifically, we thank:

Primary AHRQ Staff: Gopal Khanna, Francis Chesley, Jeff Brady, Erin Grace, Karen Chaves, Nancy Wilson, Darryl Gray, Barbara Barton, Irim Azam, and Doreen Bonnett.

HHS Interagency Workgroup for the QDR: Girma Alemu (HRSA), Nancy Breen (NIH-NIMHD), Victoria Cargill (NIH), Amy Chanlongbutra (HRSA), Hazel Dean (CDC), Melissa Evans (CMS), Kirk Greenway (IHS), Sarah Heppner (HRSA), Edwin Huff (CMS), DeLoris Hunter (NIH-NIMHD), Susan Jenkins (ACL), Shari Ling (CMS), Tracy Matthews (HRSA), Ernest Moy (CDC-NCHS), Kathleen Palso (CDC-NCHS), Asel Ryskulova (CDC-NCHS), Adelle Simmons (ASPE), Marsha Smith (CMS), Loida Tamayo (CMS), Caroline Taplin (ASPE), Emmanuel Taylor (NCI), Barbara Wells (NIH-NHLBI), and Ying Zhang (IHS).

QDR Team: Irim Azam (CQuIPS), Barbara Barton (CQuIPS), Doreen Bonnett (OC), Cecilia Casale (OEREP), Xiuhua Chen (SSS), Frances Chevarley (CFACT), James Cleeman (CQuIPS), Diane Cousins (CQuIPS), Noel Eldridge (CQuIPS), Camille Fabiyi (OEREP), Erin Grace (CQuIPS), Darryl Gray (CQuIPS), Kevin Heslin (CDOM), Anil Koninty (SSS), Lan Liang (CFACT), Kamila Mistry (OEREP), Margie Shofer (CQuIPS), Nancy Wilson (CQuIPS), and Yanling Zhao (SSS).

HHS Data Experts: Cuong Bui (HRSA), Lara Bull (CDC), Frances Chevarley (AHRQ), Robin Cohen (CDC-NCHS), Joann Fitzell (CMS), Elizabeth Goldstein (CMS), Irene Hall (CDC-HIV), Norma Harris (CDC-HIV), Kevin Heslin (AHRQ), Jessica King (NPCR), Amanda Lankford (CDC), Denys Lau (CDC-NCHS), Lan Liang (AHRQ), Sharon Liu (SAMHSA), Marlene Matosky (HRSA), Tracy Matthews (HRSA), Robert Morgan (CMS), Richard Moser (NIH-NCI), Kathleen Palso (CDC-NCHS), Robert Pratt (CDC), Neil Russell (SAMHSA), Asel Ryskulova (CDC-NCHS), Alek Sripipatana (HRSA), Reda Wilson (CDC-ONDIEH-NCCDPHP), Emily Zammitti (CDC-NCHS), and Xiaohong (Julia) Zhu (HRSA).

Other Data Experts: Mark Cohen (American College of Surgeons, NSQIP), Ashley Eckard (University of Michigan), Sheila Eckenrode (MPSMS-Qualidigm), Michael Halpern (American Cancer Society), Clifford Ko (American College of Surgeons, NSQIP), Vivian Kurtz (University of Michigan), Robin Padilla (University of Michigan KECC), Bryan Palis (American College of Surgeons, NCDB), and Yun Wang (MPSMS-Qualidigm).

Other AHRQ Contributors: Cindy Brach, Edwin Lomotan, Iris Mabry-Hernandez, Karen Migdail, Pamela Owens, Wendy Perry, Richard Ricciardi, Mary Rolston, Bruce Seeman, Randie Siegel, and Michele Valentine.

Data Support Contractors: Social & Scientific Systems (SSS).