# LOOKING FORWARD

The National Healthcare Quality and Disparities Report (QDR) continues to track the nation’s performance on healthcare access, quality, and disparities. The QDR data demonstrate significant progress in some areas and identify other areas that merit more attention where wide variations persist. The number of measures in each priority area varies, and some measures carry more significance than others as they affect more people or have more significant consequences. The summary charts (Figures 11-12, 18-30) are a way to quantify and illustrate progress toward achieving accessible, high-quality, and affordable care at the national level using available nationally representative data.

This report shows that while performance for most access measures did not change significantly over time (2000-2014), insurance coverage rates did improve (2000-2016). Quality of healthcare improved in most areas but some disparities persist, especially for poor and low-income households and those without health insurance.

U.S. Department of Health and Human Services (HHS) agencies are working on research and conducting programs in many of the priority areas, most notably opioid misuse, patient safety, effective treatment, and health disparities.

Opioid Misuse. In 2016, nearly 116 people died everyday from opioid-related drug overdose (HHS, 2018) and 11.5 million people age 12 and over misused prescription pain relievers in the past year (SAMHSA, 2017). Drug overdose deaths in the United States continue to increase. The 5-point strategy of HHS to combat the opioid crisis (https://www.hhs.gov/opioids/) is:

1. Improving access to treatment and recovery services;
2. Promoting use of overdose-reversing drugs;
3. Strengthening our understanding of the epidemic through better public health surveillance;
4. Providing support for cutting-edge research on pain and addiction; and
5. Advancing better practices for pain management.

The National Pain Strategy (https://www.hhs.gov/ash/about-ash/news/2016/national-pain-strategy-outlines-actions-improving-pain-care/index.html) (NPS) is the federal government’s first coordinated plan for reducing the burden of chronic pain that affects millions of Americans, and a roadmap toward achieving a system of care in which all people receive appropriate, high-quality and evidence-based care for pain. Data from the QDR can inform the NPS to address the opioid crisis.

Patient Safety. The AHRQ National Scorecard on Hospital-Acquired Conditions (https://www.ahrq.gov/sites/default/files/wysiwyg/professionals/quality-patient-safety/pfp/natlhacratereport-rebaselining2014-2016_0.pdf) estimates that 350,000 hospital-acquired conditions were avoided, and the rate was reduced by 8% from 2014 to 2016. Federal experts note that the gains in safety among hospital patients echoed earlier successes, including 2.1 million hospital-acquired conditions avoided between 2010 and 2014.

Future improvements in patient safety are expected as ambulatory settings focus on improving patient safety. AHRQ’s new Community-Acquired Pneumonia Clinical Decision Support Implementation Toolkit (https://www.ahrq.gov/professionals/quality-patient-safety/hais/tools/ambulatory-care/cap-toolkit.html?utm_source=ahrq&utm_medium=en-9&utm_term=&utm_content=9&utm_campaign=ahrq_en1_24_2018) helps clinicians in emergency departments, primary care, and other ambulatory settings implement and adopt a clinical decision support alert for identifying and managing patients with community-acquired pneumonia.

Clinical staff working in ambulatory care settings have a new resource to improve the quality and safety of care transitions, especially for patients with chronic conditions. AHRQ’s Safe Transitions Toolkit (https://www.ahrq.gov/professionals/quality-patient-safety/hais/tools/ambulatory-care/safetransitions.html?utm_source=ahrq&utm_medium=en-2&utm_term=&utm_content=2&utm_campaign=ahrq_en1_9_2018) provides practical and evidence-based tools to help clinical staff work more effectively with patients for new and followup appointments.

AHRQ has also released a new resource, the Toolkit To Promote Safe Surgery (https://www.ahrq.gov/professionals/quality-patient-safety/hais/tools/surgery/index.html), which helps hospitals make care safer for their patients who undergo surgery. Hospitals can use the toolkit to apply the proven principles and methods of AHRQ’s Comprehensive Unit-based Safety Program to prevent surgical site infections and other complications and improve safety culture in their perioperative and surgical units. The latest tool developed by AHRQ to address adverse drug events is the Patient and Family Engagement in Primary Care guide (https://www.ahrq.gov/professionals/quality-patient-safety/patient-family-engagement/pfeprimarycare/interventions/medmanage.html).

Effective Treatment. The findings of the 2018 National Impact Assessment of the Centers for Medicare & Medicaid Services (CMS) Quality Measures Report (https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/QualityMeasures/National-Impact-Assessment-of-the-Centers-for-Medicare-and-Medicaid-Services-CMS-Quality-Measures-Reports.html) show that the quality and efficiency impact for patients in Medicare and Medicaid improved for 60% of measures analyzed.

A report, Quitting Smoking Among Adults — United States, 2000–2015 (https://www.cdc.gov/mmwr/volumes/65/wr/mm6552a1.htm?s_cid=mm6552a1_w), was recently released by CDC’s Office on Smoking and Health (OSH). The report discusses healthcare quality-related disparities in the delivery and receipt of tobacco cessation interventions and treatments.

Health Disparities. HHS continues to address health disparities through targeted initiatives throughout the department. The HHS Health Disparities Council was established in 2004 to develop, influence, and advise on programs, policies, research, data, and communications on racial and ethnic minority health. The Council works to identify and facilitate collaborative, action-oriented approaches to address the HHS minority health, racial and ethnic health disparities, and health equity agenda and priorities, and to more effectively and efficiently share information within HHS.

Increasing data and resources to address health disparities, especially among racial and ethnic minorities, continues to be a priority. The Federal Interagency Health Equity Team (FIHET) published the Data Compendium (https://minorityhealth.hhs.gov/NPA/Materials/FIHET_Data_Compendium_508_version_FINAL_11_28_2016.pdf) of data sources available. The purpose of the FIHET is to identify opportunities for federal collaboration, partnership, coordination and/or action on efforts relevant to the National Partnership for Action; provide leadership and guidance for federal, regional, state, tribal, territorial, and local efforts to address health equity; and infuse health disparities and health equity goals and strategies into member agency policies and practices.

The 2014 Native Hawaiian and Pacific Islander National Health Interview Survey (https://www.cdc.gov/nchs/nhis/nhpi.html) (NHPI NHIS) public-use data were released in August 2017 by CDC. The NHPI NHIS was an unprecedented opportunity to collect rich and accurate information from a large NHPI sample about the health of NHPIs in all 50 states. The NHPI NHIS data show that NHPI adults were more likely than all U.S. adults to be in fair or poor health, to have diabetes, and to have ever had asthma, but they were less likely to have cancer.

A recent report from the Health Resources and Services Administration (HRSA) focuses on health equity. The Health Equity Report 2017 (https://www.hrsa.gov/sites/default/files/hrsa/health-equity/2017-HRSA-health-equity-report-PRINTER.pdf) presents a comprehensive analysis of HRSA’s program efforts in reducing health disparities and promoting health equity for various populations at the national, state, and local levels. The report describes trends in health disparities and improvements in health equity for multiple HRSA programs, such as maternal and child health, primary healthcare access and quality, HIV/AIDS, health workforce, and rural-urban and geographic disparities.

Recently, the National Institute on Minority Health and Health Disparities (https://www.nimhd.nih.gov/) launched a new online resource, HDPulse (https://hdpulse.nimhd.nih.gov/?utm_medium=email&utm_source=govdelivery), for public health professionals and researchers. The Data Portal allows users to explore issues related to health disparities and access data, published reports, and public-use files.

The Intradepartmental Council for Native American Affairs advises the HHS Secretary on Native American issues, coordinates all federal agencies’ resources for Native Americans, develops and implements policies on Native American affairs for HHS, and ensures policy consistency throughout HHS and, where possible, throughout the federal government.

Through various quality improvement and patient safety initiatives, HHS and other federal agencies drive us toward better healthcare. The 2017 QDR documents ongoing progress toward the goal of high-quality healthcare that is accessible to all Americans and identifies areas for improvement. Policymakers, researchers, and others can use these findings to direct future efforts toward making healthcare safer and more effective, coordinated, affordable, and equitable.