# QUALITY AND DISPARITIES IN QUALITY OF HEALTHCARE

The QDR examines quality and disparities based on six priority areas and access. The findings below provide examples of quality measures that showed significant disparities, worsening disparities, or large improvements over time. A comprehensive list of measures improving, worsening, or staying the same, as well as disparities with reference groups and trends in disparities, can be found in Appendix B.

## Trends in Quality

### Quality of healthcare improved overall through 2014, but the pace of improvement varied by priority area

Figure 18 Number and percentage of all quality measures that were improving, not changing, or worsening, total and by priority area, from 2000 through 2016

Key: n = number of measures.

Note: Most measures are tracked from 2000 through 2016. For more information, review Appendix B.

Bar chart showing number and percentage Total (n=179), Improving, 100, 56%, Not Changing, 61, 34%, Worsening, 18, 10% Person-Centered Care (n=16), Improving, 11, 69%, Not Changing, 5, 31%, Worsening, 0 Patient Safety (n=36), Improving, 25, 69%, Not Changing, 9, 25%, Worsening, 2, 6% Healthy Living (n=54), Improving, 29, 54%, Not Changing, 21, 39%, Worsening, 4, 7% Effective Treatment (n=40), Improving, 21, 52.5%, Not Changing, 14, 35%, Worsening, 5, 12.5% Care Coordination (n=28), Improving, 14, 50%, Not Changing, 8, 29%, Worsening, 6, 21% Affordable Care (n=5), Improving, 0, Not Changing, 4, 80%, Worsening, 1, 20%

#### Trends in Person-Centered Care

Person-centered care means defining success not just by the resolution of clinical symptoms but also by whether patients achieve their desired outcomes. Almost 70% of person-centered care measures were improving overall (Figure 18).

- For example, overall trends from 2002 to 2015 showed significant improvement in provider-patient communication for adults who had doctor visits in the past 12 months who reported their health provider sometimes or never listened carefully (10.3% compared with 6.7%) (Appendix A, Graph 18).

#### Trends in Patient Safety

Ensuring patient safety means providing care free from accidental injury due to medical care or medical errors (Kohn, et al., 2000). The QDR tracks a number of patient safety measures organized by the major healthcare settings responsible for measuring, understanding, and improving healthcare. Measures include healthcare-associated infections, pressure ulcers in nursing homes, inappropriate prescription medications, and hospital readmissions.

More than two-thirds of patient safety measures were improving overall (Figure 18), including:

- Hospital admissions with central venous catheter-related bloodstream infections, which declined from 1.9 per 1,000 discharges in 2008 to 0.67 per 1,000 discharges in 2015 (AHRQ, Healthcare Cost and Utilization Project [HCUP], Nationwide Inpatient Sample [NIS], 2008-2011; State Inpatient Databases [SID], 2012-2015; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 19).
- Adult patients receiving hip joint replacement due to degenerative conditions who had adverse events, which improved from 4.0% in 2009 to 1.7% in 2015 (AHRQ and Centers for Medicare & Medicaid Services [CMS], Medicare Patient Safety Monitoring System [MPSMS]) (Appendix A, Graph 20).
- Adult patients receiving knee replacement who had adverse events, which improved from 3.3% in 2009 to 1.7% in 2015 (AHRQ and CMS, MPSMS) (Appendix A, Graph Section 8) (Appendix A, Graph 21).

Two patient safety measures worsened:

- Postoperative physiologic and metabolic derangements per 1,000 elective-surgery admissions, adults age 18 and over, which increased from 1.22 in 2000 to 1.51 in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 22).^viii^
- Adults who reported the provider asked to see all the prescription and over-the-counter medicines they were taking when they initiated home healthcare, which decreased from 78.8% in 2012 to 77.6% in 2016 (CMS, Home Health Consumer Assessment of Healthcare Providers and Systems [HHCAHPS]). (Appendix A, Graph 23).

#### Trends in Healthy Living

Healthy living measures in the QDR track process measures that focus on helping individuals maintain healthy lifestyles and wellness in their communities. These include measures for clinical preventive services, maternal and child care, obesity prevention, functional status preservation and rehabilitation, and supportive and palliative care.

More than half of healthy living measures were improving overall (Figure 18), including adolescent vaccinations and influenza vaccinations:

- From 2008 to 2015, the percentage of adolescents ages 13-15 and 16-17 who received Tdap^ix^ vaccine since age 10 increased from 46.7% to 87.1% and from 31.9% to 85.3%, respectively (CDC, National Center for Immunizations and Respiratory Diseases [NCIRD] and National Center for Health Statistics [NCHS], National Immunization Survey - Teen) (Appendix A, Graph 24 and Graph 25).
- Hospital patients who received influenza vaccination increased from 87.2% in 2012 to 94.1% in 2015 (CMS Clinical Data Warehouse) (Appendix A, Graph 26).

About 7% of all healthy living measures showed worsening performance, including one women’s health measure and one children’s health measure.

- Hospital admissions for immunization-preventable influenza per 100,000 population age 65 and over, which increased from 77.5 in 2000 to 259.8 in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 27).
- Women ages 21-65 who received a Pap test in the last 3 years, which decreased from 87.5% in 2000 to 81.2% in 2015 (CDC, NCHS, NHIS) (Appendix A, Graph 28).
- Adolescents ages 12-19 with obesity, which increased from 16.0% in 1999-2002 to 20.5% in 2011-2014 (CDC, NCHS, National Health and Nutrition Examination Survey [NHANES]) (Appendix A, Graph 29).

#### Trends in Effective Treatment

Delivering optimal treatment for acute illness can help reduce the effects of illness and promote the best possible recovery. The QDR Effective Treatment measures include process measures for preventive care, treatment of acute illness, and chronic disease management. Some outcome measures are also tracked in the QDR since timely treatment of acute illness and injury and meticulous management of chronic disease can positively affect mortality, morbidity, and quality of life.

More than half of Effective Treatment measures were improving (Figure 18), including improvements in cancer care and pneumonia:

- Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined, which increased from 60.9% in 2005 to 91.2% in 2014 (National Cancer Data Base [NCDB]) (Appendix A, Graph 30).
- Women under age 70 treated for breast cancer with breast-conserving surgery who received radiation therapy to the breast within 1 year of diagnosis, which increased from 85.3% in 2005 to 92.5% in 2013 (NCDB) (Appendix A, Graph 31).
- Deaths per 1,000 adult hospital admissions with pneumonia, which declined from 73.2 in 2000 to 17.5 in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 32).

However, several areas show no statistically significant changes overall, including diabetes care and treatment for mental health and substance use overall.

Worsening performance overall in Effective Treatment measures were observed for:

- Hemodialysis patients whose hemoglobin level is less than 10 g/dL, which increased from 1.7% in 2006 to 16.8% in 2015 (University of Michigan Kidney Epidemiology and Cost Center, Dialysis Facility Reports) (Appendix A, Graph 33).
- Emergency department visits involving opioid-related diagnoses per 100,000 population, which increased from 89.1 in 2005 to 209.0 in 2015 (AHRQ, HCUP, NIS and Nationwide Emergency Department Sample [NEDS], and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 34).^x^
- Hospital inpatient stays involving opioid-related diagnoses per 100,000 population, which increased from 136.8 in 2005 to 251.3 in 2015 (AHRQ, HCUP, SID, and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 35).^xi^
- Suicide deaths among people age 12 and over per 100,000 population, which increased from 10.4 in 2000 to 16.0 in 2015 (CDC, NCHS, National Vital Statistics System [NVSS] - Mortality) (Appendix A, Graph 36).
- People with current asthma who are now taking preventive medicine daily or almost daily (either oral or inhaler), which decreased from 29.6% in 2003 to 23.0% in 2015 (AHRQ, MEPS) (Appendix A, Graph 37).

#### Trends in Care Coordination

Care coordination is a conscious effort to ensure that all key information needed to make care decisions is available to healthcare consumers and providers. Care coordination is defined as the deliberate organization of patient care activities between two or more participants involved in a person’s care to facilitate appropriate delivery of healthcare services (Shojania, et al., 2007).

Coordinating basic patient information among providers is essential so that important information is not ignored, lost, or never communicated. Incomplete or inaccurate information and lack of followup care lead to confusion, higher costs, and misuse of medications, tests, and therapies for all patients, which result in poor outcomes (Carney Moore, et al., 2015).

Half of Care Coordination measures were improving overall (Figure 18), including:

- Potentially avoidable hospital admissions for angina per 100,000 population, adults age 18 and over, which fell from 81.5 in 2000 to 11.8 in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 38).
- Potentially avoidable hospital admissions for pediatric gastroenteritis per 100,000 population, children ages 3 months to 17 years, which fell from 169.4 in 2000 to 50.8 in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 39).
- Adult hospital patients who did not receive good communication about discharge information, which fell from 15.8% in 2009 to 10.5% in 2016 (CMS, Hospital Consumer Assessment of Healthcare Providers and Systems [HCAHPS]) (Appendix A, Graph 40).

However, nearly one-quarter of Care Coordination measures showed worsening overall, including:

- Emergency department visits with a principal diagnosis related to substance abuse only, per 100,000 population, which increased from 438.0 in 2007 to 713.0 in 2015 (AHRQ, HCUP, NEDS) (Appendix A, Graph 41).
- Emergency department visits with a principal diagnosis related to co-occurring mental health, alcohol abuse, and substance abuse, per 100,000 population, which increased from 27.0 in 2007 to 43.9 in 2015 (AHRQ, HCUP, NEDS) (Appendix A, Graph 42).
- Potentially avoidable hospital admissions for short-term complications of diabetes per 100,000 population, adults age 18 and over, which worsened from 50.8 in 2000 to 85.8 in 2015 (AHRQ, HCUP) (Appendix A, Graph 43).

#### Trends in Affordable Care

Health insurance is designed to protect individuals from the burden of high healthcare costs. However, even with health insurance, the financial burden of healthcare can be high and is increasing (Banthin & Bernard, 2006).

High premiums and out-of-pocket payments can be a significant barrier to accessing needed medical treatment, resulting in higher comorbidity and lower quality of life (Henrikson, et al., 2017). In addition, the advent of high-deductible health plans is placing a financial burden on many people, especially those with chronic conditions (Reed, et al., 2012; Zimmerman, 2011). Ensuring healthcare is affordable remains an important factor in achieving access to high-quality care.

Data presented in this report show that 4 of 5 care affordability measures had no statistically significant changes overall (Figure 18). One measure of care affordability worsened overall:

- People without a usual source of care who indicated a financial or insurance reason for not having a source of care, which increased from 2002 (15.6%) until 2013 (24%) and then decreased through 2015 (14.9%) (AHRQ, MEPS) (Appendix A, Graph 44).

## Trends in Disparities

### Although some gaps are getting smaller, disparities remain

Measures in this report were analyzed by comparing race/ethnicity, income, and insurance status with their reference groups in order to show disparities that may exist between these groups. Figure 19 shows disparities between racial/ethnic groups and Whites, and Figure 20 shows changes in the gaps between racial/ethnic groups and Whites.

Figure 19 Number and percentage of quality measures for which members of selected groups experienced better, same, or worse quality of care compared with reference group (White) in 2014-2016

Key: n = number of measures; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Bar chart showing number and percentage Black vs. White (n=176), Better, 19, 11%, Same, 83, 47%, Worse, 74, 42% Asian vs. White (n=152), Better, 39, 26%, Same, 85, 56%, Worse, 28, 18% AI/AN vs. White (n=89), Better, 15, 17%, Same, 46, 52%, Worse, 28, 31% NHPI vs. White (n=43), Better, 6, 14%, Same, 23, 53%, Worse, 14, 33% Hispanic vs. Non-Hispanic White (n=145), Better, 27, 19%, Same, 72, 50%, Worse, 46, 32% (does not add to 100% due to rounding)

Figure 20 Number and percentage of quality measures with disparity at baseline for which disparities related to race and ethnicity were improving, not changing, or worsening, 2000 through 2014-2016

Key: n = number of measures; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Bar chart showing number and percentage Black vs. White (n=75), Improving, 16, 21%, Not Changing, 56, 75%, Worsening, 3, 4% Asian vs. White (n=35), Improving, 3, 9%, Not Changing, 32, 91%, Worsening, 0 AI/AN vs. White (n=21), Improving, 2, 10%, Not Changing 19, 90%, Worsening, 0 NHPI vs. White (n=8), Improving, 1, 12.5%, Not Changing, 7, 87.5%, Worsening, 0 Hispanic vs. Non-Hispanic White (n=52), Improving, 10, 19%, Not Changing, 42, 81%, Worsening, 0

#### Disparities for Blacks

Figure 21 Number and percentage of all quality measures that were improving, not changing, or worsening, total for Blacks and by priority area, from 2000 through 2016

Bar chart showing number and percentage Total (n=164), Improving, 91, 55%, Not Changing, 60, 37%, Worsening, 13, 8% Person-Centered Care (n=16), Improving, 9, 56%, Not Changing, 6, 38%, Worsening, 1, 6% Patient Safety (n=30), Improving, 18, 60%, Not Changing, 10, 33%, Worsening, 2, 7% Healthy Living (n=54), Improving, 26, 48%, Not Changing, 26, 48%, Worsening, 2, 4% Effective Treatment (n=38), Improving, 24, 63%, Not Changing, 11, 29%, Worsening, 3, 8% Care Coordination (n=21), Improving, 14, 67%, Not Changing, 3, 14%, Worsening, 4, 19% Affordable Care (n=5), Improving, 0, Not Changing, 4, 80%, Worsening, 1, 20%

Data for the most recent year show that disparities remain for about 40% of quality measures for Blacks (Figure 19).^xii^ The largest disparities for Blacks compared with Whites include the following:

- In 2016, the rate of new HIV cases per 100,000 population age 13 and over was worse for Blacks compared with Whites (52.9 compared with 6.0, National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention [NCHHSTP], Division of HIV/AIDS [DHAP], National HIV/AIDS Surveillance System [NHSS]) (Appendix A, Graph 45).
- In 2015, the rate of HIV infection deaths per 100,000 population was worse for Blacks compared with Whites (7.9 compared with 1.1, CDC, NVSS-Mortality) (Appendix A, Graph 46).
- In 2015, the rate of adults with potentially avoidable hospital admissions for hypertension per 100,000 population was worse for Blacks than for Whites (170.3 admissions per 100,000 compared with 33.9 admissions per 100,000, AHRQ, HCUP, SID, 2001-2015; and AHRQ Quality Indicators, version 4.4)^xiii^ (Appendix A, Graph 47).

Trends show about 55% of quality measures improving overall for Blacks (Figure 21). Largest improvements include the following:

- From 2012 to 2015, the percentage of Black hospital patients who received influenza vaccination improved from 84.9% to 93.5% (CMS Clinical Data Warehouse) (Appendix A, Graph 48).
- From 2008 to 2015, the percentage of Black adolescents ages 16-17 who received 1 or more doses of the Tdap vaccine improved from 26.5% to 84.1% (CDC, NCIRD and NCHS, National Immunization Survey - Teen) (Appendix A, Graph 49).

The gap between Blacks and Whites remained the same for 75% of measures (Figure 20). Three measures showed an increasing gap between Blacks and Whites:

- Children ages 2-19 who visited the emergency department for asthma. In 2006-2008, the rate was 220.8 and in 2012-2014, the rate was 252.5 for Blacks. In 2006-2008, the rate was 60.0 and in 2012-2014, the rate was 76.0 for Whites (CDC, NCHS, National Hospital Ambulatory Medical Care Survey) (Appendix A, Graph 50).
- In 2001, Blacks had a rate of 156.7 per 100,000 population of potentially avoidable hospital admissions with hypertension compared with Whites, who had a rate of 33.2 per 100,000 population. In 2015, this disparity was increasing as Blacks had a rate of 170.3 and Whites had a rate of 33.9 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators, version 4.4)^xiv^ (Appendix A, Graph 51).
- In 2009, 24.2% of Black infants received exclusive breastfeeding through 3 months compared with 39.6% of White infants. In 2014, this disparity had increased. Fewer Black infants (28.9%) received breastfeeding exclusively through 3 months compared with White infants (51.6%) (CDC, NCIRD and NCHS, National Immunization Survey) (Appendix A, Graph 52).

#### Disparities for Asians

Figure 22 Number and percentage of all quality measures that were improving, not changing, or worsening, total for Asians and by priority area, from 2000 through 2016

Bar chart showing number and percentage Total (n=137), Improving, 83, 61%, Not Changing, 47, 34%, Worsening, 7, 5% Person-Centered Care (n=16), Improving, 13, 81%, Not Changing, 3, 19%, Worsening, 0 Patient Safety (n=24), Improving, 12, 50%, Not Changing, 11, 46%, Worsening, 1, 4% Healthy Living (n=45), Improving, 26, 58%, Not Changing, 17, 38%, Worsening, 2, 4% Effective Treatment (n=29), Improving, 17, 59%, Not Changing, 10, 34%, Worsening, 2, 7% Care Coordination (n=20), Improving, 15, 75%, Not Changing, 3, 15%, Worsening, 2, 10% Affordable Care (n=3), Improving, 0, Not Changing, 3, 100%, Worsening, 0

Data for the most recent year show that disparities remain for about 20% of quality measures for Asians (Figure 19).^xv^ Largest disparities for Asians compared with Whites were in patient safety and person-centered care:

- In 2015, the percentage of hospital patients with an anticoagulant-related adverse drug event with heparin was higher for Asians than for Whites (11.4% compared with 2.7%, AHRQ and CMS, MPSMS) (Appendix A, Graph 53).
- In 2015, the percentage of adults with limited English proficiency and a usual source of care (USC) whose USC had language assistance was lower for Asians than for Whites (78.3% compared with 92.3%, AHRQ, MEPS) (Appendix A, Graph 54).

Trends show 60% of quality measures improving overall for Asians (Figure 22). Largest improvements over time for Asians were observed in:

- Asian hospital patients who received influenza vaccination, which improved from 83.3% to 95.1% from 2012 to 2015 (CMS Clinical Data Warehouse) (Appendix A, Graph 55).
- Asian hospital patients who received pneumococcal immunization, which improved from 85.7% to 94.9% from 2012 to 2015 (CMS Clinical Data Warehouse) (Appendix A, Graph 56).
- Asian adolescents ages 16-17 who received 1 or more doses of the Tdap vaccine from 2008 to 2015, which improved from 38.4% to 87.5% (CDC, NCIRD and NCHS, National Immunization Survey - Teen) (Appendix A, Graph 57).

Disparities persist for Asians, with the gap between Asians and Whites remaining the same for about 90% of measures (Figure 20). Three quality measures showed a decreasing gap between Asians and Whites over time:

- From 2012 to 2015, the gap decreased between Asian and White hospital patients who received pneumococcal immunization. In 2012, 85.7% of Asians and 90% of Whites received this immunization. In 2015, 94.9% of Asians and 88.4% of Whites were immunized (CMS, Clinical Data Warehouse) (Appendix A, Graph 58).
- In 2005, Asians and Whites had a rate of 165.7 and 136.7, respectively, for deaths per 1,000 elective-surgery admissions having developed specified complications of care during hospitalization.^xvi^ In 2015, the gap between these populations decreased, and the mortality rates were 122.4 per 1,000 and 108.1 per 1,000 for Asians and Whites, respectively (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators, version 4.4^xvii^ (Appendix A, Graph 59).
- In 2010, 72.2% of Asian and 85.9% of White people living with HIV knew their serostatus. In 2014, this gap decreased, with 80.4% of Asian people and 87.7% of White people living with HIV knowing their serostatus (NCHHSTP, DHAP, NHSS) (Appendix A, Graph 60).

#### Disparities for American Indians/Alaska Natives

Figure 23 Number and percentage of all quality measures that were improving, not changing, or worsening, total for American Indians and Alaska Natives and by priority area, from 2000 through 2016

Bar chart showing number and percentage Total (n=79), Improving, 27, 34%, Not Changing, 47, 60%, Worsening, 5, 6% Person-Centered Care (n=14), Improving, 2, 14%, Not Changing, 11, 79%, Worsening, 1, 7% Patient Safety (n=6), Improving, 1, 17%, Not Changing, 3, 50%, Worsening, 2, 33% Healthy Living (n=37), Improving, 13, 35%, Not Changing, 24, 65%, Worsening, 0 Effective Treatment (n=18), Improving, 10, 56%, Not Changing, 6, 33%, Worsening, 2, 11% Care Coordination (n=3), Improving, 1, 33%, Not Changing, 2, 67%, Worsening, 0 Affordable Care (n=1), Improving, 0, Not Changing, 1, 100%, Worsening, 0

Data for the most recent year show that disparities remain for about 30% of quality measures for AI/ANs (Figure 19). Largest disparities between AI/ANs and Whites include:

- Hospital patients who received influenza vaccination (85.2% compared with 94.7%, CMS Clinical Data Warehouse) (Appendix A, Graph 61).
- Adults who had a doctor’s office or clinic visit in the last 12 months who rated their healthcare as poor^xviii^ (26.0% compared with 10.3%, AHRQ, MEPS) (Appendix A, Graph 62).
- Infant mortality^xix^ per 1,000 live births in 2014 (3.9 compared with 1.8, CDC, NCHS, NVSS - Linked Birth and Infant Death Data) (Appendix A, Graph 63).

Trends show almost 35% of quality measures improving for AI/ANs overall (Figure 23). Largest improvements over time for AI/ANs were observed in:

- Adolescents ages 16-17 who received 1 or more doses of the Tdap vaccine, which improved from 43.7% to 90.6% from 2008 to 2014^xx^ (CDC, NCIRD and NCHS, National Immunization Survey - Teen) (Appendix A, Graph 64).
- Adolescents ages 13-15 who received 1 or more doses of meningococcal conjugate vaccine, which improved from 51.8% to 88.3% from 2008 to 2015 (CDC, NCIRD and NCHS, National Immunization Survey - Teen) (Appendix A, Graph 65).

Disparities persist for AI/ANs, with the gap between AI/ANs and Whites remaining the same for about 90% of measures (Figure 20). Two quality measures showed the gap between AI/ANs and Whites decreasing over time:

- From 2008 to 2015, the disparities gap between AI/ANs and Whites decreased for the adjusted incident rate of end stage renal disease due to diabetes. For AI/ANs, the rate decreased (from 526 per million population to 275.8 per million) and for Whites did not statistically change (from 133.3 per million to 139.8 per million) (National Institutes of Health [NIH], National Institute on Diabetes and Digestive and Kidney Diseases [NIDDK], U.S. Renal Data System [RDS]) (Appendix A, Graph 66).
- From 2002 to 2015, the disparities gap between AI/ANs and Whites decreased for the percentage of children ages 2-17 for whom a health provider gave advice within the past 2 years about healthy eating. For AI/ANs the rate increased (from 28.7% to 58.2%) and for Whites the rates also increased (46.8% to 64.7%) (AHRQ, MEPS) (Appendix A, Graph 67).

#### Disparities for Native Hawaiians/Pacific Islanders

Figure 24 Number and percentage of all quality measures that were improving, not changing, or worsening, total for NHPIs and by priority area, from 2001 through 2016

Note: Measures of Affordable Care were not available or had statistically unreliable data for NHPIs.

Bar chart showing number and percentage Total (n=31), Improving, 8, 34%, Not Changing, 20, 60%, Worsening, 3, 6% Person-Centered Care (n=10), Improving, 3, 30%, Not Changing, 7, 70%, Worsening, 0 Patient Safety (n=6), Improving, 0, Not Changing, 3, 50%, Worsening, 3, 50% Healthy Living (n=10), Improving, 2, 20%, Not Changing, 8, 80%, Worsening, 0 Effective Treatment (n=2), Improving, 2, 100%, Not Changing, 0, Worsening, 0 Care Coordination (n=3), Improving, 1, 33%, Not Changing, 2, 67%, Worsening, 0

Data for the most recent year show that disparities remain for nearly one-third of quality measures for Native Hawaiians/Pacific Islanders (NHPIs) (Figure 19). Largest disparities for NHPIs compared with Whites include the following:

- In 2014, the percentage of adults who received a blood pressure measurement in the last 2 years and could state whether their blood pressure was normal or high was worse for NHPIs than for Whites (84.2% compared with 91.9%, CDC, NCHS, NHIS) (Appendix A, Graph 68).
- In 2016, the percentage of adults who reported that home health providers always treated them with courtesy and respect in the last 2 months was worse for NHPIs than for Whites (88.7% compared with 94.2%, CMS, HHCAHPS) (Appendix A, Graph 69).

Trends show about 25% of quality measures improving over time for NHPIs (Figure 24). Largest improvements include:

- From 2008 to 2011, the percentage of NHPI adolescents ages 16-17 who received 1 or more doses of meningococcal conjugate vaccine, which improved from 29.5% to 90.7% (CDC, NCIRD and NCHS, National Immunization Survey - Teen) (Appendix A, Graph 70).
- From 2008 to 2013, the percentage of NHPI adolescents ages 16-17 who received 1 or more doses of the Tdap vaccine, which improved from 41.9% to 92.4% (CDC, NCIRD and NCHS, National Immunization Survey - Teen)^xxi^ (Appendix A, Graph 71).
- From 2010 to 2014, the percentage of NHPIs living with HIV who knew their serostatus, which improved from 75.2% to 82.8% (NCHHSTP, DHAP, NHSS) (Appendix A, Graph 72).

The gap between NHPIs and Whites remained the same for all but one quality measure (Figure 20)^xxii^:

- In 2008, 9.5% of NHPI and 21.3% of White adolescent females ages 16-17 received 3 or more doses of human papillomavirus vaccine. In 2011, the gap improved between NHPIs and Whites (86.7% compared with 42.6%) (CDC, NCIRD and NCHS, National Immunization Survey - Teen) (Appendix A, Graph 73).

#### Disparities for Hispanics

Figure 25 Number and percentage of all quality measures that were improving, not changing, or worsening, total for Hispanics and by priority area, from 2000 through 2016

Bar chart showing number and percentage Total (n=152), Improving, 90, 59%, Not Changing, 52, 34%, Worsening, 10, 7% Person-Centered Care (n=16), Improving, 7, 44%, Not Changing, 9, 56%, Worsening, 0 Patient Safety (n=27), Improving, 16, 59%, Not Changing, 8, 30%, Worsening, 3, 11% Healthy Living (n=49), Improving, 34, 69%, Not Changing, 13, 27%, Worsening, 2, 4% Effective Treatment (n=35), Improving, 20, 57%, Not Changing, 13, 37%, Worsening, 2, 6% Care Coordination (n=20), Improving, 13, 65%, Not Changing, 5, 25%, Worsening, 2, 10% Affordable Care (n=5), Improving, 0, Not Changing, 4, 80%, Worsening, 1, 20%

Data for the most recent year show that disparities remain for nearly one-third of quality measures for Hispanics (Figure 19). Largest disparities between Hispanics and non-Hispanic Whites include:

- Children ages 2-5 with obesity in 2011-2014 (15.6% compared with 5.2%, CDC, NCHS, NHANES) (Appendix A, Graph 74).
- New HIV cases per 100,000 population age 13 and over (23.1 compared with 6.2) (CDC, NCHHSTP, DHAP, NHSS) (Appendix A, Graph 75).

Trends show about 60% of quality measures improving for Hispanics overall (Figure 25). Largest improvements for Hispanics over time were observed in:

- Adolescents ages 16-17 who received 1 or more doses of the Tdap vaccine, which improved from 29.4% to 81.4% from 2008 to 2015 (CDC, NCIRD and NCHS, National Immunization Survey - Teen) (Appendix A, Graph 76).
- Adolescents ages 13-15 who received 1 or more doses of the Tdap vaccine, which improved from 48.5% to 87.6% from 2008 to 2015 (CDC, NCIRD and NCHS, National Immunization Survey - Teen) (Appendix A, Graph 77).

Disparities persist for Hispanics, with the gap between Hispanics and non-Hispanic Whites remaining the same for about 80% of quality measures (Figure 20). The gap is getting smaller over time for about 20% of quality measures, including the following:

- From 2001 to 2015, the gap between Hispanics and non-Hispanic Whites decreased for the rate of potentially avoidable hospital admissions for uncontrolled diabetes. The rate decreased both for Hispanics (from 46.0 per 100,000 to 17.6 per 100,000) and for non-Hispanic Whites (from 17.6 per 100,000 to 8.9 per 100,000). (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 78).
- From 2001 to 2015, the gap between Hispanics and non-Hispanic Whites decreased for the rate of potentially avoidable hospital admissions for short-term complications of diabetes. However, the rate actually increased for both Hispanics (from 51.8 per 100,000 to 64.6 per 100,000) and non-Hispanic Whites (from 42.1 per 100,000 to 75.4 per 100,000) (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 79).
- In 2001, the adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population for non-Hispanic Whites was 114.5 and for Hispanics was 410.0 per million population. In 2015, the rate for non-Hispanic Whites was 116.8 and for Hispanics, 302.6 per million population (NIH, NIDDK, USRDS) (Appendix A, Graph 80).
- In 2001, the rate of potentially avoidable hospital admissions for long-term complications of diabetes per 100,000 population was worse for Hispanic adults (206.6) compared with non-Hispanic White adults (96.7). In 2015, this disparity was smaller. Hispanics had a rate of 165.9 per 100,000 population and non-Hispanic Whites had a rate of 88.8 per 100,000 population (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 81).

#### Disparities by Income and Insurance

Figure 26 Number and percentage of all quality measures that were improving, not changing, or worsening, total for poor people and by priority area, from 2000 through 2015

Key: n = number of measures.

Bar chart showing number and percentage Total (n=123), Improving, 70, 57%, Not Changing, 40, 33%, Worsening, 13, 11% (does not add to 100 due to rounding) Person-Centered Care (n=6), Improving, 6, 100%, Not Changing, 0, Worsening, 0 Patient Safety (n=18), Improving, 15, 83%, Not Changing, 2, 11%, Worsening, 1, 6% Healthy Living (n=47), Improving, 25, 53%, Not Changing, 21, 45%, Worsening, 1, 2% Effective Treatment (n=23), Improving, 12, 52%, Not Changing, 8, 35%, Worsening, 3, 13% Care Coordination (n=24), Improving, 10, 42%, Not Changing, 7, 29%, Worsening, 7, 29% Affordable Care (n=5), Improving, 2, 40%, Not Changing, 2, 40%, Worsening, 1, 20%

Figure 27 Number and percentage of quality measures for which income groups experienced better, same, or worse quality of care compared with reference group (high income), 2014-2015

Key: n = number of measures.

Bar chart showing number and percentage Poor (n=126), Better, 6, 5%, Same, 44, 35%, Worse, 76, 60% Low Income (n=125), Better, 4, 3%, Same, 48, 38%, Worse, 73, 58% (does not add to 100% due to rounding) Middle income (n=126), Better, 3, 2%, Same, 65, 52%, Worse, 58, 46%

Figure 28 Number and percentage of quality measures with disparity at baseline for which disparities related to income were improving, not changing, or worsening, 2000 through 2015

Key: n = number of measures.

Bar chart showing number and percentage Poor (n=82), Improving, 14, 17%, Not Changing, 62, 76%, Worsening, 6, 7% Low Income (n=79), Improving, 8, 10%, Not Changing, 69, 87%, Worsening, 2, 3% Middle income (n=66), Improving, 0, Not Changing, 65, 98%, Worsening, 1, 2%

Figure 29 Number and percentage of quality measures for which insurance groups experienced better, same, or worse quality of care compared with reference group (privately insured), 2014-2015

Key: n = number of measures.

Bar chart showing number and percentage Total (n=139), Better, 16, 12%, Same, 51, 37%, Worse, 72, 52% (does not add to 100% due to rounding) Public (n=70), Better, 8, 11%, Same, 35, 50%, Worse, 27, 39% Uninsured (n=69), Better, 8, 12%, Same, 16, 23%, Worse, 45, 65%

- There were significant disparities for poor and uninsured populations in all priority areas. Figures 26-29 show that overall, while some disparities were getting smaller from 2000^xxiii^ through 2014-2015, disparities persist, especially among people in poor and low-income households and uninsured people.

### Variation in care persisted across the urban-rural continuum in 2014-2016

This report uses the 2006 National Center for Health Statistics (NCHS) classification for analyzing healthcare quality and disparities by geographic location (Ingram & Franco, 2012). The NCHS scheme includes six urbanization categories, including:

- Four metropolitan county designations:
  ■ Large Central Metropolitan: Large central metropolitan counties in a metropolitan statistical area (MSA) of 1 million or more population:
    1. That contain the entire population of the largest principal city of the MSA, or
    2. Whose entire population resides in the largest principal city of the MSA, or
    3. That contain at least 250,000 of the population of any principal city in the MSA.
  ■ Large Fringe Metropolitan: Counties in an MSA of 1 million or more population that do not qualify as large central.^xxiv^
  ■ Medium Metropolitan: Counties in an MSA of 250,000 to 999,999 population.
  ■ Small Metropolitan: Counties in an MSA of 50,000 to 249,999 population.
- Two nonmetropolitan county designations:
  ■ Micropolitan: Counties in a micropolitan statistical area.
  ■ Noncore: Counties not in a micropolitan statistical area.

Figure 30 Number and percentage of quality and access measures for which members of selected groups experienced better, same, or worse quality of care compared with reference group (large fringe metro) in 2014-2016, by geographic location

Key: n = number of measures.

Note: The measures represented in this chart are available in Appendix B. Definitions of geographic locations are available at https://www.cdc.gov/nchs/data_access/urban_rural.htm and in Appendix D.

Bar chart showing number and percentage Large Central Metro vs. Large Fringe Metro (n=123), Better, 3, 2%, Same, 93, 76%, Worse, 27, 22% Medium Metro vs. Large Fringe Metro (n=122), Better, 4, 3%., Same, 101, 83%, Worse, 17, 14% Small Metro vs. Large Fringe Metro (n=122), Better, 8, 7%, Same, 94, 77%, Worse, 20, 16% Micropolitan vs. Large Fringe Metro (n=118), Better, 6, 5%, Same, 75, 64%, Worse, 37, 31% Noncore vs. Large Fringe Metro (n=103), Better, 8, 8%, Same, 60, 58%, Worse, 35, 34%

#### Large Central Metropolitan Areas

Areas categorized as large central metropolitan areas include areas such as Denver County, Colorado; Washington, DC; and Cook County, Illinois. Performance for most quality measures was not significantly different from that in large fringe metropolitan areas (reference group) (Figure 30). Some improvements over time in healthcare quality have been observed in large central metropolitan areas in patient safety and care coordination:

- Hospital admissions with central venous catheter-related bloodstream infection declined from a rate of 2.26 per 1,000 discharges in 2008 to 0.71 per 1,000 discharges in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015 NIS; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 82).
- Potentially avoidable hospital admissions for angina per 100,000 population declined from 79.4 in 2000 to 12.9 in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015 NIS; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 83).
- Hospital admissions for pediatric gastroenteritis per 100,000 population, children ages 3 months to 17 years, improved from 164.3 in 2000 to 52.8 in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015 NIS; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 84).

However, some disparities persist in the areas of care coordination and access to care:

- In 2015, the rate of potentially avoidable hospital admissions for asthma was worse for children ages 2-17 in large central metropolitan areas (125.9 per 100,000 population) compared with children ages 2-17 in large fringe metropolitan areas (73.0 per 100,000 population) (AHRQ, HCUP) (Appendix A, Graph 85).
- In 2015, the percentage of adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the services was worse for residents in large central metropolitan areas (8.8%) compared with residents in large fringe metropolitan areas (5.6%) (AHRQ, MEPS) (Appendix A, Graph 86).

#### Medium Metropolitan Areas

Areas categorized as medium metropolitan areas include Scott County, Kentucky; York County, Maine; and Douglas County, Nebraska. Performance for most quality measures was not significantly different from that in large fringe metropolitan areas. Some improvements over time in healthcare quality have occurred in medium metropolitan areas in patient safety and care coordination, including:

- Hospital admissions with central venous catheter-related bloodstream infection, which declined from a rate of 1.9 per 1,000 discharges in 2008 to 0.69 per 1,000 discharges in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015 NIS; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 87).
- Potentially avoidable hospital admissions for angina per 100,000 population, which declined from 51.4 per 100,000 in 2000 to 9.7 per 100,000 in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015 NIS; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 88).
- Hospital admissions for pediatric gastroenteritis per 100,000 population, children ages 3 months to 17 years, which improved from 144.4 in 2000 to 45.2 in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015 NIS; and AHRQ Quality Indicators, version 4.4) (Appendix A, Graph 89).

However, some disparities persist in obesity prevention, patient safety, and access to care:

- In 2015, the percentage of children who had their height and weight measured by a health provider within the past 2 years was worse for children in medium metropolitan areas (92.8%) compared with children in large fringe metropolitan areas (95.4%) (AHRQ, MEPS) (Appendix A, Graph 90).
- In 2015, the rate of accidental puncture or laceration during procedure for children was worse in medium metropolitan areas (0.64 per 1,000 medical and surgical admissions) than in large fringe metropolitan areas (0.41 per 1,000 medical and surgical admissions) (AHRQ, HCUP, SID, and AHRQ Quality Indicators version 4.4) (Appendix A, Graph 91).
- In 2015, the percentage of people under 65 with any private insurance was lower for residents of medium metropolitan areas (65%) compared with residents of large fringe metropolitan areas (73.7%) (CDC, NCHS, NHIS) (Appendix A, Graph 92).

#### Small Metropolitan Areas

Areas categorized as small metropolitan areas include Allen County, Ohio; Wayne County, North Carolina; and Carson City County, Nevada. Performance for most quality measures was not significantly different from that in large fringe metropolitan areas. Some improvements over time in small metropolitan areas include measures in effective care for cancer, care coordination, and patient safety:

- The percentage of patients with colon cancer who received surgical resection of colon cancer improved from 60.2% in 2005 to 90.5% in 2014 (National Cancer Database [NCDB]) (Appendix A, Graph 93).
- The rate of potentially avoidable hospital admissions for angina for adults improved from 60.7 per 100,000 population in 2000 to 11.5 per 100,000 population in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators version 4.4) (Appendix A, Graph 94).
- The rate of hospital admissions with central venous catheter-related bloodstream infection declined from 1.53 per 1,000 discharges in 2008 to 0.57 per 1,000 discharges in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators version 4.4) (Appendix A, Graph 95).

However, some disparities have persisted in patient safety, healthy living, and access to care.

- In 2015, deaths per 1,000 hospital admissions with expected low mortality was worse for residents of small metropolitan areas (0.45) compared with residents of large fringe metropolitan areas (0.25) (AHRQ, HCUP) (Appendix A, Graph 96).
- In 2014, infant mortality per 1,000 live births where birth weight was more than 2,499 grams was higher for small metropolitan areas (2.4) compared with large fringe metropolitan areas (1.7) (CDC, NVSS-Linked Birth and Infant Death Data) (Appendix A, Graph 97).
- In 2016, the percentage of people under 65 with any private insurance was lower for residents of small metropolitan areas (61.2%) compared with residents of large fringe metropolitan areas (72.9%) (CDC, NHIS) (Appendix A, Graph 98).

#### Micropolitan

Areas categorized as micropolitan areas include Love County, Oklahoma; Cherokee County, South Carolina; and Harrison County, West Virginia. Performance for most quality measures was not significantly different from that in large fringe metropolitan areas. Some improvements over time in micropolitan areas include measures in effective care for cancer, care coordination, and patient safety:

- Patients with colon cancer who received surgical resection of colon cancer improved from 53.8% in 2005 to 89.9% in 2014 (NCDB) (Appendix A, Graph 99).
- Potentially avoidable hospital admissions for angina for adults improved from 113.1 per 100,000 population in 2000 to 14.1 per 100,000 population in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators version 4.4) (Appendix A, Graph 100).
- Hospital admissions with central venous catheter-related bloodstream infection declined from 1.37 per 100,000 population in 2008 to 0.57 per 100,000 population in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators version 4.4) (Appendix A, Graph 101).

However, some disparities persist in care coordination, patient safety, and access to care:

- In 2015, the rate of emergency department visits with a principal diagnosis related to dental conditions was worse for residents of micropolitan and noncore areas combined (496.7 per 100,000 population) compared with residents of large fringe metropolitan areas (238.2 per 100,000 population) (AHRQ, HCUP, NEDS) (Appendix A, Graph 102).
- In 2015, the rate of accidental puncture or laceration during procedure per 1,000 medical and surgical admissions for children was worse in micropolitan areas (0.74) compared with large fringe metropolitan areas (0.41) (AHRQ, HCUP, SID; and AHRQ Quality Indicators version 4.4) (Appendix A, Graph 103).
- In 2016, the percentage of people under age 65 with any private health insurance was worse in micropolitan areas (58.0%) compared with large fringe metropolitan areas (72.9%) (CDC, NCHS, NHIS) (Appendix A, Graph 104).

#### Noncore

Areas categorized as noncore areas include Wallowa, Oregon; Bedford, Pennsylvania; and Crane, Texas. Performance for most quality measures was not significantly different from that in large fringe metropolitan areas. Some improvements over time in noncore areas include measures in effective care for cancer, care coordination, and patient safety:

- Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined improved from 57.9% in 2005 to 89.9% in 2014 (NCDB) (Appendix A, Graph 105).
- Potentially avoidable hospital admissions for angina for adults improved from 140.3 per 100,000 population in 2000 to 13.3 per 100,000 population in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators version 4.4) (Appendix A, Graph 106).
- Hospital admissions with central venous catheter-related bloodstream infection declined from 1.21 per 1,000 discharges in 2008 to 0.54 per 1,000 discharges in 2015 (AHRQ, HCUP, NIS, 2000-2011; SID, 2012-2015; and AHRQ Quality Indicators version 4.4) (Appendix A, Graph 107).

However, some disparities persist in care coordination, infant mortality, and person-centered care:

- In 2015, the rate of potentially avoidable hospital admissions for bacterial pneumonia per 100,000 population for adults in noncore areas (460.4) was worse than for adults in large fringe metropolitan areas (233.4) (AHRQ, HCUP) (Appendix A, Graph 108).
- In 2014, the infant mortality rate per 1,000 live births was higher for noncore areas (2.9) compared with large fringe metropolitan areas (1.7) (CDC, NVSS - Linked Birth and Infant Death Data) (Appendix A, Graph 109).
- In 2015, the percentage of adults who reported low ratings for their doctor’s office or clinic was worse in noncore areas (17.1%) than in large fringe metropolitan areas (10.1%) (AHRQ, MEPS) (Appendix A, Graph 110).

viii Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, including states, and special handling of 2015 data, see the HCUP Methods Series Report, Methods Applying AHRQ Quality Indicators to Healthcare Cost and Utilization Project (HCUP) Data for the 2017 National Healthcare Quality and Disparities Report (QDR) at https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp.

ix Tdap = tetanus, diphtheria, and acellular pertussis.

x These statistics are based on a comprehensive set of all-listed (principal and secondary) diagnoses of opioid abuse, dependence, poisoning, and adverse effects. Therefore, the opioid-related hospital admissions and emergency department visits summarized here encompass a broader range of issues than effective care for opioid misuse. However, such measures of utilization do indicate the need for acute care for individuals with opioid-related diagnoses.

xi Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9_th_ Revision coding. For more information on the sampling approach, including states, and special handling of 2015 data, see the HCUP Methods Series Report, Methods Applying AHRQ Quality Indicators to Healthcare Cost and Utilization Project (HCUP) Data for the 2017 National Healthcare Quality and Disparities Report (QDR), at https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp.

xii The following measure is not included in Figure 19 due to unreliable data for Blacks: Live-born infants with low birth weight (less than 2,500 g).

xiii Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, including states, and special handling of 2015 data, see the HCUP Methods Series Report, Methods Applying AHRQ Quality Indicators to Healthcare Cost and Utilization Project (HCUP) Data for the 2017 National Healthcare Quality and Disparities Report (QDR) at https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp.

xiv Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, including states, and special handling of 2015 data, see the HCUP Methods Series Report, Methods Applying AHRQ Quality Indicators to Healthcare Cost and Utilization Project (HCUP) Data for the 2016 National Healthcare Quality and Disparities Report (QDR) at https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp.

xv The following measure is not included in Figure 19 due to unreliable data for Asians: HIV infection deaths per 100,000 population.

xvi Ages 18-89 or obstetric admissions.

xvii Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, including states, and special handling of 2015 data, see the HCUP Methods Series Report, Methods Applying AHRQ Quality Indicators to Healthcare Cost and Utilization Project (HCUP) Data for the 2016 National Healthcare Quality and Disparities Report (QDR) at https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp.

xiii Rating of healthcare 0-6 on a scale from 0 to 10 (best grade) by adults who had a doctor’s office or clinic visit in the last 12 months.

xix Infant mortality per 1,000 live births, birth weight more than 2,499 grams.

xx Data do not meet the criteria for statistical reliability, data quality, or confidentiality for AI/AN in 2015.

xxi Data statistically unreliable for NHPIs for 2012-2015.

xxii Only quality measures with statistically significant disparities at baseline data year are included. Eight quality measures met this criterion for this analysis of change in disparities over time for NHPIs.

xxiii Most of the data collection for this set of measures began in 2000. Two CDC/NHIS measures have data from 1998: Adults who received a blood cholesterol measurement in the last 5 years and Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high.

xxiv For comparisons across geographic areas, residents of large fringe MSAs (large city suburbs) are used as the reference group since these counties have the lowest levels of poverty and typically have the best quality and access to healthcare.