# ACCESS TO HEALTHCARE AND DISPARITIES IN ACCESS

To obtain high-quality care, Americans must first gain entry into the healthcare system. Measures of access to care tracked in the QDR include having health insurance, having a usual source of care, encountering difficulties when seeking care, and receiving care as soon as wanted.

Historically, Americans have experienced variable access to care based on race, ethnicity, socioeconomic status, age, sex, disability status, sexual orientation, gender identity, and residential location.^v^ This report discusses findings that showed the largest statistically significant disparities related to some of these variables where data are available.

## Overall Trends in Access

Figure 11 Number and percentage of access measures for which measure trends were improving, not changing, or worsening, 2000-2016

Key: n = number of measures.

Note: The measures represented in this chart are available in Appendix B.

Bar chart showing number and percentage of measures Improving, 9, 43% Not changing, 9, 43% Worsening, 3, 14%

- Overall, some access measures improved (Figure 11). Some of the largest improvements in access include:
  ■ Children who had any appointments for routine healthcare in the last 12 months who sometimes or never^vi^ got an appointment for routine care as soon as needed, which declined from 10.2% in 2002 to 5.2% in 2015 (AHRQ, Medical Expenditure Panel Survey [MEPS]) (Appendix A, Graph 1).
  ■ People who were in fair or poor health with a specific source of ongoing care, which increased from 87.5% in 2009 to 90.5% in 2016 (Centers for Disease Control and Prevention [CDC], National Center for Health Statistics [NCHS], National Health Interview Survey [NHIS]) (Appendix A, Graph 2).
  ■ People with a specific source of ongoing care, which increased from 85.5% in 2009 to 88.2% in 2016 (CDC, NCHS, NHIS). (Appendix A, Graph 3).
- Some measures got worse, including:
  ■ Children who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, which increased from 4.2% in 2008 to 4.8% in 2015 (AHRQ, MEPS) (Appendix A, Graph 4).

## Trends in Access Disparities

Most disparities in access to care showed no statistically significant changes, with a few exceptions. The following access measures showed that disparities over time improved (the difference between the comparison group and reference group decreased) from the baseline data year to the most recent data year^vii^:

- From 2002 to 2015, disparities between AI/ANs and Whites decreased for the percentage of people with a usual source of care, excluding hospital emergency rooms, who has office hours at night or on weekends. The percentage for AI/ANs increased (from 35.0% to 45.8%) while the percentage did not change significantly for Whites (from 45.3% to 41.0%) (AHRQ, MEPS, 2015) (Appendix A, Graph 5).
- From 2008 to 2015, disparities between uninsured and privately insured people decreased for the percentage of adults ages 18-64 who reported that they sometimes or never found it easy to access care, tests, or treatment. The percentage for uninsured people decreased (from 29.7% to 18.5%) while the change for privately insured people (from 7.5% to 6.9%) was not statistically significant (AHRQ, MEPS, 2015) (Appendix A, Graph 6).
- From 2008 to 2015, disparities between Asians and Whites decreased for the percentage of adults ages 18-64 who reported that they sometimes or never found it easy to access care, tests, or treatment. The percentage decreased both for Asians (from 21.1% to 8.7%) and for Whites (from 8.2% to 6.7%) (AHRQ, MEPS, 2015) (Appendix A, Graph 7).

## Snapshot of Disparities in Access

Figure 12 Number and percentage of access measures for which members of selected groups experienced better, same, or worse access to care compared with reference group, 2014-2016

Key: n = number of measures; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: The measures represented in this chart are available in Appendix B. The number of measures is based on the measures that have data for each population group.

Bar chart showing number and percentage of measures Poor vs. High Income (n=20), same, 2, 10%; worse, 18, 90% Black vs. White (n=21), better, 1, 5%; 9, 43%, worse, 11, 52% Asian vs. White (n=19), better, 7, 37% same, 7, 37%, worse, 5, 26% AI/AN vs. White (n=11), same, 7, 64%, worse, 4, 36% NHPI vs. White (n=4), same, 4, 100% Hispanic vs. Non-Hispanic White (n=20), better, 3, 15%, same, 3, 15%, worse, 14, 70%

For the most recent data year (2015-2016), findings show that many disparities persist in access to care. Selected findings below show the largest disparities for each population.

### Poor People

Poor people (at or below 100% of the Federal Poverty Level [FPL]) experienced worse access to care compared with high-income people (400% or more of FPL) for 18 of 20 access measures (Figure 12; see Appendix B). Across the QDR measure set for 2015-2016 (most recent data year), the following access measures showed the largest disparities between poor people and high-income people:

- People under age 65 who were uninsured all year (15.5% for poor compared with 4.2% for high income) (AHRQ, MEPS, 2015) (Appendix A, Graph 8).
- People under age 65 with any period of uninsurance during the year (30.6% for poor compared with 10.2% for high income) (AHRQ, MEPS, 2015) (Appendix A, Graph 9).

### Blacks

Blacks experienced worse access to care compared with Whites for 52% of the measures and the same access to care for 43% of the measures (Figure 12; see Appendix B). Access measures that showed the largest disparities between Blacks and Whites include:

- Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, which was higher for Blacks compared with Whites (8.8% compared with 4.3%) (AHRQ, MEPS, 2015) (Appendix A, Graph 10).
- Adults who needed care right away for an illness, injury, or condition in the last 12 months who sometimes or never got care as soon as needed, which was higher for Blacks compared with Whites (17.1% compared with 10.5%) (AHRQ, MEPS, 2015) (Appendix A, Graph 11).

### Asians

Asians experienced worse access to care compared with Whites for 26% of the measures, the same access for 37% of the measures in the QDR measure set, and better access for 37% of the measures (Figure 12; see Appendix B). Access measures that showed the largest disparities between Asians and Whites include:

- Adults who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, which was higher for Asians than for Whites (25.3% compared with 12.6%) (AHRQ, MEPS, 2015) (Appendix A, Graph 12).
- Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, which was higher for Asians than for Whites (13.0% compared with 4.3%) (AHRQ, MEPS, 2015) (Appendix A, Graph 13).

### American Indians and Alaska Natives

Among the 11 measures in the QDR measure set that had data for AI/ANs for the most recent data year 2015-2016, 4 showed worse care for AI/ANs compared with Whites, and 7 showed the same access to care for AI/ANs (Figure 12; see Appendix B). Access measures that showed the largest disparities between AI/ANs and Whites include:

- People under age 65 with health insurance, which was lower for AI/ANs than for Whites (74.6% compared with 89.8%) (CDC, NCHS, NHIS, 2016) (Appendix A, Graph 14).
- People under age 65 who were uninsured all year, which was higher for AI/ANs than for Whites (20.1% compared with 9.6%) (AHRQ, MEPS, 2015) (Appendix A, Graph 15).

### Native Hawaiians/Pacific Islanders

Only 4 measures in the QDR measure set had data for NHPIs and all 4 showed the same access to care (Figure 12; see Appendix B).

### Hispanics

Hispanics experienced worse access to care compared with non-Hispanic Whites for 70% of the measures in the QDR measure set for the most recent data year 2015-2016, the same access for 15% of the measures, and better access for 15% of the measures (Figure 12; see Appendix B). Access measures that showed the largest disparities between Hispanics and non-Hispanic Whites include:

- People under age 65 who were uninsured all year, which was higher for Hispanics compared with non-Hispanic Whites (18.9% compared with 6.5%) (AHRQ, MEPS, 2015) (Appendix A, Graph 16).
- Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, which was higher for Hispanics than for non-Hispanic Whites (7.7% compared with 3.1%) (AHRQ, MEPS, 2015) (Appendix A, Graph 17).

## Trends in Health Insurance Coverage

The Early Release Program of the National Health Interview Survey (NHIS) provides timely data on health insurance coverage in the United States. Since these are the latest data published, these data are not included in the summary analyses conducted for this report. However, it is important to note the status of health insurance coverage with the most recent data available at the time this report was released.

Below are findings from the Health Insurance Coverage: Early Release of Estimates From the National Health Interview Survey, 2017 Report. More information about the estimates are available on the NHIS website at https://www.cdc.gov/nchs/nhis.htm.

Figure 13 Adults ages 18-64 who were uninsured or had private or public coverage at the time of interview, 1997-2017

Note: A small number of people were covered by both public and private plans and were included in both categories.

Line graph showing trend in percentage 1997, Private, 72.8%, Public, 10.2%, uninsured, 18.9% 2005, Private, 70.9%, Public, 11.5%, uninsured, 18.9% 2010, Private, 64.1%, Public, 15%, uninsured, 21.3% 2017, Private, 69.3%, Public, 19.3%, uninsured, 12.8%

Source: National Center for Health Statistics, National Health Interview Survey Early Release Program, 2017. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur201805.pdf.

- In 2017, among adults ages 18-64, 69.3% had private health insurance, 19.3% had public coverage, and 12.8% were uninsured at the time of interview (Figure 13).
- After generally increasing, more recently, the percentage of adults ages 18-64 who were uninsured at the time of interview generally decreased.
- Corresponding increases have occurred in both public and private coverage among adults ages 18-64.

Figure 14 Children ages 0-17 years who were uninsured or had private or public coverage at the time of interview, 1997-2017

Note: A small number of people were covered by both public and private plans and were included in both categories.

Line graph showing trend in percentage 1997, Private, 66.2%, Public, 21.4%, uninsured, 13.9% 2005, Private, 62.4%, Public, 29.9%, uninsured, 8.9% 2010, Private, 53.8%, Public, 39.8%, uninsured, 7.8% 2017, Private, 55%, Public, 41.3%, uninsured, 5%

Source: National Center for Health Statistics, National Health Interview Survey Early Release Program, 2017. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur201805.pdf.

- In 2017, among children ages 0-17 years, 55.0% had private health insurance, 41.3% had public coverage, and 5.0% were uninsured (Figure 14).
- The percentage of children who were uninsured generally decreased over time.
- While the percentage of children with private health insurance coverage has decreased and public coverage has increased over time, the percentage of children with public or private coverage has leveled off in recent years.

Figure 15 Adults ages 18–64 who were uninsured at the time of interview, by poverty status, 1997-2017

Note: For this measure, lower rates are better. Poverty categories are based on the Federal Poverty Level (FPL). Poor = below the FPL; near poor = 100% to <200% of the FPL; not poor = 200% or more of the FPL.

Line graph showing trend in percentage 1997, Poor, 40.2%, Near Poor, 34.9%, Not Poor, 9.9% 2005, Poor, 38.5%, Near Poor, 36.6%, Not Poor, 10.7% 2010, Poor, 42.2%, Near Poor, 43%, Not Poor, 12.6% 2017, Poor, 24.4%, Near Poor, 23.8%, Not Poor, 8.2%

Source: National Center for Health Statistics, National Health Interview Survey Early Release Program, 2017. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur201805.pdf.

- In 2017, among adults ages 18-64, 24.4% of those who were poor, 23.8% of those who were near poor, and 8.2% of those who were not poor lacked health insurance coverage at the time of interview (Figure 15).
- A decrease was observed in the percentage of uninsured adults from 2010 through 2017 among all three poverty status groups. However, the greatest decreases in the uninsured rate since 2013 were among adults who were poor or near poor.
- More recently, among adults who were poor, near poor, and not poor, there was no statistically significant change from 2015 through 2017 in the percentage uninsured.

Figure 16 Children ages 0-17 years who were uninsured at the time of interview, by poverty status, 1997-2017

Note: For this measure, lower rates are better. Poverty categories are based on the Federal Poverty Level (FPL). Poor = below the FPL; near poor = 100% to <200% of the FPL; not poor = 200% or more of the FPL.

Line graph showing trend in percentage 1997, Poor, 22.4%, Near Poor, 22.8%, Not Poor, 6.1% 2005, Poor, 13%, Near Poor, 14.7%, Not Poor, 4.6% 2010, Poor, 10.2%, Near Poor, 12.6%, Not Poor, 4.6% 2017, Poor, 6%, Near Poor, 7.5%, Not Poor, 3.8%

Source: National Center for Health Statistics, National Health Interview Survey Early Release Program, 2017. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur201805.pdf.

- In 2017, among children ages 0-17 years, 6.0% of those who were poor, 7.5% of those who were near poor, and 3.8% of those who were not poor lacked health insurance coverage at the time of interview (Figure 16).
- A general decrease in the percentage of uninsured children was observed among poor, near poor, and not poor households from 2010 through 2015.
- From 2015 through 2017, among children who were near poor and not poor, there was no statistically significant change in the percentage who were uninsured.
- Among poor children, the percentage who were uninsured increased from 4.4% in 2015 to 6.5% in 2016. The decline from 6.5% in 2016 to 6.0% in 2017 was not statistically significant.

Figure 17 Adults ages 18-64 who were uninsured at the time of interview, by race/ethnicity, 2010-2017

Note: For this measure, lower rates are better. White, Black, and Asian are non-Hispanic. Hispanic includes all races. Data for Native Hawaiians/Pacific Islanders and American Indians/Alaska Natives are not available for this measure.

Line graph showing trend in percentage White, 2010, 16.4, 2017, 8.5 Black, 2010, 27.2, 2017, 14.1 Asian, 2010, 19.5, 2017, 7.6 Hispanic, 2010, 43.2, 2017, 27.2

Source: National Center for Health Statistics, National Health Interview Survey Early Release Program, 2017. https://www.cdc.gov/nchs/data/nhis/earlyrelease/insur201805.pdf.

- In 2017, among adults ages 18-64, 8.5% of Whites, 14.1% of Blacks, 7.6% of Asians, and 27.2% of Hispanics lacked health insurance coverage at the time of interview (Figure 17).
- Significant decreases in the percentage of uninsured adults were observed from 2013 through 2017 for Whites, Blacks, Asians, and Hispanics.
- Hispanic adults had the greatest percentage point decrease in the uninsured rate from 2013 (40.6%) through 2016 (25.0%).
- The observed increase among Hispanic adults between 2016 (25.0%) and 2017 (27.2%) was not statistically significant; nor were there any statistically significant changes for the other groups during this time.

v Data on measures for these populations are available in the Data Query system. For some categories, such as sexual orientation and gender identity, data are not available. Further data collection efforts may be needed for these areas.

vi The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes or Never is a combined category that is the opposite of Always.

vii Trends in disparities are defined as a change in the difference between a comparison group and reference group from the baseline data year to the most recent data year. The change in disparities is the absolute difference in annual percentage of change between the comparison group and reference group. The annual percentage of change is estimated using unweighted linear regression. For more information, see Introduction and Methods.