# STATE VARIATION IN HEALTHCARE QUALITY AND DISPARITIES

State-level data show that healthcare quality and disparities vary widely depending on state and region. Although a state may perform well in overall quality, the same state may face significant disparities in healthcare access or disparities within specific areas of quality.

Figure 9 Overall quality of care, by state, 2014-2016

Note: All state-level measures with data are used to compute an overall quality score for each state based on the number of quality measures above, at, or below the average across all states. States were ranked and quartiles are shown on the map. The states with the worst quality score are in the fourth quartile, and states with the best quality score are in the first quartile. See Appendix B for a list of measures used for this map.

Map showing quality in quartiles, with the first quartile the highest, or best, and the fourth quartile the lowest, or worst: Quartile 4: Alaska, Arizona, Arkansas, California, District of Columbia, Florida, Kentuckey, Mississippi, Nevada, New York, Oklahoma, West Virginia Quartile 3: Alabama, Georgia, Illinois, Indiana, Kansas, Kentucky, Louisiana, Maryland, Missouri, Nebraska, New Mexico, Oregon, Tennessee, Texas, Utah Quartile 2: Delaware, Idaho, Iowa, Michigan, Montana, New Jersey, Ohio, South Carolina, South Dakota, Vermont, Virginia, Washington, Wyoming Quartile 1: Colorado, Connecticut, Hawaii, Maine, Massachusetts, Minnesota, New Hampshire, North Carolina, North Dakota, Pennsylvania, Rhode Island, Vermont, Wisconsin

- Overall quality of care varied across the United States (Figure 9):
  ■ Some states in the Midwest (Minnesota, North Dakota, and Wisconsin), some in the Northeast (Connecticut, Maine, Massachusetts, New Hampshire, Pennsylvania, and Rhode Island), and Colorado, Hawaii, and North Carolina had the highest overall quality scores. Scores were based on the number of measures that were better, same, or worse than the national average for each measure.
  ■ Many Southern and Southwestern states (Arkansas, District of Columbia, Florida, Kentucky, Mississippi, Oklahoma, and West Virginia), several Western states (Arizona, California, and Nevada), and New York and Alaska had the lowest overall quality scores.

Figure 10 Average differences in quality of care for Blacks, Hispanics, and Asians compared with Whites, by state, 2015-2016

Note: All measures in this report that had state-level data to assess racial and ethnic disparities were used. Separate quality scores were computed for Whites, Blacks, Hispanics, and Asians. For each state, the average of the Black, Hispanic, and Asian scores was divided by the White score. State-level AI/AN data were not available for analysis. States were ranked on this ratio, and quartiles are shown on the map. The states with the worst disparity score are in the fourth quartile, and states with the best disparity score are in the first quartile. Disparity scores were not risk adjusted for population characteristics in each state, so these findings do not take into account population differences between states. See Appendix B for a list of measures used for this map.

Map showing disparities in quartiles, with the first quartile the lowest, or best, and the fourth quartile the highest, or worst: Quartile 1: Colorado, Connecticut, Delaware, Idaho, Missouri, Nevada, South Carolina, Tennessee, Utah, Virginia, Wyoming Quartile 2: Alaska, Florida, Indiana, Iowa, Kansas, Maryland, Mississippi, New Mexico, North Carolina, Oregon, Rhode Island, Washington Quartile 3: Alabama, Arizona, California, District of Columbia, Georgia, Kentucky, Minnesota, Nebraska, New Jersey, North Dakota, Ohio, West Virginia Quartile 4: Arkansas, Illinois, Louisiana, Massachusetts, Michigan, New York, Oklahoma, Pennsylvania, Texas, Wisconsin

- Racial and ethnic disparities varied across the United States (Figure 10):
  ■ Some Western and Midwestern states (Colorado, Idaho, Missouri, Nevada, Utah, and Wyoming), several Southern states (Delaware, South Carolina, Tennessee, and Virginia) and Connecticut had the fewest racial and ethnic disparities overall.
  ■ Several Northeastern states (Massachusetts, New York, and Pennsylvania), some Midwestern states (Illinois, Michigan, and Wisconsin), some Southern states (Arkansas, Louisiana, Oklahoma, and Texas), and Hawaii had the most racial and ethnic disparities overall.