# OVERVIEW OF HEALTHCARE COSTS IN THE UNITED STATES

The cost of healthcare is an important factor not only for access to healthcare but also for value and efficiency in healthcare, which are considerations when assessing quality of care. In 2015, U.S. healthcare spending increased 5.8% to $3.2 trillion, or $9,990 per person. In addition, the overall share of the U.S. economy devoted to healthcare spending increased slightly, from 17.4% in 2014 to 17.8% in 2015 (CMS, 2015).

Expenditures from multiple sources channeled to both the public and private sectors of care make it challenging to control growth in healthcare costs. New delivery system models such as the patient-centered medical home (PCMH) have been developed to coordinate fragmented care across sectors and may promote more efficient healthcare spending.

Figure 7 Personal healthcare expenditures, by type of expenditure, 2015

Note: Personal healthcare expenditures are outlays for goods and services related directly to patient care. These expenditures are total national health expenditures minus expenditures for investment, health insurance program administration and the net cost of insurance, and public health activities. More detailed information is available at https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/Downloads/DSM-16.pdf. Percentages do not add to 100 due to rounding.

Pie chart showing percentages: Hospital care, 38 Physician and clinical services, 23 Prescription drugs, 12 Nursing care, 6 Other health care, 13 Dental services, 4 Home health care, 3

Source: Centers for Medicare & Medicaid Services, National Health Expenditures by type of service and source of funds, CY 1960-2015. https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/NationalHealthAccountsHistorical.html.

- In 2015, hospital care expenditures were $1.04 trillion, nearly 40% of personal healthcare expenditures (Figure 7).
- Expenditures for physician and clinical services were $634.9 billion, almost one-fourth of personal healthcare expenditures
- Prescription drug expenditures were $324.6 billion, 12% of personal healthcare expenditures.
- Expenditures for dental services were $117.5 billion, 4% of personal healthcare expenditures.
- Nursing care facility expenditures were $156.8 billion and home healthcare expenditures were $88.8 billion, 6% and 3% of personal healthcare expenditures, respectively.

Figure 8 Personal healthcare expenditures, by source of funds, 2015

Note: Personal healthcare expenditures are outlays for goods and services related directly to patient care. These expenditures are total national health expenditures minus expenditures for investment, health insurance program administration and the net cost of insurance, and public health activities. Percentages do not add to 100 due to rounding.

Pie chart showing percentages: Private, 35 Medicare, 22 Medicaid, 18 Out of pocket, 12 Other third party, 12 Children’s health insurance program, 0.5

Source: Centers for Medicare & Medicaid Services, National Health Expenditures Account, as reported in Health, United States, 2016. https://www.cdc.gov/nchs/hus/index.htm.

- In 2015, private insurance accounted for 35% of personal healthcare expenditures, followed by Medicare, Medicaid, and out of pocket (Figure 8).
- Sources of funds varied by type of expenditure (data not shown):
  ■ Private insurance accounted for 39% of hospital, 43% of physician, 11% of home health, 9% of nursing home, 47% of dental, and 43% of prescription drug expenditures.
  ■ Medicare accounted for 25% of hospital, 23% of physician, 40% of home health, 24% of nursing home, 0.4% of dental, and 29% of prescription drug expenditures.
  ■ Medicaid accounted for 18% of hospital, 11% of physician, 36% of home health, 32% of nursing home, 10% of dental, and 10% of prescription drug expenditures.
  ■ Out-of-pocket payments accounted for 3% of hospital, 9% of physician, 10% of home health, 26% of nursing home, 40% of dental, and 14% of prescription drug expenditures.

Personal health expenditures illustrate the economic burden of disease and barriers to access to healthcare. Findings from the Access and Disparities in Access to Healthcare section of this report show the progress and opportunities for improvement in overcoming these barriers.