# OVERVIEW OF DISEASE BURDEN IN THE UNITED STATES

The aim of a healthcare system is to mitigate the effects of the leading causes of morbidity and mortality. The QDR tracks care for most of these conditions. Variation in access to care and care delivery across communities contributes to disparities related to race, ethnicity, sex, and socioeconomic status.

The concept of years of potential life lost (YPLL) involves estimating the average time a person would have lived had he or she not died prematurely. This measure is used to help quantify social and economic loss owing to premature death, and it has been promoted to emphasize specific causes of death affecting younger age groups. YPLL inherently incorporates age at death, and its calculation mathematically weights the total deaths by applying values to death at each age (Gardner & Sanborn, 1990).

Figure 4 Years of potential life lost before age 65, United States, 2016

Key: YPLL = years of potential life lost.

Note: The perinatal period occurs from 22 completed weeks (154 days) of gestation and ends 7 completed days after birth.^iv^

Bar chart showing age-adjusted rate of years of potential life lost per 100,000 Cerebrovascular Disease, 80 Diabetes, 88 Liver Disease, 107 Congenital Anomalies, 166 Homicide, 225 Perinatal Period, 296 Suicide, 333 Heart Disease, 466 Cancer, 578 Unintentional Injury, 1,022

Source: Centers for Disease Control and Prevention, National Center for Injury Prevention and Control (https://www.cdc.gov/injury), Years of Potential Life Lost (YPLL) Reports, 1999–2016. https://webappa.cdc.gov/sasweb/ncipc/ypll.html.

- The three leading diseases and injuries contributing to years of potential life lost (YPLLs) (unintentional injury, cancer, and heart disease) did not change between 2006 and 2016 (Figure 4).
- From 2006 to 2016, there was a 26% increase in YPLLs caused by suicide, moving its rank from number 5 to number 4.
- From 2006 to 2016, there was a 24% increase in YPLLs caused by liver disease, moving its rank from number 10 to number 8.
- From 2006 to 2016, YPLLs caused by HIV decreased by 65%, moving from 9 to 15 in the ranking (data not shown).
- From 2006 to 2016, diabetes moved from 11 to 9 in the ranking.

Figure 5 Years lived with disability, United States, 2015

Key: YLD = years lived with disability.

Bar chart showing age-adjusted rate of years lived with disability per 100,000 population: Cancer and Tumors, 263 Circulatory Illnesses, 386 Chronic Respiratory Diseases, 470 Injuries, 575 Skin Diseases, 622 Sense Organ Diseases, 624 Nervous System, 877 Endocrine (Diabetes, Kidney Disease), 1,085 Musculoskeletal Disorders, 2,310 Mental Health and Substance Use Disorders, 2,829

Source: Kaiser Family Foundation analysis of data from Institute for Health Metrics and Evaluation. Global Burden of Disease Study 2015 (GBD 2015) Data Downloads.

- Years lived with disability (YLD) accounts for the severity of the disability and is typically weighted so that young adult ages are valued higher than infants or very old adults, since young adults are in their years of peak productivity.
- Mental health and substance use disorders (2,829 per 100,000 population), musculoskeletal disorders (2,310 per 100,000 population), and endocrine disorders, including diabetes and kidney disease (1,085 per 100,000 population) accounted for most YLDs in 2015 (Figure 5).
- Cancer and tumors ranked 10^th^, with a rate of 263 per 100,000 population.

Figure 6 Leading causes of death for the total population, United States, 2015 and 2016

Bar chart showing age-adjusted deaths per 100,000 population Kidney Disease, 2015, 13.4; 2016, 13.1 Suicide, 2015, 13.3; 2016, 13.5 Pneumonia and Flu, 2015, 15.2; 2016, 13.5 Diabetes, 2015, 21.3; 2016, 21 Alzheimer’s Disease, 2015, 29.4; 2016, 30.3 Cerebrovascular Disease, 2015, 37.6; 2016, 37.3 Chronic Lower Respiratory Diseases, 2015, 41.6; 2016, 40.6 Unintentional Injuries, 2015, 43.2; 2016, 47.4 Cancer, 2015, 158.5; 2016, 155.8 Heart Disease, 2015, 168.5; 2016, 165.5

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Mortality. Mortality in the United States, 2016. https://www.cdc.gov/nchs/products/databriefs/db293.htm.

- In 2015 and 2016, heart disease, cancer, unintentional injuries, chronic lower respiratory diseases, cerebrovascular disease, Alzheimer’s disease, and diabetes were among the leading causes of death for the overall U.S. population (Figure 6).
- Suicide, the 10^th^ leading cause of death in 2015, became the 9^th^ leading cause in 2016.
- From 2015 to 2016, age-adjusted death rates decreased for 7 of 10 leading causes of death and increased for 3.
- The rate decreased 1.8% for heart disease, 1.7% for cancer, 2.4% for chronic lower respiratory diseases, 0.8% for cerebrovascular disease, 1.4% for diabetes, 11.2% for pneumonia and flu, and 2.2% for kidney disease.
- The rate increased 9.7% for unintentional injuries, 3.1% for Alzheimer’s disease, and 1.5% for suicide.

The years of potential life lost, years with disability, and leading causes of death illustrate the burden of disease experienced by the American people. Findings highlighted in the Trends in Quality section of this report attempt to quantify progress made in improving the quality of care, reducing disparities in healthcare, and ultimately reducing disease burden.

iv World Health Organization, Maternal and Perinatal Health. http://www.who.int/maternal_child_adolescent/topics/maternal/maternal_perinatal/en/.