# OVERVIEW OF QUALITY AND ACCESS IN THE U.S. HEALTHCARE SYSTEM

Healthcare in the United States is complex. The healthcare industry employs millions of workers providing billions of services each year. In 2016, there were 626 health systems in the United States (Figure 1).

Figure 1 U.S. hospitals in health systems

Note: The hospital figures represent all nonfederal general acute care hospitals in the United States. A health system is an organization that includes at least one hospital and at least one group of physicians that provides comprehensive care (including primary and specialty care) and is connected with each other and with the hospital through common ownership or joint management.

Pie chart showing that 88.2 percent of U.S. hospital beds are in systems. Figure also shows 69.7 percent of U.S. hospitals are in health systems and 91.6 percent of U.S. hospital discharges are from system hospitals

Source: Agency for Healthcare Research and Quality, Snapshot of U.S. Health Systems, 2016 Data Highlight No.1 (https://www.ahrq.gov/sites/default/files/wysiwyg/snapshot-of-us-health-systems-2016v2.pdf).

The QDR tracks care delivered by providers in many types of healthcare settings. The goal is to provide high-quality healthcare that is culturally and linguistically sensitive, patient centered, timely, affordable, well coordinated, and safe. The receipt of appropriate high-quality services and counseling about healthy lifestyles can facilitate the maintenance of well-being and functioning. In addition, social determinants of health, such as education, income, and residence location, can affect access to care and quality of care.

Improving care requires facility administrators and providers to work together to expand access, enhance quality, and reduce disparities. It also requires coordination between the healthcare sector and other sectors for social welfare, education, and economic development. For example, Healthy People 2020 includes 33 social determinants of health objectives for federal programs and interventions.^iii^

The numbers of health service encounters and people working in health occupations illustrate the large scale and inherent complexity of the U.S. healthcare system. The tracking of healthcare quality measures in this report, notably in the Trends in Quality section, attempts to quantify progress made in improving quality and reducing disparities in the delivery of healthcare to the American people.

Figure 2 Number of healthcare service encounters, United States, 2013, 2014, 2015

Bar chart showing millions in visits or days: Home Health Care Visits (2015), 117 Hospice Days (2015), 120 Hospital Days (2014), 213 Nursing Home Days (2014), 500 Hospital Outpatient Visits (2014), 803 Physician Office Visits (2013), 923

Source: National Center for Health Statistics (NCHS), Health, United States, 2016 (physician [Table 76] and hospital outpatient visits and hospital days [Table 82]) (https://www.cdc.gov/nchs/data/hus/hus16.pdf); NCHS, Long-term care providers and services users in the United States: data from the National Study of Long-Term Care Providers, 2013-2014 (https://www.cdc.gov/nchs/data/series/sr_03/sr03_038.pdf) (nursing home days); Medicare Payment Advisory Commission (MedPAC), Health care spending and the Medicare Program: a data book, June 2017 (http://medpac.gov/docs/default-source/data-book/jun17_databookentirereport_sec.pdf) (home health [Chart 8-9]) and hospice data [Chart 11-7]).

- In 2013, there were 923 million physician office visits, including visits to physicians in health centers (Figure 2).
- In 2014, there were 803 million hospital outpatient visits.
- In 2014, patients spent 500 million days in nursing homes and 213 million days in hospitals.
- In 2015, patients spent 120 million days in hospice.
- In 2015, there were 117 million home health visits.

Figure 3 Number of people working in health occupations, United States, 2016

Note: Doctors of Medicine includes Doctors of Osteopathic Medicine. Other health practitioners include physician assistants, medical assistants, dental assistants, chiropractors, dietitians and nutritionists, optometrists, podiatrists, and audiologists, as well as massage therapists, medical equipment preparers, medical transcriptionists, pharmacy aides, veterinary assistants and laboratory animal caretakers, phlebotomists, and healthcare support workers. Aides include nursing, psychiatric, home health, occupational therapy, and physical therapy assistants and aides. Therapists include occupational therapists, physical therapists, radiation therapists, recreational therapists, respiratory therapists, speech-language pathologists, and exercise physiologists.

Bar chart showing number in thousands: Dentists (2015), 196 Advanced Practice Nurses, 196 Emergency Medical Technicians and Paramedics, 245 Pharmacists, 306 Other Health Practitioners, 361 Therapists, 651 Doctors of Medicine (2017), 951 Other Health Occupations, 1,485 Health Technologists, 2,398 Aides, 2,559 Registered Nurses, 2,857

Source: National Center for Health Statistics, Health, United States, 2016 (https://www.cdc.gov/nchs/data/hus/hus16.pdf) (dentists); The Henry J. Kaiser Family Foundation, State Health Facts, Provider and Service Use, 2017 (https://www.kff.org/state-category/providers-service-use/) (doctors); and Bureau of Labor Statistics Occupational Employment Statistics (https://www.bls.gov/oes/), 2016 (all other occupations).

- In 2017, there were 951,000 active medical doctors in the United States, which include doctors of medicine and doctors of osteopathy (Figure 3).
- In 2015, there were 196,000 dentists.
- In 2016, there were also 2.9 million registered nurses, 2.4 million health technologists, and 2.6 million nursing and other aides.
- In 2016, 361,000 other health practitioners provided care, including more than 104,000 physician assistants.

iii For more information, refer to Healthy People 2020 midcourse review. Chapter IV: Leading Health Indicators. Hyattsville, MD; National Center for Health Statistics; 2016. https://www.cdc.gov/nchs/data/hpdata2020/HP2020MCR-B04-LHI.pdf . Also refer to Chapter 39: Social Determinants of Health (SDOH). https://www.cdc.gov/nchs/data/hpdata2020/HP2020MCR-C39-SDOH.pdf.