# EXECUTIVE SUMMARY

## Key Findings

- Access: An estimated 43% of access measures showed improvement (2000-2016), 43% did not show improvement, and 14% showed worsening. For example, from 2000 to 2017, there were significant gains in the percentage of people who reported having health insurance.
- Quality: Quality of healthcare improved overall from 2000 through 2014-2015 but the pace of improvement varied by priority area:
  ■ Person-Centered Care: Almost 70% of person-centered care measures were improving overall.
  ■ Patient Safety: More than two-thirds of patient safety measures were improving overall.
  ■ Healthy Living: More than half of healthy living measures were improving overall.
  ■ Effective Treatment: More than half of effective treatment measures were improving overall.
  ■ Care Coordination: Half of care coordination measures were improving overall.
  ■ Care Affordability: Eighty percent of care affordability measures did not change overall.
- Disparities: Overall, some disparities were getting smaller from 2000 through 2014-2015, but disparities persist, especially for poor and uninsured populations in all priority areas.
  ■ Trends show that about 55% percent of quality measures are improving overall for Blacks.^i^ However, most recent data in 2014-2015 show that about 40% of quality measures were worse for Blacks compared with Whites.
  ■ Trends show that about 60% of quality measures are improving overall for Asians. However, most recent data in 2014-2015 show that 20% of quality measures were worse for Asians compared with Whites.
  ■ Trends show that almost 35% of quality measures are improving overall for American Indians/Alaska Natives (AI/ANs). However, most recent data in 2014-2015 show that about 30% of quality measures were worse for AI/ANs compared with Whites.
  ■ Trends show that about one-quarter of quality measures are improving overall for Native Hawaiians/Pacific Islanders (NHPIs). However, most recent data in 2014-2015 show that nearly one-third of quality measures were worse for NHPIs compared with Whites.
  ■ Trends show that about 60% of quality measures are improving overall for Hispanics, but in 2014-2015, nearly one-third of quality measures were worse for Hispanics compared with non-Hispanic Whites.
  ■ Variation in care persisted across the urban-rural continuum in 2014-2016, especially in access to care and care coordination.

## About the National Healthcare Quality and Disparities Report

For the 15th year in a row, AHRQ is reporting on healthcare quality and disparities. The annual National Healthcare Quality and Disparities Report (QDR) is mandated by Congress to provide a comprehensive overview of the quality of healthcare received by the general U.S. population and disparities in care experienced by different racial and socioeconomic groups.

The report assesses the performance of our healthcare system and identifies areas of strength and weakness, as well as disparities, for access to healthcare and quality of healthcare. Quality measures are grouped by priority areas, including person-centered care, patient safety, healthy living, effective treatment, care coordination, and affordable care.

More than 250 measures used in these reports span a wide range of structure, process, and outcome measures for which existing national data sources can be used. Selected findings in each priority area are shown in this report, as are examples of large disparities, disparities worsening over time, and disparities showing improvement. A U.S. Department of Health and Human Services (HHS) Interagency Work Group (IWG)^ii^ that supports the reports selected the measures for tracking based on their importance, scientific soundness, and feasibility.

In 2015, the National Academy of Medicine published Vital Signs: Core Metrics for Health and Health Care Progress. This consensus-based report laid out a broad framework for assessing health and healthcare in the United States. As the National Healthcare Quality and Disparities Report works to provide an indepth look at healthcare quality in the United States, the Vital Signs framework can be used as a guide.

It is recognized that coordination and collaboration beyond the health sector is necessary to achieve the best possible outcomes for health and well-being for all Americans. A comparison of the QDR core measures with the Vital Signs core metrics illustrates how findings from the QDR can be used to fill in details needed to inform a broader discussion of health and well-being in the United States (see Appendix E).

i Throughout this report and its appendixes, “Blacks” refers to Blacks or African Americans, and “Hispanics” refers to Hispanics or Latinos. More information is available in the Reporting Conventions section of the Introduction and Methods.

ii Federal participants on IWG: AHRQ, Administration for Children and Families, Administration for Community Living, Assistant Secretary for Planning and Evaluation, Centers for Disease Control and Prevention, Centers for Medicare & Medicaid Services, Health Resources and Services Administration, Indian Health Service, and National Institutes of Health.