# ABBREVIATIONS USED IN THE REPORT

- ACS NSQIP: American College of Surgeons National Surgical Quality Improvement Program
- AI/AN: American Indian or Alaska Native
- FIHET: Federal Interagency Healthcare Equity Team
- FPL: Federal Poverty Level
- HCUP: Healthcare Cost & Utilization Project
- HHCAHPS: Home Health Consumer Assessment of Healthcare Providers and Systems
- ICD-9-CM: International Classification of Diseases, 9^th^ Revision, Clinical Modification; ICD-10-CM refers to the 10^th^ Revision.
- IWG: Interagency Work Group
- MEPS: Medical Expenditure Panel Survey
- MPSMS: Medicare Patient Safety Monitoring System
- NHSS: National HIV/AIDS Surveillance System
- NCDB: National Cancer Data Base
- NEDS: National Emergency Department Sample
- NHANES: National Health and Nutrition Examination Survey
- NHIS: National Health Interview Survey
- NHPI: Native Hawaiian/Pacific Islander
- NIS: National Immunization Survey
- NVSS: National Vital Statistics System
- QDR: National Healthcare Quality and Disparities Report
- SID: State Inpatient Databases
- UM-KECC: University of Michigan Kidney Epidemiology and Cost Center
- USRDS: U.S. Renal Data System
- YLD: years lived with disability
- YPLL: years of potential life lost

## Agencies and Offices in the U.S. Department of Health and Human Services

- AHRQ: Agency for Healthcare Research and Quality
  ■ CDOM: Center for Delivery, Organization, and Markets
  ■ CFACT: Center for Financing, Access, and Cost Trends
  ■ CQuIPS: Center for Quality Improvement and Patient Safety
  ■ OC: Office of Communications
  ■ OEREP: Office of Extramural Research, Education, and Priority Populations
- ASPE: Office of the Assistant Secretary for Planning and Evaluation
- CDC: Centers for Disease Control and Prevention
  ■ NCHHSTP DHAP: National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, Division of HIV/AIDS Prevention
  ■ NCHS: National Center for Health Statistics
  ■ NCIRD: National Center for Immunizations and Respiratory Diseases
  ■ NPCR: National Program of Cancer Registries
  ■ NCCDPHP-ONDIEH: National Center for Chronic Disease Prevention and Health Promotion, Office of Noncommunicable Diseases, Injury and Environmental Health
- CMS: Centers for Medicare & Medicaid Services
  ■ QIO: Quality Improvement Organization Program
- HRSA: Health Resources and Services Administration
- IHS: Indian Health Service
- NIH: National Institutes of Health
  ■ NCI: National Cancer Institute
  ■ NHLBI: National Heart, Lung, and Blood Institute
  ■ NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases
  ■ NIMHD: National Institute on Minority Health and Health Disparities

SAMHSA: Substance Abuse and Mental Health Services Administration