# APPENDIX E NATIONAL HEALTHCARE QUALITY AND DISPARITIES REPORT CROSSWALK WITH VITAL SIGNS: CORE METRICS FOR HEALTH AND HEALTHCARE PROGRESS

A comparison of the QDR core measures with the Vital Signs core metrics illustrates how findings from the QDR can be used to fill in details needed to inform a broader discussion of health and well-being in the United States.

Table 1 NHQDR and Vital Signs crosswalk

Domain | Key Element | Core Measure Focus | Vital Signs Measure | Relevant Measures | Source | Year | Current National Performance
Healthy people | Length of life | Life expectancy at birth | Life expectancy at birth | Life expectancy at birth for the total U.S. population | CDC NCHS, NVSS^i^ | 2015 | 78.8 years
Healthy people | Quality of life | Well-being | Self-reported health | Adults who reported their health status as excellent, very good, or good^1^ | QDR AHRQ, MEPS | 2015 | 86.9%
Healthy people | | Overweight and obesity | Body mass index (BMI) | Prevalence of obesity among youth ages 2-19 and adults age 20 and older^2^ | CDC, NHANES | 2015-2016 | 18.5% of youth; 39.8% of adults
Healthy people | Healthy behaviors | Addictive behavior | Addiction death rate | Death rates for drug poisoning and drug poisoning involving opioid analgesics and heroin per 100,000 population^3^ | CDC NCHS | 2015 | 16.3 people
Healthy people | | Unintended pregnancy | Teen pregnancy rate | Births per 1,000 females, ages 15-19 | CDC NCHS, NVSS | 2015 | 22.3%
Healthy people | Healthy social circumstances | Healthy communities | High school graduation rate | Percentage of public high school freshmen who graduate with a regular diploma within 4 years of starting 9th grade | ED NCES | 2014-2015 | 83%
| Prevention | Preventive services | Childhood immunization rate | Children ages 19-35 months who received ≥4 doses of diphtheria-tetanus-pertussis vaccine, ≥3 doses of polio vaccine, ≥1 dose of measles-mumps-rubella vaccine, full series for HiB, ≥3 doses of hepatitis B vaccine, ≥1 dose of varicella vaccine, and ≥4 doses of PCV | QDR CDC, NIS^ii^ | 2015 | 72.2%
| Access to care | Care access | Unmet care need | Adults who needed care right away for an illness, injury, or condition in the last 12 months who sometimes or never got care as soon as needed | QDR AHRQ, MEPS | 2015 | 11.9%
Care quality | Safe care | Patient safety | HAI rate | Postoperative sepsis per 1,000 elective-surgery admissions of ≥4 days, age 18 and over; catheter-associated urinary tract infections in surgery patients age 18 and over | QDR AHRQ, HCUP; AHRQ, MPSMS | 2015 | 15.3 per 1,000; 2.67%
| Appropriate treatment | Evidence-based care | Preventable hospitalization rate | Potentially avoidable hospitalizations for all conditions per 100,000 population, adults 18 and over | QDR AHRQ, HCUP | 2015 | 1,415.7 people
| Person-centered care | Care match with patient goals | Patient-clinician communication satisfaction | Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers always listened carefully, explained things clearly, respected what they had to say, and spent enough time with them | QDR AHRQ, MEPS | 2015 | 64.45%
Care cost | Affordability | Personal spending burden | High-spending relative to income | People under age 65 whose family’s health insurance premiums and out-of-pocket medical expenditures were more than 10% of total family income | QDR AHRQ, MEPS | 2016 | 16.7%
| Sustainability | Population spending burden | Per capita expenditures on healthcare | Healthcare expenditure per capita | CMS, NHE^iii^ | 2016 | $10,348
Engaged people | Individual engagement | Individual engagement | Health literacy rate | Adults ≥18 who report their healthcare provider always gave them easy-to-understand instructions about what to do to take care of their illness or health condition; adults who reported their provider always asked them to describe how they would follow instructions (teach-back); and adults who reported their provider’s office always offered help in filling out forms | AHRQ, MEPS | 2015 | 68.4%; 30.1%; 17.2%
Engaged people | Community engagement | Community engagement | Social support | Inadequate family and social support | CDC, BRFSS | 2005-2011 | 21%

Additional Related NHQDR Measures

1 People in fair or poor health with a specific source of ongoing care

2 Adults age ≥20 with obesity who had been told by a doctor or health professional that they were overweight

3 People age ≥12 who needed treatment for illicit drug use or an alcohol problem and who received such treatment at a specialtyfacility in the last 12 months

People age ≥12 treated for substance abuse who completed the treatment course

## Reference

Institute of Medicine. 2015. Vital Signs: Core Metrics for Health and Health Care Progress. Washington, DC: The National Academies Press. 10.17226/19402.

i CDC NCHS = Centers for Disease Control and Prevention, National Center for Health Statistics; NVSS = National Vital Statistics System; QDR = National Healthcare Quality and Disparities Report; AHRQ, MEPS = Agency for Healthcare Research and Quality, Medical Expenditure Survey; NHANES = National Health and Nutrition Examination Survey; ED NCES = Department of Education National Center for Education Statistics.

ii HiB = Haemophilus influenzae type B; PCV = pneumococcal conjugate vaccine; NIS = National Immunization Survey; HAI = healthcare-associated infection; HCUP = Healthcare Cost & Utilization Project; MPSMS = Medicare Patient Safety Monitoring System.

iii CMS, NHE = Centers for Medicare & Medicaid National Health Expenditures data; BRFSS = Behavioral Risk Factor Surveillance System.