# APPENDIX B LIST OF MEASURES AND SUMMARY OF RESULTS FOR FIGURES

Measures Included in Figure 9: Overall Quality of Care by State, 2015-2016

Measures Included in Figure 10: Average Differences in Quality of Care for Blacks, Hispanics, and Asians Compared With Whites, by State, 2015-2016

Measures Included in Figure 11: Number and Percentage of Access Measures for Which Measure Trends Were Improving, Not Changing, or Worsening, 2000-2016

Measures Included in Figure 12: Number and Percentage of Access Measures for Which Members of Selected Groups Experienced Better, Same, or Worse Access to Care Compared With Reference Group, 2014-2016

Measures Included in Figure 18: Number and Percentage of All Quality Measures That Were Improving, Not Changing, or Worsening, Total and by Priority Area, From 2000 Through 2016

Measures Included in Figure 19: Number and Percentage of Quality Measures for Which Members of Selected Groups Experienced Better, Same, or Worse Quality of Care Compared With Reference Group (White) in 2014-2016

Measures Included in Figure 20: Number and Percentage of Quality Measures With Disparity at Baseline for Which Disparities Related to Race and Ethnicity Were Improving, Not Changing, or Worsening, 2000 Through 2014-2016

Measures Included in Figure 21: Number and Percentage of All Quality Measures That Were Improving, Not Changing, or Worsening, Total for Blacks and by Priority Area, From 2000 Through 2016

Measures Included in Figure 22: Number and Percentage of All Quality Measures That Were Improving, Not Changing, or Worsening, Total for Asians and by Priority Area, From 2000 Through 2016

Measures Included in Figure 23: Number and Percentage of All Quality Measures That Were Improving, Not Changing, or Worsening, Total for American Indians and Alaska Natives and by Priority Area, From 2000 Through 2016

Measures Included in Figure 24: Number and Percentage of All Quality Measures That Were Improving, Not Changing, or Worsening, Total for Native Hawaiians/Pacific Islanders and by Priority Area, From 2001 Through 2016

Measures Included in Figure 25: Number and Percentage of All Quality Measures That Were Improving, Not Changing, or Worsening, Total for Hispanics and by Priority Area, From 2000 Through 2016

Measures Included in Figure 26: Number and Percentage of All Quality Measures That Were Improving, Not Changing, or Worsening, Total for Poor People and by Priority Area, From 2000 Through 2015

Measures Included in Figure 27: Number and Percentage of Quality Measures for Which Income Groups Experienced Better, Same, or Worse Quality of Care Compared With Reference Group (High Income), 2014-2015

Measures Included in Figure 28: Number and Percentage of Quality Measures With Disparity at Baseline for Which Disparities Related to Income Were Improving, Not Changing, or Worsening, 2000 Through 2015

Measures Included in Figure 29: Number and Percentage of Quality Measures for Which Insurance Groups Experienced Better, Same, or Worse Quality of Care Compared With Reference Group (Privately Insured), 2014-2015

Measures Included in Figure 30: Number and Percentage of Quality and Access Measures for Which Members of Selected Groups Experienced Better, Same, or Worse Quality of Care Compared With Reference Group (Large Fringe Metro) in 2014-2016, by Geographic Location