# APPENDIX A SELECTED MEASURE DATA

## Overall Trends in Access

### Improving Measures

Graph 1 Improving: Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, 2002-2015

Note: For this measure, lower rates are better. The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

Line graph showing trend in percentage: 2002, 10.2 2003, 8.7 2004, 7 2005, 7.1 2006, 7 2007, 7.3 2008, 6.5 2009, 5.5 2010, 5.5 2011, 6 2012, 5.2 2013, 5.5 2014, 5.3 2015, 5.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2015.

Graph 2 Improving: People in fair or poor health with a specific source of ongoing care, 2009-2016

Line graph showing trend in percentage: 2009, 87.5 2010, 87.9 2011, 87.8 2012, 86.3 2013, 88.3 2014, 90.5 2015, 89.8 2016, 90.5

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2009-2016.

Graph 3 Improving: People with a specific source of ongoing care, 2009-2016

Line graph showing trend in percentage: 2009, 85.5 2010, 85.5 2011, 86.8 2012, 85.9 2013, 86.6 2014, 87.9 2015, 87.7 2016, 88.2

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2009-2016.

### Worsening Measures

Graph 4 Worsening: Children who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, 2008-2015

Note: For this measure, lower rates are better. The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

Line graph showing trend in percentage: 2008, 4.2 2009, 4.6 2010, 4.3 2011, 4.4 2012, 4.4 2013, 4.9 2014, 5.2 2015, 4.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2008-2015.

## Trends in Access Disparities

### Improving (Disparities Getting Smaller)

Graph 5 Improving: People with a usual source of care, excluding hospital emergency rooms, who has office hours at night or on weekends, AI/AN vs. White, 2002-2015

Key: AI/AN = American Indian or Alaska Native.

Line graph showing trend: 2002, Total, 45.4%; AI/AN, 35%; White, 45.3% 2015, Total, 41.9%; AI/AN, 45.8%; White, 41%

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2015.

Graph 6 Improving: Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, uninsured vs. private insurance, 2008-2015

Note: For this measure, lower rates are better. The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

Line graph showing trend: 2008, Total, 9.2%; Uninsured, 29.7%; Private Insurance, 7.5% 2015, Total, 7.3%; Uninsured, 18.5%; Private Insurance, 6.9%

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2008-2015.

Graph 7 Improving: Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, Asian vs. White, 2008-2015

Note: For this measure, lower rates are better. The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

Line graph showing trend: 2008, Total, 9.2%; Asian, 21.1%; White, 8.2% 2015, Total, 7.3%; Asian, 6.7%; White, 6.7%

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2008-2015.

### Worse Access to Care

#### Largest Disparities for Poor People

Graph 8 People under age 65 who were uninsured all year, poor vs. high income, 2015

Note: For this measure, lower rates are better.

Bar chart showing percentages in 2015: Total, 9.5 Poor, 15.5 High Income, 4.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

Graph 9 People under age 65 with any period of uninsurance during the year, poor vs. high income, 2015

Note: For this measure, lower rates are better.

Bar chart showing percentages in 2015: Total, 20.7 Poor, 30.6 High Income, 10.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

#### Largest Disparities for Blacks

Graph 10 Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, Black vs. White, 2015

Note: For this measure, lower rates are better. The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

Bar chart showing percentages in 2015: Total, 5.2 Black, 8.8 White, 4.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

Graph 11 Adults who needed care right away for an illness, injury, or condition in the last 12 months who sometimes or never got care as soon as needed, Black vs. White, 2015

Note: For this measure, lower rates are better. The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

Bar chart showing percentages in 2015: Total, 11.9 Black, 17.1 White, 10.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

#### Largest Disparities for Asians

Graph 12 Adults who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, Asian vs. White, 2015

Note: For this measure, lower rates are better. The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

Bar chart showing percentages in 2015: Total, 13.8 Asian, 25.3 White, 12.6

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

Graph 13 Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, Asian vs. White, 2015

Note: For this measure, lower rates are better. The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

Bar chart showing percentages in 2015: Total, 5.2 Asian, 13 White, 4.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

#### Largest Disparities for American Indians and Alaska Natives

Graph 14 People under age 65 with health insurance, AI/AN vs. White, 2016

Key: AI/AN = American Indian/Alaska Native.

Bar chart showing percentages in 2016: Total, 89.7 AI/AN, 74.6 White, 89.8

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2016.

Graph 15 People under age 65 who were uninsured all year, AI/AN vs. White, 2015

Key: AI/AN = American Indian/Alaska Native.

Note: For this measure, lower rates are better.

Bar chart showing percentages in 2015: Total, 9.5 AI/AN, 20.1 White, 9.6

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

#### Largest Disparities for Hispanics

Graph 16 People under age 65 who were uninsured all year, Hispanic vs. non-Hispanic White, 2015

Note: For this measure, lower rates are better.

Bar chart showing percentages in 2015: Total, 9.5 Hispanic, 18.9 Non-Hispanic White, 6.5

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

Graph 17 Children who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, Hispanic vs. non-Hispanic White, 2015

Note: For this measure, lower rates are better. The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

Bar chart showing percentages in 2015: Total, 5.2 Hispanic, 7.7 Non-Hispanic White, 3.1

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

## Trends in Quality

### Person-Centered Care

#### Improving Measures

Graph 18 Improving: Adults who had a doctor’s office or clinic visit in the last 12 months whose health providers sometimes or never listened carefully, 2002-2015

Note: For this measure, lower rates are better. The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

Line graph showing trend in percentage: 2002, 10.3 2003, 9.3 2004, 8.7 2005, 9 2006, 9.4 2007, 8.6 2008, 8.8 2009, 8.6 2010, 7.7 2011, 8.3 2012, 7.8 2013, 7.8 2014, 6.6 2015, 6.7

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2015.

### Patient Safety

#### Improving Measures

Graph 19 Improving: Hospital admissions with central venous catheter-related bloodstream infection per 1,000 medical and surgical discharges of length 2 or more days, adults age 18 and over or obstetric admissions, 2008-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 1,000 discharges: 2008, 1.9 2009, 1.67 2010, 1.55 2011, 1.18 2012, 0.97 2013, 0.77 2014, 0.67 2015, 0.67

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample (NIS), 2008-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2008-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 20 Improving: Adult patients age 18 and over receiving hip joint replacement due to degenerative conditions who had adverse events, 2009-2015

Note: For this measure, lower rates are better.

Line graph showing trend in percentage: 2009, 3.98 2010, 5.06 2011, 4.6 2012, 3.62 2013, 3.28 2014, 2.91 2015, 1.66

Source: Agency for Healthcare Research and Quality and Centers for Medicare & Medicaid Services, Medicare Patient Safety Monitoring System, 2009-2015.

Graph 21 Improving: Adult patients age 18 and over receiving knee replacement who had adverse events, 2009-2015

Note: For this measure, lower rates are better.

Line graph showing trend in percentage: 2009, 3.29 2010, 4.92 2011, 4.75 2012, 3.64 2013, 2.25 2014, 2.63 2015, 1.66

Source: Agency for Healthcare Research and Quality and Centers for Medicare & Medicaid Services, Medicare Patient Safety Monitoring System, 2009-2015.

#### Worsening Measures

Graph 22 Worsening: Postoperative physiologic and metabolic derangements per 1,000 elective-surgery admissions, age 18 and over, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 1,000 admissions 2000, 1.22 2001, 1.24 2002, 1.29 2003, 1.53 2004, 1.5 2005, 1.46 2006, 1.27 2007, 1.4 2008, 1.42 2009, 1.61 2010, 1.67 2011, 1.46 2012, 1.38 2013, 1.42 2014, 1.83 2015, 1.51

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 23 Worsening: Adults who reported the provider asked to see all the prescription and over-the-counter medicines they were taking when they initiated home health care, 2012-2016

Line graph showing trend in percentage 2012, 78.8 2013, 78.9 2014, 78.3 2015, 77.8 2016, 77.6 Achievable Benchmark: 86.1%

Source: Centers for Medicare & Medicaid Services, Home Health Consumer Assessment of Healthcare Providers and Systems, 2012-2016.

### Healthy Living

#### Improving Measures

Graph 24 Improving: Adolescents ages 13-15 years who received 1 or more doses of tetanus-diphtheria-acellular pertussis (Tdap) vaccine, 2008-2015

Line graph showing trend in percentage 2008, 46.7 2009, 62.2 2010, 74.2 2011, 80.5 2012, 85.3 2013, 87.5 2014, 88.3 2015, 87.1 Achievable Benchmark: 94.9%

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2015.

Graph 25 Improving: Adolescents ages 16-17 years who received 1 or more doses of tetanus-diphtheria-acellular pertussis (Tdap) vaccine, 2008-2015

Line graph showing trend in percentage 2008, 31.9 2009, 45.3 2010, 60.2 2011, 74.8 2012, 83.6 2013, 83.7 2014, 86.6 2015, 85.3 Achievable Benchmark: 95.6%

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2015.

Graph 26 Improving: Hospital patients who received influenza vaccination, 2012-2015

Line graph showing trend in percentage 2012, 87.2 2013, 92.2 2014, 93.8 2015, 94.1 Achievable Benchmark: 97.0%

Source: Centers for Medicare & Medicaid Services Clinical Data Warehouse, 2012-2015.

#### Worsening Measures

Graph 27 Worsening: Hospital admissions for immunization-preventable influenza per 100,000 population age 65 and over, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, 77.5 2001, 13.9 2002, 38.4 2003, 69.2 2004, 45.1 2005, 102.3 2006, 59.6 2007, 22 2008, 94.6 2009, 45.1 2010, 12.9 2011, 56.6 2012, 54.2 2013, 135.8 2014, 146 2015, 259.8 Achievable Benchmark: 142.8 per 100,000 population

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 28 Worsening: Women ages 21-65 who received a Pap test in the last 3 years, 2000-2015

Line graph showing trend in percentage 2000 87.5 2005 85.3 2008 84.5 2010 82.8 2013 80.7 2015 81.2 Achievable Benchmark: 86.9%

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2000-2015.

Graph 29 Worsening: Adolescents ages 12-19 with obesity, 1999-2002 to 2011-2014

Note: For this measure, lower rates are better.

Line graph showing trend in percentage 1999-2002, 16 2003-2006, 17.6 2007-2010, 18.2 2011-2014, 20.5

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999-2002 to 2011-2014.

### Effective Treatment

#### Improving Measures

Graph 30 Improving: Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined, 2005-2014

Line graph showing trend in percentage 2005, 60.9 2006, 67.6 2007, 77.7 2008, 81.7 2009, 84.5 2010, 86.1 2011, 87.5 2012, 88.6 2013, 90.3 2014, 91.2 Achievable Benchmark: 95.9%

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2014.

Graph 31 Improving: Women under age 70 treated for breast cancer with breast-conserving surgery who received radiation therapy to the breast within 1 year of diagnosis, 2005-2013

Line graph showing trend in percentage 2005, 85.3 2006, 87.1 2007, 88.1 2008, 89 2009, 90.8 2010, 92.3 2011, 92.8 2012, 92.7 2013, 92.5

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2013.

Graph 32 Improving: Deaths per 1,000 adult hospital admissions with pneumonia, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 1,000 admissions 2000, 73.2 2001, 71 2002, 66.1 2003, 59.8 2004, 54.8 2005, 48.9 2006, 45.1 2007, 41 2008, 36.9 2009, 32 2010, 28.5 2011, 26.7 2012, 24.4 2013, 22.1 2014, 20.4 2015, 17.5 Achievable Benchmark: 12.8 per 1,000 admissionsLine graph showing trend in rate per 1,000 admissions 2000, 73.2 2001, 71 2002, 66.1 2003, 59.8 2004, 54.8 2005, 48.9 2006, 45.1 2007, 41 2008, 36.9 2009, 32 2010, 28.5 2011, 26.7 2012, 24.4 2013, 22.1 2014, 20.4 2015, 17.5 Achievable Benchmark: 12.8 per 1,000 admissions

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

#### Worsening Measures

Graph 33 Worsening: Hemodialysis patients whose hemoglobin level is less than 10 g/dL, 2006-2015

Note: For this measure, lower rates are better.

Line graph showing trend in percentage 2006, 1.69 2007, 1.69 2008, 2.3 2009, 2.77 2010, 3.1 2011, 4.6 2012, 10.11 2013, 12.3 2014, 14.4 2015, 16.8

Source: University of Michigan Kidney Epidemiology and Cost Center, Dialysis Facility Reports, 2006-2015.

Graph 34 Worsening: Emergency department visits involving opioid-related diagnoses per 100,000 population, 2005-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2005, 89.1 2006, 91.8 2007, 82.6 2008, 94.1 2009, 107.4 2010, 117.5 2011, 131.2 2012, 146.8 2013, 166.2 2014, 177.7 2015, 209 Achievable Benchmark: 51.2 per 100,000 population

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample and Nationwide Emergency Department Sample, and AHRQ Quality Indicators, version 4.4, 2005-2015.

Graph 35 Worsening: Hospital inpatient stays involving opioid-related diagnoses per 100,000 population, 2005-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2005, 136.8 2006, 164.2 2007, 159 2008, 165.7 2009, 181.4 2010, 197.1 2011, 207.8 2012, 210.4 2013, 213.7 2014, 224.6 2015, 251.3 Achievable Benchmark: 99.5 per 100,000 population

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, State Inpatient Databases and AHRQ Quality Indicators, version 4.4, 2005-2015.

Graph 36 Worsening: Suicide deaths among people age 12 and over per 100,000 population, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, 10.4 2001, 10.7 2002, 10.9 2003, 10.8 2004, 13.2 2005, 13.2 2006, 10.9 2007, 11.3 2008, 14 2009, 14.2 2010, 14.6 2011, 14.9 2012, 15.2 2013, 15.2 2014, 15.7 2015, 16 Achievable Benchmark: 9.4 per 100,000 population

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Mortality, 2000-2015.

Graph 37 Worsening: People with current asthma who are now taking preventive medicine daily or almost daily (either oral or inhaler), 2003-2015

Line graph showing trend in percentage 2003, 29.6 2004, 29.7 2005, 31.2 2006, 30.9 2007, 28.3 2008, 25.9 2009, 25.1 2010, 26.5 2011, 24.4 2012, 22.5 2013, 22.5 2014, 23.8 2015, 23

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2003-2015.

### Care Coordination

#### Improving Measures

Graph 38 Improving: Potentially avoidable hospital admissions for angina per 100,000 population, adults age 18 and over, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, 81.5 2001, 74.3 2002, 67.6 2003, 54 2004, 48.5 2005, 39.1 2006, 36.9 2007, 31.3 2008, 25.2 2009, 23.3 2010, 20 2011, 18.1 2012, 15.7 2013, 13.3 2014, 11.9 2015, 11.8 Achievable Benchmark: 4.9 per 100,000 population

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 39 Improving: Potentially avoidable hospital admissions for pediatric gastroenteritis per 100,000 population, children ages 3 months to 17 years, 2000-2015

Denominator: Children ages 0-17.

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, 169.4 2001, 193.8 2002, 171.1 2003, 183.7 2004, 181.6 2005, 192.8 2006, 183.5 2007, 141.0 2008, 99.3 2009, 99.9 2010, 69.3 2011, 63.6 2012, 59.1 2013, 53.4 2014, 36.5 2015, 50.8

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 40 Improving: Adult hospital patients who did not receive good communication about discharge information, 2009-2016

Note: For this measure, lower rates are better. Good communication about discharge means that when patients left the hospital they had a good understanding of the things they were responsible for in managing their health.

Line graph showing trend in percentage 2009, 15.8 2010, 14.6 2011, 13.7 2012, 12.9 2013, 11.8 2014, 11.3 2015, 10.9 2016, 10.5 Achievable Benchmark: 7.7%

Source: Centers for Medicare & Medicaid Services, Hospital Consumer Assessment of Healthcare Providers and Systems, 2009-2016.

#### Worsening Measures

Graph 41 Worsening: Emergency department visits with a principal diagnosis related to substance abuse only per 100,000 population, 2007-2015

Note: For this measure, lower rates are better. Estimates for 2015 were based on 9 months of data (January-September 2015) with International Classification of Diseases, 9^th^ Revision coding. The number of visits is not reported.

Line graph showing trend in rate per 100,000 population 2007, 438 2008, 458 2009, 487 2010, 510 2011, 540 2012, 545 2013, 578 2014, 640 2015, 713

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2007-2015.

Graph 42 Worsening: Emergency department visits with a principal diagnosis related to co-occurring mental health, alcohol abuse, and substance abuse per 100,000 population, 2007-2015

Note: For this measure, lower rates are better. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. The number of visits is not reported.

Line graph showing trend in rate per 100,000 population 2007, 27 2008, 31 2009, 30 2010, 32 2011, 34 2012, 35 2013, 37 2014, 41 2015, 44

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2007-2015.

Graph 43 Worsening: Potentially avoidable hospital admissions for short-term complications of diabetes per 100,000 population, adults age 18 and over, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, 50.8 2001, 51.6 2002, 53.9 2003, 55.2 2004, 54.5 2005, 55.4 2006, 58.7 2007, 58.7 2008, 60.2 2009, 63.7 2010, 68.3 2011, 71.7 2012, 73.2 2013, 82.6 2014, 81.5 2015, 85.8 Achievable benchmark: 56.8 per 100,000 population

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2000-2015.

### Care Affordability

#### Worsening Measures

Graph 44 Worsening: People without a usual source of care who indicated a financial or insurance reason for not having a source of care, 2002-2015

Note: For this measure, lower rates are better.

Line graph showing trend in percentage 2002, 15.6 2003, 16.3 2004, 14.8 2005, 16 2006, 17 2007, 18 2008, 17.6 2009, 21.1 2010, 21.2 2011, 19.9 2012, 20.2 2013, 24 2014, 20 2015, 14.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2015.

## Trends in Disparities

Disparities are grouped by race, ethnicity, and geographic location. Improving disparities are disparities that are narrowing. Worsening disparities are disparities that are widening.

### Race

#### Largest Disparities for Blacks

Graph 45 Largest Disparities: New HIV cases per 100,000 population age 13 and over, 2016

Note: For this measure, lower rates are better.

Bar chart showing rate per 100,000 population White, 6 Black, 52.9 Achievable Benchmark: 4.3 per 100,000 population

Source: National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, Division of HIV/AIDS, National HIV/AIDS Surveillance System, 2016.

Graph 46 Largest Disparities: HIV-infection deaths per 100,000 population, 2015

Note: For this measure, lower rates are better.

Bar chart showing rate per 100,000 population White, 1.1 Black, 7.9 Achievable Benchmark: 0.75 per 100,000 population

Source: Centers for Disease Control and Prevention, National Vital Statistics System - Mortality, 2015.

Graph 47 Largest Disparities: Potentially avoidable admissions for hypertension per 100,000 population age 18 and over, by race/ethnicity, 2015

Note: For this measure, lower rates are better.

Bar chart showing rate per 100,000 population White, 33.9 Black, 170.3 Achievable Benchmark: 20.4 per 100,000 population

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), State Inpatient Databases, 2001-2015, weighted to provide national estimates using the same methodology as the HCUP Nationwide Inpatient Sample; and the AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included States, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

#### Largest Improvements for Blacks

Graph 48 Improving: Hospital patients who received influenza vaccination, 2012-2015

Line graph showing trends in percentage 2012, Total, 87.2; Black, 84.9 2013, Total, 92.2; Black, 90.7 2014, Total, 93.8; Black, 92.5 2015, Total, 94.1; Black, 93.5

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse, 2012-2015.

Graph 49 Improving: Adolescents ages 16-17 years who received 1 or more doses of tetanus-diphtheria-acellular pertussis (Tdap) vaccine, 2008-2015

Line graph showing trends in percentage 2008, Total, 31.9; Black, 26.5 2015, Total, 85.3; Black, 84.1

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2015.

#### Gap Between Blacks and Whites

Graph 50 Worsening: Emergency department visits for asthma, children ages 2-19, 2006-2008 to 2012-2014

Note: For this measure, lower rates are better.

Line graph showing trend in disparities in rate per 10,000 population 2006-2008, White, 60; Black, 220.8 2012-2014, White, 76; Black, 252.5

Source: Centers for Disease Control and Prevention, National Hospital Ambulatory Medical Care Survey, 2006-2008 to 2012-2014.

Graph 51 Worsening. Potentially avoidable admissions for hypertension per 100,000 population age 18 and over, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2001, White, 33.2; Black, 156.7 2015, White, 33.9; Black, 170.3 Achievable Benchmark: 20.4 per 100,000 population

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and the AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 52 Worsening: Infants who received exclusive breastfeeding through 3 months, 2009-2014

Line graph showing trend in disparities in percentage 2009, White, 39.6; Black, 24.2 2014, White, 51.6; Black, 28.9

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey, 2009-2014.

#### Largest Disparities for Asians

Graph 53 Largest Disparities: Hospital patients with an anticoagulant-related adverse drug event to low-molecular-weight heparin (LMWH) and factor Xa, age 18 and over, 2015

Note: For this measure, lower rates are better.

Bar chart showing percentage Total, 3.0 White, 2.7 Asian, 11.4

Source: Agency for Healthcare Research and Quality and Centers for Medicare & Medicaid Services, Medicare Patient Safety Monitoring System, 2015.

Graph 54 Largest Disparities: Adults with limited English proficiency and a usual source of care that offered language assistance, 2015

Bar chart showing percentage Total, 89.6 White, 92.3 Asian, 78.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

#### Largest Improvements for Asians

Graph 55 Improving: Hospital patients who received influenza vaccination, 2012-2015

Line chart showing trend in percentage 2012,Total,87.2; Asian,83.3 2013,Total,92.2; Asian,90.8 2014,Total,93.8; Asian,93.5 2015,Total,94; Asian,95.1

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse, 2012-2015.

Graph 56 Improving: Hospital patients who received pneumococcal immunization, 2012-2015

Line graph showing trend in percentage 2012, Total, 89; Asian, 85.7 2013, Total, 92.2; Asian, 90.5 2014, Total, 89.3; Asian, 91.2 2015, Total, 87.7; Asian, 94.9

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse, 2012-2015.

Graph 57 Improving: Adolescents ages 16-17 years who received 1 or more doses of tetanus-diphtheria-acellular pertussis (Tdap) vaccine, 2008-2015

Note: Asian data do not meet the criteria for statistical reliability, data quality, or confidentiality for 2014.

Line graph showing trend in percentage 2008, Total, 31.9; Asian, 38.4 2009, Total, 45.3; Asian, 47.2 2010, Total, 60.2; Asian, 67.8 2011, Total, 74.8; Asian, 84.8 2012, Total, 83.6; Asian, 82.1 2013, Total, 83.7; Asian, 88.8 2014, Total, 86.6; Asian, data statistically unreliable 2015, Total, 85.3; Asian, 87.5

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2015.

#### Gap Between Asians and Whites

Graph 58 Improving: Hospital patients who received pneumococcal immunization, 2012-2015

Line graph showing trend in disparity in percentage 2012, White, 90; Asian,85.7 2013, White, 92.8; Asian, 90.5 2014, White, 90; Asian, 91.2 2015, White, 88.4; Asian, 94.9

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse, 2012-2015.

Graph 59 Improving: Deaths per 1,000 elective-surgery admissions having developed specified complications of care during hospitalization, ages 18-89 or obstetric admissions, 2005-2015

Note: For this measure, lower rates are better.

Line graph showing trend in disparity in rate per 1,000 admissions 2005, White, 136.7; Asian, 165.7 2015, White, 108.1; Asian, 122.4

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and the AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 60 Improving: People age 13 years and over living with HIV who know their serostatus, 2010-2014

Line graph showing trend in disparity in percentage 2010, White, 85.9; Asian, 72.2 2014, White, 87.7; Asian, 80.4

Source: National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, Division of HIV/AIDS, National HIV/AIDS Surveillance System, 2010-2014.

#### Largest Disparities for American Indians and Alaska Natives

Graph 61 Largest Disparities: Hospital patients who received influenza vaccination, 2015

Key: AI/AN = American Indian or Alaska Native.

Bar chart showing percentage Total, 94.1 White, 94.7 AI/AN, 85.2

Source: Centers for Medicare & Medicaid Services, Clinical Data Warehouse, 2015.

Graph 62 Largest Disparities: Rating of health care 0-6 on a scale from 0 to 10 (best grade) by adults who had a doctor’s office or clinic visit in the last 12 months, 2015

Key: AI/AN = American Indian or Alaska Native.

Note: For this measure, lower rates are better.

Bar chart showing percentage Total, 11.1 White, 10.3 AI/AN, 26

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

Graph 63 Largest Disparities: Infant mortality per 1,000 live births, birth weight more than 2,499 grams, 2014

Key: AI/AN = American Indian or Alaska Native.

Note: For this measure, lower rates are better.

Bar chart showing rate per 1,000 live births Total, 2 White, 1.8 AI/AN, 3.9

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Linked Birth and Infant Death Data, 2014.

#### Improvements for American Indians and Alaska Natives

Graph 64 Improving: Adolescents ages 16-17 years who received 1 or more doses of tetanus-diphtheria-acellular pertussis (Tdap) vaccine, 2008-2015

Key: AI/AN = American Indian or Alaska Native.

Note: AI/AN data do not meet the criteria for statistical reliability, data quality, or confidentiality for 2015.

Line graph showing trend in percentage 2008, Total, 31.9; AI/AN, 43.7 2009, Total, 45.3; AI/AN, 61.9 2010, Total, 60.2; AI/AN, 58 2011, Total, 74.8; AI/AN, 63.3 2012, Total, 83.6; AI/AN, 88.9 2013, Total, 83.7; AI/AN, 90.5 2014, Total, 86.6; AI/AN, 90.6 2015, Total, 85.3; AI/AN, data statistically unreliable

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2015.

Graph 65 Improving: Adolescents ages 13-15 years who received 1 or more doses of meningococcal conjugate vaccine, 2008-2015

Key: AI/AN = American Indian or Alaska Native.

Note: AI/AN data do not meet the criteria for statistical reliability, data quality, or confidentiality for 2014.

Line graph showing trend in percentage 2008, Total, 43.9; AI/AN, 51.8 2009, Total, 54.8; AI/AN, 45.1 2010, Total, 64.8; AI/AN, 53.7 2011, Total, 71.5; AI/AN, 76.2 2012, Total, 73.8; AI/AN, 84.3 2013, Total, 78.1; AI/AN, 79.8 2014, Total, 79.4; AI/AN, data statistically unreliable 2015, Total, 80.8; AI/AN, 88.3

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2015.

#### Gap Between American Indians and Alaska Natives and Whites

Graph 66 Improving: Adjusted incident rates of end stage renal disease due to diabetes per million population, 2001-2015

Key: AI/AN = American Indian or Alaska Native.

Note: For this measure, lower rates are better.

Line graph showing change in disparity in pate per million population 2001, White, 133.3; AI/AN, 526 2015, White, 139.8; AI/AN, 275.8

Source: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases, U.S. Renal Data System, 2001-2015.

Graph 67 Improving: Children ages 2-17 for whom a health provider gave advice within the past 2 years about healthy eating, 2002-2015

Key: AI/AN = American Indian or Alaska Native.

Note: AI/AN data do not meet the criteria for statistical reliability, data quality, or confidentiality for 2003-2007, 2010-2012, and 2014.

Line graph showing trend in disparity in percentage 2002, White, 46.8; AI/AN, 28.7 2015, White, 64.7; AI/AN, 58.2

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2015.

#### Largest Disparities for Native Hawaiians/Pacific Islanders

Graph 68 Largest Disparities: Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high, 2014

Key: NHPI = Native Hawaiian/Pacific Islander.

Bar chart showing percentage Total, 91.8 White, 91.9 NHPI, 84.2

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2014.

Graph 69 Largest Disparities: Adults who reported that home health providers always treated them with courtesy and respect in the last 2 months, 2016

Key: NHPI = Native Hawaiian/Pacific Islander.

Bar chart showing percentage White, 94.2; NHPI, 88.7 Achievable Benchmark: 95%

Source: Centers for Medicare & Medicaid Services, Home Health Consumer Assessment of Healthcare Providers and Systems, 2016.

#### Improvements for Native Hawaiians/Pacific Islanders

Graph 70 Improving: Adolescents ages 16-17 who received 1 or more doses of meningococcal conjugate vaccine, 2008-2011

Line graph showing trend in percentage 2008, Total, 38.6; NHPI, 29.5 2009, Total, 51.8; NHPI, 54.7 2010, Total, 59.5; NHPI, 87.2 2011, Total, 69; NHPI, 90.7

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2011.

Graph 71 Improving: Adolescents ages 16-17 years who received 1 or more doses of tetanus-diphtheria-acellular pertussis (Tdap) vaccine, 2008-2015

Key: NHPI = Native Hawaiian/Pacific Islander.

Note: NHPI data do not meet the criteria for statistical reliability, data quality, or confidentiality for 2014 and 2015. Data not analyzed for 2012.

Line graph showing trend in percentage 2008, Total, 31.9; NHPI, 41.9 2009, Total, 45.3; NHPI, 58.1 2010, Total, 60.2; NHPI, 63.3 2011, Total, 74.8; NHPI, 60.7 2012, Total, 83.6; NHPI, data statistically unreliable 2013, Total, 83.7; NHPI, 92.4 2014, Total, 86.6; NHPI, data statistically unreliable 2015, Total, 85.3; NHPI, data statistically unreliable

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2015.

Graph 72 Improving: People age 13 years and over living with HIV who know their serostatus, 2010-2014

Line graph showing trend in percentage 2010, Total, 82.7; NHPI, 75.2 2011, Total, 83.3; NHPI, 77.1 2012, Total, 83.9; NHPI, 79.7 2013, Total, 84.4; NHPI, 81.9 2014, Total, 85; NHPI, 82.8

Source: National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, Division of HIV/AIDS, National HIV/AIDS Surveillance System, 2010-2014.

#### Gap Between Native Hawaiians/Pacific Islanders and Whites

Graph 73 Improving: Adolescent females ages 16-17 years who received 3 or more doses of human papillomavirus vaccine, 2008-2011

Line graph showing trend in disparity in percentage 2008, White, 21.3; NHPI, 9.5 2009, White, 34; NHPI, 54.7 2010, White, 37.6; NHPI, 100 2011, White, 42.6; NHPI, 86.7

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2011.

### Ethnicity

#### Largest Disparities for Hispanics

Graph 74 Largest Disparities: Children ages 2-5 with obesity, 2011-2014

Note: For this measure, lower rates are better.

Bar chart showing percentage Total, 8.9 Non-Hispanic White, 5.2 Hispanic, 15.6

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health and Nutrition Examination Survey, 2011-2014 combined.

Graph 75 Largest Disparities: New HIV cases per 100,000 population age 13 and over, 2014

Note: For this measure, lower rates are better.

Bar chart showing rate per 100,000 population Total, 15.1 Non-Hispanic White, 6.2 Hispanic, 23.1

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2014.

#### Improvements for Hispanics

Graph 76 Improving: Adolescents ages 16-17 years who received 1 or more doses of tetanus-diphtheria-acellular pertussis (Tdap) vaccine, 2008-2015

Line graph showing trend in percentage 2008, Total, 31.9; Hispanic, 29.4; Non-Hispanic White, 33.7 2015, Total, 85.3; Hispanic, 81.4; Non-Hispanic White, 86.7

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2015.

Graph 77 Improving: Adolescents ages 13-15 years who received 1 or more doses of tetanus-diphtheria-acellular pertussis (Tdap) vaccine, 2008-2015

Line graph showing trend in percentage Hispanic Total 2008, Hispanic, 48.5; Total, 46.7 2015, Hispanic, 87.6; Total, 87.1

Source: Centers for Disease Control and Prevention, National Center for Immunizations and Respiratory Diseases and National Center for Health Statistics, National Immunization Survey – Teen, 2008-2015.

#### Gap Between Hispanics and Non-Hispanic Whites

Graph 78 Improving: Potentially avoidable hospital admissions for uncontrolled diabetes without complications per 100,000 population, adults age 18 and over, 2001-2015

Note: For this measure, lower rates are better.

Line graph showing trend in disparity in rate per 100,000 population Total, 27.9; Hispanic, 46; Non-Hispanic White, 17.6 2015, Total, 12.7; Hispanic, 17.6; Non-Hispanic White, 8.9 Achievable Benchmark: 3.3 per 100,000 population

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 79 Improving: Potentially avoidable hospital admissions for short-term complications of diabetes per 100,000 population, adults age 18 and over, 2001-2015

Note: For this measure, lower rates are better.

Line graph showing trend in disparity in rate per 100,000 population 2001, Total, 54.4; Non-Hispanic White, 42.1; Hispanic, 51.8 2015, Total, 85.8; Non-Hispanic White, 75.4; Hispanic, 64.6 Achievable Benchmark: 56.8 per 100,000 population

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), State Inpatient Databases, 2001-2015, weighted to provide national estimates using the same methodology as the HCUP Nationwide Inpatient Sample; and the AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 80 Improving: Adjusted incident rates of end stage renal disease due to diabetes per million population, 2001-2015

Note: For this measure, lower rates are better.

Line graph showing trend in disparity in rate per million population 2001, Total, 177.8; Non-Hispanic White, 114.5; Hispanic, 410 2015, Total, 164.1; Non-Hispanic White, 116.8; Hispanic, 302.6

Source: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases, U.S. Renal Data System, 2001-2015.

Graph 81 Improving: Potentially avoidable hospital admissions with diabetes with long-term complications per 100,000 population, age 18 and over, 2001-2015

Note: For this measure, lower rates are better.

Line graph showing trend in disparity in rate per million population 2001, Total, 128.1; Non-Hispanic White, 96.7; Hispanic, 206.6 2015, Total, 115.9; Non-Hispanic White, 88.8; Hispanic, 165.9

Source: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases, U.S. Renal Data System, 2001-2015

### Geographic Location

Geographic location is based on the Centers for Disease Control and Prevention 2006 Urban-Rural Classification Scheme for Counties (www.cdc.gov/nchs/data_access/urban_rural.htm). Counties are classified into six categories:

1. Large central metropolitan: Counties in a metropolitan statistical area of 1 million or more population:
  - That contain the entire population of the largest principal city of the metropolitan statistical area, or
  - Whose entire population resides in the largest principal city of the metropolitan statistical area, or
  - That contain at least 250,000 of the population of any principal city in the metropolitan statistical area.
2. Large fringe metropolitan: Counties in a metropolitan statistical area of 1 million or more population that do not qualify as large central.
3. Medium metropolitan: Counties in a metropolitan statistical area of 250,000 to 999,999 population.
4. Small metropolitan: Counties in a metropolitan statistical area of 50,000 to 249,999 population.
5. Micropolitan: Counties in a micropolitan statistical area.
6. Noncore: Counties not in a micropolitan statistical area.

#### Large Central Metropolitan – Improvements

Graph 82 Improving: Hospital admissions with central venous catheter-related bloodstream infection per 1,000 medical and surgical discharges of length 2 or more days, adults age 18 and over or obstetric admissions, 2008-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 1,000 discharges 2008, Total, 1.9; Large Central Metropolitan, 2.26 2009, Total, 1.67; Large Central Metropolitan, 1.95 2010, Total, 1.55; Large Central Metropolitan, 1.89 2011, Total, 1.18; Large Central Metropolitan, 1.36 2012, Total, 0.97; Large Central Metropolitan, 1.12 2013, Total, 0.77; Large Central Metropolitan, 0.87 2014, Total, 0.67; Large Central Metropolitan, 0.73 2015, Total, 0.67; Large Central Metropolitan, 0.71

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2008-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and the AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 83 Improving: Potentially avoidable hospital admissions for angina per 100,000 population, adults age 18 and over, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, Total, 81.5; Large Central Metropolitan, 79.4 2015, Total, 11.8; 12.9 Achievable Benchmark: 4.9 per 100,000 population

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and the AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 84 Improving: Hospital admissions for pediatric gastroenteritis per 100,000 population, children ages 3 months to 17 years, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, Total, 169.4, Large Central Metropolitan, 164.3 2015, Total, 50.8, Large Central Metropolitan, 52.8

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

#### Large Central Metropolitan – Largest Disparities

Graph 85 Largest Disparities: Potentially avoidable hospital admissions for asthma per 100,000 population, children ages 2-17, large central metropolitan vs. large fringe metropolitan, 2015

Note: For this measure, lower rates are better.

Bar chart showing rate per 100,000 population Total, 87.2 Large Fringe Metropolitan, 73 Large Central Metropolitan, 125.9

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2015.

Graph 86 Largest Disparities: Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, large central metropolitan vs. large fringe metropolitan, 2015

Note: For this measure, lower rates are better. The wording reflects a Likert-type scale with the following options: Always, Usually, Sometimes, Never. Sometimes and Never are combined into a single category that is the opposite of Always.

Bar chart showing percentage Total, 7.3 Large Fringe Metropolitan, 5.6 Large Central Metropolitan, 8.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

#### Medium Metropolitan - Improvements

Graph 87 Improving: Hospital admissions with central venous catheter-related bloodstream infection per 1,000 medical and surgical discharges of length 2 or more days, adults age 18 and over or obstetric admissions, 2008-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 1,000 discharges 2008, Total, 1.9; Medium Metropolitan, 1.85 2009, Total, 1.67; Medium Metropolitan. 1.62 2010, Total, 1.55; Medium Metropolitan, 1.43 2011, Total, 1.18; Medium Metropolitan, 1.26 2012, Total, 0.97; Medium Metropolitan, 0.95 2013, Total, 0.77; Medium Metropolitan, 0.75 2014, Total, 0.67; Medium Metropolitan, 0.7 2015, Total, 0.67; Medium Metropolitan, 0.69

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 88 Improving: Potentially avoidable hospital admissions for angina per 100,000 population, adults age 18 and over, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, Total, 81.5; Medium Metropolitan, 51.4 2015, Total, 11.8; Medium Metropolitan, 9.7 Achievable Benchmark: 4.9 per 100,000 population

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and the AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 89 Improving: Hospital admissions for pediatric gastroenteritis per 100,000 population, children ages 3 months to 17 years, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, Total, 169.4; Medium Metropolitan, 144.4 2015, Total, 50.8; Medium Metropolitan, 45.2

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

#### Medium Metropolitan - Largest Disparities

Graph 90 Largest Disparities: Children who had their height and weight measured by a health provider within the past 2 years, medium metropolitan vs. large fringe metropolitan, 2015

Bar chart showing percentage Total, 93.8 Large Fringe Metropolitan, 95.4 Medium Metropolitan, 92.8

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.

Graph 91 Largest Disparities: Accidental puncture or laceration during procedure per 1,000 medical and surgical admissions, children under 18 years, medium metropolitan vs. large fringe metropolitan, 2015

Note: For this measure, lower rates are better.

Bar chart showing rate per 1,000 admissions Total, 0.49 Large Fringe Metropolitan, 0.41 Medium Metropolitan, 0.64

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), State Inpatient Databases, 2001-2015, weighted to provide national estimates using the same methodology as the HCUP Nationwide Inpatient Sample; and the AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp)., 2015.

Graph 92 Largest Disparities: People under age 65 with any private health insurance, medium metropolitan vs. large fringe metropolitan, 2016

Bar chart showing percentage Total, 65.7 Large Fringe Metropolitan, 72.9 Medium Metropolitan, 65.2

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2016.

#### Small Metropolitan - Improvements

Graph 93 Improving: Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined, 2005-2014

Line graph showing trend in percentage 2005, Total, 60.9; Small Metropolitan, 60.2 2014, Total, 91.2; Small Metropolitan, 90.5 Achievable Benchmark: 95.9%

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2014.

Graph 94 Improving: Potentially avoidable hospital admissions for angina per 100,000 population, adults age 18 and over, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, Total, 81.5; Small Metropolitan, 60.7 2015, Total, 11.8; Small Metropolitan, 11.5 Achievable Benchmark: 4.9 per 100,000 population

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 95 Improving: Hospital admissions with central venous catheter-related bloodstream infection per 1,000 medical and surgical discharges of length 2 or more days, adults age 18 and over or obstetric admissions, 2008-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 1,000 discharges 2008, Total, 1.9; Small Metropolitan, 1.53 2009, Total, 1.67; Small Metropolitan, 1.43 2010, Total, 1.55; Small Metropolitan, 1.39 2011, Total, 1.18; Small Metropolitan, 0.94 2012, Total, 0.97; Small Metropolitan, 0.75 2013, Total, 0.77; Small Metropolitan, 0.75 2014, Total, 0.67; Small Metropolitan, 0.63 2015, Total, 0.67; Small Metropolitan, 0.57

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

#### Small Metropolitan - Largest Disparities

Graph 96 Largest Disparities: Deaths per 1,000 hospital admissions with expected low-mortality, small metropolitan vs. large fringe metropolitan, 2015

Note: For this measure, lower rates are better.

Bar chart showing rate per 1,000 population Total, 0.31 Large Fringe Metropolitan, 0.25 Small Metropolitan, 0.45

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2015.

Graph 97 Largest Disparities: Infant mortality per 1,000 live births, birth weight more than 2,499 grams, small metropolitan vs. large fringe metropolitan, 2014

Bar chart showing rate per 1,000 live births Total, 2 Large Fringe Metropolitan, 1.7 Small Metropolitan, 2.4

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System – Linked Birth and Infant Death Data, 2014.

Graph 98 Largest Disparities: People under age 65 with any private health insurance, small metropolitan vs. large fringe metropolitan, 2016

Bar chart showing percentage Total, 65.7 Large Fringe Metropolitan, 72.9 Small Metropolitan, 61.2

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2016.

#### Micropolitan - Improvements

Graph 99 Improving: Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined, 2005-2014

Line graph showing trend in percentage 2005, Total, 60.9; Micropolitan, 53.8 2014, Total, 91.2; Micropolitan, 89.9 Achievable Benchmark: 95.9%

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2014.

Graph 100 Improving: Potentially avoidable hospital admissions for angina per 100,000 population, adults age 18 and over, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, Total, 81.5; Micropolitan, 113.1 2014, Total, 11.8; Micropolitan, 14.1 Achievable Benchmark: 4.9 per 100,000 population

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and the AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 101 Improving: Hospital admissions with central venous catheter-related bloodstream infection per 1,000 medical and surgical discharges of length 2 or more days, adults age 18 and over or obstetric admissions, 2008-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 1,000 discharges 2008, Total, 1.9, Micropolitan, 1.37 2009, Total, 1.67, Micropolitan, 1.3 2010, Total, 1.55, Micropolitan, 1.27 2011, Total, 1.18, Micropolitan, 0.89 2012, Total, 0.97, Micropolitan, 0.82 2013, Total, 0.77, Micropolitan, 0.61 2014, Total, 0.67, Micropolitan, 0.59 2015, Total, 0.67, Micropolitan, 0.57

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

#### Micropolitan - Largest Disparities

Graph 102 Largest Disparities: Emergency department visits with a principal diagnosis related to dental conditions per 100,000 population, micropolitan and noncore combined vs. large fringe metropolitan, 2015

Note: For this measure, lower rates are better.

Bar chart shwoing rate per 100,000 population Total, 312.9 Large fringe metropolitan, 238.2 Micropolitan/noncore (combined), 496.7

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, Nationwide Emergency Department Sample, 2015.

Graph 103 Largest Disparities: Accidental puncture or laceration during procedure per 1,000 medical and surgical admissions, children, micropolitan vs. large fringe metropolitan, 2015

Note: For this measure, lower rates are better.

Bar chart showing rate per 1,000 admissions Total, 0.49 Large Fringe Metropolitan, 0.41 Micropolitan, 0.74

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), State Inpatient Databases, 2001-2015, weighted to provide national estimates using the same methodology as the HCUP Nationwide Inpatient Sample; and the AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp)., 2015.

Graph 104 Largest Disparities: People under age 65 with any private health insurance, micropolitan vs. large fringe metropolitan, 2016

Bar chart showing percentage Total, 65.7 Large Fringe Metropolitan, 72.9 Micropolitan, 58

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Health Interview Survey, 2016.

#### Noncore - Improvements

Graph 105 Improving: Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined, 2005-2014

Line graph showing trend in percentage 2005, Total, 60.9, Noncore, 57.9 2014, Total, 91.2, Noncore, 89.9 Achievable Benchmark: 95.9%

Source: Commission on Cancer, American College of Surgeons and American Cancer Society, National Cancer Data Base, 2005-2014.

Graph 106 Improving: Potentially avoidable hospital admissions for angina per 100,000 population, adults age 18 and over, 2000-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 100,000 population 2000, Total, 81.5, Noncore, 140.3 2015, Total, 11.8, Noncore, 13.3 Achievable Benchmark: 4.9 per 100,000 population

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

Graph 107 Improving: Hospital admissions with central venous catheter-related bloodstream infection per 1,000 medical and surgical discharges of length 2 or more days, adults age 18 and over or obstetric admissions, 2008-2015

Note: For this measure, lower rates are better.

Line graph showing trend in rate per 1,000 discharges 2008, Total, 1.9, Noncore, 1.21 2009, Total, 1.67, Noncore, 1 2010, Total, 1.55, Noncore, 1.19 2011, Total, 1.18, Noncore, 0.87 2012, Total, 0.97, Noncore, 0.71 2013, Total, 0.77, Noncore, 0.59 2014, Total, 0.67, Noncore, 0.48 2015, Total, 0.67, Noncore, 0.54

Source: Agency for Healthcare Research and Quality (AHRQ), Healthcare Cost and Utilization Project (HCUP), Nationwide Inpatient Sample (NIS), 2000-2011; State Inpatient Databases, 2012-2015, weighted to provide national estimates using the same methodology as the 2000-2011 NIS; and AHRQ Quality Indicators, version 4.4. Estimates for 2015 were based on 9 months of data (January-September) with International Classification of Diseases, 9^th^ Revision coding. For more information on the sampling approach, included states, and special handling of 2015 data, see the HCUP Methods Series Report on Methods Applying AHRQ Quality Indicators to HCUP Data (https://www.hcup-us.ahrq.gov/reports/methods/methods.jsp).

#### Noncore - Largest Disparities

Graph 108 Largest Disparities: Avoidable hospital admissions for bacterial pneumonia per 100,000 population, adults age 18 and over, noncore vs. large fringe metropolitan, 2015

Note: For this measure, lower rates are better.

Bar chart showing rate per 100,000 population Large Fringe Metropolitan, 233.4 Noncore, 460.4 Achievable Benchmark: 161.5 per 100,000 population

Source: Agency for Healthcare Research and Quality, Healthcare Cost and Utilization Project, 2015.

Graph 109 Largest Disparities: Infant mortality per 1,000 live births, birth weight more than 2,499 grams, noncore vs. large fringe metropolitan, 2014

Note: For this measure, lower rates are better.

Bar chart showing rate per 1,000 live births Total, 2 Large Fringe Metropolitan, 1.7 Noncore, 2.9

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System - Linked Birth and Infant Death Data, 2014.

Graph 110 Largest Disparities: Rating of health care 0-6 on a scale from 0 to 10 (best grade) by adults who had a doctor’s office or clinic visit in the last 12 months, noncore vs. large fringe metropolitan, 2015

Notes: For this measure, lower rates are better.

Bar chart showing percentage Total, 11.1 Large Fringe Metropolitan, 10.1 Noncore, 17.1

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2015.