# PART 3 TRENDS IN ACCESS AND PRIORITIES OF THE NATIONAL QUALITY STRATEGY

## QDR Chartbooks

- QDR supported by a series of related chartbooks that:
  ■ Present information on individual measures
  ■ Are updated annually
  ■ Are posted on the Web (http://www.ahrq.gov/research/findings/nhqrdr/2014chartbooks/ (https://archive.ahrq.gov/research/findings/nhqrdr/2014chartbooks/index.html))
- Order and topics of chartbooks:
  ■ Access to care
  ■ Priorities of the National Quality Strategy
  ■ Access and quality of care for priority populations
- Information on individual measures is available through chartbooks posted on the Web (http://www.ahrq.gov/research/findings/nhqrdr/2014chartbooks/ (https://archive.ahrq.gov/research/findings/nhqrdr/2014chartbooks/index.html)).

## Six Chartbooks Organized Around Priorities of the National Quality Strategy

1. Making care safer by reducing harm caused in the delivery of care.
2. Ensuring that each person and family is engaged as partners in their care.
3. Promoting effective communication and coordination of care.
4. Promoting the most effective prevention and treatment practices for the leading causes of mortality, starting with cardiovascular disease.
5. Working with communities to promote wide use of best practices to enable healthy living.
6. Making quality care more affordable for individuals, families, employers, and governments by developing and spreading new health care delivery models.

## Other Chartbooks Organized Around AHRQ’s Priority Populations

- AHRQ’s priority populations, specified in the Healthcare Research and Quality Act of 1999 (Public Law 106-129):
  ■ Racial and ethnic minority groups
  ■ Low-income groups
  ■ Women
  ■ Children (under age 18)
  ■ Older adults (age 65 and over)
  ■ Residents of rural areas
  ■ Individuals with special health care needs, including:
    ◆ Individuals with disabilities
    ◆ Individuals who need chronic care or end-of-life care

## Access to Health Care

### Access Disparities

Key: AI/AN = American Indian or Alaska Native; n = number of measures.

Note: Poor indicates family income less than the Federal poverty level; high income indicates family income four times the Federal poverty level or greater. Numbers of measures differ across groups because of sample size limitations. Measures that achieve an overall performance level of 95% or better are not reported in the QDR and are not included in these analyses. Because disparities are typically eliminated when overall performance reaches 95%, our analyses may overstate the percentage of measures exhibiting disparities.

The relative difference between a selected group and its reference group is used to assess disparities.

- Better = Population had better access to care than reference group. Differences are statistically significant, are equal to or larger than 10%, and favor the selected group.
- Same = Population and reference group had about the same access to care. Differences are not statistically significant or are smaller than 10%.
- Worse = Population had worse access to care than reference group. Differences are statistically significant, are equal to or larger than 10%, and favor the reference group.

Example: Compared with Whites, Blacks had worse access to care on 12 of the 22 access measures, similar access on 10 measures, and better access on no measures.

- Groups With Disparities:
  ■ People in poor households experienced the largest number of disparities, followed by Hispanics and Blacks.
  ■ In 2013, people in poor households had worse access to care than people in high-income households on all access measures (green).
  ■ Blacks had worse access to care than Whites for about half of access measures.
  ■ Hispanics had worse access to care than Whites for more than two-thirds of access measures.
  ■ Asians and American Indians and Alaska Natives had worse access to care than Whites for about one-third of access measures.

### Uninsurance

- Trends: All racial/ethnic groups displayed a decrease from 2013 Q4 to 2015 Q2:
  ■ White: 14.0% to 8.8%
  ■ Black: 24.6% to 13.5%
  ■ Hispanic: 40.3% to 26.1%
- Groups With Disparities: Black adults ages 18-64 were significantly more likely than Whites to be uninsured from January 2010 to June 2015. The percentage peaked in the third quarter of 2010 at 28.6%, then significantly decreased to 13.5% for the second quarter of 2015.

### Usual Source of Care

- Groups With Disparities:
  ■ From January to June 2015, after adjustment for age and sex, the percentage of people with a usual place to go for medical care was 82.6% for Hispanics, 89.0% for Whites, and 86.6% for Blacks.
  ■ In all 3 years, Blacks were less likely to have a usual place to go for medical care compared with Whites.

### Delays in Care

- Trends: From 2002 to 2013, there were no statistically significant changes overall or for any racial group in the percentage of adults who needed care right away who sometimes or never got care as soon as wanted.
- Groups With Disparities:
  ■ In 2013, the percentage of Blacks who needed care right away who sometimes or never got care as soon as wanted was significantly higher than the percentage of Whites who sometimes or never received care as soon as wanted.
  ■ Among those with private insurance, the percentage who sometimes or never got care as soon as wanted was significantly higher for Blacks than for Whites.

### HRSA-Supported Health Center Population

- Groups With Disparities:
  ■ In 2014, 71.2% of the health center population was at or below the Federal poverty level compared with 14.8% of the U.S. population. The health center population also had higher percentages of uninsurance (27.9%) and Medicaid enrollment (47.3%) than the U.S. population (10.4% and 19.5%, respectively).
  ■ In 2014, the percentage of the health center population who was Black was nearly one-quarter (23.4%), nearly twice as much as the percentage in the U.S. population (13.2%). Slightly less than two-thirds (65.1%) of the health center population was Hispanic, which was much higher than the percentage in the U.S. population (17.4%).

## National Quality Strategy Priorities

### Quality Measures

Key: n = number of measures

Improving = Quality is going in a positive direction at an average annual rate greater than 1% per year.

No Change = Quality is not changing or is changing at an average annual rate less than 1% per year.

Worsening = Quality is going in a negative direction at an average annual rate greater than 1% per year.

- Quality of care for Blacks:
  ■ Improved for 59% (106 of 179) of the measures.
  ■ Worsened for 9% (16 of 179) of the measures.
  ■ Did not change for 32% (57 of 179) of the measures.
- Among the NQS priorities, quality of care for Blacks:
  ■ Improved for 74% (17 of 23) of Patient Safety measures and did not change for 22% (5 of 23).
  ■ Improved for 72% (13 of 18) of Person-Centered Care measures and did not change for 28% (5 of 18).
  ■ Improved for 63% (12 of 19) of Care Coordination measures and did not change for 21% (4 of 19).
  ■ Improved for 57% (27 of 47) of Effective Treatment measures and did not change for 32% (15 of 47).
  ■ Improved for 58% (37 of 64) of Healthy Living measures and did not change for 36% (23 of 64).
  ■ There are insufficient numbers of reliable measures of Care Affordability to summarize in this way.

### Quality Disparities

Key: n = number of measures.

Note: For most measures, data from 2013 are shown. Measures that achieve an overall performance level of 95% or better are not reported in the QDR and are not included in these analyses. Because disparities are typically eliminated when overall performance reaches 95%, our analyses may overstate the percentage of measures exhibiting disparities.

The relative difference between a selected group and its reference group is used to assess disparities.

- Better = Population received better quality of care than reference group. Differences are statistically significant, are equal to or larger than 10%, and favor the selected group.
- Same = Population and reference group received about the same quality of care. Differences are not statistically significant or are smaller than 10%.
- Worse = Population received worse quality of care than reference group. Differences are statistically significant, equal to or larger than 10%, and favor the reference group.

- Groups With Disparities:
  ■ Blacks received worse care for about 70% of Care Coordination measures.
  ■ Blacks received worse care for nearly 50% of Person-Centered Care measures.
  ■ Blacks received worse care for about 40% of measures of Patient Safety and Effective Treatment and almost one-third of Healthy Living measures.

### Disparity Trends

Key: n = number of measures.

Note: For the majority of measures, trend data are available from 2001-2002 to 2013.

For each measure with Black-White disparities in the baseline year, average annual percentage changes were calculated for select populations and reference groups. Measures are aligned so that positive rates indicate improvement in access to care.

Differences in rates between groups were used to assess trends in disparities.

- Worsening = Disparities are getting larger. Differences in rates between groups are statistically significant and reference group rates exceed population rates by at least 1% per year.
- No Change = Disparities are not changing. Differences in rates between groups are not statistically significant or differ by less than 1% per year.
- Improving = Disparities are getting smaller. Differences in rates between groups are statistically significant and population rates exceed reference group rates by at least 1% per year.

- Disparity Trends:
  ■ Through 2013, most Black-White disparities in quality of care in the baseline year showed no significant change over time (blue), neither getting smaller nor larger.
  ■ When changes in disparities occurred, measures of disparities were more likely to show improvement (green) than decline (black).

### New Quality Disparities

#### QUALITY DISPARITIES: Several new Black-White disparities developed

- Three new Black-White disparities not present at baseline developed
- Person Centered Care
  ■ Family caregivers who did not want more information about what to expect while the patient was dying
- Healthy Living
  ■ Breast cancer diagnosed at advanced stage per 100,000 women age 40 and over
  ■ Home health care patients who get better at getting in and out of bed

### Quality Disparities by State

- Geographic Disparities:
  ■ There was significant variation in overall quality among States. States in the New England, Middle Atlantic, West North Central, and Mountain census divisions tended to have higher overall quality (blue and green) while States in the South census region tended to have lower quality (yellow and red).
  ■ There was also significant variation among States in quality for Blacks. Blacks tended to receive higher quality care in States in the South Atlantic and East South Central census divisions (blue and green) and lower quality care in States in the New England, Middle Atlantic, and West South Central census divisions (yellow and red).
  ■ The variation in State performance on overall quality and among specific priority populations may point to differential strategies for improvement. States with high overall quality but poor quality for Blacks might target this population for support; States with low overall quality and high quality for Blacks might seek to improve care for everyone.
  ■ The State Snapshots tool (http://nhqrnet.ahrq.gov/inhqrdr/state/select), part of the QDR Web site, focuses on variation across States and helps State health leaders, researchers, and consumers understand the status of health care in individual States and the District of Columbia. It is based on more than 100 QDR measures for which State estimates are possible.

### NQS Priority: Patient Safety

- Patient Safety is the first of six National Quality Strategy (NQS) Priorities to be covered by this chartbook. The other five Priorities are Person- and Family-Centered Care, Care Coordination, Effective Treatment, Healthy Living, and Care Affordability.

#### Postoperative Sepsis

- Overall Rate: In 2013, the postoperative sepsis rate was 14.3 per 1,000 adult discharges with an elective operating room procedure (data not shown).
- Trends: From 2008 to 2013, there were no statistically significant changes overall or for any racial/ethnic group in the rate of postoperative sepsis.
- Groups With Disparities:
  ■ In all years, Hispanic patients and Black patients had higher rates of postoperative sepsis than their White counterparts.
  ■ In 2013, among Medicare patients, the rate of postoperative sepsis was higher for Blacks than for Whites. Black-White differences in other insurance groups were not statistically significant.

#### Colorectal Surgery Mortality

- Importance: Colon and rectal procedures are ranked among the most harmful procedures, with high rates of postoperative complications, which are often a result of nonadherence to best practices.
- Overall Rate: In 2013, the unadjusted rate of 30-day postoperative mortality for colorectal surgeries was 2.9% among ACS-NSQIP participating hospitals in the United States.
- Trend: From 2008 to 2013, rates decreased by 44% among Hispanics, 27% among Blacks, and 33% among Whites.
- Groups With Disparities:
  ■ In 2013, 30-day postoperative mortality rates were higher for Blacks (3.1%) compared with Whites (2.8%).
  ■ In 4 of 5 years, Blacks had higher rates compared with Whites.

#### Medical Care Visits Due to Adverse Effects of Medical Care

- Importance:
  ■ Adverse effects of medical care can arise from medical and surgical procedures as well as from adverse drug reactions. Although patient safety initiatives focus mainly on inpatient hospital events, adverse effects of medical care are much more commonly treated at visits to outpatient settings, with more than 12 million such visits occurring annually. Providers treating adverse events in outpatient settings may include office-based physicians, hospital outpatient departments, and hospital emergency departments.
  ■ Events treated in ambulatory settings may be less severe than those occurring in inpatient settings. Some adverse events, such as known side effects of appropriately prescribed medications, may be unavoidable, while others may be considered medical errors. Although the measure here does not distinguish between the two types of events, it provides an overall sense of the burden these events place on the population.
- Overall Rate: In 2008-2009, the rate of ambulatory care visits for adverse effects of medical care was 33.2 per 1,000 population (data not shown).
- Groups With Disparities: In 2008-2009, there were no statistically significant differences between Blacks and Whites in rates of ambulatory care visits for adverse effects of medical care.

#### Long-Stay Nursing Home Residents With Urinary Tract Infections

- Importance: Urinary tract infections (UTIs) can spread and become more serious or cause further complications, such as delirium.
- Overall Rate: In 2013, the percentage of long-stay nursing home residents with a UTI was 6.4%.
- Groups With Disparities: In 2013, Black, Asian, and Native Hawaiian and Other Pacific Islander (NHOPI) nursing home residents had lower rates of UTIs compared with White residents.
- Achievable Benchmark:
  ■ In 2011, the top 5 State achievable benchmark for UTIs was 6.1%. The States that contributed to the achievable benchmark are Connecticut, Hawaii, Minnesota, North Dakota, and Pennsylvania.
  ■ In both 2012 and 2013, Blacks, Asians, and NHOPIs all achieved the 2011 benchmark of 6.1%, with Blacks and Asians having the best rate among all racial groups (4.7%) in 2013.

#### Long-Stay Nursing Home Residents With Restraints

- Importance: Residents who are restrained can become weak, lose their ability to go to the bathroom by themselves, and develop pressure ulcers or other medical conditions.
- Overall Rate: In 2013, the percentage of long-stay nursing home residents who were physically restrained was 1.4%.
- Groups With Disparities: In 2013, the percentage of nursing home residents with restraints was higher for Asians (2.0%) than for Whites (1.4%). The percentage was lower for Blacks (1.2%), who had the lowest percentage among all racial groups.
- Achievable Benchmark:
  ■ In 2011, the top 5 State achievable benchmark for restraint use was 0.7%. The States that contributed to the achievable benchmark are Kansas, Maine, Nebraska, New Hampshire, and Vermont.
  ■ By 2013, no group had achieved the benchmark.

### NQS Priority: Person- and Family-Centered Care

#### Poor Communication With Health Providers: Adults

- Importance: Optimal health care requires good communication between patients and providers, yet barriers to provider-patient communication are common. To provide all patients with the best possible care, providers need to understand patients’ diverse health care needs and preferences and communicate clearly with patients about their care.
- Trends: From 2002 to 2013, the percentage of adults who reported poor communication with health providers significantly decreased overall and for Blacks, Whites and Asians.
- Groups With Disparities:
  ■ In all years except 2006, Blacks were significantly more likely than Whites to have poor communication with their health providers.
  ■ In 2013, high-income Blacks were more likely than high-income Whites to have poor communication with their health providers. Differences among other income groups were not statistically significant.

#### Poor Communication With Health Providers: Children

- Trends: From 2002 to 2013, the percentage of children whose parents reported poor communication with health providers significantly decreased for Whites and Blacks.
- Groups With Disparities:
  ■ In 2013, parents of Black children were significantly more likely to report poor communication compared with parents of White children.
  ■ Parents of Black girls were significantly more likely to report poor communication compared with parents of White girls. Differences among boys were not statistically significant.

#### Provider-Patient Communication Among Home Health Care Patients

- Importance: Communication between providers and patients is an important element of patient outcomes. The Consumer Assessment of Healthcare Providers and Systems (CAHPS^®^) Home Health Care Survey (Home Health Care CAHPS Survey) was designed to measure the experiences of people receiving home health care from Medicare-certified home health care agencies. In April 2012, the Centers for Medicare & Medicaid Services began publicly reporting results from this survey on Home Health Compare to create incentives for home health agencies to improve quality of care and to provide patients with information to help them choose home health care providers.
- Overall Rate: In 2014, among adult home health care patients, about 80% reported that home health care providers always informed them about when they would arrive, always explained things in a way they could understand, and always listened carefully to them. About 90% reported that home health care providers always treated them as gently as possible and with courtesy and respect (data not shown).
- Groups With Disparities: In 2014, among home health care patients:
  ■ Blacks were less likely than Whites to always be treated as gently as possible.
  ■ Blacks were less likely to always be treated with courtesy and respect.

#### Providers Asking for Patient’s Help To Make Treatment Decisions

- Importance: The increasing prevalence of chronic diseases has placed more responsibility on patients, since conditions such as diabetes and hypertension require self-management. Patients need to be provided with information that allows them to make educated decisions and feel engaged in their treatment. Treatment plans also need to incorporate their values and preferences.
- Trends:
  - From 2008 to 2013, the percentage of people whose providers sometimes or never asked for their help with treatment decisions decreased overall from 21.9% to 16.4%.
  - Improvement was observed for Whites, Blacks, and Asians.
- Groups With Disparities:
  ■ In all years except 2008, Blacks were significantly more likely to have a usual source of care who sometimes or never asked them to help make treatment decisions.
  ■ In 2013, among all groups defined by number of chronic conditions, the percentage of people whose providers sometimes or never asked for their help with treatment decisions was higher for Blacks than for Whites.

#### Help for Hospice Patients for Feelings of Anxiety or Sadness

- Importance: Hospice care includes practical, psychosocial, and spiritual support for the patient and family.
- Overall Rate: In 2014, 90.7% of hospice patients received the right amount of help for feelings of anxiety or sadness.
- Trends: From 2008 to 2014, there were no statistically significant changes in the percentage of hospice patients who received the right amount of help for feelings of anxiety or sadness overall or for any racial groups.
- Groups With Disparities: In 2014, compared with Whites, Blacks (85.4%), Asians and Pacific Islanders (APIs) (80.2%), and American Indians and Alaska Natives (AI/ANs) (87.3%) were significantly less likely to receive the right amount of help for feelings of anxiety or sadness.

#### Hospice Patient Care Consistent With Their End-of-Life Wishes

- Importance: The goal of end-of-life care is to achieve a “good death,” defined by the Institute of Medicine as “free from avoidable distress and suffering for patients, families, and caregivers; in general accord with the patients’ and families’ wishes; and reasonably consistent with clinical, cultural, and ethical standards” (Field & Cassell, 1997).
- Overall Rate: In 2014, the percentage of hospice patients who received care consistent with their stated end-of-life wishes was 94.8%.
- Trends: From 2008 to 2014, the percentage of hospice patients who received care consistent with their stated end-of-life wishes improved overall and for White hospice patients. There were no statistically significant changes among Black, API, or AI/AN hospice patients.
- Groups With Disparities: In 2014, Black, API, and AI/AN hospice patients were significantly less likely than White hospice patients to receive care consistent with their stated end-of-life wishes.

#### AHRQ Health Care Innovations in Person-Centered Care

The AIDS Foundation of Chicago (https://innovations.ahrq.gov/profiles/foundation-develops-community-based-hiv-testing-and-partnerships-medical-homes-leading-more)

- Location: Chicago, Illinois
- Population: Young Black gay and bisexual men
- Intervention: The AIDS foundation of Chicago develops community testing programs and partners with 11 medical homes to provide real-time linkages to care for newly diagnosed HIV patients.
- Outcomes: Enhanced access to testing for hard-to-reach populations, nearly doubled the percentage of newly diagnosed HIV patients linked to care, and generated high levels of patient satisfaction.

### NQS Priority: Care Coordination

#### Potentially Avoidable Hospitalizations

- Groups With Disparities: In 2013, in all income groups, rates of potentially avoidable hospitalizations were higher for Blacks than for Whites. Rates for Whites in the lowest income quartile were lower than the rates for Blacks in the highest income quartile.
- Achievable Benchmark:
  ■ In 2011, the top 4 State achievable benchmark for all potentially avoidable hospitalizations was 939 per 100,000 population. The States that contributed to the achievable benchmark are Hawaii, Oregon, Utah, and Washington.
  ■ Whites in the two highest income quartiles have already achieved the benchmark. No other groups have achieved the benchmark.

#### Provider Ability To Share Medical Information Electronically

- Trends: From 2008 to 2014, the percentage of Black, White, Asian, and Hispanic patients who reported that it was very important that their doctors and other health care providers be able to share their medical information electronically increased significantly.
- Groups With Disparities: In 2014, there were no statistically significant differences between Blacks and Whites in the percentage who reported that it was very important that their doctors and other health care providers be able to share their medical information electronically.

#### Patient Electronic Access to Medical Information

- Trends: From 2008 to 2014, the percentage of Black patients who reported that it was very important to be able to get their medical information electronically increased from 54.1% to 80.9%; for Whites, the percentage increased from 58.8% to 70.3%.
- Groups With Disparities: In 2014, the percentage of patients who reported that it was very important to be able to get their medical information electronically was 80.9% for Blacks, 70.3% for Whites, 73.0% for Asians, and 61.2% for Hispanics.

#### Willingness To Exchange Medical Information Electronically

- Groups With Disparities:
  ■ The percentage of patients very willing to exchange appointment reminders electronically was higher for Whites (60.2%) and Asians (61.0%) than for Blacks (57.4%) and Hispanics (59.8%).
  ■ The percentage of patients very willing to exchange medication reminders electronically was higher for Blacks (45.8%) and Hispanics (48.4%) than for Whites (36.4%) and Asians (39.1%).
  ■ The percentage of patients very willing to exchange lab/test results electronically was lower for Blacks (23.8%) than for Whites (33.5%), Asians (40.8%), and Hispanics (42.4%).
  ■ The percentage of patients very willing to exchange diagnostic information (e.g., medical illnesses) electronically was lower for Blacks (19.3%) than for Whites (24.2%), Asians (31.4%), and Hispanics (32.6%).
  ■ The percentage of patients very willing to exchange vital signs (e.g., heart rate, blood pressure, glucose levels) electronically was lower for Blacks (29.2%) and Whites (30.9%) than for Asians (38.5%) and Hispanics (34.4%).
  ■ The percentage of patients very willing to exchange lifestyle behaviors (e.g., physical activity, food intake, sleep patterns) electronically was higher for Blacks (28.1%) and Hispanics (30.6%) than for Whites (24.6%).
  ■ The percentage of patients very willing to exchange symptoms (e.g., nausea, pain, dizziness) electronically was higher for Hispanics (36.6%) and Asians (32.6%) than for Blacks (29.3%) and Whites (27.8%).

#### AHRQ Health Care Innovations in Care Coordination

Emory University (https://innovations.ahrq.gov/profiles/care-managers-enhance-access-medical-care-low-income-individuals-severe-mental-illness)

- Population: Low-income individuals with serious and persistent mental illness
- Location: Atlanta, Georgia
- Intervention: Case managers assist patients with severe mental illnesses in accessing needed preventive, primary, and specialty medical services. Between visits care managers monitor patients’ progress, provide additional support, and coordinate with primary care and mental health clinicians.
- Outcomes: Enhanced access to needed preventive primary care and specialty medical services, leading to improved physical and mental health. Also reduced cost of care.

### NQS Priority: Effective Treatment

- Most measures of Effective Treatment tracked in the QDR relate to priorities of the Heckler Report. Here, we illustrate effective treatment of conditions tracked in the QDR that were not priorities in the Heckler Report:
  ■ Chronic kidney diseases
  ■ Musculoskeletal diseases
  ■ Respiratory diseases

#### Nephrologist Visit Before Renal Replacement Therapy

- Importance:
  ■ Early referral to a nephrologist is important for patients with progressive chronic kidney disease who are approaching kidney failure.
  ■ Patients who begin nephrology care more than a year before kidney failure are less likely to begin dialysis with a catheter, experience infections related to vascular access, or die during the months after dialysis initiation (USRDS, 2013).
- Groups With Disparities: From 2009 to 2012, the percentage of end stage renal disease (ESRD) patients who began nephrology care at least 12 months prior to initiation of renal replacement therapy was higher for White and Asian patients than for Black, Native Hawaiian and Other Pacific Islander, and American Indian and Alaska Native patients.

#### Doctor Visits for Chronic Joint Symptoms

- Overall: In 2013, 72% of adults with chronic joint symptoms reported seeing a doctor or other health professional for joint symptoms.
- Trends: There were no statistically significant improvements overall or among any racial group.
- Groups With Disparities:
  ■ In 3 of 5 years, Blacks were more likely than Whites to report seeing a doctor or other health professional for joint symptoms.
  ■ In 3 of 5 years, Asians were less likely than Whites to report seeing a doctor or other health professional for joint symptoms.
  ■ In 2013, uninsured Blacks (55.9%) were less likely than privately insured Blacks (76%) to report seeing a doctor or other health professional for joint symptoms.

#### Completion of Tuberculosis Treatment

- Overall: In 2011, 89.1% patients with tuberculosis completed a curative course of treatment within 1 year of initiation of treatment.
- Trends: From 2008 to 2011, there were improvements overall (84.7% to 89.1%) and among Blacks (86.4% to 90.2%) and Whites (83.6% to 88.9%) in the percentage of patients with tuberculosis who completed a curative course of treatment within 1 year of initiation of treatment.
- Groups With Disparities:
  ■ In 2 of 4 years, Blacks were more likely than Whites to have completed a curative course of treatment within 1 year of initiation.
  ■ In 2011, AI/ANs (79.3%) were less likely than Whites (88.9%) to have completed a curative course of treatment within 1 year of initiation.

#### AHRQ Health Care Innovations in Asthma Care

Blue Cross Blue Shield of Minnesota (https://innovations.ahrq.gov/profiles/culturally-competent-parent-mentors-support-families-minority-children-asthma-leading)

- Population: Black and Latino children between 2 and 18
- Location: Milwaukee, Wisconsin
- Intervention: Parents of Black and Latino asthmatic children are paired with trained, culturally competent parent mentors to help them understand and care for their children’s asthma. Parent mentors conduct home visits, phone parents monthly, and meet monthly with groups of children and their families at community sites to educate and support.
- Outcomes: Improved parents’ ability to recognize when their child’s breathing problems could be controlled at home. Significantly reduced wheezing, asthma exacerbations, missed school and parent work days, and ED visits. Also led to significant cost savings for participants.

### NQS Priority: Healthy Living

#### Well-Child Visits

- Trends:
  ■ Overall, the percentage of children ages 0-17 years who had a well-child visit (as distinct from a symptom-driven visit) in the last 12 months increased from 71% in 2000 to 83% in 2013.
  ■ From 2000 to 2013, the percentage of children who had a well-child visit increased significantly for Whites (71.3% to 83.3%), Blacks (75.4% to 87.8%), and Hispanics (65.3% to 79.0%).
- Groups With Disparities:
  ■ In all years, Hispanic children were less likely than White children to have had a well-child visit.
  ■ In 12 of 14 years, Black children were less likely than White children to have had a well-child visit.

#### Receipt of Vaccinations by Children

#### Receipt of 4:3:1:3:3:1:4 Vaccine Series

- Trends:
  ■ From 2009 to 2013, the percentage of children ages 19-35 months who received the 4:3:1:3:3:1:4 vaccination series improved from 44.3% to 70.4%.
  ■ From 2009 to 2013, the percentage of children who received all recommended vaccinations improved for Blacks (40.0% to 65.1%), Asians (43.1% to 72.8%), multiple-race children (40.6% to 72.4%), and Whites (45.7% to 71.3%).
- Groups With Disparities: In 4 of 5 years, Black children were less likely than White children to receive all recommended vaccines.
- Achievable Benchmark:
  ■ The 2012 top 5 State achievable benchmark was 72%. The top 5 States that contributed to the achievable benchmark are Louisiana, Maryland, Massachusetts, New Hampshire, and Ohio.
  ■ Black children could achieve the benchmark within a year. White children could achieve the benchmark in less than a year. Asian and multiple-race children have already achieved the benchmark.

#### Advice to Adults About Exercise

- Overall Rate: In 2013, overall, 63.5% of adults with obesity had ever received advice from a health provider to exercise more.
- Trends: From 2002 to 2013, the percentage of obese adults who ever received advice from a health provider to exercise more improved for Blacks (from 55.9% to 64.8%).
- Groups With Disparities:
  ■ In 11 of 12 years, there were no statistically significant differences between Whites and Blacks in the percentage of adults with obesity who ever received advice from a health provider to exercise more. In 2012, the percentage of Black adults with obesity who received advice to exercise (62.5%) was higher compared with White adults with obesity (58.2%).
  ■ In 2013, among Black adults with obesity, the percentage who ever received advice from a health provider to exercise more was lower for those without insurance (51.9%) compared with those with private insurance (67.8%).

#### Advice to Adults About Healthy Eating

- Overall Rate: In 2013, overall, 51.3% of adults with obesity had ever received advice from a health provider about eating fewer high-fat or high-cholesterol foods.
- Trends: From 2002 to 2013, the percentage of adults with obesity who ever received advice about healthy eating improved for Blacks (from 46.8% to 49.3%).
- Groups With Disparities:
  ■ There were no statistically significant differences between Whites and Blacks in the percentage of adults with obesity who ever received advice about healthy eating.
  ■ In 2013, among Black adults with obesity, the percentage who ever received advice about healthy eating was lower for those without insurance (35.4%) compared with those with private insurance (51.6%).

#### AHRQ Health Care Innovations in Healthy Eating

University of South Carolina (https://innovations.ahrq.gov/profiles/culturally-tailored-lifestyle-counseling-tied-readiness-change-helps-underserved-african)

- Location: Columbia, South Carolina
- Population: Black women
- Intervention: Using culturally tailored materials and techniques, primary care physicians and nurses engage patients in motivational counseling and goal setting. Health educators provide additional support and counseling during monthly calls.
- Outcomes: Reduced dietary fat intake and increased leisure time physical activity.

#### Pneumococcal and Influenza Immunization

- Importance: Hospitals are important sites for ensuring that people receive needed immunizations, including pneumococcal and influenza immunizations.
- Pneumococcal Immunization:
  ■ Overall Rate: In 2013, 92.2% of hospital patients received pneumococcal immunization.
  ■ Groups With Disparities: In both years, the percentage of hospital patients who received pneumococcal immunization was lower among Blacks, Asians, and AI/ANs compared with Whites.
  ■ Achievable Benchmark: The 2012 top 5 State achievable benchmark was 93%. The top 5 States that contributed to the achievable benchmark are Delaware, Florida, Ohio, South Carolina, and West Virginia. All groups were below the benchmark.
- Influenza Immunization:
  ■ Overall Rate: In 2013, 92.2% of hospital patients received influenza immunization.
  ■ Groups With Disparities: In both years, the percentage of hospital patients who received pneumococcal immunization was lower among Blacks, Asians, and AI/ANs compared with Whites.
  ■ Achievable Benchmark: The 2012 top 5 State achievable benchmark was 93%. The top 5 States that contributed to the achievable benchmark are Delaware, Maryland, New Hampshire, South Carolina, and West Virginia. All groups were below the benchmark except for Whites are close to the benchmark.

#### Improvement in Mobility Among Home Health Patients

- Importance: Many patients who receive home health care are recovering from an injury or illness and may have difficulty walking or moving around safely. Maintaining and improving functional status, such as patients’ ability to ambulate, improves quality of life and allows them to stay at home as long as possible. Getting better at walking or moving around may be a sign that their health is improving.
- Overall Rate: In 2013, 61.8% of home health patients showed improvement in walking or moving around.
- Trends: From 2010 to 2013, the percentage of adult home health patients whose ability to move or walk around improved overall and for all racial groups.
- Groups With Disparities: From 2011 to 2013, White home health patients were more likely than Black and AI/AN home health patients to get better at walking or moving around.
- Achievable Benchmark:
  ■ The 2010 top 5 State achievable benchmark was 62.5%. The top 5 States that contributed to the achievable benchmark are Maine, Missouri, New Jersey, South Carolina, and Utah.
  ■ Whites have already achieved the benchmark. At current rates of improvement, the overall, multiple-race, and Asian rates could reach the benchmark within a year. The other racial groups could reach the benchmark within 2 years.

#### Shortness of Breath in Home Health Patients

- Importance: Many patients who receive home health care are recovering from an injury or illness and may have difficulty walking or moving around safely. Maintaining and improving functional status, such as patients’ ability to ambulate, improves quality of life and allows them to stay at home as long as possible. Shortness of breath interferes with activities such as walking and is an important health status indicator.
- Overall Rate: In 2013, 65.0% of home health patients had less shortness of breath.
- Trends: From 2010 to 2013, the percentage of adult home health patients whose episodes of shortness of breath decreased improved overall and for AI/ANs, Blacks, and Whites.
- Groups With Disparities: In 2 of 4 years, AI/ANs were less likely than Whites to show improvement in shortness of breath.
- Achievable Benchmark:
  ■ The 2010 top 5 State achievable benchmark was 71%. The top 5 States that contributed to the achievable benchmark are District of Columbia, Hawaii, Maryland, New Jersey, and South Carolina.
  ■ At current rates of improvement, the overall rate could reach the benchmark in 6 years and the racial groups could achieve the benchmark within 9 years.

#### Management of Oral Medications by Home Health Patients

- Importance: Patients who have problems taking their medications as prescribed are at risk for adverse outcomes, including lack of improvement, worsening of disease, serious side effects, and death.
- Overall Rate: In 2013, 52.5% of Black home health patients got better at taking their medications.
- Groups With Disparities: In 2013, Black home health patients in age groups 75-84 (49.8%) and 85 and over (39.8%) were less likely than those ages 0-64 (58.5%) to get better at taking their medications.

### NQS Priority: Care Affordability

#### Lack of Usual Source of Care Due to Cost

- Importance: High-quality health care is facilitated by having a regular provider, but some Americans may not be able to afford one.
- Overall Rate: In 2013, 24% of people without a usual source of care indicated a financial or insurance reason for not having a source of care.
- Trends: The percentage worsened overall (15.6% to 24%) and among Blacks (13.1% to 25.8%) and Whites (15.9% to 24.5%).
- Groups With Disparities: In 2013, the percentage of people without a usual source of care who indicated a financial or insurance reason for not having a source of care was higher among uninsured Blacks (48.8%) compared with Blacks with private insurance (13.1%).

#### AHRQ Health Care Innovations in Reducing Costs

Methodist Le Bonheur Healthcare (https://innovations.ahrq.gov/profiles/church-health-system-partnership-facilitates-transitions-hospital-home-urban-low-income)

- Location: Memphis, Tennessee
- Intervention: The Congregational Health Network, a partnership between Methodist Le Bonheur Healthcare and 512 congregations in Memphis, supports the transition from hospital to home for church members. A hospital-employed navigator visits the patient to determine his or her needs and then works with a church-based volunteer liaison to arrange postdischarge services and facilitate the transition to the community.
- Outcomes: Reduced mortality, health care costs and charges, inpatient utilization, readmission rates, and time to readmission. Increased referrals to home health and hospice care and improved satisfaction with hospital care.

## References

Field M, Cassell C, eds. Approaching death: improving care at the end of life. Washington, DC: National Academy Press; 1997. http://www.nap.edu/catalog/5801/approaching-death-improving-care-at-the-end-of-life. Accessed February 9, 2016.
Hwang W, Weller W, Ireys H, . Out-of-pocket medical spending for care of chronic conditions. Health Aff 2001;20(6):267–78. http://content.healthaffairs.org/content/20/6/267.long. Accessed February 9, 2016.
U.S. Renal Data System. USRDS 2013 annual data report: atlas of chronic kidney disease and end-stage renal disease in the United States. Bethesda, MD: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases; 2013. http://www.usrds.org/atlas.aspx. Accessed September 19, 2013.