# PART 2 TRENDS IN PRIORITIES OF THE HECKLER REPORT

## Report of the Secretary’s Task Force on Black and Minority Health (Heckler Report)

The year 2015 marked the 30th anniversary of the Report of the Secretary’s Task Force on Black and Minority Health (also known as the Heckler Report), released in 1985 under the leadership of then U.S. Department of Health and Human Services (HHS) Secretary Margaret M. Heckler. The landmark report marked the first convening of a group of health experts by the U.S. government to conduct a comprehensive study of racial and ethnic minority health and elevated minority health onto a national stage.

heckler.PNG

The Heckler Report documented persistent health disparities that accounted for 60,000 excess deaths each year and synthesized ways to advance health equity. This marked the beginning of a new era in addressing minority health issues, beginning with the creation of the HHS Office of Minority Health in 1986 and leading up to the Affordable Care Act in 2010.

## Black Population Before and After Heckler Report (Census Years 1980 and 2010)

- Census data on race:
  ■ Collected for more than two centuries
  ■ Did not include ethnic groups until the 1970s
  ■ Was not precisely defined for non-Whites
  ■ Was self-reported in 1980 and 2010
- Office of Management and Budget racial groups:
  ■ Defined five categories in 1997:
    ◆ White
    ◆ Black or African American
    ◆ American Indian or Alaska Native
    ◆ Asian
    ◆ Native Hawaiian
  ■ Added sixth category (Some Other Race) in 2010 and allowed people to identify more than one race
- Question 6 of the 2010 Census regarding race had 15 different choices and respondents could identify one or more choice.
- Historically, there has been undercounting of the population in key geographic areas, particularly those with increased minority representation.
- Data from the 1980 and 2010 Census were used whenever possible for this section; data from the Current Population Survey were used to depict a more updated view of the population within these time periods (1985 and 2015) and are so noted.

### U.S. Black Population, 1980 vs. 2010

| 1980 | 2010
Total population (millions) | 26.5 | 38.9 (42.0)
Percentage of total population | 11.7 | 12.6 (13.6)
Urban vs. rural (% of total) | 13.5 vs 6.6 | 28.1 vs. 8.2
Regional Distribution (%)
South | 53 | 56.5 (55.0)
Midwest | 20 | 17.9 (18.1)
Northeast | 18 | 16.8 (17.1)
West | 9 | 8.8 (9.8)

2010 Source: The Black population: 2010. 2010 Census Briefs. Suitland, MD: U.S. Census Bureau; September 2011 ; for urban/rural data: Race & ethnicity in rural America. Rural Research Brief. Washington, DC: Housing Assistance Council; April 2012. http://www.ruralhome.org/storage/research_notes/rrn-race-and-ethnicity-web.pdf

1980 Source: Demographic trends in the 20^th^ century. Suitland, MD: U.S. Census Bureau; November 2002 ; for urban/rural data: 1980 Census of Populations. Table 37. Summary of General Characteristics: 1980. U.S. Census Bureau. http://www2.census.gov/prod2/decennial/documents/1980/1980censusofpopu8011u_bw.pdf

- African Americans or Blacks in the United States have undergone different definitions as a racial/ethnic minority. Census data represent the most reliable and consistent data available; however, methods and definitions of race, poverty, environment, and other categories have changed over time. These different definitions make comparison of data challenging. Information on all populations is provided in certain areas to best show how the African American population is being affected.
- Total population data used were “Black only” reported in the 1980 census. For the 2010 data, the first number represents “Black only” and the number in parentheses represents Black alone or in combination with another race.
- According to the 1980 census definition, the urban population comprises all persons living in places of 2,500 or more inhabitants incorporated as cities, villages, boroughs (except in Alaska and New York), and towns (except in the New England States, New York, and Wisconsin).

### Geographic Distribution of the U.S. Black Population

Top 10 States With Largest Number of Blacks | | Top 10 States With Largest Percentage of Blacks
1980 | 2010 | 1980 | 2010
New York | New York | District of Columbia | District of Columbia
California | Florida | Mississippi | Mississippi
Illinois | Texas | Louisiana | Louisiana
Georgia | Georgia | South Carolina | Georgia
Texas | California | Georgia | Maryland
Florida | North Carolina | Maryland | South Carolina
Louisiana | Illinois | Alabama | Alabama
North Carolina | Maryland | North Carolina | North Carolina
Michigan | Virginia | Virginia | Delaware
Ohio | Louisiana | Delaware | Virginia

Source: Bureau of the Census. 1980 Census of population. Volume 1. Characteristics of the population. Chapter B. General population characteristics. Part 1. United States summary. Washington, DC: Government Printing Office; May 1983. Publication No. PC80-1-B1. http://www2.census.gov/prod2/decennial/documents/1980/1980censusofpopu8011u_bw.pdf ; Rastogi S, Johnson Td, Hoeffel EM, . The Black population: 2010. 2010 Census Briefs. Suitland, MD: U.S. Census Bureau; September 2011. Publication No. C2010BR-06. https://www.census.gov/prod/cen2010/briefs/c2010br-06.pdf

- According to the U.S. Census Bureau, Blacks live throughout the country, with the highest concentration in the South (about 55%). In 2010, the District of Columbia had the largest percentage of Blacks (51%), and Mississippi was second with 37%. New York had the largest number of Black residents (3.1 million) although States in the South had a higher percentage of Blacks.
- According to a report by the University of South Carolina (Probst, et al., 2002):
  ■ Seventy percent of poor Blacks in nonmetropolitan areas live in Mississippi, Georgia, North Carolina, Louisiana, Alabama, and South Carolina.
  ■ “Rural poverty affects both individuals and communities. The proportion of poor persons is higher among minority populations, and total community economic resources are more constrained in communities where minority groups represent over half of the population.”
  ■ Thirty-four percent of the nonmetropolitan Black population is poor compared with 13% of the nonmetropolitan White population.
  ■ In nonmetropolitan counties where the majority of the population is Black, the average total county income is 67% of the national value, and bank deposits average 56% of the value for majority White counties.

### U.S. Black Population by Selected Characteristics, 1980 and 2010

| 1980 | 2010
Age (U.S. Census Bureau, 1983 and 2011)
Median Age | 24.9 years | 31.4 years
Under 18 | 35.4% | 29.4%
18-64 | 56.8% | 62.0%
65+ | 7.8% | 8.6%
Life Expectancy (Arias, 2015)
Total | 68.1 | 75.1
Male | 63.8 | 71.8
Female | 72.5 | 78.0
Family Composition (U.S. Census Bureau, 1981; Lofquist, et al., 2012)
Married Couples | 56% | 28.5%
Female Head of Household | 40% | 30.1%
Income (U.S. Census Bureau, 1982; DeNavas-Walt & Proctor, 2015)
Median Household Income | $10,674 (29,455) | $34,882
Mean Household Income | $13,970 (38,228) | $48,817
% Below Federal Poverty Level | 32.5 (all races, 13) | 27.4 (all races, 15)
Business Ownership (Peters, 1987; U.S. Census Bureau, 2007)
Business Ownership | 1.2% | 7.0%
Education (U.S. Census Bureau, 1999 and 2012)
High School Graduate | 51.2% (age 25+) | 82%
College Graduate | 8.4% (age 25+) | 18.0%

- The percentage of female head of household with children under 18 years at home has increased for all races since the 1950s. Blacks had the largest increase from the 1950s to the present.
- Between 1970 and 1980 the percentage of Black women maintaining a household more than doubled. In 1980, women first became eligible to be identified as “householder of a married couple household”; since then, they have “…represented an increasing proportion of all married couple householders for every race and Hispanic origin since 1980” (Hobbs & Stoops, 2002).
- In 1950, 78% of Black families were married couples, compared with 56% in 1980 and 28.5% in 2010. In 2010, the percentage of Black families maintained by a single female was 30%. In 2010, nonfamily households represented 35% of Black households. Unmarried couple households (opposite and same sex) could be family or nonfamily, depending on the relationship of others in the household; these represented 7% of Black households.
- Blacks’ median income is under the level of all other racial and ethnic groups, including Whites, Asian, and Hispanics.
- From 1960 to the present, Black-owned businesses have transitioned from predominantly small personal service types (e.g., beauty salons, barber shops) to industrial types. The business ownership rate for Blacks has been lower than for other racial and ethnic groups. For example, in 1982, Blacks owned 12.1 firms per thousand, compared to 62.9 for Whites, 28.6 for Asians and 19.5 for Hispanics (Peters, 1987). In 2007, 7% of U.S. firms were owned by Blacks, and 1.9% of U.S. firms with employees were owned by Blacks (U.S. Census Bureau, 2007).
- “[B]usinesses owned by disadvantaged minorities tend to be smaller and less successful than non-minority-owned businesses.” (Fairlie & Robb, 2008).

### Health of the Black Population in the United States

Relative Risks and/or Prevalence
1980 | 2010
Hypertension | Hypertension
Diabetes | Overweight and obesity
Anemia | Diabetes
Tuberculosis | Complications during perinatal period
Homicide | Asthma
Heart disease | HIV/AIDS
Low birth weight | Periodontitis
Top 10 Causes of Mortality in Blacks
1980 | 2010
Diseases of the heart | Diseases of the heart
Malignant neoplasm | Malignant neoplasm
Cerebrovascular diseases | Cerebrovascular diseases
Unintentional injuries | Diabetes mellitus
Homicide | Unintentional injuries
Diseases originating in perinatal period | Nephritis, nephrotic syndrome, and nephrosis
Pneumonia and influenza | Chronic lower respiratory diseases
Diabetes mellitus | Homicide
Chronic liver disease and cirrhosis | Septicemia
Nephritis, nephrotic syndrome, and nephrosis | Alzheimer’s disease

- A 2002 South Carolina University report indicated that “84% of counties where African Americans are the majority of the population are HPSA’s [Health Professions Shortage Areas]” (Probst, 2002). The 1985 Heckler report indicated, “Relative risks for specific causes of death… are disturbingly high among Blacks compared to the White populations…Relative risk does not indicate the largest numbers of deaths; rather, it reflects the comparative likelihood of dying from a particular cause.” For Blacks, tuberculosis, hypertension, homicide, and anemia were among the top life-limiting conditions. Diabetes was also identified as a reason for increased morbidity among Blacks in the 1980s.
- In the early 1980s, HIV/AIDS was not well identified or diagnosed. In the 21st century, it had high prevalence and is the 11th or 12th (depending on gender and age) leading cause of death among Blacks. In 2010, 49% of all HIV-related death were among Blacks. In the United States in 2011, the diagnosis rate of HIV/AIDS was 15.8 per 100,000, but among Blacks this rate was 60.4. Of total HIV diagnoses made between 2008 and 2011, Blacks made up 47% of the total, 64% of women, 66% of infections documented as heterosexual contact, and 67% of children under age 13 years. Blacks diagnosed with HIV are less likely to be linked to care, remain in care, or receive adequate treatment (CDC, 2014).

### Historic Events Before and After the Heckler Report

##### Major Accomplishments, Challenges, Significant Moments in History Prior to Heckler Report

- Blood bank invention by a Black physician, surgeon, and medical researcher
- 1961 – Affirmative Action. Executive Order 10925 by President Kennedy to ensure contractors are treated equally, without regard to race, creed, color, or national origin
- 1965 – Executive Order 11246 by President Johnson to prevent discrimination by organizations receiving Federal funding
- 1965 – Passage of Civil Rights legislation ending segregation
- 1967 – First Black Supreme Court Justice appointed by President Johnson.
- U.S. Congress – More than 50 Blacks elected to the U.S. House of Representatives and 3 elected to the Senate

##### Major Accomplishments, Challenges, Significant Moments in History After Heckler Report

- More than 100 additional Blacks have been elected to Congress, including 6 Senators, among them the first female Black Senator, elected in 1993 (remaining members were elected to the House of Representatives).
- 1992 – First Black woman to travel in space was an American physician and NASA astronaut.
- 2008 – First Black President of the United States was elected.
- Healthy People 2010 and 2020 reported gaps in health for Blacks, which persist and in some cases widen.
- 2010 – Affordable Care Act was passed, providing health insurance to many people not previously insured, including a large percentage of Blacks.

- Blacks in the United States, including slaves, descendants of slaves, and other immigrants have been an integral part of America’s history. They have been scientists, educators, laborers, and leaders; they have been part of every major event or era in America’s history.
- After the Emancipation Proclamation by President Lincoln, they have also been essential to the U.S. government. Since the 41^st^ Congress in 1869, there has been Black representation in Congress, mostly in the House of Representatives.
- Three Senators were elected in the period before the Heckler report, and six Senators have been elected since. The first Black female Senator was elected for the 103^rd^ Congress in 1993.
- Several Black Supreme Court Justices have been appointed, the first by President Johnson in 1967, the Court’s 96^th^ Justice. Another Black Justice was appointed in 1991.
- The first Black President was elected in 2008.

## Priorities of the Heckler Report

- The Heckler Report found that six causes of death accounted for more than 80% of mortality among Blacks and other minority groups compared with Whites. These include cancer; cardiovascular disease and stroke; chemical dependency (measured by deaths due to cirrhosis); diabetes; homicide and accidents (unintentional injuries); and infant mortality. Based on the findings, the report outlined recommendations in areas of urgent need, including health information and education; health services delivery and financing; health professions development; data development; and research agenda.
- Data on “other minorities,” including Hispanics:
  ■ Was very limited in the 1980s.
  ■ Is much more available today.
- With the rapidly increasing diversity of the Nation and persistence of health disparities, the Heckler Report 30th anniversary serves as a call for all Americans to take action and accelerate efforts toward ending health disparities and achieving health equity in their community.

## Progress on Priorities of the Heckler Report for Blacks

Priority | Trends | Most Recent Disparity | Disparity Change
Care for Cancer | 71% Improving | 50% Worse | 67% Narrowing
Care for Cardiovascular Diseases | 78% Improving | 33% Worse | No Change
Care for Substance Use Disorders | No Improvement | No Disparity | No Change
Care for Diabetes | 25% Improving | 78% Worse | 67% Narrowing
Suicide Prevention and Mental Health Care | 33% Worsening | 75% Worse | No Change
Infant Mortality and Maternity Care | 100% Improving | 33% Better | No Change

- Trends:
  ■ All measures for infant mortality and maternity care and most measures of care for cancer and care for cardiovascular diseases were improving for Blacks.
  ■ No measures of care for substance use disorders were improving and suicide prevention seemed to be getting worse for Blacks.
- Groups With Disparities:
  ■ For many measures of care for mental health disorders, diabetes, and infant mortality, Blacks received worse quality of care than Whites. Blacks tended to receive better quality of maternity care.
  ■ Of measures for which Blacks received worse quality of care than Whites, narrowing of the gap was observed for several measures of cancer and diabetes care. No narrowing of disparities was observed among measures of cardiovascular and mental health care.
- Summary: Of priorities in the Heckler Report:
  ■ Suicide prevention and mental health care for Blacks is worsening, with many disparities and no reductions in disparities over time.
  ■ Blacks also experience many disparities in care for diabetes.
  ■ Care for substance use disorders is poor for all ethnic groups.

## Care for Cancer

- Thirty years ago, the Heckler Report found that:
  ■ Overall age-adjusted cancer incidence rates for Blacks were higher than for Whites or minorities. Specific sites of excess incidence among Blacks were the stomach, prostate, esophagus, pancreas, and cervix.
  ■ The overall 5-year relative survival rate of Blacks was lower than that of Whites.
- In addition, quality care for cancer has changed. Evidence-based mass screening is recommended in specific populations for four cancers: breast, cervical, colorectal, and lung cancer. Screening is the first step in the process of cancer prevention (Pap testing for cervical and colonoscopy for colorectal) and early detection (mammography for breast and CT scan for lung) in the process of cancer control. Thus, cancers amenable to screening are included in this chartbook.

### Breast Cancer Care for Blacks

Measure | Most Recent Disparity | Disparity Change
Women ages 50-74 who received a mammogram in the last 2 years | Same | No Change
Breast cancer diagnosed at advanced stage per 100,000 women age 40+ | Worse | Growing
Women with clinical Stage I-IIb breast cancer who received axillary node dissection or sentinel lymph node biopsy at the time of surgery | Same | No Change
Women under age 70 treated for breast cancer with breast-conserving surgery who received radiation therapy to the breast within 1 year of diagnosis | Same | Narrowing
Breast cancer deaths per 100,000 female population per year | Worse | No Change

- Trends: Most measures of breast cancer care for Blacks were improving.
- Groups With Disparities:
  ■ Rates of mammography were similar between Black and White women. This disparity did not change over time.
  ■ Rates of diagnosis with advanced stage breast cancer were worse for Blacks compared with Whites and these disparities worsened over time.
  ■ Rates of women with clinical Stage I-IIb breast cancer who received axillary node dissection at time of surgery were similar between Black and White women. This disparity did not change over time.
  ■ Rates of women who received radiation therapy after breast-conserving surgery were similar between Black and White women, and this disparity narrowed over time.
  ■ Breast cancer death rates were worse for Blacks compared with Whites. This disparity did not change over time.

#### Breast Cancer Surgery and Radiation

- Importance: Radiation therapy after breast-conserving surgery reduces the risk of cancer recurrence and death.
- Trends: From 2004 to 2011, the percentage of women with breast-conserving surgery who received radiation therapy to the breast improved overall and for Blacks and Hispanics.
- Groups With Disparities:
  ■ In 7 of 9 years, Black and Hispanic women were less likely to receive radiation therapy to the breast compared with White women.
  ■ In 2012, Black women with public insurance (80.3%) were less likely than those with private insurance (85.3%) to receive radiation therapy to the breast.
- Achievable Benchmark:
  ■ The 2008 top 5 State achievable benchmark was 95%. The top 5 States that contributed to the achievable benchmark are Kansas, Minnesota, Montana, New Hampshire, and Wisconsin.
  ■ At the current rates of improvement, the benchmark could be achieved overall within 9 years.
  ■ At the current rates of improvement, Blacks and Hispanics would need 11 and 12 years, respectively, to reach the benchmark. Whites are moving away from the benchmark.

### Colorectal Cancer Care for Blacks

Measure | Most Recent Disparity | Disparity Change
Men and women ages 50-75 who report that they had a blood stool test in the past year, sigmoidoscopy in the past 5 years and blood stool test in the past 3 years, or colonoscopy in the past 10 years | Same | No Change
Colorectal cancer diagnosed at advanced stage per 100,000 men and women age 50 and over | Worse | No Change
Patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined | Worse | No Change
Colorectal cancer deaths per 100,000 population per year | Worse | No Change

- Trends: All measures of colorectal cancer care for Blacks were improving.
- Groups With Disparities:
  ■ Rates for colorectal cancer screening were similar between Blacks and Whites. This disparity did not change over time.
  ■ Rates of diagnosis with advanced stage colorectal cancer, surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined, and deaths due to colorectal cancer were worse for Blacks compared with Whites. These disparities were not changing over time.

#### Colorectal Cancer Screening

- Importance: Screening can detect abnormal colorectal growths before they develop into cancer. Early detection increases treatment options and the chances for cure. Effective screening modalities include fecal occult blood testing (FOBT), FOBT with flexible sigmoidoscopy, and colonoscopy.
- Trends: From 2000 to 2013, the percentage of adults ages 50-75 who received appropriate colorectal cancer screening increased overall (from 34.1% to 58.2%) and among all racial/ethnic groups.
- Groups With Disparities:
  ■ In 5 of 6 years, the percentage of adults who received appropriate colorectal cancer screening was lower among Asians compared with Whites.
  ■ In 3 of 6 years, the percentage of adults who received appropriate colorectal cancer screening was lower among Blacks compared with Whites.
  ■ In 2013, the percentage of adults who received appropriate colorectal cancer screening was lower among poor (47.6%), low-income (51.5%), and middle income (61.7%) Blacks compared with high-income Blacks (71.6%).

#### Surgical Resection of Colon Cancer

- Importance: Recommended cancer treatment depends on different factors, such as the stage or extent of the cancer within the body, especially whether the disease has spread from the original site to other parts of the body. Colon cancer typically begins as a benign polyp that may become cancerous and then spread to local lymph nodes. Hence, ensuring adequate examination of lymph nodes when surgery is performed is important.
- Trends: From 2004 to 2012, the percentage of patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined improved overall (55.4% to 88.2%) and for all racial/ethnic groups.
- Groups With Disparities:
  ■ From 2004 to 2012, there were almost no statistically significant differences between racial/ethnic groups in the percentage of patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined. In 2 years, Blacks were less likely than Whites to receive surgery, and in 1 year, Hispanics were less likely than Whites to receive surgery.
  ■ In 2012, the percentage of patients with colon cancer who received surgical resection of colon cancer that included at least 12 lymph nodes pathologically examined was lower among poor (87.7%) and low-income (86.5%) Blacks compared with high-income Blacks (96.6%).
- Achievable Benchmark:
  ■ The 2008 top 5 State achievable benchmark was 90%. The top 5 States that contributed to the achievable benchmark are Delaware, Missouri, Utah, Vermont, and Wisconsin.
  ■ At the current rates of improvement, the achievable benchmark could be attained overall and for all racial/ethnic groups within a year.

### Other Cancer Care for Blacks

Measure | Most Recent Disparity | Disparity Change
All cancer deaths per 100,000 population per year | Worse | No Change
Women ages 21-65 who received a Pap smear in the last 3 years | Same | No Change
Invasive cervical cancer incidence per 100,000 women age 20 and over | Worse | Narrowing
Men age 75+ without prostate cancer who had a PSA test or digital rectal exam for prostate cancer screening within the past year | Same | No Change
Lung cancer deaths per 100,000 population per year | Same | No Change

- Trends: Most measures of other cancer care for Blacks were improving.
- Groups With Disparities:
  ■ Death rates were higher among Blacks compared with Whites and were not changing over time.
  ■ Blacks were more likely to develop invasive cervical cancer compared with Whites. This disparity was narrowing over time.
  ■ Rates among Blacks and Whites were similar for Pap smears, prostate cancer screening, and lung cancer deaths and these disparities were not changing over time.

#### Pap Smears

- Importance: Screening with Pap smears can detect high-grade precancerous cervical lesions that can be removed before they become cancerous.
- Trends: From 2000 to 2013, the percentage of women ages 21-65 who received a Pap smear in the last 3 years decreased overall (87.5% to 80.7%) and for Whites (88.1% to 81.4%) and Blacks (90.3% to 82.2%).
- Groups With Disparities:
  ■ In all years, the percentage of women who received a Pap smear was lower among Asian women compared with White women. The disparities between Asians and American Indians/Alaska Natives (AI/ANs) and Whites are narrowing. This is due to a decline in the White rates.
  ■ In 2013, uninsured Black women (65.8%) were less likely to receive a Pap smear compared with Black women with private insurance (88.2%).
- Achievable Benchmark:
  ■ The 2008 top 5 State achievable benchmark was 90%. The top 5 States that contributed to the achievable benchmark are Delaware, District of Columbia, Massachusetts, Rhode Island, and Vermont.
  ■ The total and all racial/ethnic groups except AI/ANs are moving away from the achievable benchmark. AI/ANs could achieve the benchmark, although it would take 22 years.

### AHRQ Health Care Innovations in Cancer Screening

Contra Costa Breast Cancer Partnership (https://innovations.ahrq.gov/profiles/countywide-partnership-promotes-culturally-appropriate-outreach-and-education-leading)

- Location: Contra Costa County, California
- Population: Low-income minority women, particularly Black women, age 40 and over
- Intervention: Contra Costa Breast Cancer Partnership aimed to reduce disparities in breast cancer-related health outcomes by developing culturally appropriate outreach and education designed to reduce the stigma surrounding breast cancer, encourage screening, and secure access to affordable treatment.
- Outcomes: Enhanced access to breast cancer screening and earlier detection of breast cancer among Black and Hispanic women.

## Care for Cardiovascular Diseases

- Thirty years ago, the Heckler Report found that:
  ■ Cardiovascular disease (CVD) was a major cause of death in Blacks, and the rate was higher than in Whites.
  ■ There appeared to be a strong inverse relationship between socioeconomic status (SES) and hypertension in Blacks, similar to that found for Hispanics and Whites.
  ■ Diabetes mellitus was a major problem in Blacks.
  ■ The generally higher prevalence of obesity, noninsulin-dependent diabetes, hypertension, high low-density lipoprotein (LDL) cholesterol and low high-density lipoprotein (HDL) cholesterol levels in Blacks might be expected to increase their CVD risk.

### Cardiovascular Care for Blacks

Measure | Most Recent Disparity | Disparity Change
Adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high | Same | No Change
Adult admissions for hypertension | Same | No Change
Adult admissions for angina without cardiac procedure | Worse | No Change
Adult admissions for congestive heart failure | Worse | No Change
Hospital patients with heart attack given fibrinolytic medication within 30 minutes of arrival | Same | No Change

- Trends: Most measures of cardiovascular care for Blacks were improving.
- Groups With Disparities:
  ■ The rates between Blacks and Whites were similar for those who received their blood pressure measurement and for hypertension admissions. These disparities did not change over time.
  ■ Blacks had higher rates of admission than Whites for angina and congestive heart failure and these disparities did not change over time.
  ■ Blacks and Whites had similar rates of receipt of fibrinolytic medication for heart attack and these disparities did not change over time.

#### Blood Pressure Measurement

- Importance: Early detection and treatment of high blood pressure can prevent heart failure, kidney failure, and stroke. Because high blood pressure typically causes no symptoms, screening is essential.
- Trends: From 1998 to 2012, the percentage of adults who received a blood pressure measurement in the last 2 years and can state whether their blood pressure was normal or high did not change overall or for any racial/ethnic group.
- Groups With Disparities:
  ■ In 2 of 4 years, Black adults were more likely than Whites to receive a blood pressure measurement. In 2 of 4 years, Asian adults were less likely than Whites to receive a blood pressure measurement.
  ■ In 2012, uninsured Black adults (81.5%) were less likely than Black adults with private insurance (93.9%) to receive a blood pressure measurement.

#### Admissions for Congestive Heart Failure

- Importance: Racial disparities in care for congestive heart failure have been observed.
- Trends: From 2002 to 2013, the rate of admission for congestive heart failure among adults decreased significantly for all racial/ethnic groups.
- Groups With Disparities:
  ■ In all years, compared with Whites, Blacks had higher rates of admission for congestive heart failure. In 10 of 12 years, the rates of admission for congestive heart failure were higher among Hispanics compared with Whites.
  ■ In 2013, poor (851.1 per 100,000) and low-income (707.0 per 100,000) Black adults had higher rates of admission for congestive heart failure compared with Black adults with high income (544.7 per 100,000).
- Achievable Benchmark:
  ■ The 2008 top 4 State achievable benchmark for adult congestive heart failure admissions was 182 admissions per 100,000 population. The top 4 States that contributed to the achievable benchmark are Colorado, Utah, Vermont, and Wyoming.
  ■ At current rates of improvement, it would take the overall rate 10 years to achieve the benchmark, Blacks could achieve the benchmark in 15 years, Whites could achieve it in 7 years, and Hispanics would need 6 years to achieve the benchmark.

#### Heart Attack Patients Given Fibrinolytic Medication

- Importance: Some heart attacks are caused by blood clots. Early actions, such as fibrinolytic medication, may open blockages caused by blood clots, reduce heart muscle damage, and save lives. To be effective, these actions need to be performed quickly after the start of a heart attack.
- Trends: From 2005 to 2013, the percentage of patients who received timely fibrinolytic medication improved overall (27.7% to 51.4%).
- Groups With Disparities: In 6 of 9 years, the percentage of patients who received timely fibrinolytic medication was lower for Blacks than for Whites.

### Outcomes of Cardiovascular Care for Blacks

Measure | Most Recent Disparity | Disparity Change
Deaths per 1,000 hospital admissions with acute myocardial infarction (AMI), age 18+ | Better | No Change
Deaths per 1,000 hospital admissions with congestive heart failure (CHF), age 18+ | Better | No Change
Deaths per 1,000 hospital admissions with abdominal aortic aneurysm repair, age 18+ | Better | Narrowing
Deaths per 1,000 hospital admissions with coronary artery bypass graft, age 40+ | Same | No Change
Deaths per 1,000 hospital admissions with percutaneous transluminal coronary angioplasty, age 40+ | Better | No Change

- Trends: Most measures of cardiovascular-related deaths among Blacks were improving.
- Groups With Disparities:
  ■ The death rates for Blacks were better compared with Whites when hospitalized for:
    ◆ Acute myocardial infarction.
    ◆ Congestive heart failure.
    ◆ Abdominal aortic aneurysm repair.
    ◆ Percutaneous transluminal coronary angioplasty.
  ■ The death rates for Blacks and Whites were similar for hospital admissions with coronary artery bypass graft. This disparity did not change over time.
  ■ The disparities between Blacks and Whites did not change over time for all measures except deaths per 1,000 hospital admissions for abdominal aortic aneurysm repair, which narrowed.

#### Inpatient Deaths Among Adult Admissions With Heart Attack

- Importance: Racial disparities in heart attack care have been observed.
- Trends: From 2001 to 2013, the risk-adjusted inpatient mortality rate for hospital admissions with heart attack decreased significantly overall (data not shown) and for all racial/ethnic groups.
- Groups With Disparities: In 9 of 12 years, Black patients had lower inpatient mortality rates than Whites for hospital admissions with heart attack.
- Achievable Benchmark:
  ■ The 2008 top 4 State achievable benchmark for inpatient heart attack mortality was 48 deaths per 1,000 admissions. By 2012, this benchmark had been attained overall and for all racial/ethnic groups.
  ■ Because the 2008 benchmark was achieved by the total population, a new 2012 top 4 State achievable benchmark was set at 41 deaths per 1,000 admissions. The top 4 States that contributed to the achievable benchmark are Alaska, Arizona, Michigan, and Rhode Island.
  ■ Blacks have already achieved the benchmark. At current rates of improvement, Whites could achieve the benchmark in a year and Hispanics in less than a year.

### AHRQ Health Care Innovations in Cardiovascular Disease

Aetna’s Racial and Ethnic Equality Initiative (https://innovations.ahrq.gov/profiles/culturally-competent-disease-management-improves-self-monitoring-and-blood-pressure-control)

- Population: Black Aetna members
- Location: All 50 States
- Intervention: Disease management program targeting Blacks that combines home blood pressure monitoring with culturally appropriate counseling and education.
- Outcomes: Significantly improved self-monitoring and blood pressure control.

## Care for Substance Use Disorders

- Thirty years ago, the Heckler Report found that:
  ■ Mortality statistics for the United States did not identify Blacks separately, and until 1976, most other common measures of alcohol-related problems such as arrest and hospital discharge rates did not provide a Black identifier. The 1979 National Institute on Alcohol Abuse and Alcoholism National Survey indicated that based on self-reported data, Black American males age 18 and over had higher levels of heavy drinking and higher rates of alcohol-related problems than nonminorities.
  ■ Results from the 1983 single-room occupancy hotels study of drug abuse in New York City suggested that Blacks had higher rates of drug use than Whites for marijuana, cocaine, heroin, and illicit methadone.
  ■ Lung and esophageal cancer morbidity and mortality rates, known to be related to smoking, were lower for Blacks than for Whites.

### Care for Substance Use Disorders for Blacks

Measure | Most Recent Disparity | Disparity Change
People age 12 and over who received any illicit drug or alcohol abuse treatment in the last 12 months | Same | No Change
People age 12 and over who needed treatment for illicit drug use or an alcohol problem and who received such treatment at a specialty facility in the last 12 months | Same | No Change
People age 12 and over treated for substance abuse who completed treatment course | Same | No Change

- Trends: No measure of care for substance use disorders was improving for Blacks.
- Groups With Disparities: Blacks and Whites had similarly low rates of treatment for substance use disorders.

#### Treatment for Illicit Drug Use or Alcohol Problem

- Overall Rate: In 2013, only 10.9% of people age 12 and over who needed treatment for illicit drug use or an alcohol problem received such treatment at a specialty facility in the last 12 months.
- Groups With Disparities: From 2010 to 2013, there were no statistically significant differences by race. In 2013, there was no statistically significant difference between Blacks and Whites at any educational level.
- Achievable Benchmark:
  ■ The 2011 top 6 State achievable benchmark was 15%. The top 6 States that contributed to the achievable benchmark are Alabama, Alaska, Delaware, Maryland, Oregon, and Utah.
  ■ The total population, Blacks, and Whites are making no progress toward the benchmark.

#### Completion of Substance Abuse Treatment

- Overall Rate: In 2011, 43.7% of people age 12 and over treated for substance abuse completed their treatment course.
- Groups With Disparities:
  ■ In 4 of 7 years, Blacks who were treated for substance abuse were significantly less likely than Whites to complete treatment.
  ■ There were no statistically significant differences in treatment completion between Blacks and Whites in the 3 most recent years, 2009-2011.
- Achievable Benchmark:
  ■ The 2008 top 5 State achievable benchmark was 74%. The top 5 States that contributed to the achievable benchmark are Colorado, Connecticut, District of Columbia, Mississippi, and Texas.
  ■ No group showed progress toward the benchmark.

## Care for Diabetes

- Thirty years ago, the Heckler Report found:
  ■ Prevalence of diabetes was 33% higher in the Black population than in the White population. Diabetes prevalence for Black females was 50% greater than for White females.
  ■ Although diabetes accounts for less than 2 percent of male excess deaths and 5 percent of female excess deaths (to age 70), it is a major risk factor for heart disease and leads to other serious consequences, including amputation and blindness, if uncontrolled.

### Diabetes Care for Blacks

Measure | Most Recent Disparity | Disparity Change
Adults age 40 and over with diabetes whose condition was diagnosed | Same | Worse
Adults age 40 and over with diagnosed diabetes who received all four recommended services for diabetes in the calendar year | Worse | No Change
Adults age 40 and over with diagnosed diabetes with hemoglobin A1c under control | Same | Insufficient Data
Adults age 40 and over with diagnosed diabetes with blood pressure under control | Worse | No Change

- Trends: Measures of diabetes care were not improving for Blacks.
- Groups With Disparities:
  ■ After diagnosis, Blacks were less likely than Whites to receive recommended services for diabetes and this disparity was not changing over time.
  ■ Blacks diagnosed with diabetes were less likely than Whites to have their hemoglobin A1c and blood pressure under control and this disparity was not changing over time.

#### Recommended Services for Diabetes

- Importance:
  ■ Regular hemoglobin A1c (HbA1c) tests, foot exams, dilated eye exams, and flu shots help people keep their diabetes under control and avoid diabetic complications.
  ■ A composite measure is used to track the national rate of receipt of all four of these recommended annual diabetes interventions.
- Trends:
  ■ From 2008 to 2013, among adults age 40 and over with diagnosed diabetes, there were no statistically significant improvements overall or among any racial groups.
- Groups With Disparities:
  ■ In 2013, overall, Blacks were less likely than Whites to receive the recommended services. Among adults age 60 and over, Blacks were also less likely than Whites to receive the recommended services.
  ■ In 2013, among Black adults, those ages 40-59 were less likely than those age 60 and over to receive the recommended services (13.7% compared with 22.3%).

#### Written Diabetes Management Plans

- Importance:
  ■ A successful partnership for diabetes care requires providers to educate patients about daily management of their diabetes. Therefore, providers should develop a written diabetes management plan, especially for patients with a history of uncontrolled diabetes.
  ■ National data on diabetes management and outcomes for some underserved populations are not available from the national data sources in the QDR. These populations include people with limited English proficiency; individuals who speak a language other than English at home; and Black subpopulations. To address some of these data gaps, we show additional data from the California Health Interview Survey.
- Overall Rate: Only 43% of Californians with current diabetes had a written diabetes management plan in 2011-2013.
- Groups With Disparities: Among Black Californians with diabetes, those who were poor were less likely than those with middle and high income to have a written diabetes management plan.

#### Adults With Diabetes With Hemoglobin A1c and Blood Pressure Under Control

- Importance: People diagnosed with diabetes are often at higher risk for cardiovascular conditions, such as high blood pressure. Having these conditions in combination with diagnosed diabetes increases the likelihood of complications, such as heart and kidney diseases, blindness, nerve damage, and stroke. Patients who manage their diagnosed diabetes and maintain an HbA1c level <8% and blood pressure <140/80 mm Hg can decrease these risks.
- Overall Rate: In 2011-2012, among adults age 40 and over with diagnosed diabetes, 69.2% achieved HbA1c less than 8% and 68.5% achieved blood pressure less than 140/80 mm Hg.
- Groups With Disparities:
  ■ In 2003-2006, Blacks and Mexican Americans were less likely than Whites to have their HbA1c under control. Differences in 2007-2010 and 2011-2012 were not statistically significant.
  ■ In 2007-2010 and 2011-2012, Blacks were less likely than Whites to have their blood pressure under control.

### Outcomes of Diabetes Care for Blacks

Measure | Most Recent Disparity | Disparity Change
Admissions for uncontrolled diabetes without complications per 100,000 population, age 18 and over | Worse | No Change
Admissions with diabetes with short-term complications per 100,000 population, age 18 and over | Worse | Narrowing
Admissions with diabetes with short-term complications per 100,000 population, ages 6-17 | Worse | No Change
Admissions with diabetes with long-term complications per 100,000 population, age 18 and over | Worse | No Change
Adjusted incident rates of end stage renal disease (ESRD) due to diabetes per million population | Worse | Narrowing

- Trends: Less than half of outcomes of diabetes care for Blacks were improving.
- Groups With Disparities:
  ■ Blacks had higher rates of admission than Whites for uncontrolled diabetes and for long-term complications of diabetes. These disparities did not change over time.
  ■ Black adults had higher rates of admission than Whites for admission for short-term complications of diabetes but the disparity was narrowing over time.
  ■ Black children had higher rates of admission for short-term complications than White children and this disparity was not changing over time.
  ■ Blacks had higher rates of ESRD due to diabetes than Whites and this disparity was narrowing over time.

#### Hospital Admissions for Uncontrolled Diabetes Without Complications

- Importance:
  ■ Individuals who do not achieve good control of their diabetes may develop symptoms that require correction through hospitalization.
  ■ Admission rates for uncontrolled diabetes may be reduced by better outpatient treatment and patients’ tighter adherence to the recommended diet and medication.
- Trends:
  ■ The rate of hospital admissions for uncontrolled diabetes without complications per 100,000 population decreased from 27.2 in 2001 to 15.4 in 2013.
  ■ From 2001 to 2013, the rate of hospital admissions per 100,000 population decreased for all populations:
    ◆ For Blacks, from 88.3 to 45.3.
    ◆ For Whites, from 17.6 to 10.3.
    ◆ For APIs, from 14.2 to 5.9.
    ◆ For Hispanics, from 46.0 to 21.7.
- Groups With Disparities: In all years, the rate of hospital admissions for uncontrolled diabetes was higher for Blacks and Hispanics compared with Whites.
- Achievable Benchmark:
  ■ The 2008 top 4 State achievable benchmark was 5 admissions per 100,000 population age 18 and over. The top 4 States that contributed to the achievable benchmark are Colorado, Hawaii, Utah, and Vermont.
  ■ At the current rate, the benchmark could not be met for the total population for approximately 16 years.
  ■ At the current rates, both Whites and Blacks would need 15 years to reach the benchmark. Hispanics could reach the benchmark in less than 8 years and APIs in less than 3 years.

#### Hospital Admissions for Uncontrolled Diabetes Without Complications, Stratified by Income

- Importance:
  ■ Individuals who do not achieve good control of their diabetes may develop symptoms that require correction through hospitalization.
  ■ Admission rates for uncontrolled diabetes may be reduced by better outpatient treatment and patients’ tighter adherence to the recommended diet and medication.
- Groups With Disparities: The rate of hospital admissions for uncontrolled diabetes was higher for Blacks in the highest income quartile compared with Whites in the lowest income quartile.
- Achievable Benchmark:
  ■ The 2008 top 4 State achievable benchmark was 5 admissions per 100,000 population age 18 and over. The top 4 States that contributed to the achievable benchmark are Colorado, Hawaii, Utah, and Vermont.
  ■ No group has reached the benchmark.

#### New Cases of End Stage Renal Disease Due to Diabetes

- Importance: Diabetes is the most common cause of kidney failure. Keeping blood glucose levels under control can prevent or slow the progression of kidney disease. When kidney disease is detected early, medication can slow the disease’s progress; when detected late, it commonly progresses to end stage renal disease requiring dialysis or kidney transplantation. While some cases of kidney failure due to diabetes cannot be avoided, other cases reflect inadequate control of blood glucose or delayed detection and treatment of early kidney disease due to diabetes.
- Trends: From 2003 to 2013, the overall rate of new cases of ESRD due to diabetes decreased for Blacks.
- Groups With Disparities: In all years, Blacks had higher rates than Whites.
- Achievable Benchmark:
  ■ The 2008 top 5 State achievable benchmark was 90 per million population. The top 5 States that contributed to the achievable benchmark are Alaska, Maine, New Hampshire, Rhode Island, and Vermont.
  ■ At current rates of change, the benchmark would not be achieved overall or by any racial group for decades.

### AHRQ Health Care Innovations in Diabetes Care

Vidant Health (https://innovations.ahrq.gov/profiles/teams-diabetes-educators-regularly-visit-rural-clinics-coach-african-american-patients)

- Population: Low-income, rural Black patients with diabetes
- Location: Eastern North Carolina
- Intervention: Based on a patient-centered medical home model and supported by a common electronic health record and diabetes registry, this intervention features a team of certified diabetes educators who regularly visit clinics to provide comprehensive, culturally tailored patient education during primary care visits.
- Outcomes: Improved glycemic control, lipids, and blood pressure in Black patients with diabetes from medically underserved communities. Also, potentially saves money by reducing inpatient admission and emergency department visits.

## Suicide Prevention and Mental Health Care

### Mental Health Care for Blacks

Measure | Most Recent Disparity | Disparity Change
Adults with a major depressive episode in the last 12 months who received treatment | Same | No Change
Adolescents ages 12-17 with a major depressive episode in the last 12 months who received treatment | Worse | No Change
Suicide deaths per 100,000 population | Better | Narrowing

- Trends: The percentage of adults with major depressive episode who received treatment improved.
- Groups With Disparities:
  ■ The percentage of adults who received treatment for depression was the same for Blacks and Whites and this disparity did not change over time.
  ■ The percentage of adolescents who received treatment for depression was lower for Blacks than for Whites and this disparity did not change over time.
  ■ Blacks had a lower suicide death rate than Whites but this disparity is narrowing as Black suicide deaths increased.

#### Adults Who Received Treatment for Depression

- Importance: The United States Preventive Services Task Force (USPSTF) recommends screening for depression in the general adult population, including pregnant and postpartum women. Screening should be implemented with adequate systems in place to ensure accurate diagnosis, effective treatment, and appropriate followup (USPSTF, 2016).
- Overall Rate: In 2013, 68.6% of adults with a major depressive episode received treatment for depression.
- Groups With Disparities: From 2008 to 2012, Black adults with depression were less likely than White adults to receive treatment. In 2013, this disparity was no longer statistically significant.

#### Adolescents Who Received Treatment for Depression

- Importance:
  ■ Outpatient mental health treatment and psychotropic medication use in children and adolescents increased in the United States between 1996-1998 and 2010-2012. Although youths with less severe or no impairment accounted for most of the absolute increase in service use, youths with more severe impairment had the greatest relative increase in use, yet less than half accessed services in 2010-2012 (Olfson, et al., 2015).
  ■ The United States Preventive Services Task Force (USPSTF) recommends screening of adolescents ages 12-18 years for major depressive disorder when systems are in place to ensure accurate diagnosis, psychotherapy (cognitive-behavioral or interpersonal), and followup (USPSTF, 2015).
- Overall Rate: In 2013, 38.1% of adolescents with a major depressive episode (MDE) received treatment for depression.
- Trends: From 2008 to 2013, there were no statistically significant changes over time overall, for Blacks, or for Whites in the percentage of adolescents receiving treatment for depression.
- Groups With Disparities: In all years except 2011 and 2012, Black adolescents were less likely to receive needed treatment for MDE than Whites. In 2013, 30.8% of Black adolescents with MDE received treatment for depression compared with 40.2% for Whites.

#### Suicide Deaths

- Importance: According to the Centers for Disease Control and Prevention (Xu, et al., 2014), the rate for the top 10 leading causes of death has decreased or held steady, except the 10th leading cause of death in the United States, suicide. Rates of attempted suicide vary considerably among demographic groups. The economic cost of suicide death in the United States was estimated in 2010 to be more than $44 billion annually.
- Overall Rate: In 2013, the overall suicide death rate was 15.2 per 100,000 population age 12 and over.
- Trends: From 2008 to 2013, suicide death rates worsened for the total population, Whites, Asians and Pacific Islanders (APIs), and American Indians and Alaska Natives (AI/ANs), but not for Blacks.
- Groups With Disparities:
  ■ From 2008 to 2013, Blacks, APIs, and AI/ANs had lower suicide death rates than Whites.
  ■ In 2013, males had higher suicide death rates compared with females. White females had a higher rate than Black females and White males had a higher rate than Black males.
- Achievable Benchmark:
  ■ The 2008 top 5 State achievable benchmark was 9 suicide deaths per 100,000 population. The top 5 States that contributed to the achievable benchmark are Connecticut, District of Columbia, Massachusetts, New Jersey, and New York.
  ■ APIs and Blacks have achieved the benchmark.
  ■ The total population, AI/ANs, and Whites are moving away from the benchmark.

## Infant Mortality and Maternity Care

- Thirty years ago, the Heckler Report found that:
  ■ A smaller percentage of Black women than White women begin prenatal care in the first trimester of pregnancy (63% versus 76% in 1980), a factor related to the high Black infant mortality rate.
  ■ Although Blacks shared in the decline in infant mortality, a significant disparity remained, with Black rates being essentially twice those of Whites, 20.0 versus 10.5 in 1983.
  ■ Among White babies, 5.6% had low birth weight compared with 12.4% of Black babies.
  ■ After adjusting for education, marital status, trimester of first care, parity, and age, Black women still had twice the risk of low birth weight babies compared with White women.

### Heckler Infant Mortality and Maternity Care Findings

- The neonatal mortality rate for Blacks in 1981 was 13.4 per 1,000 live births, almost twice the rate for Whites (7.1). The postneonatal mortality rate for Blacks was 6.6, almost twice the 3.4 rate for Whites. In 1983, 11,060 Black babies died before 1 year of age.
- Black women are much more likely to have a teenage birth, an out-of-wedlock birth, or a high-parity birth, all of which are more likely to be unintended and associated with adverse perinatal outcomes.
- In 1982, 61% of Black mothers received care in the first trimester compared with 79% of White mothers. Black mothers were twice as likely as White mothers (10% versus 5%) to receive either no care or care beginning in the third trimester of pregnancy.
- It is also possible that there is a biologic role influencing birth weight that gives a different meaning to low birth weight for Blacks than for Whites. This issue deserves research attention. It is clear, unfortunately, that normal weight Black babies have far higher rates of neonatal mortality.

### Maternity Care for Blacks

Measure | Most Recent Disparity | Disparity Change
Live-born infants with low birth weight (less than 2,500 grams) | Worse | No Change
Live-born infants with very low birth weight (less than 1,500 grams) | Worse | No Change
Infant mortality per 1,000 live births (more than 2,499 grams) | Worse | No Change
Birth trauma - injury to newborn per 1,000 live births | Same | No Change
Obstetric trauma per 1,000 vaginal deliveries without instrument assistance | Better | No Change
Obstetric trauma per 1,000 instrument-assisted vaginal deliveries | Better | No Change

- Trends:
  ■ Low birth weight, infant mortality, birth trauma, and obstetric trauma rates were all improving over time.
- Groups With Disparities:
  ■ Blacks had lower rates of obstetric trauma than Whites.
  ■ Blacks had higher rates of low birth weight and infant mortality and these disparities were not changing over time.

#### Live-Born Infants With Low Birth Weight

- Importance: In 2012, Black mothers were 2.3 times as likely as White mothers to delay prenatal care to the third trimester or to not receive prenatal care at all (10.0% compared with 4.3%). Adequate prenatal care can help ensure that babies are born full term and at a healthy weight. Low birth weight can put infants at risk of various complications and death.
- Trends: From 2007 to 2013, the percentage of live-born infants with low birth weight decreased among Blacks but did not change overall or for other racial groups.
- Groups With Disparities:
  ■ In all years, Black infants were more likely than White infants to be low birth weight.
  ■ Among all maternal age groups, Black infants were more likely than White infants to be low birth weight.

#### Live-Born Infants With Very Low Birth Weight

- Trends: From 2007 to 2013, the percentage of live-born infants with very low birth weight decreased overall and among Blacks but did not change among other racial groups.
- Groups With Disparities:
  ■ In all years, Black infants were more likely than White infants to have very low birth weight.
  ■ Among all maternal age groups, Black infants were more likely than White infants to have very low birth weight.

#### Infant Mortality

- Importance:
  ■ Blacks have 2.2 times the infant mortality rate of Whites (Mathews, et al., 2015).
  ■ Black infants (260.7 per 100,000 live births) are 3.5 times as likely to die as White infants (74.4 per 100,000 live births) due to complications related to low birth weight (Mathews, et al., 2015).
  ■ Blacks had more than twice the rate of sudden unexpected infant death as Whites (171.8 compared with 84.4 per 100,000 live births) (CDC, no date).
- Trends:
  ■ From 2003 to 2012, the overall rate decreased from 6.8 per 1,000 live births to 6.0.
  ■ The rate of infant mortality per 1,000 live births decreased overall and among all racial groups.
- Groups With Disparities:
  ■ In all years, mortality was significantly higher among Black infants than White infants.
  ■ In 2012, mortality was significantly higher among Black infants than White infants for all maternal age groups.

#### Birth Trauma

- Trends:
  ■ From 2004 to 2013, birth trauma-neonatal injury rates fell from 2.6 per 1,000 live births in 2004 to 1.9 per 1,000 live births in 2013.
  ■ Between 2004 and 2012, birth trauma-neonatal injury rates fell for all racial/ethnic groups. Blacks decreased from 2.9 in 2004 to 2.0 in 2013.
- Groups With Disparities:
  ■ In 2013, White and Black neonates both experienced an injury rate of 2.0 per 1,000 live births compared with 1.6 per 1,000 live births for Hispanic neonates.

### AHRQ Health Care Innovations in Maternal and Child Health

Baltimore Healthy Start (https://innovations.ahrq.gov/profiles/urban-healthy-start-program-offers-support-each-stage-childbearing-cycle-leading-fewer-low)

- Location: Baltimore, Maryland
- Population: Black women
- Intervention: Baltimore Healthy Start works to reduce infant mortality by offering services for women and their families. Program covers each stage of the childbearing cycle: pregnancy, postpartum period, early childhood, and between pregnancies. Trained staff from the local community reach out to and enroll at-risk residents, assessing their needs, offering relevant education, and connecting enrollees and their families with needed medical and social services.
- Outcomes: Enhanced access to pre- and postnatal services, generated high levels of satisfaction among clients, produced a lower rate of infant mortality, and reduced the percentage of women delivering low- and very low–birth weight babies. This reduction, in turn, led to significant cost savings.

## References

Arias E. United States life tables, 2011. Natl Vital Stat Rep 2015;64(11). http://www.cdc.gov/nchs/data/nvsr/nvsr64/nvsr64_11.pdf
Centers for Disease Control and Prevention. Health Disparities in HIV/AIDS, Viral Hepatitis, STDs, and TB. Last updated March 2014. http://www.cdc.gov/nchhstp/healthdisparities/AfricanAmericans.html
DeNavas-Walt C, Proctor BD. Income and poverty in the United States: 2014. Current Population Reports, P60-252. Washington, DC: U.S. Government Printing Office; 2015. http://www.census.gov/content/dam/Census/library/publications/2015/demo/p60-252.pdf
Fairlie, RW, Robb AM. Policy Brief #12. The causes of racial disparities in business performance. In: Race and entrepreneurial success: Black-, Asian-, and White-owned businesses in the United States. Cambridge, MA: MIT Press; 2008. http://www.npc.umich.edu/publications/policy_briefs/brief12/
Hobbs F, Stoops N, U.S. Census Bureau, Census 2000 Special Reports, Series CENSR-4, Demographic trends in the 20th century, Washington, DC: U.S. Government Printing Office; 2002.
Lofquist D, Lugaila T, O’Connell M, . Households and families: 2010. 2010 Census Briefs. Suitland, MD: U.S. Census Bureau; April 2012. Publication No. C2010BR-14. https://www.census.gov/prod/cen2010/briefs/c2010br-14.pdf
Peters A. Black Business Trends in the United States. Conference on Negritude, Ethnicity and Afro Cultures in the Americas. Miami, FL: Florida International University, 26 February 1987. https://www.sec.gov/news/speech/1987/022687peters.pdf
Probst JC, Samuels ME, Jespersen KP, . Minorities in rural America: an overview of population characteristics. (Prepared under Grant No. 6 U1C RH 00045-01 with the Federal Office of Rural Health Policy, Health Resources and Services Administration). Columbia, SC: South Carolina Rural Health Research Center, Norman J. Arnold School of Public Health, University of South Carolina; 2002. https://sc.edu/study/colleges_schools/public_health/research/research_centers/sc_rural_health_research_center/documents/11aminoritiesinruralamerica2002.pdf
U.S. Bureau of the Census. 1980 Census of population. Volume 1. Characteristics of the population. Chapter B. General population characteristics. Part 1. United States summary. Washington, DC: Government Printing Office; May 1983. Publication No. PC80-1-B1. http://www2.census.gov/prod2/decennial/documents/1980/1980censusofpopu8011u_bw.pdf
U.S. Bureau of the Census. Household and family characteristics: March 1980. Current Population Reports, Series P-20, No. 366. Washington, DC: U.S. Government Printing Office; 1981. https://www.census.gov/library/publications/1981/demo/p20-366.html
U.S. Bureau of the Census. Money income of households, families, and persons in the United States: 1980. Current Population Reports, P60-132. Washington, DC: U.S. Government Printing Office; 1982.
U.S. Census Bureau. 2007 Survey of Business Owners summaries of findings. http://www.census.gov/econ/sbo/getsof.html?07black
U.S. Census Bureau. Current Population Survey, Annual Social and Economic Supplement, 2010. Table 4. Black alone population. Released June 2011. https://www.census.gov/population/age/data/2010comp.html
U.S. Census Bureau. Facts for Features. Black (African-American) History Month: February 2012. Released January 4, 2012. Publication No. CB12-FF.01. https://www.census.gov/newsroom/releases/archives/facts_for_features_special_editions/cb12-ff01.html
U.S. Census Bureau. Statistical abstract of the United States. Released 1999. Section 4. http://www.census.gov/prod/99pubs/99statab/sec04.pdf
Centers for Disease Control and Prevention. Sudden Unexpected Infant Death and Sudden Infant Death Syndrome. Data and Statistics. http://www.cdc.gov/sids/data.htm
Heckler M; Task Force on Black and Minority Health. Report of the Secretary’s Task Force on Black and Minority Health. Washington, DC: U.S. Department of Health and Human Services; 1985. https://collections.nlm.nih.gov/catalog/nlm:nlmuid-8602912-mvset
Mathews TJ, MacDorman MF, Thoma ME. Infant mortality statistics from the 2013 period linked birth/infant death data set. Natl Vital Stat Rep 2015 Aug 6;64(9). http://www.cdc.gov/nchs/data/nvsr/nvsr64/nvsr64_09.pdf
Olfson M, Druss BG, Marcus SC. Trends in mental health care among children and adolescents. New Engl J Med 2015;372(21):2029–38.25992747
U.S. Preventive Services Task Force. Depression in adults: screening. January 2016. http://www.uspreventiveservicestaskforce.org/Page/Document/UpdateSummaryFinal/depression-in-adults-screening1
Xu JQ, Kochanek KD, Murphy SL, . Mortality in the United States, 2012. NCHS Data Brief No. 168. Hyattsville, MD: National Center for Health Statistics; 2014. http://www.cdc.gov/nchs/data/databriefs/db168.pdf