# References

American Cancer Society. Cancer Facts & Figures 2015. Atlanta: American Cancer Society; 2015.
American Foundation for Suicide Prevention. Facts and Figures. https://www.afsp.org/understanding-suicide/facts-and-figures. Accessed August 13, 2015.
American Foundation for Suicide Prevention. Suicide prevention investment needed to reverse trend of increasing suicide. https://www.afsp.org/news-events/in-the-news/suicide-prevention-investment-needed-to-reverse-trend-of-increasing-suicide. Accessed August 13, 2015.
American Geriatrics Society 2012 Beers Criteria Update Expert Panel. American Geriatrics Society updated Beers Criteria for potentially inappropriate medication use in older adults. J Am Geriatr Soc 2012 Apr;60(4):616–31 22376048
Anderson EB. Patient centeredness: a new approach. Nephrol News Issues 2002 Nov;16(12):80–2.12452113
Boudreau RM, McNally C, Rensing EM, . Improving the timeliness of written patient notification of mammography results by mammography centers. Breast J 2004 Jan-Feb;10(1):10–9.14717754
Centers for Disease Control and Prevention. Most recent asthma data. http://www.cdc.gov/asthma/most_recent_data.htm. Accessed September1, 2015.
Centers for Disease Control and Prevention. Web-based Injury Statistics Query and Reporting System (WISQARS) [Online]. (2013). http://www.cdc.gov/injury/wisqars/index.html. Accessed September 1, 2015.
Chevan J, Riddle DL, Reed SD. Out-of-pocket spending for ambulatory physical therapy services from 2008 to 2012: National Panel Survey. Phys Ther 2015 Jun 25. [Epub ahead of print]
Child Health USA 2014. Infant Mortality. Rockville, MD: Health Resources and Services Administration; 2014. http://mchb.hrsa.gov/chusa14/health-status-behaviors/infants/infant-mortality.html. Accessed August 31, 2015.
Collins-Sharp B. Cardiovascular disease and other chronic conditions in women. Recent findings (Program Brief). Rockville, MD: Agency for Healthcare Research and Quality; October 2012. AHRQ Pub. No. 12(13)-P011-EF. http://www.ahrq.gov/research/findings/factsheets/women/womheart/index.html. Accessed August 14, 2015.
FDA licensure of bivalent human papillomavirus vaccine (HPV2, Cervarix) for use in females and updated HPV vaccination recommendations from Advisory Committee on Immunization Practices (ACIP). MMWR 2010 May 28;59(20):626–9. http://www.cdc.gov/mmwr/preview/mmwrhtml/mm5920a4.htm. Accessed August 31, 2015.20508593
Field MJ, Cassel CK, eds. Committee on Care at the End of Life. Institute of Medicine Division of Health Care Services. Approaching death: improving care at the end of life. Washington, DC: National Academy Press; 1997. http://www.nap.edu/openbook.php?record_id=5801. Accessed September 15, 2015.
Health Resources and Services Administration. Women’s Health USA 2013. http://www.mchb.hrsa.gov/whusa13/index.html. Accessed September 15, 2015.
Healthy People 2020. Access to Health Services. Washington, DC: U.S. Department of Health and Human Services, Office of Disease Prevention and Health Promotion. http://www.healthypeople.gov/2020/topics-objectives/topic/Access-to-Health-Services. Accessed September 1, 2015.
Heidenreich PA. Editor’s Perspective. Time for a thorough evaluation of patient-centered care. Circ Cardiovasc Qual Outcomes 2013;6:2–4. http://circoutcomes.ahajournals.org/content/6/1/2.full 23322803
Hurtado MP, Swift EK, Corrigan JM, eds., Institute of Medicine, Committee on the National Quality Report on Health Care Delivery. Envisioning the National Health Care Quality Report. Washington, DC: National Academy Press; 2001.
Kountz DS. Strategies for improving low health literacy. Postgrad Med 2009 Sep;121(5):171–7. PMID: 19820287.19820287
Lo E, Nicolle L, Classen D, . Strategies to prevent catheter-associated urinary tract infections in acute care hospitals. Infect Contr 2008;29(S1);S41–S50.
Mitchell SE, Sadikova E, Jack BW, . Health literacy and 30-day postdischarge hospital utilization. J Health Commun 2012;17 Suppl 3:325–38. PMID: 23030580.23030580
Mozzafarian D, Benjamin EJ, Go AS, . Heart disease and stroke statistics-2015 update: a report from the American Heart Association. Circulation 2015;e29–322.
National Heart, Lung, and Blood Institute. Reducing Asthma Disparities. http://www.nhlbi.nih.gov/health-pro/resources/lung/naci/discover/disparities.htm. Accessed August 14, 2015.
Nwankwo T, Yoon SS, Burt V, . Hypertension among adults in the US: National Health and Nutrition Examination Survey, 2011-2012. NCHS Data Brief, No. 133. Hyattsville, MD: National Center for Health Statistics, Centers for Disease Control and Prevention; 2013.
Owens PL, Mutter R, Stocks C. Mental health and substance abuse-related emergency department visits among adults, 2007. HCUP Statistical Brief #92. Rockville, MD: Agency for Healthcare Research and Quality; July 2010. http://www.hcup-us.ahrq.gov/reports/statbriefs/sb92.pdf. Accessed September 21, 2015.
Pretorius RW, Gataric G, Swedlund SK, . Reducing the risk of adverse drug events in older adults. Am Fam Physician 2013 Mar 1;87(5):331–6.23547549
Sabatino SA, White MC, Thompson TD, . Cancer screening test use—United States, 2013. MMWR 2015;64(17):464–8.25950253
Selden C, Zorn M, Ratzan S, ., compilers. Health literacy: January 1990 through October 1999 [bibliography]. February 2000; p. vi. (Current Bibliographies in Medicine; CBM 2000-1).
Smart NA, Titus TT. Outcomes of early versus late nephrology referral in chronic kidney disease: a systematic (http://www.lung.org/lung-disease/disparities-reports/rise-of-copd-in-women/) review. Am J Med 2011 Nov;124(11):1073–80e2.22017785
Taking her breath away: the rise of COPD in women. Disparities in Lung Health Series (http://www.uspreventiveservicestaskforce.org/Page/Document/UpdateSummaryFinal/cervical-cancer-screening). Chicago, IL (http://www.uspreventiveservicestaskforce.org/Page/Document/UpdateSummaryFinal/cervical-cancer-screening): American Lung Association (http://www.uspreventiveservicestaskforce.org/Page/Document/UpdateSummaryFinal/cervical-cancer-screening); June 2013. http://www.lung.org/our-initiatives/research/lung-health-disparities/the-rise-of-copd-in-women.html (http://www.uspreventiveservicestaskforce.org/Page/Document/UpdateSummaryFinal/cervical-cancer-screening). Accessed August 14, 2015.
U.S. Preventive Services Task Force. Cervical Cancer Screening. http://www.uspreventiveservicestaskforce.org/Page/Document/UpdateSummaryFinal/cervical-cancer-screening and http://www.uspreventiveservicestaskforce.org/Page/Document/RecommendationStatementFinal/cervical-cancer-screening#consider. Accessed 1 September 1, 2015.
Washington DL, Bean-Mayberry B, Riopelle D, . Access to care for women veterans: delayed healthcare and unmet need. J Gen Intern Med 2011;26(2):655–61.21989618
Xu JQ, Kochanek KD, Murphy SL, . Mortality in the United States, 2012. NCHS Data Brief, no 168. Hyattsville, MD: National Center for Health Statistics; 2014.