# ACKNOWLEDGMENTS

The National Healthcare Quality and Disparities Report (NHQDR) is the product of collaboration among agencies across the U.S. Department of Health and Human Services (HHS). Many individuals guided and contributed to this report. Without their magnanimous support, the report would not have been possible.

Specifically, we thank:

HHS Women’s Healthcare Chartbook Authors: Bethany Applebaum (HRSA), Barbara Barton (SSS), Beth Collins-Sharp (HHS OWH), Sebastiana Gianci (AHRQ), Ashley Hirai (HRSA), Sabrina Matoff-Stepp (HRSA), Atlang Mompe (SSS), Jennifer Moore (MHPA/IMI), Michelle Roberts (AHRQ), Veronica Soileau (AHRQ), and Chinagozi Ugwu (AHRQ).

AHRQ Staff: Richard Kronick, Jeff Brady, Amy Helwig, Ernest Moy, Sebastiana Gianci, Veronica Soileau, Darryl Gray, Nancy Wilson, and Doreen Bonnett.

HHS Interagency Workgroup for the NHQR/NHDR: Girma Alemu (HRSA), Chisara N. Asomugha (CMS), Kirsten Beronio (ASPE), Nancy Breen (NCI), Sarah Bryce (HRSA), Miya Cain (ACF), Victoria Cargill (NIH), Steven Clauser (NCI), Wayne Duffus (CDC), Olinda Gonzalez (SAMHSA), Kirk Greenway (IHS), Chris Haffer (CMS-OMH) , Linda Harlan (NCI), Rebecca Hines (CDC-NCHS), Edwin Huff (CMS), Deloris Hunter (NIH), Sonja Hutchins (CDC), Ruth Katz (ASPE), Tanya Telfair LeBlanc (CDC), Shari Ling (CMS), Darlene Marcoe (ACF), Tracy Matthews (HRSA), Karen McDonnell (CMS), Curt Mueller (HRSA), Karen Nakano (CMS), Iran Naqvi (HRSA), Ann Page (ASPE), Kimberly Proctor (CMS-OMH), D.E.B. Potter (ASPE), Asel Ryskulova (CDC-NCHS), Adelle Simmons (ASPE), Alan Simon (CDC-NCHS), Marsha Smith (CMS), Caroline Taplin (ASPE), Emmanuel Taylor (NCI), Sayeedha Uddin (CDC-NCHS), Nadarajen Vydelingum (NIH), Chastity Walker (CDC), Barbara Wells (NHLBI), Valerie Welsh (OASH-OMH), and Tia Zeno (ASPE).

Data Support Contractor: Social & Scientific Systems.