# REFERENCES

• American Geriatrics Society 2015 Beers Criteria Update Expert Panel. American Geriatrics Society 2015 Updated Beers Criteria for Potentially Inappropriate Medication Use in Older Adults. J Am Geriatr Soc 2015 Nov;63(11):2227–46. https://www.ncbi.nlm.nih.gov/pubmed/26446832. Accessed May 15, 2020.26446832
• Association of Asian Pacific Community Health Organizations. 2014 Fact Sheet: Limited English Proficiency (LEP) of Asian Americans, Native Hawaiians, and Other Pacific Islanders (AA&NHOPIs). https://www.aapcho.org/wp/wp-content/uploads/2014/08/AANHOPI-LEP-Fact-Sheet_2014_final.pdf. Accessed May 15, 2020.
• Artiga S, Foutz J, Cornachione E, Garfield R. Key Facts on Health and Health Care by Race and Ethnicity. Menlo Park, CA: Henry J. Kaiser Family Foundation; June 2016. http://files.kff.org/attachment/Chartpack-Key-Facts-on-Health-and-Health-Care-by-Race-and-Ethnicity. Accessed May 15, 2020.
• Barnes PM, Adams PF, Powell-Griner E. Health Characteristics of the Asian Adult Population: United States, 2004-2006. Adv Data. 2008 Jan 22;(394):1–22. https://www.cdc.gov/nchs/data/ad/ad394.pdf. Accessed May 15, 2020.
• Beach MC, Sugarman J, Johnson RL, Arbelaez JJ, Duggan PS, Cooper LA. Do patients treated with dignity report higher satisfaction, adherence, and receipt of preventive care? Ann Fam Med. 2005;3:331–8. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC1466898/. Accessed May 15, 2020.16046566
• Centers for Disease Control and Prevention (CDC). 10 Leading Causes of Death, United States, 2017, Asian/Pac Islander, Non-Hispanic, Both Sexes. WISQARS Leading Cause of Death Reports. https://webappa.cdc.gov/sasweb/ncipc/leadcause.html. Accessed May 15, 2020.
• CDC. HIV and Asians. https://www.cdc.gov/hiv/group/racialethnic/asians/index.html. Last reviewed November 2019a. Accessed May 15, 2020.
• CDC. HIV and Native Hawaiians and Other Pacific Islanders. https://www.cdc.gov/hiv/group/racialethnic/nhopi/index.html. Last reviewed November 2019b. Accessed May 15, 2020.
• CDC. Pneumonia Can Be Prevented—Vaccines Can Help. November 2019c. https://www.cdc.gov/pneumonia/prevention.html. Accessed May 15, 2020.
• Curtin SC, Hedegaard H. Suicide Rates for Females and Males by Race and Ethnicity: United States, 1999 and 2017. NCHS Health E-Stat. 2019. https://www.cdc.gov/nchs/data/hestat/suicide/rates_1999_2017.htm. Accessed May 15, 2020.
• Demaerschalk BM, Hwang HM, Leung G. Cost analysis review of stroke centers, telestroke, and rtPA. Am J Manag Care. 2010 Jul;16(7):537–44. https://www.ncbi.nlm.nih.gov/pubmed/20645669. Accessed May 15, 2020.20645669
• Fagan SC, Morgenstern LB, Petitta A, Ward RE, Tilley BC, Marler JR, Levine SR, Broderick JP, Kwiatkowski TG, Frankel M, Brott TG, Walker M. Cost-effectiveness of tissue plasminogen activator for acute ischemic stroke. NINDS rt-PA Stroke Study Group. Neurology 1998;50:883–90. https://www.ncbi.nlm.nih.gov/pubmed/9566367. Accessed May 15, 2020.9566367
• Jensen MD, Ryan DH, Apovian CM, .; American College of Cardiology/American Heart Association Task Force on Practice Guidelines; Obesity Society. 2013 AHA/ACC/TOS guideline for the management of overweight and obesity in adults: a report of the American College of Cardiology/American Heart Association Task Force on Practice Guidelines and The Obesity Society. Circulation. 2014 Jun 24;129(25 Suppl 2):S102–38. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5819889/. Accessed May 15, 2020.24222017
• Johnston S. The economic case for new stroke thrombolytics. Stroke. 2010 Oct;41(10 Suppl):S59–S62. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2955402/. Accessed May 15, 2020.20876507
• Kelly RL. 2015 Kelly Report: Health Disparities in America. https://cbcbraintrust-kelly.house.gov/media-center/kelly-report. Accessed May 15, 2020.
• King GL, McNeely MJ, Mau MLM. Understanding and Addressing Unique Needs of Diabetes in Asian Americans, Native Hawaiians, and Pacific Islanders. Diabetes Care 2012 May;35:1181–88. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3329823/. Accessed May 15, 2020.22517939
• National Institute of Allergy and Infectious Diseases. Pneumococcal Disease. 2014.
• National Institute of Dental and Craniofacial Research, National Institutes of Health. Oral Health in America: A Report of the Surgeon General. Rockville, MD: U.S. Department of Health and Human Services; 2000. https://www.nidcr.nih.gov/sites/default/files/2017-10/hck1ocv.%40www.surgeon.fullrpt.pdf. Accessed May 15, 2020.
• Office of Disease Prevention and Health Promotion. Healthy People 2020. Access to Health Services. Washington, DC: U.S. Department of Health and Human Services. http://www.healthypeople.gov/2020/topics-objectives/topic/Access-to-Health-Services. Accessed May 15, 2020.
• Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. 62 Federal Register 58782; 30 Oct 1997. http://federalregister.gov/a/97-28653. Accessed May 15, 2020.
• Office of Minority Health. Mental and Behavioral Health - Asian Americans. 2019. https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=4&lvlid=54. Accessed May 15, 2020.
• Ritenour D, Rodriguez J, Wilson-Frederick S, Giordano L, Gualtieri B. Understanding the Health Needs of Diverse Groups of Asian and Native Hawaiian or Other Pacific Islander Medicare Beneficiaries. CMS OMH Data Highlight No. 10; August 2017. https://www.hosonline.org/globalassets/hos-online/publications/cms-omh-data-highlight-vol10-aug-2017.pdf. Accessed May 15, 2020.
• Roberts M. Racial and Ethnic Differences in Health Insurance Coverage and Usual Source of Health Care, 2002. MEPS Chartbook No. 14. Rockville, MD: Agency for Healthcare Research and Quality; 2006. AHRQ Pub. No. 06-0004. https://www.meps.ahrq.gov/data_files/publications/cb14/cb14.pdf. Accessed May 15, 2020.
• Smart NA, Titus TT. Outcomes of early versus late nephrology referral in chronic kidney disease: a systematic review. Am J Med. 2011 Nov;124(11):1073–80e2. https://www.ncbi.nlm.nih.gov/pubmed/22017785. Accessed May 15, 2020.22017785
• A Snapshot of Behavioral Health Issues for Asian American/Native Hawaiian/Pacific Islander Boys and Men: Jumpstarting an Overdue Conversation. Rockville, MD: Substance Abuse and Mental Health Services Administration; 2016. HHS Publication No. (SMA) 16-4959. https://store.samhsa.gov/product/A-Snapshot-of-Behavioral-Health-Issues-for-Asian-American-Native-Hawaiian-Pacific-Islander-Boys-and-Men-Jumpstarting-an-Overdue-Conversation/SMA16-4959. Accessed May 15, 2020.
• Tsoh JY, Sentell T, Gildengorin G, . Healthcare communication barriers and self-rated health in older Chinese American immigrants. J Community Health. 2016 Aug;41(4):741–52. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4930414/. Accessed May 15, 2020.26746205
• Vespa J, Armstrong DM, Medina L. Demographic Turning Points for the United States: Population Projections From 2020 to 2060. Suitland, MD: U.S. Census Bureau; 2019. Report Number P25-1144. https://www.census.gov/library/publications/2020/demo/p25-1144.html. Accessed May 15, 2020.
• Van de Ven, AH. What matters most to patients? Participative provider care and staff courtesy. Patient Experience Journal 2014;1(1):Article 17. https://pxjournal.org/journal/vol1/iss1/17/. Accessed May 15, 2020.
• Wyatt LC, Ung T, Park R, Kwon SC, Trinh-Shevrin C. Risk factors of suicide and depression among Asian American, Native Hawaiian, and Pacific Islander youth: a systematic literature review. J Health Care Poor Underserved. 2015 May;26(2 Suppl):191–237. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4530970/. Accessed May 15, 2020.25981098