# ACKNOWLEDGMENTS

The National Healthcare Quality and Disparities Report (QDR) is the product of collaboration among agencies across the U.S. Department of Health and Human Services (HHS). Many individuals guided and contributed to this effort. Without their magnanimous support, this chartbook would not have been possible. Specifically, we thank:

Authors:

- AHRQ: Barbara Barton, Celeste Torio, Bill Freeman, Brenda Harding, Erofile Gripiotis
- SAMHSA: Victoria Chau
- Health Services Advisory Group (HSAG): Robert Fornango, Paul Niemann, Michael Lichter, Cindy Strickland, Mitchell Keener, Fredericka Thompson

Primary AHRQ Staff: Gopal Khanna, David Meyers, Jeff Brady, Francis Chesley, Erin Grace, Kamila Mistry, Celeste Torio, Karen Chaves, Barbara Barton, Bill Freeman, Erofile Gripiotis, Brenda Harding, Irim Azam, Tahleah Chappel, Doreen Bonnett.

HHS Interagency Workgroup for the QDR: Irim Azam (AHRQ/CQuIPS), Girma Alemu (HRSA), Doreen Bonnett (AHRQ/OC), Deron Burton (CDC/DDID/NCHHSTP/OD), Victoria Chau (SAMHSA), Karen H. Chaves (AHRQ), Christine Lee (FDA), Deborah Duran (NIH/NIMHD), Ernest Moy (VA), Melissa Evans (CMS/CCSQ), Camille Fabiyi (AHRQ/OEREP), Darryl Gray (AHRQ/CQuIPS), Kirk Greenway (IHS/HQ), Sarah Heppner (HRSA), Edwin D. Huff (CMS/CCSQ), DeLoris Hunter (NIH/NIMHD), Susan M. Jenkins (ACL), Doris C. Lefkowitz (AHRQ/CFACT), Lan Liang (AHRQ/CFACT), Jesse Lichstein (HRSA), Shari Ling (CMS/CCSQ), Iris Mabry-Hernandez (AHRQ/CEPI), Marlene Matosky (HRSA), Tracy Matthews (HRSA), Christine Merenda (FDA), Kamila Mistry (AHRQ/OEREP), Pradip Muhuri (AHRQ/CFACT), Samia Noursi (NIH/NIDA), Kathy O’Connor (CDC/DDPHSS/NCHS/DHCS), Paul Gorrell (Atlas Research), Rajasri Roy (NIH/OD/ORWH), Dianne Rucinski (OS/OASH), Asel Ryskulova (CDC/DDPHSS/NCHS/DAE), Adelle Simmons (HHS/ASPE), Robin Streeter (HRSA), Loida Tamayo (CMS/OMH), Caroline Taplin (HHS/ASPE), Emmanuel Taylor (NIH/NCI), Michelle Washko (HRSA), Ellen Werner (NIH/NHLBI), Xiuhua Chen (Atlas Research), Ying Zhang (IHS/HQ).

Data Support Contractors:

- ActioNet: Tomas Montgomery, Robyn Thomas
- HSAG: Rob Fornango, Gosia Skinner, Paul Niemann, David Carnell, Cindy Strickland, Fredericka Thompson, Michael Lichter, Mitchell Keener
- Impaq: Andreea Balan-Cohen
- Atlas Research: Paul Gorrell, Xiuhua Chen