# RESOURCES

- Health, United States, 2016 With Chartbook on Long-term Trends in Health. Hyattsville, MD: National Center for Health Statistics; 2017. https://www.cdc.gov/nchs/data/hus/hus16.pdf. Accessed May 15, 2020 .
- Health, United States, 2015 With Special Feature on Racial and Ethnic Health Disparities. Hyattsville, MD: National Center for Health Statistics; 2016. https://www.cdc.gov/nchs/data/hus/hus15.pdf. Accessed May 15, 2020.
- Office of Minority Health and HSAG. Understanding the Health Needs of Diverse Groups of Asian and Native Hawaiian or Pacific Islander Medicare Beneficiaries. Baltimore, MD: CMS; 2017. https://www.cms.gov/About-CMS/Agency-Information/OMH/Downloads/ANHOPI-HOS-Baseline-Cohort-Report.pdf. Accessed May 15, 2020.
- Think Cultural Health. National CLAS Standards. https://thinkculturalhealth.hhs.gov/clas. Accessed May 15, 2020.