# PART 3 HEALTHCARE ACCESS AND PRIORITY AREAS

## Access to Care

### Disparities in Access: Number and Percentage of Access Measures for Which Selected Groups Experienced Disparities in Access, 2016, 2017

Key: n = number of measures; AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: The measures represented in this chart are available in Appendix A. The number of measures is based on the measures that have data for each population group.

Stacked columns showing number of access measures Poor vs. High Income (n=20), 1 same, 19 worse Black vs. White (n=21), 1 better, 11 same, 9 worse Asian vs. White (n=19), 6 better, 6 same, 7 worse AI/AN vs. White (n=11), 6 same, 5 worse NHPI vs. White (n=4), 4 same Hispanic vs. Non-Hispanic White (n=20), 3 better, 2 same, 15 worse

- For the most recent data year (2016 or 2017), findings show that many disparities persist in access to care.

### Health Insurance

#### Health Insurance Status, 2017

Health Insurance Status | United States | Asian | NHPI
Private | 67.6% | 74.3% | 66.9%
Public | 35.5% | 25.7% | 33.5%
Uninsured | 8.7% | 6.4% | 8.3%

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

Note: Includes all individuals in the civilian noninstitutionalized population. All race categories include individuals reporting one race alone or in combination with one or more races. Hispanics/Latinos may include individuals of any race. Totals exceed 100 percent because individuals may have both private and public coverage.

- Compared with the total U.S. population in 2017, Asian and NHPI individuals were:
  ■ More likely or as likely to have private health insurance.
  ■ Less likely to have public coverage.
  ■ Less likely to be uninsured.
- Compared with other racial and ethnic groups, Asians were the most likely to have private health insurance, while Hispanics/Latinos (of any race) were least likely (49.0%).
- Conversely, Asians were the least likely to have public coverage, while Blacks or African Americans were the most likely (43.8%), followed closely by American Indians and Alaska Natives (43.2%).
- Hispanics were the most likely to be uninsured (17.8%), while Asians were the least likely.

Individuals with no health insurance coverage, Asian subpopulations, 2017

* Excluding Taiwanese.

Note: Data include civilian noninstitutionalized population, all ages. Data also include individuals reporting one race alone or in combination with one or more races.

Bar chart showing percentage of Asian subpopulations with no health insurance Chinese (6%) Indian (5%) Filipino (5.3%) Vietnamese (7.6%) Korean (8.3%) Japanese (4.11%) Pakistani (9.9%) Cambodian (8.2%) Thai (10.3%) Hmong (6.8%)

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

- In 2017, over 8.0% of Thais, Pakistanis, Koreans, and Cambodians were uninsured, the highest among Asian subpopulations.
- For individuals with health insurance coverage, the source varied considerably across groups. Among these Asian subpopulations, Japanese people had the highest level of private health insurance (84%) and Hmong people had the lowest level (58.1%).
- Conversely, Hmong people had the highest level of public health coverage (41.3%) and Indians had the lowest level (16.3%).
- Variations among groups likely reflect historical differences across the groups in how long they have been settling in the United States, the conditions under which they migrated, and their relationship to the labor market.

Individuals with no health insurance coverage, NHPI subpopulations, 2017

Note: Data include civilian noninstitutionalized population, all ages. Data also include individuals reporting one race alone or in combination with one or more races.

Bar chart showing percentage: of NHPI subpopulations with no health insurance Native Hawaiian (5.5%) Samoan (8.4%) Guamanian or Chamorro (7.9%) Tongan (9.9%)

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

- In 2017, among the NHPI subpopulations, Tongans were most likely to be uninsured (9.9%) and Native Hawaiians were the least likely (5.5%).
- For individuals with health insurance coverage, the source varied less among these NHPI subpopulations than among the Asian subpopulations shown previously.
- Guamanians/Chamorros were most likely to have private health insurance (71.1%) and Samoans were least likely (61.5%).
- Samoans were most likely to have public coverage (36.8%) and Guamanians/Chamorros were least likely to have public coverage (30.4%).

### Access to Providers

People with a usual primary care provider, by race, 2002-2016

Denominator: U.S. civilian noninstitutionalized population.

Key: AI/AN = American Indian or Alaska Native.

Note: Hispanics may be included in any racial group. A person is determined to have had a primary care provider if his or her usual source of care setting was either a physician’s office or a hospital setting (other than an emergency room), and he or she reported going to this usual source of care for new health problems, preventive health services, and referrals. Trends could not be calculated for NHPI adults because data for 2007, 2008, and 2013-2016 did not meet the criteria for statistical reliability, data quality, and confidentiality.

Line graph showing percentage of people with a usual primary care provider. Key data are presented in the text after the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- Importance: Having adequate access to a primary care provider can significantly influence appropriate healthcare use and health outcomes. Lacking a usual source of care may have important implications for the appropriateness, quality, and continuity of care received and patient outcomes (Roberts, 2002). The likelihood of having a usual source of healthcare may differ among Asian and NHPI subpopulations (Barnes, et al., 2008).
- Overall Rate: In 2016, 76.5% of people had a usual primary care provider.
- Groups With Disparities: In 2002, the baseline year for this analysis:
  ■ Asians were less likely to have a usual primary care provider compared with Whites (69.3% vs. 78.1%). This gap did not narrow over time (71.8% for Asians in 2016 vs. 77.4% for Whites).
  ■ Blacks were less likely to have a usual primary care provider compared with Whites (74.9% vs. 78.1%). This gap did not narrow over time (72.4% for Blacks in 2016 vs. 77.4% for Whites).

People who were unable to get or delayed in getting needed dental care in the last 12 months, by race, 2002-2016

Denominator: U.S. civilian noninstitutionalized population.

Note: For this measure, lower percentages are better. Data for NHPI adults did not meet the criteria for statistical reliability, data quality, and confidentiality.

Line graph showing percentage of people unable to get or delayeed in getting dental care Total, 2002, 5.5, 2016, 4.9 White, 2002, 5.5, 2016, 4.7 Black, 2002, 5.7, 2016, 5.4 Asian, 2002, 2.9, 2016, 3.9

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- Importance: Oral health is important to an individual’s overall health and well-being. While advances in oral health have benefited most Americans, some cannot afford all the care they need, resulting in needless pain and suffering, complications that may devastate overall health and well-being, and social costs that diminish quality of life (National Institute of Dental and Craniofacial Research, 2000).
- Overall Rate: In 2016, 4.9% were unable to get or delayed in getting needed dental care in the last 12 months.
- Trends:
  ■ The percentage of Asians unable to get or delayed in getting needed dental care in the last 12 months worsened between 2002 and 2016, increasing from 2.9% to 3.9%.

Adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment who sometimes or never found it easy to get the care, tests, or treatment, by race, 2008-2016

Denominator: U.S. civilian noninstitutionalized adults age 18 and over who needed care, tests, or treatment in the last 12 months.

Note: For this measure, lower percentages are better. Disparities could not be calculated for NHPI adults because data did not meet the criteria for statistical reliability, data quality and confidentiality.

Line graph showing percentage of adults who had difficulty getting care, tests, or treatment. Key data are presented in the text after the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, Self-Administered Questionnaire, 2008-2016.

- Importance: Timely delivery of appropriate care can help reduce mortality and morbidity for chronic conditions (Smart and Titus, 2011) and is a measure of the healthcare system’s capacity to provide care quickly after a need is recognized (Healthy People 2020).
- Overall Rate: In 2016, 7.8% of adults sometimes or never found it easy to get [struck: the] care, tests, or treatment in the last 12 months.
- Trend: All groups improved between 2008 and 2016.
- Groups With Disparities: In 2008, the baseline year for this analysis:
  ■ The percentage of adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment and sometimes or never found it easy to get the care, tests, or treatment was higher for Asians (21.1%) than for Whites (8.2%). This gap did not narrow over time (11.6% for Asians vs. 6.8% for Whites).
  ■ The percentage of adults who had a doctor’s office or clinic visit in the last 12 months and needed care, tests, or treatment and sometimes or never found it easy to get the care, tests, or treatment was higher for Blacks (14.1%) than for Whites (8.2%). This gap did not narrow over time (12.3% for Blacks vs. 6.8% for Whites).

Adults who had any appointments for routine healthcare in the last 12 months who sometimes or never got an appointment for routine care as soon as needed, by race, 2002-2016

Denominator: U.S. civilian noninstitutionalized population age 18 and over who made an appointment for regular or routine healthcare in the past 12 months and had a valid response to the question, “In the last 12 months, how often did you get an appointment for regular or routine healthcare as soon as you wanted?”

Note: For this measure, lower percentages are better. Disparities could not be calculated for NHPI adults because data did not meet the criteria for statistical reliability, data quality and confidentiality.

Line graph showing percentage of adults who had difficulty getting an appointment. Key data are presented in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, Self-Administered Questionnaire, 2002-2016.

- Importance: Timely delivery of appropriate care can help reduce mortality and morbidity for chronic conditions (Smart and Titus, 2011) and is a measure of the healthcare system’s capacity to provide care quickly after a need is recognized (Healthy People 2020).
- Overall Rate: In 2016, 14% of adults sometimes or never got an appointment for routine healthcare as soon as they needed.
- Trend: All groups improved between 2002 and 2016.
- Groups With Disparities: In 2002, the baseline year for this analysis, among adults who had any appointments for routine healthcare in the last 12 months:
  ■ Asians were more likely to answer that they sometimes or never got an appointment for routine care as soon as needed compared with Whites (30.1% vs. 15.8%). This gap did not narrow over time (25.8% for Asians in 2016 compared with 12.6% for Whites).
  ■ Blacks were more likely to answer that they sometimes or never got an appointment for routine care as soon as needed compared to Whites (19.8% vs. 15.8%). This gap did not narrow over time (17.1% for Blacks in 2016 compared with 12.6% for Whites).

## Quality of Care

### DISPARITIES IN QUALITY: Number and Percentage of Quality Measures for Which Selected Groups Experienced Disparities in Quality of Care

Key: n = number of measures; NHPI = Native Hawaiian/Pacific Islander; AI/AN = American Indian or Alaska Native.

Note: The most recent data years are used for this analysis. Different data sources have different data years for most recent data year. For example, the most recent data year from NIDDK USRDS is 2013 and from AHRQ HCUP is 2016.

Stacked bar chart showing number of quality measures Black (n=190), Better, 28, Same, 86, Worse, 76 Asian (n=172), Better, 48, Same, 77, Worse, 47 AI/AN (n=106), Better, 14, Same, 50, Worse, 42 NHPI (n=57), Better, 8, Same, 26, Worse, 23 Hispanic, All Races (n=167), Better, 39, Same, 70, Worse, 58

- For the most recent data year (2016 or 2017), findings show that many disparities persist.
- Asians performed better than Whites on 28% of quality measures and NHPIs Asians performed better than Whites on 14% of quality measures.

### Priority Area: Patient Safety

Patient Safety is the first of five healthcare priorities covered by this chartbook. The other four priorities are Person- and Family-Centered Care, Effective Treatment, Healthy Living, and Care Affordability. A sixth priority, Care Coordination, was addressed separately in the Chartbook on Care Coordination, available at https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/carecoordination/index.html.

Adults age 65 and over who received in the calendar year at least 1 of 33 potentially inappropriate prescription medications for older adults, by race, 2002-2016

Denominator: U.S. civilian noninstitutionalized population age 65 and over.

Note: For this measure, lower percentages are better. Data for Asians prior to 2007 and data for NHPIs do not meet criteria for statistical reliability, data quality, and confidentiality. Prescription medications received include all prescribed medications initially purchased or otherwise obtained during the calendar year, as well as any refills. For more information on inappropriate medications, refer to the American Geriatrics Society 2012 BEERS Criteria Update Expert Panel: American Geriatrics Society Updated Beers Criteria for Potentially Inappropriate Medication Use in Older Adults. J Am Geriatr Soc 2012 Apr;60(4):616–31. https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3571677/ 22376048 .

Line graph showing percentage of older adults who received potentially inapprpriate medications. Key data are presented in the text below the chart.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- Importance: Some drugs prescribed for older adults are known to be potentially harmful for this age group and can lead to adverse drug events that are both expensive and associated with poor health outcomes (American Geriatrics Society, 2015).
- Overall Rate: In 2016, 9.9% of adults age 65 and over had received at least one of 33 potentially inappropriate medications during the calendar year.
- Trends:
  ■ From 2007 to 2016, there was no statistically significant change in the percentage of older Asian adults who were prescribed potentially inappropriate medications.
  ■ For all other groups, the percentage decreased between 2002 and 2016.
- Groups With Disparities:
  ■ In 2016, Asians were less likely than Whites to have received any of the 33 potentially inappropriate medications (5.6% vs. 10.0%).

### Priority Area: Person- and Family-Centered Care

Person- and Family-Centered Care is one of five healthcare priorities covered by this chartbook. The other four priorities are Patient Safety, Effective Treatment, Healthy Living, and Care Affordability. A sixth priority, Care Coordination, was addressed separately in the Chartbook on Care Coordination, available at https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/carecoordination/index.html.

Adults who reported that home health providers always treated them with courtesy and respect in the last 2 months of care, by race, 2012-2017

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian and Pacific Islander

Denominator: Adult home health patients age 18 and over who provided a valid response to the question, “In the last 2 months of care, how often did home health providers from this agency treat you with courtesy and respect?” excluding nonrespondents.

Line graph showing percentage of adults who reported that home health providers treated them with courtesy and respect. Key data are described in the text below the chart.

Source: Centers for Medicare & Medicaid Services, Home Health Consumer Assessment of Healthcare Providers and Systems, 2012-2017.

- Importance: A person- and family-centered approach to healthcare is defined by the inclusion and participation of patients and their families in decision making and treatment. A fundamental basis for inclusivity is treating patients with courtesy and respect. There is a positive association between being treated with courtesy, dignity, and respect and improved patient experiences with care and health outcomes (Beach, 2005; Van de Ven, 2014).
- Overall Rate: In 2017, 93.5% of adults reported that home health providers always treated them with courtesy and respect in the last 2 months of care.
- Trends: From 2012 to 2017, adults who reported that home health providers always treated them with courtesy and respect in the last 2 months of care improved for Asians (83.4% to 84.3%) and overall (93.2% to 93.5%).
- Groups With Disparities: In 2012, the baseline year for this analysis:
  ■ Asian adults were less likely to report that home health providers always treated them with courtesy and respect in the last 2 months of care compared with White adults (83.4% vs. 94.0%). This gap did not narrow over time (84.3% for Asians in 2017 vs. 94.2% for Whites).
  ■ NHPI adults were less likely to report that home health providers always treated them with courtesy and respect in the last 2 months of care compared with White adults (88.9% vs. 94.0%). This gap did not narrow over time (88.5% for NHPIs in 2017 vs. 94.2% for Whites).
  ■ American Indian or Alaska Native (AI/AN) adults were less likely to report that home health providers always treated them with courtesy and respect in the last 2 months of care compared with White adults (90.5% vs. 94.0%). This gap did not narrow over time (90.3% for AI/ANs in 2017 vs. 94.2% for Whites).
  ■ Black adults were less likely to report that home health providers always treated them with courtesy and respect in the last 2 months of care compared with White adults (93.0% vs. 94.0%). This gap did not narrow over time (92.8% for Blacks in 2017 vs. 94.2% for Whites).

Adults who reported that home health providers always treated them as gently as possible in the last 2 months of care, by race, 2012-2017

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Denominator: Adult home health patients age 18 and over who provided a valid response to the question, “In the last 2 months of care, how often did home health providers from this agency treat you as gently as possible?” excluding nonrespondents.

Line graph showing percentage of adults who reported that home health providers treated them gently. Key data are described in the text below the chart.

Source: Centers for Medicare & Medicaid Services, Home Health Consumer Assessment of Healthcare Providers and Systems, 2012-2017.

- Importance: A person- and family-centered approach to healthcare is defined by the inclusion and participation of patients and their families in decision making and treatment. A fundamental basis for inclusivity is treating patients with courtesy and respect. There is a positive association between being treated with courtesy, dignity, and respect and improved patient experiences with care and health outcomes (Beach, 2005; Van de Ven, 2014).
- Overall Rate: In 2017, 90.1% of adults reported that that home health providers always treated them as gently as possible in the last 2 months of care.
- Trends: Between 2012 and 2017, the percentage of Asian adults who reported that home health providers always treated them as gently as possible in the last 2 months of care improved from 78.4% to 79.6%.
- Groups With Disparities: In 2012, the baseline year for this analysis:
  ■ Asians were less likely to report that home health providers always treated them as gently as possible in the last 2 months of care compared with Whites (78.4% vs. 90.9%). This gap did not narrow over time (79.6% for Asians in 2017 vs. 90.9% for Whites).
  ■ NHPIs were less likely to report that home health providers always treated them as gently as possible in the last 2 months of care compared with Whites (85.9% vs. 90.9%). This gap did not narrow over time (84.4% For NHPIs in 2017 vs. 90.9% for Whites).
  ■ AI/ANs were less likely to report that home health providers always treated them as gently as possible in the last 2 months of care compared with Whites (87.3% vs. 90.9%). This gap did not narrow over time (86.9% for AI/ANs in 2017 vs. 90.9% for Whites).
  ■ Blacks were less likely to report that home health providers always treated them as gently as possible in the last 2 months of care compared with Whites (89.7% vs. 90.9%). This gap did not narrow over time (89.3% for Blacks in 2017 vs. 90.9% for Whites).

Adults with limited English proficiency who had a usual source of care, by race, 2016

Denominator: U.S. civilian noninstitutionalized adults age 18 and over.

Note: Data did not meet the criteria for statistical reliability, data quality, and confidentiality for any groups other than Whites and Asians. The source data could not be disaggregated for Asian and NHPI subpopulations and thus does not reflect the variance among subpopulations that has been observed in rates of LEP.

Bar chart showing percentage of adults with limited English proficiency who had a usual source of care White, 60.3%; Asian, 77.7%

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- Importance: Having adequate access to healthcare services and language-appropriate care can significantly influence healthcare utilization and health outcomes. People with limited English proficiency (LEP) face additional communication challenges when interacting with the healthcare system that can contribute to fewer physician visits, less preventive care, reduced patient safety, and healthcare disparities (Association of Asian Pacific Community Health Organizations, 2014; Tsoh, et al., 2016).
- Overall Rate: In 2016, 62.9% of adults with LEP had a usual source of care.
- Groups With Disparities: In 2016, among adults with LEP, Asians were more likely to have a usual source of care compared with Whites (77.7% vs. 60.3%).

Adults with limited English proficiency and usual source of care (USC) whose USC had language assistance, by race, 2016

Denominator: U.S. civilian noninstitutionalized adults age 18 and over with limited English proficiency and a usual source of care.

Note: Data did not meet the criteria for statistical reliability, data quality, and confidentiality for any groups other than Whites and Asians. The source data could not be disaggregated for Asian and NHPI subpopulations and thus does not reflect the variance among subpopulations that has been observed in rates of LEP.

Bar chart showing percentage of adults with limited English proficiency whose usual source of care had language assistance White, 95.9%; Asian, 89.2%

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2016.

- Importance: Having adequate access to healthcare services and language-appropriate care can significantly influence healthcare utilization and health outcomes. People with limited English proficiency face additional communication challenges when interacting with the healthcare system that can contribute to fewer physician visits, less preventive care, reduced patient safety, and healthcare disparities (Association of Asian Pacific Community Health Organizations, 2014; Tsoh, et al., 2016).
- Overall Rate: In 2016, 94.1% of adults with limited English proficiency and USC had language assistance.
- Groups With Disparities: In 2016, among adults with limited English proficiency and USC, Asians were less likely to have language assistance compared with Whites (89.2% vs. 95.9%).

### Priority Area: Effective Treatment

Effective Treatment is one of five healthcare priorities covered by this chartbook. The other four priorities are Patient Safety, Person- and Family-Centered Care, Healthy Living, and Care Affordability. A sixth priority, Care Coordination, was addressed separately in the Chartbook on Care Coordination, available at https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/carecoordination/index.html.

Acute stroke patients for whom IV thrombolytic therapy was initiated at hospital within 3 hours of time last known well, by race, 2013-2016

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian and Pacific Islander.

Denominator: All Patients age 18 years and over with a diagnosis of acute stroke whose time of arrival is within 3 hours (less than or equal to 180 minutes) of time last known well.

Line graph showing percentage of stroke patients who got thrombolytic therapy in a timely manner. Key data are described in the text below the chart.

Source: Centers for Medicare & Medicaid Services, Quality Improvement Organization Program, Clinical Data Warehouse for Hospital Inpatient Quality Reporting Program, 2013-2016.

- Importance: Cerebrovascular disease (stroke) is one of the leading causes of death and serious long-term disability in the United States (Demaerschalk, et al., 2010). The appropriately timed administration of thrombolytic agents to carefully screened eligible patients with acute ischemic stroke has been shown to save lives, improve outcomes, and lower costs (Fagan, et al., 1998; Johnston, 2010). Obesity-related stroke risk may differ among Asian and NHOPI subpopulations (Ritenour, et al., 2017).
- Overall Rate: In 2016, 87.9% of adults who were acute stroke patients had IV thrombolytic therapy initiated at the hospital within 3 hours of time last known well.
- Trends: All groups improved between 2013 and 2016 except AI/ANs, which did not change significantly during this time.
- Groups With Disparities:
  ■ In 2016, Asians were more likely to have IV thrombolytic therapy initiated at the hospital within 3 hours of time last known well compared with Whites (92.3% vs. 88.5%).
  ■ AI/ANs were less likely to have IV thrombolytic therapy initiated at the hospital within 3 hours of time last known well compared with Whites (80.3% vs. 88.5%).

People age 13 and over living with HIV who know their serostatus, by race/ethnicity, 2010-2015

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Denominator: Adolescents and adults age 13 and over.

Note: White, Black, Asian, NHPI, and AI/AN are non-Hispanic. Hispanic includes all races. For more information on Asians and NHPIs and HIV, see, for example, Substance Abuse and Mental Health Services Administration, A Snapshot of Behavioral Health Issues for Asian American/Native Hawaiian/Pacific Islander Boys and Men: Jumpstarting an Overdue Conversation. Rockville, MD: Substance Abuse and Mental Health Services Administration; 2016. HHS Publication No. (SMA) 16-4959 .

Line graph showing percentage of people living with HIV who knew their serostatus. Key data are described in the text below the chart.

Source: Centers for Disease Control and Prevention, National Center for HIV, Viral Hepatitis, STD, and TB Prevention, Division of HIV/AIDS Prevention, National HIV/AIDS Surveillance System, 2010-2015.

- Importance: People with HIV need to know they are HIV positive so they can take medicine to treat HIV. Taking HIV medicine as prescribed can make the level of virus in their body very low or even undetectable. A person with HIV who gets and stays virally suppressed or undetectable can stay healthy and has significantly low risk of transmitting HIV to HIV-negative partners through sex (CDC, 2019a, 2019b).
- Overall Rate: In 2015, 85.5% of people age 13 years and over living with HIV knew their serostatus.
- Trend: All groups improved from 2010 to 2015.
- Groups With Disparities: In 2010, the baseline year for this analysis, among people age 13 years and over living with HIV:
  ■ Asians were less likely to know their serostatus compared with Whites (70.5% vs. 86.4%). This gap narrowed over time (80.4% for Asians in 2015 vs. 88.1% for Whites).
  ■ NHPIs were less likely to know their serostatus compared with Whites (74.0% vs. 86.4%). This gap narrowed over time (82.2% for NHPIs in 2015 vs. 88.1% for Whites).
  ■ AI/ANs were less likely to know their serostatus compared with Whites (76.3% vs. 86.4%). This gap did not narrow over time (81.3% for AI/ANs in 2015 vs. 88.1% for Whites).
  ■ Blacks were less likely to know their serostatus compared with Whites (82.0% vs. 86.4%). This gap did not narrow over time (84.9% for Blacks in 2015 vs. 88.1% for Blacks).
  ■ Hispanics were less likely to know their serostatus compared with Whites (80.9% vs. 86.4%). This gap did not narrow over time (83.5% for Hispanics in 2015 vs. 88.1% for Whites).

Suicide deaths among people age 12 and over per 100,000 population, by race, 2008-2016

Key: API = Asian/Pacific Islander; AI/AN = American Indian or Alaska Native.

Denominator: U.S. resident population age 12 and over.

Note: For this measure, lower rates are better. Suicides may be undercounted because of difficulty in the determination of suicidal intent by the coroner or medical examiner. Estimates are age adjusted to the 2000 U.S. standard population. Individuals for whom age is not reported are not included in the age adjustment calculations and are excluded from numerators. This data source combined data for Asian and NHPI into a single category, API.

Line graph showing suicide deaths per 100,000 population: Total, 2008, 14, 2016, 16.3 White, 2008, 15.7, 2016, 18.4 Black, 2008, 6.3, 2016, 7.3 API, 2008, 6.7, 2016, 8.1 AI/AN, 2008, 12.2, 2016, 16.4

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System—Mortality, 2008-2016.

- Importance: The age-adjusted suicide rate in the United States in 2017 was increasing and was 33% higher than the rate in 1999 (Curtin and Hedegaard, 2019). In 2017, suicide was the leading cause of death for Asian Americans ages 15 to 24 (Office of Minority Health, 2019) and the second leading cause for those ages 25 to 34 (CDC, 2017). Among the Asian and Pacific Islander population, complex interactions between social environments, developmental contexts, and acculturation serve as both risk and protective factors for the manifestation of depression and suicide (SAMHSA, 2016; Wyatt, et al., 2015).
- Overall Rate: In 2016, 16.3 per 100,000 people age 12 and over died by suicide.
- Trends: Suicide deaths per 100,000 population for people age 12 and over increased for all groups between 2008 and 2016.

Suicide deaths among people age 12 and over per 100,000 population, by race and sex, 2016

Key: API = Asian or Pacific Islander; AI/AN = American Indian or Alaska Native.

Denominator: U.S. resident population age 12 and over.

Note: For this measure, lower rates are better. Suicides may be undercounted because of difficulty in the determination of suicidal intent by the coroner or medical examiner. Estimates are age adjusted to the 2000 U.S. standard population. Individuals for whom age is not reported are not included in the age adjustment calculations and are excluded from numerators. This data source combined data for Asian and NHPI into a single category, Asian/Pacific Islander.

Bar chart showing suicide deaths per 100,000 population Total, male, 25.8, female, 7.3 White, male, 28.8, female, 8.3 Black, male, 12.3, female, 2.9 API, male, 12.2, female, 4.3 AI/AN, male, 25.0, female, 7.8

Source: Centers for Disease Control and Prevention, National Center for Health Statistics, National Vital Statistics System—Mortality, 2016.

- Importance: The age-adjusted suicide rate in the United States in 2017 was 33% higher than the rate in 1999. Suicide rates are typically higher among males than females (Curtin and Hedegaard, 2019; SAMHSA, 2016).
- Overall Rate: In 2016, 16.3 per 100,000 people age 12 and over died by suicide.
- Groups With Disparities: In 2016, among people age 12 and over:
  ■ Overall and across all racial groups, males were significantly more likely to die by suicide than females. (Other results reported below were not tested for statistical significance.)
  ■ Overall, the suicide rate was 25.8 per 100,000 for males and 7.3 per 100,000 for females.
  ■ The ratio of male to female suicides was largest among Blacks (4.2:1) and lowest among Asians/Pacific Islanders (2.8:1)
  ■ Among males, Whites were the most likely to die by suicide (28.8 per 100,000), while Asians/Pacific Islanders were the least likely (12.2 per 100,000).
  ■ Among females, Whites were the most likely to die by suicide (8.3 per 100,000) and Blacks were the least likely (2.9 per 100,000).

### Priority Area: Healthy Living

Healthy Living is one of five healthcare priorities covered by this chartbook. The other four priorities are Patient Safety, Person- and Family-Centered Care, Effective Treatment, and Care Affordability. A sixth priority, Care Coordination, was addressed separately in the Chartbook on Care Coordination, available at https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/carecoordination/index.html.

Hospital patients who received pneumococcal immunization, by race, 2012-2015

Key: AI/AN = American Indian or Alaska Native.

Denominator: Discharged hospital patients age 65 years and over and ages 5-64 years with a high-risk condition.

Note: NHPI is excluded from this analysis because data were only available for 2013-2015; 4 years of data are required for inclusion in trend analyses. Estimates are calculated using hospital-level scores. Further information on this and other immunization measures is available at https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/HospitalQualityInits/HospitalProcessOfCareMeasures.html.

Line graph showing percentage of hospital patients who received pneumococcal immunization. Key data are described in the text below the chart.

Source: Centers for Medicare & Medicaid Services, Quality Improvement Organization Clinical Data Warehouse for Hospital Inpatient Quality Reporting Program.

- Importance: Pneumococcal disease is caused by bacteria and can result in a range of ailments, from mild ear infection to meningitis, sepsis, and fatal pneumonia (NIAID, 2014). Adults over age 65 and individuals of any age with chronic illness are at increased risk for pneumococcal disease and death. The best way to prevent pneumococcal disease is by getting vaccinated (CDC, 2019c). Immunization rates may differ among Asian and NHPI subpopulations (Barnes, et al., 2008).
- Overall Rate: In 2015, 87.7% of hospital patients age 65 years and over and ages 5-64 years with a high-risk condition received pneumococcal immunization.
- Trend: The percentage of Asian hospital patients age 65 years and over and ages 5-64 years with a high-risk condition who received a pneumococcal immunization increased from 85.7% in 2012 to 94.9% in 2015. No other group experienced a statistically significant change over this period.
- Groups With Disparities: In 2012, the baseline year for this analysis, among hospital patients age 65 years and over and ages 5-64 with a high-risk condition:
  ■ Asians were less likely to receive the pneumococcal immunization compared with Whites (85.7% vs. 90.0%). By 2015, Asians were more likely than Whites to receive pneumococcal immunization (94.9% vs. 88.4%).
  ■ American Indians/Alaska Natives were less likely to receive the pneumococcal immunization compared with Whites (83.5% vs. 90.0%). This gap did not narrow over time (83.4% for AI/ANs in 2015 vs. 88.4% for Whites).
  ■ Blacks were less likely to receive the pneumococcal immunization compared with Whites (86.1% vs. 90.0%). This gap did not narrow over time (81.8% for Blacks in 2015 vs. 88.4% for Whites).
  ■ In 2015, Native Hawaiians/Pacific Islanders were more likely to receive the pneumococcal immunization compared with Whites (95.6% vs. 88.4%).

Adults with obesity who ever received advice from a health professional about eating fewer high-fat or high-cholesterol foods, by race, 2002-2016

Denominator: U.S. civilian noninstitutionalized population age 18 and over with a body mass index (BMI) of 30 or greater, excluding pregnant women.

Note: Data for Asians before 2008 do not meet criteria for statistical reliability, data quality, and confidentiality. BMI is based on reported height and weight. Estimates are age adjusted to the 2000 U.S. standard population using three age groups: 18-44, 45-64, and 65 and over. Nonrespondents and “Don’t Know” responses were excluded from the analysis. Data were not included for NHPI adults because they did not meet the criteria for statistical reliability, data quality, and confidentiality.

Line graph showing percentage of adults with obesity who received advice about healthy eating. Total, 2002, 48, 2016, 47.6 White, 2002, 47.8, 2016, 47.8 Black, 2002, 47.3, 2016, 47.9 Asian, 2008, 54.2, 2016, 49--data before 2008 are statistically unreliable.

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- Importance: Obesity increases the risks for numerous diseases and detrimental health conditions, such as hypertension, diabetes, coronary heart disease, stroke, sleep apnea, and depression. In addition, obesity increases individual risk for mortality, particularly from cardiovascular disease and cancer (Jensen, et al., 2014).
- Overall Rate: In 2016, 47.6% of adults with obesity received advice from a health professional about eating fewer high-fat or high-cholesterol foods.
- Trends:
  ■ The percentage of Asian adults with obesity who ever received advice from a health professional about eating fewer high-fat or high-cholesterol foods decreased from 54.2% to 49.0% between 2008 and 2016.

### Priority Area: Affordable Care

Care Affordability is one of five healthcare priorities covered by this chartbook. The other four priorities are Patient Safety, Person- and Family-Centered Care, Effective Treatment, and Healthy Living. A sixth priority, Care Coordination was addressed separately in the Chartbook on Care Coordination, available at https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/carecoordination/index.html.

People under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income, by race, 2002-2016

Key: AI/AN = American Indian or Alaska Native.

Denominator: U.S. civilian noninstitutionalized population under age 65.

Note: For this measure, lower percentages are better. Health insurance premium is the sum of insurance premiums (imputed) and Medicare Part B expenditures. Total family income is the sum of person-level pretax total income, refund income, and sales income. “Family” is defined in terms of health insurance eligibility units (HIEUs), which are composed of individuals who could be covered as a family under most private health insurance plans. For income, insurance, expenditures, and premiums, a family is defined in terms of HIEUs. Trends could not be calculated for NHPI adults because data did not meet the criteria for statistical reliability, data quality, and confidentiality.

Line graph showing percentage of people with health expenditures more than 10% of family income Total, 2002, 14.3, 2016, 17.1 White, 2002, 14.6, 2016,18.3 Black, 2002, 13.1, 2016, 12.5 Asian, 2002, 11, 2016, 15.8 AI/AN, 2002, 20.6, 2016, 15.3

Source: Agency for Healthcare Research and Quality, Medical Expenditure Panel Survey, 2002-2016.

- Importance: Healthcare costs can represent a significant financial burden on patients and their families. Even with commercial insurance, Medicare or Medicaid coverage, patients still face out-of-pocket costs for premiums, deductibles, cost sharing, and costs for noncovered services. These healthcare costs can pose a challenge, particularly for individuals with modest incomes and those with significant medical needs.
- Overall Rate: In 2016, 17.1% of the population under age 65 family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income.
- Trends:
  ■ Between 2002 and 2016, the percentage of people under age 65 whose family’s health insurance premium and out-of-pocket medical expenditures were more than 10% of total family income increased for Asians (from 11.0% to 15.8%) and Whites (from 14.6% to 18.3%).
  ■ There was no statistically significant change in the overall trend or the trend for other groups included in the analysis.
- Groups With Disparities:
  ■ Blacks under age 65 were less likely to spend more than 10% of total family income on their family’s health insurance premiums and out-of-pocket medical expenditures compared with Whites (12.5% vs. 18.3%).