# PART 2 DEMOGRAPHICS OF ASIANS AND NHPIS

## Health of the Asian and NHPI Populations in the United States

Asians and NHPIs have lower rates of mortality than other racial and ethnic groups for several top causes of death in the United States (Artiga, et al., 2016). The health of Asians and NHPIs is influenced by various social determinants,^i^ such as:

- Socioeconomic status,
- Educational attainment,
- Time in the United States,
- English proficiency,
- Household size, and
- Other cultural characteristics.

Asians and NHPIs have lower death rates for diabetes, heart disease, and cancer.

## Growth Rate of Asian and NHPI Populations

Asians are projected to be the second fastest growing racial/ethnic group in the United States in the next few decades:

- Rapid growth in the Asian population is driven by immigration rather than births.
- NHPIs are also among the fastest growing racial groups (Census Bureau, 2019).

The fastest growing racial or ethnic group is “Two or More Races,” driven by natural increase (the excess of births over deaths); next is “Asian Alone,” with international migration the primary driver. Third is “Hispanic,” with natural increase the primary driver.

## Geographic Distribution of the U.S. Asian Population, 2017

Note: Data include individuals reporting one race alone, not in combination with any other race.

U.S. map showing percentage of NHPIs in each county, ranging from 0 to 33.72. Most NHPis are on the West Coast and in Alaska and Hawaii.

Source: U.S. Census Bureau, 2013-2017 American Community Survey 5-Year Estimates, Table B02001.

## Geographic Distribution of the U.S. NHPI Population, 2017

Note: Data include individuals reporting one race alone, not in combination with any other race.

U.S. map showing percentage of Asians in each county, ranging from 0 to 42.88. Most Asians are on the West Coast, in the Northeast, and in Alaska and Hawaii.

Source: U.S. Census Bureau, 2013-2017 American Community Survey 5-Year Estimates, Table B02001.

## Geographic Distribution of Asian and NHPI Populations

Ten States are home to 72.3% of Asian and NHPI populations:

- California (31.4%)
- New York (9.3%)
- Texas (7.4%)
- New Jersey (4.7%)
- Illinois (3.7%)
- Hawaii (3.7%)
- Washington (3.6%)
- Florida (3.2%)
- Virginia (2.9%)
- Massachusetts (2.4%)

Data are from the 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau. Data include individuals reporting one race alone. Individuals reporting two or more races make up 3.3% of the total population.

## Asian and NHPI Populations Compared, 2017

| Asian | NHPI
Population | 21.6 million | 1.4 million
Male | 47.8% | 50.2%
Female | 52.2% | 49.8%
Percentage of Total U.S. Population | 6.6% | 0.4%
U.S. born | 9.1 million (41.9%) | 1.2 million (84.3%)
Foreign born | 12.6 million (58.1%) | 0.2 million (15.7%)
U.S.-Born Group as a Percentage of Total U.S. Population^*^ | 2.8% | 0.4%
Foreign-Born Group as a Percentage of Total U.S. Population^*^ | 3.9% | 0.1%

* U.S.-Born Group and Foreign-Born Group percentages may not add to Percentage of Total U.S. Population U.S. born or foreign born due to rounding.

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

Note: Data include individuals reporting one race alone or in combination with one or more races. Total U.S. population in 2017: 325.7 million.

## Marital Status of the Population Age 15 Years and Over, 2017

Note: Data include individuals reporting one race alone or in combination with one or more races. Other includes Widowed, Divorced, and Separated.

Stacked bar chart showing percentage of people currently married, never married, and other. Key data are noted in the text. For the United States, 47.8% were married, 33.7% were never married, and 18.5% were other.

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

- As of 2017, 55.8% of Asians and 42.1% of NHPIs reported being married, while 33.4% and 43.3%, respectively, reported never being married.

## Households by Type, 2017

- Among both the Asian and NHPI populations in 2017, approximately three-quarters (72.7% and 71.2%, respectively) lived in a family household.
- In 2017, approximately one-quarter of Asians and NHPIs (27.3% and 28.8%, respectively) lived in a non-family household.
- The average household size in 2017 was 3.04 for Asians and 3.23 for NHPIs, compared with 2.65 for the U.S. population as a whole.
- For the U.S. population as a whole, 65.5% lived in family households and 34.5% in non-family households in 2017.

Data are from the 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau. Data include individuals reporting one race alone or in combination with one or more races.

## Educational Attainment of the Population Age 25 Years and Over, 2017

Note: High school graduate includes equivalency and some college or associate’s degree. Data include individuals reporting one race alone or in combination with one or more races.

Stacked bar chart showing percentage of people with less than high school, high school grad, bachelor's degree, and graduate/professional degree. Asian and NHPI data are noted in the text. For the United States, 12% had less than high school, 56% were high school grads, 19.7% had a bachelor's degree, and 12.3% had a graduate/professional degree.

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

- In 2017, 53% of Asians had a bachelor’s degree or higher (30.0% with bachelor’s degrees and 23.0% with graduate/professional degrees), 34.6% were high school graduates, and 12.5% had less than a high school diploma.
- By contrast, among the NHPI population in the same year, 23.3% had a bachelor’s degree or higher (16.4% with bachelor’s degrees and 6.9% with graduate/professional degrees), 66.1% were high school graduates, and 10.6% had less than a high school diploma.

## Disaggregation of Subpopulation Data

This chartbook does not include health and disparity data broken down by subpopulations because quality data are not yet available. This chartbook does include select demographic data for subpopulations to illustrate:

- The wide range of variability among subpopulations.
- The importance of collecting data at a more granular level.

A more granular view may become possible given the evolution of data collection instruments to allow disaggregation into smaller subpopulations of Asians and NHPIs:

- 2011: The U.S. Department of Health and Human Services (HHS) adopted data collection standards that included additional specificity for Asian and NHPI racial groups on population surveys.
- 2012: The Centers for Disease Control and Prevention and the Centers for Medicare & Medicaid Services (CMS) began oversampling Asian subpopulations in some health surveys to provide additional granularity.

The two represent distinct racial groups with very different disease profiles, such as for cancer, although demographic and health data are often available only in aggregate.

### Ten Largest Asian Subpopulations, United States, 2017

* Excluding Taiwanese.

Bar chart showing largest Asian subpopulations by number and percentage: of Asian population Chinese (22.4%), 5 million Indian (19.6%), 4.4 million Filipino (18%), 4 million Vietnamese (9.4%), 2.1 million Korean (8.4%), 1.9 million Japanese (6.5%), 1.5 million Pakistani (2.4%), 0.5 million Cambodian (1.5%), 0.3 million Thai (1.4%), 0.3 million Hmong (1.4%), 0.3 million

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau. Data include individuals reporting one race alone or in combination with another race. Individuals reporting two or more races comprise 3.3 percent of the total population. Percentages represent each subpopulation as a percentage of the sum of all subpopulations. Because people may have identified with two or more subpopulations, the sum of subpopulations may exceed the total Asian population.

### Six Largest NHPI Subpopulations, United States, 2017

Note: Data include individuals reporting one race alone or in combination with another race. Individuals reporting two or more races make up 3.3 percent of the total population. Percentages represent each subpopulation as a percentage of the sum of all subpopulations. Because people may have identified with two or more subpopulations, the sum of subpopulations may exceed the total NHPI population.

Bar chart showing largest NHPI subpopulations by number and percentage: of NHPI population Native Hawaiian (41.9%), 614,600 Samoan (13.8%), 202,300 Guamanian or Chamorro (10.7%), 156,500 Tongan (4.9%), 71,500 Fijian (3.4%), 50,000 Marshallese (2.4%), 35,000

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

### Educational Attainment of Asian Subpopulations Age 25 Years and Over, 2017

* Excluding Taiwanese.

Note: Data include individuals reporting one race alone or in combination with one or more races.

Stacked bar chart showing percentage of each group with less than high school, high school diploma, bachelor's degree, and graduate/professional degree. Indians had the highest percentage with a graduate/professional degree (41.6%), and Cambodians and Hmongs had the lowest (5.8% and 6%, respectively). Filipinos had the highest percentage with a bachelor's degree only (37.7%) and Cambodians had the lowest (14.4%). Hmongs had the highest percentage with a high school diploma only (52.3%) and Indians had the lowest (18.5%). Cambodians had the highest percentage with less than a high school education (31.8%) and Japanese people had the lowest (4.3%).

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

### Educational Attainment of NHPI Subpopulations Age 25 Years and Over, 2017

Note: Data include individuals reporting one race alone or in combination with one or more races. Data are not available for Fijian and Marshallese subpopulations due to low data reliability.

Stacked bar chart showing percentage of each group with less than high school, high school diploma, bachelor's degree, and graduate/professional degree. Guamanians/Chamorros had the highest percentage with a graduate/professional degree (7.7%), and Tongans had the lowest (3.1%). Guamanians/Chamorros had the highest percentage with a bachelor's degree only (17.9%) and Tongans had the lowest (9.9%). Tongans had the highest percentage with a high school diploma only (75.2%) and Guamanians/Chamorros had the lowest (66.3%). Tongans had the highest percentage with less than a high school education (11.8%) and Native Hawaiians had the lowest (7%).

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

### Asian Subpopulations Age 5 Years and Over With Limited English Proficiency, 2017

* Excluding Taiwanese.

Note: Data include individuals reporting one race alone or in combination with one or more races. Limited English proficiency is defined as people who speak English less than “Very well.” Those who speak only English at home are not asked to rate their English proficiency.

Bar chart showing percentage of Asian subpopulations with limited English proficiency Chinese (39.4%) Indian (18.2%) Filipino (16.2%) Vietnamese (45.1%) Korean (32.4%) Japanese (13.3%) Pakistani (24.3%) Cambodian (35.4%) Thai (31.7%) Hmong (32.1%)

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

### NHPI Subpopulations Age 5 Years and Over With Limited English Proficiency, 2017

Note: Data include individuals reporting one race alone or in combination with one or more races. Limited English proficiency is defined as people who speak English less than “Very well.” Those who speak only English at home are not asked to rate their English proficiency. Data are not available for Fijian and Marshallese populations due to low data reliability.

Bar chart showing percentage: of NHPI subpopulations with limited English proficiency Native Hawaiian (2%) Samoan (7.3%) Guamanian or Chamorro (4.4%) Tongan (12.7%)

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

## Growth of the Asian and NHPI Populations

### Year of Entry of the Foreign-Born Asian and NHPI Population, 2017

As of 2017, 58.1% of Asians and 15.7% of NHPIs were foreign born.

- Almost half of the foreign-born Asian population (48.9%) had arrived in the United States before 2000 while more than one quarter (27.1%) had arrived in 2010 or later.
- Similarly, among foreign-born NHPIs as of the same year, 49.3% had arrived in the United States before 2000 and 23.8% had arrived in 2010 or later.

In 2017, nearly 9 million Asians and over 1.1 million Native Hawaiians and Pacific Islanders had been born in the U.S. Over 12 million Asians and over 200,000 Native Hawaiians and Pacific Islanders were foreign-born. Data are from 2017 American Community Survey 1 Year Estimates–U.S. Census Bureau. Data include individuals reporting one race alone or in combination with one or more races.

### Projected Growth of the U.S. Resident Population Between 2016 and 2060, by Race

Key: AI/AN = American Indian or Alaska Native; NHPI = Native Hawaiian/Pacific Islander.

Note: Categories are not mutually exclusive; therefore, percentages may add to more than 100 percent. Racial categories other than 2+ Races exclude people reporting two or more races. Whites are non-Hispanic only; all other categories may include Hispanics. Minority includes all groups other than the non-Hispanic White population.

Bar chart showing percentage of U.S. population White, 2016, 61.3%, 2060, 44.3% Minority, 2016, 38.7%, 2060, 55.7% Black, 2016, 13.3%, 2060, 15% Asian, 2016, 5.7%, 2060, 9.1% AI/AN, 2016, 1.3%, 2060, 1.4% NHPI, 2016, 0.2%, 2060, 0.3% 2+ Races, 2016, 2.6%, 2060, 6.2% Hispanic, 2016, 17.8%, 2060, 27.5%

Source: U.S. Census Bureau., Population Division. Projected Race and Hispanic Origin: Main Projections Series for the United States, 2017 to 2060. https://www.census.gov/data/tables/2017/demo/popproj/2017-summary-tables.html.

- Population estimates for July 1, 2016, are based on the 2010 U.S. Census. Population projections for 2017-2060 were developed using evidence-based assumptions regarding demographic trends. The 2016 population estimates are the baseline for the 2017-2060 population projections. (See https://www.census.gov/programs-surveys/popproj/about.html.)

### Projected Growth of Asians and NHPIs as Share of U.S. Population Age 65+ Between 2016 and 2060

Note: Excludes people reporting two or more races; does not exclude Hispanics.

Bar chart showing percentage of U.S. population age 65+ Asian, 2016, 4.4, 2020, 4.6, 2030, 5.2, 2040, 6.4, 2050, 7.6, 2060, 8.5 NHPI, 2016, 0.12, 2020, 0.13, 2030, 0.17, 2040, 0.21, 2050, 0.26, 2060, 0.29

Source: U.S. Census Bureau, Population Division. Race and Hispanic Origin by Selected Age Groups: Main Projections Series for the United States, 2017 to 2060. https://www.census.gov/data/tables/2017/demo/popproj/2017-summary-tables.html.

- Population estimates for July 1, 2016, are based on the 2010 U.S. Census. Population projections for 2017-2060 were developed using evidence-based assumptions regarding demographic trends. The 2016 population estimates are the baseline for the 2017-2060 population projections. (See https://www.census.gov/programs-surveys/popproj/about.html.)

## Labor Force Participation

### Labor Force and Employment Status of Civilian Population 16 Years and Over, 2017

In 2017, over 65% of both the Asian and NHPI populations were in the civilian labor force; only 1.1% or less of either population was in the military. Males made up a slight majority over females in the civilian labor force among both populations (5.8 million vs. 5.3 million for Asians; 356,000 vs. 321,000 for NHPIs).

For more information, refer to 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau. Data include individuals reporting Asian or NHPI race alone or in combination with one or more races.

### Occupation of the Asian Civilian Employed Population 16 Years and Over, 2017

Sector | Percentage
Management, business, sciences, and arts | 51.0%
Service occupations | 17.0%
Sales and office occupations | 19.7%
Natural resources, construction, and maintenance | 3.2%
Production, transportation, and material moving | 9.2%

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

Note: Data include individuals reporting one race alone or in combination with one or more races.

### Occupation of the NHPI Civilian Employed Population 16 Years and Over, 2017

Sector | Percentage
Management, business, sciences, and arts | 29.6%
Service occupations | 23.1%
Sales and office occupations | 25.5%
Natural resources, construction, and maintenance | 8.7%
Production, transportation, and material moving | 13.1%

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

Note: Data include individuals reporting one race alone or in combination with one or more races.

## Income

### Income and Poverty Status, Asian Households, Families, and Individuals, 2017

Income and Poverty Status | Number
Median household income | $82,180
Median family income | $95,689
Median earnings
Male | $64,883
Female | $51,428
Families living in poverty | 7.9%
Individuals living in poverty | 11.0%

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau. Data include individuals reporting one race alone or in combination with one or more races. Median earnings are reported for full-time year-round workers only.

Note: Median household income is defined by the Census Bureau at https://www.census.gov/quickfacts/fact/note/US/INC110218.

### Income and Poverty Status, NHPI Households, Families, and Individuals, 2017

Income and Poverty Status | Number
Median household income | $64,308
Median family income | $71,783
Median earnings
Male | $46,511
Female | $39,085
Families living in poverty | 13.0%
Individuals living in poverty | 15.4%

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau. Data include individuals reporting one race alone or in combination with one or more races. Median earnings are reported for full-time year-round workers only.

Note: Median household income is defined by the Census Bureau at https://www.census.gov/quickfacts/fact/note/US/INC110218.

## Age

### Largest Age Groups in the Asian and NHPI Population, 2017

The largest age group among Asians and NHPIs in 2017 was individuals ages 35-64. The next largest age group for both populations was individuals ages 18-34. The median age was 34.6 years old for Asians and 28.7 years old for NHPIs. For more information, refer to 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau. Data include individuals reporting one race alone or in combination with one or more races.

### Age Distribution Among Asian Subpopulations, 2017

* Excluding Taiwanese.

Stacked bar chart showing percentage of each group under 18, 18-34, 35-64, and 65 and over. Hmongs had the highest percentage under 18 (36.1%) and Chinese people had the lowest (22%). Hmongs had the highest percentage ages 18-34 (38.2%) and Japanese people had the lowest (22.1%). Vietnamese people had the highest percentage ages 35-64 (40.4%) and Hmongs had the lowest (22.4%). Japanese people had the highest percentage age 65 and over (16.2%) and Hmongs had the lowest (3.1%).

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau. Data include individuals reporting one race alone or in combination with one or more races.

- Among these Asian subpopulations, the Japanese population is the oldest, with 53.5% age 35 and over, and 16.2% age 65 and over.
- The Hmong population is the youngest, with 74.3% under 35 and 36.1% under 18.

### Age Distribution Among NHPI Subpopulations, 2017

Note: Data include individuals reporting one race alone or in combination with one or more races. Data are not available for Fijian and Marshallese populations due to low data reliability.

Stacked bar chart showing percentage of each group under 18, 18-34, 35-64, and 65 and over. Tongans had the highest percentage under 18 (39.6%) and Guamanian or Chamorro people had the lowest (31.8%). Tongans had the highest percentage ages 18-34 (32.3%) and Native Hawaiians had the lowest (26.1%). Native Hawaiians had the highest percentage ages 35-64 (32.3%) and Tongans had the lowest (22.2%). Native Hawaiians had the highest percentage age 65 and over (8.6%) and Samoans had the lowest (3.8%).

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

i Social determinants of health are economic and physical conditions in the environments in which people are born, live, learn, work, play, worship, and age that affect a wide range of health, functioning, and quality-of-life outcomes and risks (Kelly, 2015).