# PART 1 OVERVIEWS OF THE REPORT AND THE ASIAN AND NHPI POPULATIONS

## Quality and Disparities Report

The QDR is an annual report to Congress mandated in the Healthcare Research and Quality Act of 1999 (P.L. 106-129 (https://www.govinfo.gov/content/pkg/PLAW-106publ129/html/PLAW-106publ129.htm)). The QDR provides a comprehensive overview of the quality of healthcare received by the general U.S. population and disparities in care experienced by different racial, ethnic, and socioeconomic groups.

The purpose of the reports is to assess the performance of our healthcare system and to identify areas of strength and weaknesses along themes including access to Care, quality of Care, and QDR priorities.

The report is based on more than 260 measures of quality and disparities covering a broad array of healthcare services and settings. Clinical quality measure data are generally available through 2016; more recent data are used as available. The report is produced with the help of an Interagency Work Group led by AHRQ and submitted on behalf of the Secretary of Health and Human Services.

## Chartbook Content

This chartbook organizes QDR measures by access to care and quality of care priorities. The QDR Introduction and Methods contains information about methods used in the chartbook and is available at https://www.ahrq.gov/sites/default/files/wysiwyg/research/findings/nhqrdr/2018qdr-intro-methods.pdf. A data query tool available at http://nhqrnet.ahrq.gov/inhqrdr/data/query provides access to all data tables.

### Key Metrics Used in the Chartbook

- Trends assess the rate of change over time (typically 2002-2016) for a population.
- Disparities assess whether measure estimates for two populations differ at the most recent time point.
- Change in Disparities assesses whether the rates of change over time for two populations differ.

Trends are based on regression analysis for measures with at least 4 time points. Change in disparities is also based on regression analysis.

### Data Collection Standards for Race, 2011

The Office of Management and Budget (OMB) standard permits selection of one or more among 14 racial categories:

- The first three (White, Black or African American, American Indian or Alaska Native) are not subdivided.
- Asian has 7 subcategories:
  ■ Asian Indian
  ■ Chinese
  ■ Filipino
  ■ Japanese
  ■ Korean
  ■ Vietnamese
  ■ Other Asian
- Native Hawaiian and Pacific Islander has 4 subcategories:
  ■ Native Hawaiian
  ■ Guamanian or Chamorro
  ■ Samoan
  ■ Other Pacific Islander

In the American Community Survey (ACS), a person is counted as Asian alone if he or she identifies with at least one of the Asian subpopulations listed but does not identify with any other major race category, such as White. People who identify as both Asian and White are counted as Asian in combination with another race. The same is true for people identifying with at least one NHPI subpopulation.

In the 2017 ACS, 15.8% of people identifying as Asian also identified with another race, and 56.8% of people identifying as NHPI also identified with another race. Data are available in the 2017 ACS 1 Year Estimates – U.S. Census Bureau (https://data.census.gov/cedsci/).

## Racial Makeup of the U.S. Population, 2017

Note: All race categories exclude people reporting two or more races except the “>1 Race” category.

Pie chart showing percentage of each group: White, 72.3 Black, 12.7 American Indian/Alaska Native, 0.8 Asian, 5.6 Native Hawaiian/Pacific Islander,0.2 Some Other Race, 5.1 > 1 Race, 3.3

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau (https://data.census.gov/cedsci/table?q=United States), Table DP05.

## Ethnic Makeup of the U.S. Population, 2017

Bar chart showing percentage with Hispanic ethnicity: White, 16.2 Black, 3.1 Asian, 1.2 Native Hawaiian/Pacific Islander, 10.1

Source: 2017 American Community Survey 1 Year Estimates – U.S. Census Bureau.

- People of any race may also claim Hispanic, Latino, or Spanish origin or ethnicity.