# KEY FINDINGS OF THE CHARTBOOK ON HEALTHCARE FOR ASIANS AND NHPIs

- Asian and NHPI populations continue to be among the higher performing groups on patient safety measures.
  ■ As more specific data from subpopulations of both groups become available, important differences in measure performance may emerge.
- Asian and NHPI populations experience disparities in several areas related to person- and family-centered care, access to care, experience with home healthcare, and language assistance.
- Asian and NHPI populations with HIV were less likely than Whites to know their serostatus.

Grouping all Asian adults into a single category ignores important differences that exist among subpopulations. For example, there is wide variation in income/poverty levels, educational attainment, and time since coming to the United States. The Resources slide at the end provides resources for improving culturally appropriate care.