# HEALTHCARE FOR ASIANS AND NATIVE HAWAIIANS/PACIFIC ISLANDERS

The National Healthcare Quality and Disparities Report (QDR) is supported by a series of related chartbooks that:

- Present information on individual measures.
- Are posted on the web (https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/index.html).

Chartbooks cover different topics, such as:

- Access to care.
- Healthcare priority areas.
- Priority populations.

For a complete list and links to National Healthcare Quality & Disparities Report Chartbooks, go to https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/index.html.

## QDR Healthcare Priority Areas

- Patient Safety: Making care safer by reducing harm caused in the delivery of care
- Patient- and Family-Centered Care: Ensuring that each person and family is engaged as partners in their care
- Care Coordination: Promoting effective communication and coordination of care
- Effective Treatment: Promoting the most effective prevention and treatment practices for the leading causes of mortality, starting with cardiovascular disease
- Healthy Living: Working with communities to promote wide use of best practices to enable healthy living
- Care Affordability: Making quality care more affordable for individuals, families, employers, and governments by developing and spreading new healthcare delivery models

Five of these priorities are covered in this chartbook. Care Coordination was addressed separately in the Chartbook on Care Coordination, available at https://www.ahrq.gov/research/findings/nhqrdr/chartbooks/carecoordination/index.html.

## Other Chartbooks About AHRQ’s Priority Populations

AHRQ’s priority populations are specified in the Healthcare Research and Quality Act of 1999 (Public Law 106-129 (https://www.govinfo.gov/content/pkg/PLAW-106publ129/html/PLAW-106publ129.htm)). Existing chartbooks for priority populations include:

- Rural Healthcare.
- Healthcare for Blacks.
- Women’s Healthcare.
- Hispanic Healthcare.

## Goals of the Chartbook on Healthcare for Asians and Native Hawaiians/Pacific Islanders

This chartbook presents select demographics for Asians and Native Hawaiians/Pacific Islanders (NHPIs) and summarizes trends in healthcare and disparities by race. It is organized into three parts:

- Overview
- Demographics of the Asian and NHPI populations
- Summary of trends in healthcare for Asian and NHPI populations related to access to healthcare, quality of care, and patient experience of care

In referring to racial groups in this chartbook:

- Asian refers to Asians residing in the United States, whether they were born in the United States or foreign born (OMB, 1997).
- NHPI refers to people residing in the United States with origins in any of the original peoples of Hawaii, Guam, Samoa, or the Pacific Islands (OMB, 1997).

These terms are based on the U.S. Census definitions for defining racial groups. Prior to 1997, the U.S. Census Bureau recognized a single race called Asian or Pacific Islander and abbreviated API. Beginning in 1997, the Office of Management and Budget (OMB) and U.S. Census Bureau separated Asians from Native Hawaiians and Pacific Islanders into two separate racial groups.

In the QDR, a disparity is a statistically significant difference that is also a relative difference of at least 10 percent. Disparities are identified in this chartbook by comparing the Asian or NHPI group with the reference group, which in this chartbook is the White group. When the comparison group is defined as Hispanic or non-Hispanic, the reference group is non-Hispanic White. Otherwise, the reference group is White without respect to Hispanic ethnicity.

AHRQ identifies meaningful differences between groups based on two criteria:

- First, a statistical test of the absolute difference in rates must be significant at the p < 0.05 level in a two-tailed test.
- Second, the relative difference between the comparison group and the reference group must be at least 10 percent. For example, if the comparison group had a 22% rate and the reference group had a 20% rate, the relative difference would be ([22% - 20%]/20%) * 100 = 10%. For further information on the QDR methodology, see National Healthcare Quality and Disparities Report introduction and methods. Rockville, MD: Agency for Healthcare Research and Quality; September 2019. AHRQ Publication No. 19-0070-EF. https://www.ahrq.gov/sites/default/files/wysiwyg/research/findings/nhqrdr/2018qdr-intro-methods.pdf.