# Fetal Mortality in the United States: Final 2022–2023 and 2023–Provisional 2024

### Objective

This report describes changes in total, early, and late fetal mortality between 2023 and 2024, as well as fetal mortality by maternal race and Hispanic origin and state of residence. Comparisons are made with findings from 2022 to 2023.

### Methods

Data are based on reports of fetal death filed in the 50 states and the District of Columbia and collected via the National Vital Statistics System. In this report, only fetal deaths reported at 20 weeks of gestation or more are included. Data for 2022 and 2023 are final and data for 2024 are provisional.

### Results

From 2023 to 2024, the overall fetal mortality rate declined 2%, from 5.53 to 5.41 fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths. During this time, the early fetal mortality rate (20–27 weeks of gestation) was essentially unchanged (2.88 in 2024), while the late fetal mortality rate (28 weeks of gestation or more) declined 4% (2.55 in 2024). No significant changes in fetal mortality rates between 2023 and 2024 were observed among the race and Hispanic-origin groups. Fetal mortality rates decreased in 3 states, increased in 1 state, and were not significantly different in 46 states and the District of Columbia from 2023 to 2024. In comparison, from 2022 to 2023, the fetal mortality rate increased for early fetal deaths, for Asian non-Hispanic women, and in five states, and declined in one state.

## Introduction

This report presents 2024 provisional national fetal death data for selected maternal and fetal characteristics, providing more timely data for public health surveillance. Changes in fetal mortality rates overall and by maternal race and Hispanic origin and state of residence are examined from 2023 to 2024, and comparisons are made with findings for the period 2022 to 2023.

## Methods

The fetal death data shown in this report were collected via the National Vital Statistics System. Findings are based on data for fetal deaths occurring at 20 weeks of gestation or more to residents of the United States. Fetal death data for 2022 and 2023 are final. Data for 2024 are provisional and based on reports of fetal death received and processed by the National Center for Health Statistics (NCHS) as of May 28, 2025, representing about 99.4% of the expected count for 2024. Statistics from previous provisional reports have been shown to be consistent with the final statistics for the respective years (1–4).

Fetal mortality rates are computed as the number of fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths at 20 weeks or more. Numbers and rates are also presented for fetal deaths at 20–27 weeks of gestation (early fetal deaths) and 28 weeks of gestation or more (late fetal deaths).

Hispanic origin and race are reported separately on the U.S. Standard Report of Fetal Death. Data shown by Hispanic origin include all people of Hispanic origin of any race. Data for non-Hispanic people are shown separately for each single-race group. Data by race are based on the revised standards issued by the Office of Management and Budget in 1997 (5), which allow for the reporting of a minimum of five race categories either by single race (reported alone) or in combination (more than one race or multiple races). The race and Hispanic-origin groups shown in this report are American Indian and Alaska Native non-Hispanic, single race (subsequently, American Indian and Alaska Native); Asian non-Hispanic, single race (subsequently Asian); Black non-Hispanic, single race (subsequently, Black); Native Hawaiian and Other Pacific Islander non-Hispanic, single race (subsequently, Native Hawaiian and Other Pacific Islander); White non-Hispanic, single race (subsequently, White); and Hispanic.

Fetal mortality rates by state are based on the mother’s state of residence. The small number of fetal deaths in some states by year can limit the ability to detect statistically significant changes between years and between states.

The difference between rates is statistically significant at the 0.05 level unless otherwise noted. For information on the methods used to test for statistical significance, see the 2023 user guide (6).

New criteria for showing the number of events and rates were adopted by NCHS beginning with the 2023 data year (7). For detailed information on the new criteria, see the 2023 user guide (6).

## Results

### Changes in total, early, and late fetal mortality rates, 2022–2023 and 2023–2024

- In 2024, the provisional number of fetal deaths in the United States was 19,756 compared with 20,005 in 2023 (Table 1). The number of fetal deaths has declined 2% since 2022 (20,202).
- The total provisional fetal mortality rate was 5.41 in 2024, a 2% decline from the rate in 2023 (5.53). No significant change in the rate was observed between 2022 (5.48) and 2023 (Table 1, Figure 1).
- The early fetal mortality rate (20–27 weeks of gestation) was essentially unchanged from 2023 (2.89) to 2024 (2.88). From 2022 (2.79) to 2023, the rate increased 4%.
- The late fetal mortality rate (28 weeks of gestation or more) declined 4% from 2023 (2.66) to 2024 (2.55). The rate was not significantly different between 2022 (2.71) and 2023.

### Changes in fetal mortality rate by race and Hispanic origin, 2022–2023 and 2023–2024

- From 2023 to 2024, no significant change in fetal mortality rates was observed for any race or Hispanic-origin group: American Indian and Alaska Native (from 6.87 to 7.77), Asian (4.14 to 3.91), Black (9.95 to 9.96), Native Hawaiian and Other Pacific Islander (10.18 to 10.21), White (4.55 to 4.54), and Hispanic (4.76 to 4.62) women (Table 1, Figure 2).
- Rates for these groups were also not significantly different between 2022 and 2023 except for Asian women, for whom the rate increased by 12% (3.70 in 2022).

Table 1

Number of fetal deaths and births and fetal mortality rate, by selected characteristics: United States, 2022 and 2023 final and 2024 provisional

Selected characteristics | Number of fetal deaths | | | Number of live births | | | Fetal mortality rate^1^ | | | Percent change in rate
Selected characteristics | 2022 | 2023 | 2024 | 2022 | 2023 | 2024 | 2022 | 2023 | 2024 | 2022 to 2023 | 2023 to 2024
Total^2^ | 20,202 | 20,005 | 19,756 | 3,667,758 | 3,596,017 | 3,628,934 | 5.48 | 5.53 | 5.41 | 1 | †-2
Early^3,4^ | 10,246 | 10,431 | 10,485 | 3,667,758 | 3,596,017 | 3,628,934 | 2.79 | 2.89 | 2.88 | †4 | 0
Late^4,5^ | 9,956 | 9,574 | 9,271 | 3,667,758 | 3,596,017 | 3,628,934 | 2.71 | 2.66 | 2.55 | -2 | †-4
Non-Hispanic, single race^6^:
American Indian and Alaska Native | 187 | 170 | 188 | 25,721 | 24,571 | 24,021 | 7.22 | 6.87 | 7.77 | -5 | 13
Asian | 813 | 897 | 890 | 218,994 | 215,738 | 226,860 | 3.70 | 4.14 | 3.91 | †12 | -6
Black | 5,194 | 4,941 | 4,760 | 511,439 | 491,494 | 473,377 | 10.05 | 9.95 | 9.96 | -1 | 0
Native Hawaiian and Other Pacific Islander | 106 | 104 | 107 | 10,122 | 10,115 | 10,375 | 10.36 | 10.18 | 10.21 | -2 | 0
White | 8,280 | 8,171 | 8,124 | 1,840,739 | 1,787,051 | 1,783,156 | 4.48 | 4.55 | 4.54 | 2 | 0
Hispanic^7^ | 4,359 | 4,520 | 4,568 | 937,421 | 945,200 | 984,092 | 4.63 | 4.76 | 4.62 | 3 | -3

† Significant change (p < 0.05).

1 Number of fetal deaths in specified group per 1,000 live births and fetal deaths.

2 Fetal deaths with stated or presumed period of gestation of 20 weeks or more.

3 Fetal deaths at 20–27 weeks of gestation.

4 Not-stated gestational age proportionally distributed.

5 Fetal deaths at 28 weeks of gestation or more.

6 Race and Hispanic origin are reported separately on reports of fetal death; people of Hispanic origin may be of any race. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards. Single race is defined as only one race reported on the report of fetal death.

7 Includes all people of Hispanic origin of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Figure 1 Total, early, and late fetal mortality rates: United States, 2022 and 2023 final and 2024 provisional

^1^Significantly lower than 2023 (p < 0.05)

^2^Significantly higher than 2022 (p < 0.05)

NOTES: Fetal mortality rate is the number of fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths. Early fetal mortality rate is the number of fetal deaths at 20–27 weeks of gestation per 1,000 live births and fetal deaths at 20–27 weeks of gestation. Late fetal mortality rate is the number of fetal deaths at 28 weeks of gestation or more per 1,000 live births and fetal deaths at 28 weeks of gestation or more.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Figure 1 is a bar chart showing the total, early, and late fetal mortality rates using 2022 and 2023 final and 2024 provisional data.

Figure 2 Fetal mortality rate, by race and Hispanic origin of mother: United States, 2022 and 2023 final and 2024 provisional

^1^Significantly higher than 2022 (p < 0.05).

^2^People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Figure 2 is a bar chart showing fetal mortality by race and Hispanic origin of mother using 2022 and 2023 final and 2024 provisional data.

### Change in fetal mortality rate by state, 2022–2023 and 2023–2024

- From 2023 to 2024, the fetal mortality rate decreased in three states: Colorado (14%, from 6.11 to 5.25), Utah (16%, 6.53 to 5.50), and Mississippi (21%, 9.86 to 7.80). The rate increased in New Jersey (19%, from 5.53 to 6.58). Changes in the rate were not significant for the remaining 46 states and the District of Columbia (D.C.) (Table 2, Figure 3).
- In contrast, from 2022 to 2023, the fetal mortality rate increased in 5 states (Colorado, Indiana, Maryland, New Jersey, and Utah), decreased in 1 state (Tennessee), and was not significantly different in 44 states and D.C.

Figure 3 Changes in fetal mortality rate, by state of residence: United States, final 2023–provisional 2024 and final 2022–2023

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Figure 3 is two U.S. maps. The first shows changes in fetal mortality rates by state of residence for provisional 2024 compared with final 2023 data. The second shows changes in fetal mortality rates by state of residence for final 2023 compared with final 2022 data.

Table 2

Number of fetal deaths and births and fetal mortality rate, by state of residence: United States, 2022 and 2023 final and 2024 provisional

Area | Number of fetal deaths | | | Number of live births | | | Fetal mortality rate^1­^ | | | Percent change in rate
Area | 2022 | 2023 | 2024 | 2022 | 2023 | 2024 | 2022 | 2023 | 2024 | 2022 to 2023 | 2023 to 2024
Alabama | 426 | 436 | 445 | 58,149 | 57,858 | 57,934 | 7.27 | 7.48 | 7.62 | 3 | 2
Alaska | 54 | 42 | 43 | 9,359 | 9,015 | 8,943 | 5.74 | 4.64 | 4.79 | -19 | 3
Arizona | 492 | 494 | 479 | 78,547 | 78,096 | 78,711 | 6.22 | 6.29 | 6.05 | 1 | -4
Arkansas | 265 | 248 | 246 | 35,471 | 35,264 | 35,395 | 7.42 | 6.98 | 6.90 | -6 | -1
California | 2,115 | 1,993 | 1,923 | 419,104 | 400,108 | 402,075 | 5.02 | 4.96 | 4.76 | -1 | -4
Colorado | 305 | 378 | 339 | 62,383 | 61,494 | 64,268 | 4.87 | 6.11 | 5.25 | †25 | †-14
Connecticut | 175 | 171 | 151 | 35,332 | 34,559 | 34,599 | 4.93 | 4.92 | 4.35 | 0 | -12
Delaware | 56 | 62 | 62 | 10,816 | 10,427 | 10,550 | 5.15 | 5.91 | 5.84 | 15 | -1
District of Columbia | 65 | 55 | 55 | 8,075 | 7,896 | 7,616 | 7.99 | 6.92 | 7.17 | -13 | 4
Florida | 1,548 | 1,509 | 1,469 | 224,433 | 221,410 | 224,389 | 6.85 | 6.77 | 6.50 | -1 | -4
Georgia | 1,000 | 959 | 913 | 126,130 | 125,120 | 126,437 | 7.87 | 7.61 | 7.17 | -3 | -6
Hawaii | 97 | 90 | 87 | 15,535 | 14,808 | 14,917 | 6.21 | 6.04 | 5.80 | -3 | -4
Idaho | 91 | 123 | 121 | 22,391 | 22,397 | 23,276 | 4.05 | 5.46 | 5.17 | 35 | -5
Illinois | 737 | 740 | 740 | 128,350 | 124,820 | 125,731 | 5.71 | 5.89 | 5.85 | 3 | -1
Indiana | 439 | 496 | 559 | 79,649 | 79,000 | 80,257 | 5.48 | 6.24 | 6.92 | †14 | 11
Iowa | 163 | 159 | 166 | 36,506 | 36,052 | 36,436 | 4.45 | 4.39 | 4.54 | -1 | 3
Kansas | 205 | 184 | 165 | 34,401 | 34,065 | 33,984 | 5.92 | 5.37 | 4.83 | -9 | -10
Kentucky | 283 | 277 | 269 | 52,315 | 51,984 | 52,913 | 5.38 | 5.30 | 5.06 | -1 | -5
Louisiana | 300 | 296 | 306 | 56,479 | 54,927 | 53,305 | 5.28 | 5.36 | 5.71 | 2 | 7
Maine | 63 | 41 | 41 | 12,093 | 11,627 | 11,601 | 5.18 | 3.51 | 3.52 | -32 | 0
Maryland | 366 | 430 | 402 | 68,782 | 65,594 | 65,797 | 5.29 | 6.51 | 6.07 | †23 | -7
Massachusetts | 284 | 261 | 253 | 68,584 | 67,093 | 68,184 | 4.12 | 3.88 | 3.70 | -6 | -5
Michigan | 614 | 532 | 572 | 102,321 | 99,124 | 99,525 | 5.96 | 5.34 | 5.71 | -10 | 7
Minnesota | 351 | 319 | 300 | 64,015 | 61,715 | 62,110 | 5.45 | 5.14 | 4.81 | -6 | -6
Mississippi | 320 | 343 | 263 | 34,675 | 34,459 | 33,473 | 9.14 | 9.86 | 7.80 | 8 | †-21
Missouri | 358 | 372 | 348 | 68,985 | 67,123 | 67,998 | 5.16 | 5.51 | 5.09 | 7 | -8
Montana | 54 | 49 | 53 | 11,175 | 11,078 | 11,331 | 4.81 | 4.40 | 4.66 | -9 | 6
Nebraska | 110 | 123 | 113 | 24,345 | 24,111 | 24,785 | 4.50 | 5.08 | 4.54 | 13 | -11
Nevada | 235 | 245 | 242 | 33,193 | 31,794 | 32,381 | 7.03 | 7.65 | 7.42 | 9 | -3
New Hampshire | 56 | 44 | 37 | 12,077 | 11,936 | 11,770 | 4.62 | 3.67 | 3.13 | -21 | -15
New Jersey | 498 | 562 | 671 | 102,893 | 101,001 | 101,372 | 4.82 | 5.53 | 6.58 | †15 | †19
New Mexico | 69 | 94 | 82 | 21,614 | 20,951 | 21,328 | 3.18 | 4.47 | 3.83 | 41 | -14
New York (including New York City) | 1,211 | 1,137 | 1,162 | 207,774 | 203,612 | 205,489 | 5.79 | 5.55 | 5.62 | -4 | 1
North Carolina | 696 | 697 | 714 | 121,562 | 120,082 | 122,856 | 5.69 | 5.77 | 5.78 | 1 | 0
North Dakota | 47 | 42 | 63 | 9,567 | 9,647 | 9,634 | 4.89 | 4.33 | 6.50 | -11 | 50
Ohio | 741 | 775 | 704 | 128,231 | 126,896 | 126,795 | 5.75 | 6.07 | 5.52 | 6 | -9
Oklahoma | 293 | 275 | 295 | 48,332 | 47,909 | 47,962 | 6.03 | 5.71 | 6.11 | -5 | 7
Oregon | 195 | 179 | 169 | 39,493 | 38,298 | 38,963 | 4.91 | 4.65 | 4.32 | -5 | -7
Pennsylvania | 663 | 593 | 612 | 130,252 | 126,951 | 127,299 | 5.06 | 4.65 | 4.78 | -8 | 3
Rhode Island | 52 | 49 | 49 | 10,269 | 9,805 | 10,009 | 5.04 | 4.97 | 4.87 | -1 | -2
South Carolina | 288 | 310 | 333 | 57,820 | 57,729 | 58,768 | 4.96 | 5.34 | 5.63 | 8 | 5
South Dakota | 54 | 84 | 62 | 11,201 | 11,201 | 11,451 | 4.80 | 7.44 | 5.39 | 55 | -28
Tennessee | 538 | 471 | 510 | 82,265 | 83,021 | 83,833 | 6.50 | 5.64 | 6.05 | †-13 | 7
Texas | 1,613 | 1,615 | 1,610 | 389,741 | 387,945 | 390,828 | 4.12 | 4.15 | 4.10 | 1 | -1
Utah | 252 | 296 | 258 | 45,768 | 45,019 | 46,664 | 5.48 | 6.53 | 5.50 | †19 | †-16
Vermont | 21 | 19 | 17 | 5,316 | 5,065 | 5,023 | 3.93 | 3.74 | 3.37 | -5 | -10
Virginia | 497 | 495 | 505 | 95,630 | 92,649 | 94,054 | 5.17 | 5.31 | 5.34 | 3 | 1
Washington | 421 | 432 | 398 | 83,333 | 80,932 | 83,118 | 5.03 | 5.31 | 4.77 | 6 | -10
West Virginia | 70 | 62 | 54 | 16,929 | 16,606 | 17,022 | 4.12 | 3.72 | 3.16 | -10 | -15
Wisconsin | 320 | 314 | 295 | 60,049 | 59,754 | 59,686 | 5.30 | 5.23 | 4.92 | -1 | -6
Wyoming | 36 | 33 | 31 | 6,049 | 5,990 | 6,089 | 5.92 | 5.48 | 5.07 | -7 | -7

† Significant change (p < 0.05).

1 Number of fetal deaths per 1,000 live births and fetal deaths.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

## Summary

This analysis of provisional 2024 fetal mortality data found that the total and late fetal mortality rates declined by 2% and 4%, respectively, compared with 2023 rates, while the early fetal mortality rate was essentially unchanged. From 2023 to 2024, no significant changes were observed in the fetal mortality rates for any of the race and Hispanic-origin groups. Fetal mortality rates decreased in three states and increased in one state from 2023 to 2024; however, the small number of fetal deaths in some states by year can limit the ability to detect statistically significant changes between years and between states.

In comparison, from 2022 to 2023, the fetal mortality rate increased for early fetal deaths, for Asian women, and in five states, and declined in one state.

## References

1 Gregory ECW, Valenzuela CP, Martin JA. Fetal mortality in the United States: Trends from 2014 through 2019 and changes between 2018–2019 and 2019– 2020. Vital Statistics Rapid Release. 2022 Jan;(18):1–7. DOI: 10.15620/cdc:113008.
2 Gregory ECW, Valenzuela CP, Martin JA. Fetal mortality in the United States: Final 2019–2020 and 2020–provisional 2021. Vital Statistics Rapid Release. 2023 Jan;(26):1–7. DOI: 10.15620/cdc:122292.
3 Gregory ECW, Valenzuela CP, Martin JA. Fetal mortality in the United States: Final 2020–2021 and 2021–provisional 2022. Vital Statistics Rapid Release. 2023 Nov;(32):1–7. DOI: 10.15620/cdc:133319.
4 Gregory ECW, Valenzuela CP, Martin JA. Fetal mortality in the United States: Final 2021–2022 and 2022–provisional 2023. Vital Statistics Rapid Release. 2024 Oct;(36):1–8. DOI: 10.15620/cdc/162209.
5 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist 62(210):58781–90. 1997.
6 National Center for Health Statistics. User guide to the 2023 fetal death public use file. 2025. Available from: https://www.cdc.gov/nchs/data_access/vitalstatsonline.htm.
7 Parker JD, Talih M, Irimata KE, Zhang G, Branum AM, Davis D, et al. National Center for Health Statistics data presentation standards for rates and counts. Vital Health Stat 2. 2023 Mar;(200):1–26.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science