# Report No. 38 Births: Provisional Data for 2024

### Objectives

This report presents provisional 2024 data on U.S. births. Births are shown by age and race and Hispanic origin of mother. Data on cesarean delivery and preterm births are also presented.

### Methods

Data are based on 99.92% of all 2024 birth records received and processed by the National Center for Health Statistics as of February 4, 2025. Comparisons are made with final 2023 data and earlier years.

### Results

The provisional number of births for the United States in 2024 was 3,622,673, up 1% from 2023. The general fertility rate was 54.6 births per 1,000 females ages 15–44, an increase of less than 1% from 2023. The total fertility rate was 1,626.5 births per 1,000 women in 2024, an increase of less than 1% from 2023. Birth rates declined for females in 5-year age groups 15–24, rose for women in age groups 25–44, and were unchanged for females ages 10–14 and for women ages 45–49 in 2024. The birth rate for teenagers ages 15–19 declined by 3% in 2024 to 12.7 births per 1,000 females; the rates for younger (15–17) and older (18–19) teenagers declined 4% and 3%, respectively. The cesarean delivery rate increased to 32.4% in 2024, from 32.3% in 2023; the low-risk cesarean delivery rate was unchanged at 26.6%. The preterm birth rate was 10.41% in 2024, unchanged from the rate in 2023.

## Introduction

This report from the National Center for Health Statistics (NCHS) is part of the National Vital Statistics System (NVSS) Rapid Release Quarterly Provisional Estimates data series. This series provides timely vital statistics for public health surveillance based on provisional data received and processed by NCHS as of a specified date. Estimates for the 12-month period ending with each quarter for selected key vital statistics indicators are presented and released online through Quarterly Provisional Estimates, available from: https://www.cdc.gov/nchs/nvss/vsrr/natality-dashboard.htm. The series also includes reports that provide additional information on specific topics to help readers understand and interpret provisional natality and mortality data. In addition, monthly provisional birth data are now available and can be accessed through the Centers for Disease Control and Prevention’s CDC WONDER database.

Using provisional birth data for the 12 months of 2024 (1), this report supplements the Quarterly Provisional Estimates for 2024 by presenting longer time-based trends in context and more detail (by additional race and Hispanic-origin groups of the mother and by state of residence). Statistics from previous provisional reports have been shown to be consistent with the final statistics for the year (2,3). This report presents provisional data on births, birth rates, cesarean delivery, and preterm birth rates for the United States in 2024. Information on prenatal care, low birthweight, and other health use and maternal and infant risk factors will be presented with final birth data for 2024.

## Methods

The provisional estimates shown in this report are collected through NVSS (4). Findings are based on all birth records received and processed by NCHS for calendar year 2024 as of February 4, 2025, and these records represent nearly 100% of registered births occurring in 2024 (99.92%). The natality database, from which data for this report and the monthly data released in CDC WONDER are compiled, is made up of a continuous flow of records, both new and updated, from the states. Accordingly, provisional estimates for 2024 presented in this report and those for the same or different periods in CDC WONDER may differ. Comparisons in this report are based on final data for 2023 and earlier years (3). Data for American Samoa and Guam were not available as of the release of the 2024 provisional birth file. Detailed information on reporting completeness and criteria may be found elsewhere (4,5).

Hispanic origin and race are reported separately on the birth certificate. Data shown by Hispanic origin include all people of Hispanic origin of any race. Data for non-Hispanic people are shown separately for each single-race group. Data by race are based on the revised standards issued by the Office of Management and Budget in 1997 (6). The race and Hispanic-origin groups shown are American Indian and Alaska Native non-Hispanic single race (subsequently, American Indian and Alaska Native), Asian non-Hispanic single race (subsequently, Asian), Black non-Hispanic single race (subsequently, Black), Native Hawaiian and Other Pacific Islander non-Hispanic single race (subsequently, Native Hawaiian and Other Pacific Islander), White non-Hispanic single race (subsequently, White), and Hispanic.

Birth and fertility rates for the United States and by maternal race and Hispanic origin for 2024 are based on population projections derived from the blended base population estimates produced by the U.S. Census Bureau (instead of the April 1, 2020, decennial population count), which are a blend of 2020 census data, 2020 Demographic Analysis estimates, and Vintage 2020 estimates as of July 1, 2024 (7).

Changes and differences presented in this report are statistically significant at the 0.05 level, unless noted otherwise. For information and discussion on computing rates and percentages, and for detailed information on items presented in this report, see “User Guide to the 2023 Natality Public Use File” (4).

## Results

### Births and birth rates

Tables 1–3 and Figures 1 and 2 show the following key findings:

Figure 1 Number of live births and general fertility rate: United States, final 2000–2023 and provisional 2024

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 1 is a line chart showing the number of live births and general fertility rate for final 2000 through 2023 and provisional 2024.

Figure 2 Birth rate for teenagers, by age of mother: United States, final 1991–2023 and provisional 2024

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 2 is a line chart showing the birth rate of females ages 15 through 19, 15 through 17, and 18 through 19 for final 1991 through 2023 and provisional 2024.

Table 1

Births and birth rate, by age of mother: United States, final 2023 and provisional 2024

[Data for 2024 are based on a continuous file of records received from the states. Rates are per 1,000 women in specified age group. Rates for all ages are the total number of births (regardless of age of mother) per 1,000 females ages 15–44. Populations estimated as of July 1]
Age of mother | 2024 | | 2023
Age of mother | Number | Rate | Number | Rate
All ages | 3,622,673 | 54.6 | 3,596,017 | 54.5
10–14 | 1,725 | 0.2 | 1,766 | 0.2
15–19 | 137,020 | 12.7 | 140,977 | 13.1
15–17 | 34,405 | 5.3 | 35,714 | 5.5
18–19 | 102,615 | 23.9 | 105,263 | 24.6
20–24 | 610,548 | 56.7 | 616,970 | 57.7
25–29 | 989,140 | 91.4 | 986,567 | 91.0
30–34 | 1,110,643 | 95.4 | 1,098,052 | 94.3
35–39 | 621,464 | 55.0 | 604,631 | 54.3
40–44 | 141,204 | 12.8 | 136,333 | 12.5
45–54^1^ | 10,929 | 1.1 | 10,721 | 1.1

^1^Birth rate computed by relating the number of births to women age 45 and older to women ages 45–49, because most births in this group are to women ages 45–49.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 2

Total number of births and fertility rate, by race and Hispanic origin of mother: United States, final 2023 and provisional 2024

[Data for 2024 are based on a continuous file of records received from the states. Rates are the total number of births (regardless of age of mother) per 1,000 females ages 15–44 in specified race and Hispanic-origin group. Populations estimated as of July 1]
Year | All races and origins^1^ | Non-Hispanic, single race | | | | | Hispanic^3^
Year | All races and origins^1^ | AmericanIndian andAlaska Native^2^ | Asian^2^ | Black^2^ | Native Hawaiian and Other Pacific Islander^2^ | White^2^ | Hispanic^3^
| Number
2024 | 3,622,673 | 23,875 | 226,744 | 472,756 | 10,086 | 1,780,377 | 982,253
2023 | 3,596,017 | 24,571 | 215,738 | 491,494 | 10,115 | 1,787,051 | 945,200
| Rate
2024 | 54.6 | 46.6 | 49.4 | 51.4 | 72.2 | 51.7 | 66.1
2023 | 54.5 | 48.0 | 47.8 | 53.7 | 73.2 | 51.7 | 64.7

^1^Includes births to race and Hispanic-origin groups not shown separately, such as Hispanic single-race White, Hispanic single-race Black, and multiple-race non-Hispanic women, as well as births with origin not stated.

^2^Race groups are non-Hispanic single race. Race and Hispanic origin are reported separately on birth certificates. People of Hispanic origin may be of any race. In this table non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards. Race categories in this table include only single race, that is, the race reported alone with only one race reported.

^3^Includes all persons of Hispanic origin of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 3

Total number of births and percentage of cesarean delivery and preterm births, by race and Hispanic origin of mother: United States, final 2023 and provisional 2024

[Data for 2024 are based on a continuous file of records received from the states]
Characteristic | All races andorigins^1^ | Non-Hispanic, single race | | | | | Hispanic^3^
Characteristic | All races andorigins^1^ | AmericanIndian and Alaska Native^2^ | Asian^2^ | Black^2^ | Native Hawaiian and Other Pacific Islander^2^ | White^2^ | Hispanic^3^
Number of births | Number
2024 | 3,622,673 | 23,875 | 226,744 | 472,756 | 10,086 | 1,780,377 | 982,253
2023 | 3,596,017 | 24,571 | 215,738 | 491,494 | 10,115 | 1,787,051 | 945,200
Cesarean delivery | Percent
Total^4^:
2024 | 32.4 | 29.9 | 34.4 | 37.5 | 33.3 | 31.1 | 32.2
2023 | 32.3 | 29.9 | 34.2 | 37.0 | 32.5 | 31.1 | 32.0
Low-risk^5^:
2024 | 26.6 | 24.1 | 30.1 | 31.5 | 29.0 | 25.5 | 25.9
2023 | 26.6 | 23.6 | 30.1 | 30.8 | 28.9 | 25.6 | 25.9
Gestational age^6^
Preterm (under 37 weeks):
2024 | 10.41 | 12.59 | 9.16 | 14.86 | 12.50 | 9.49 | 10.07
2023 | 10.41 | 12.23 | 9.08 | 14.65 | 12.52 | 9.44 | 10.14
Late preterm (34–36 weeks):
2024 | 7.69 | 9.23 | 6.85 | 10.01 | 9.11 | 7.23 | 7.51
2023 | 7.64 | 9.21 | 6.79 | 9.79 | 9.28 | 7.16 | 7.52
Early preterm (under 34 weeks):
2024 | 2.72 | 3.36 | 2.30 | 4.84 | 3.39 | 2.26 | 2.56
2023 | 2.76 | 3.02 | 2.29 | 4.86 | 3.24 | 2.28 | 2.62

^1^Includes births to race and Hispanic-origin groups not shown separately, such as Hispanic single-race White, Hispanic single-race Black, and multiple-race non-Hispanic women, as well as births with origin not stated.

^2^Race groups are non-Hispanic single race. Race and Hispanic origin are reported separately on birth certificates. People of Hispanic origin may be of any race. Race categories are consistent with 1997 Office of Management and Budget standards. Race categories in this table include only single race (the race reported alone with only one race reported).

^3^Includes all persons of Hispanic origin of any race.

^4^All births by cesarean delivery per 100 live births.

^5^Low-risk cesarean is defined as singleton, term (37 weeks or more of gestation based on obstetric estimate), vertex (head-first), cesarean deliveries to women having a first birth per 100 women delivering singleton, term, vertex, first births.

^6^Completed weeks of gestation based on the obstetric estimate.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

- The provisional number of births for the United States in 2024 was 3,622,673, increasing 1% from the number in 2023 (3,596,017) (Tables 1–3 and Figure 1). The number of births declined by an average 2% per year from 2015 through 2020 and has generally fluctuated since then (3,8).
- The provisional number of births declined 4% for Black women, 3% for American Indian and Alaska Native women, and less than 1% for White women from 2023 to 2024. Births rose 4% for Hispanic and 5% for Asian women and were essentially unchanged for Native Hawaiian and Other Pacific Islander women (Tables 2 and 3).
- The provisional general fertility rate for the United States in 2024 was 54.6 births per 1,000 females ages 15–44, an increase of less than 1% from the rate in 2023 (54.5). The rate declined by 2% per year from 2014 to 2020 and has generally fluctuated since then (Tables 1 and 2 and Figure 1) (3,8).
- General fertility rates declined 4% for Black women and 3% for American Indian and Alaska Native women and rose 2% for Hispanic women and 3% for Asian women from 2023 to 2024. The general fertility rate was unchanged for White women and essentially unchanged for Native Hawaiian and Other Pacific Islander women.
- The provisional total fertility rate for the United States in 2024 was 1,626.5 births per 1,000 women, an increase of less than 1% from the rate in 2023 (1,621.0); the rate declined by 2% per year from 2014 to 2020 and has generally fluctuated since then (3,8). The total fertility rate estimates the number of births that a hypothetical group of 1,000 women would have over their lifetimes, based on the age-specific birth rate in a given year. The rate is the sum of birth rates for 5-year age groups (Table 1) multiplied by 5.
- The total fertility rate in 2024 remained below replacement—the level at which a given generation can exactly replace itself (2,100 births per 1,000 women). The rate has generally been below replacement since 1971 and consistently below replacement since 2007 (3,8,9).

#### Maternal age

Provisional birth rates declined for females in 5-year age groups 15–24 from 2023 to 2024, rose for women in age groups 25–44, and were unchanged for females ages 10–14 and 45–49 (Table 1).

- The provisional birth rate for teenagers in 2024 was 12.7 births per 1,000 females ages 15–19, down 3% from 2023 (13.1) and another record low for this age group (Table 1 and Figure 2) (3,8–10). The rate declined an average of 4% annually from 2007 to 2024 (3,8). The rate has declined by 69% since 2007 (41.5), the most recent period of continued decline, and 79% since 1991 (61.8), the most recent peak. The number of births to females ages 15–19 was 137,020 in 2024, down 3% from 2023 (3).
- Provisional birth rates for teenagers ages 15–17 and 18–19 in 2024 were 5.3 and 23.9 births per 1,000 females, respectively. The birth rate for younger teenagers (ages 15–17) declined by 4% from 2023 (5.5), and the rate for older teenagers (ages 18–19) declined by 3% (24.6), both record lows for each group (3,8–10). From 2007 to 2024, rates for teenagers ages 15–17 and 18–19 declined by 8% and 6% per year, respectively (3,8).
- The provisional birth rate for adolescents ages 10–14 was 0.2 births per 1,000 females in 2024, unchanged since 2015.
- The provisional birth rate for women ages 20–24 in 2024 was 56.7 births per 1,000 women, down 2% from 2023 (57.7) and another record low for this age group (Table 1) (3,8,9). This rate has declined by 46% since 2007. The number of births to women in their early 20s declined by 1% from 2023 to 2024.
- The provisional birth rate for women ages 25–29 was 91.4 births per 1,000 women, an increase of less than 1% from 2023 (91.0) (3,8,9). The number of births to women in their late 20s was essentially unchanged from 2023 to 2024.
- The provisional birth rate for women ages 30–34 in 2023 was 95.4 births per 1,000 women, increasing 1% from 2023 (94.3) (3,8,9). The number of births to women in their early 30s rose 1% from 2023 to 2024.
- The provisional birth rate for women ages 35–39 was 55.0 births per 1,000 women, increasing 1% from 2023 (54.3). The number of births to women in their late 30s rose 3% from 2023 to 2024.
- The provisional birth rate for women ages 40–44 in 2024 was 12.8 births per 1,000 women, up 2% from 2023 (12.5). The rate for this age group rose almost continuously from 1985 to 2024 (3,8). The number of births to these women rose 4% from 2023 to 2024.
- The provisional birth rate for women ages 45–49 (includes births to women ages 50 and older) was 1.1 births per 1,000 women, unchanged from 2023. The number of births to women in this age group was essentially unchanged from 2023 to 2024.

### Maternal and infant health characteristics

Tables 3 and 4 and Figure 3 show the following key findings:

Figure 3 Percentage of preterm births: United States, final 2007–2023 and provisional 2024

NOTE: Preterm is less than 37 completed weeks of gestation. SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 3 is a line chart showing the percentage of preterm births for final 2007 through 2023 and provisional 2024.

#### Cesarean delivery

- In 2024, the overall cesarean delivery rate increased to 32.4%, from 32.3% in 2023 (Tables 3 and 4). The rate generally declined from 2009 (32.9%) to 2019 (31.7%) and has increased almost every year from 2020 to 2024. The 2024 rate is the highest since 2013 (32.7%) (3). See Table 4 for state-specific rates.
- From 2023 to 2024, cesarean delivery increased for Black (37.0% to 37.5%) and Hispanic (32.0% to 32.2%) women and remained unchanged for White (31.1%) and American Indian and Alaska Native (29.9%) women. Increases for Asian (34.2% to 34.4%) and Native Hawaiian and Other Pacific Islander (32.5% to 33.3%) women were not significant.
- The low-risk cesarean delivery rate—that is, cesarean delivery among nulliparous (first birth), term (37 completed weeks or more based on the obstetric estimate), singleton (one fetus), vertex (head-first) births—was unchanged from 2023 to 2024 at 26.6%, the highest rate since 2013 (26.8%) (3).
- Low-risk cesarean rates increased from 2023 to 2024 for Black women (30.8% to 31.5%) and remained unchanged for Asian (30.1%) and Hispanic (25.9%) women. Changes for the other race and Hispanic-origin groups were not significant.

#### Preterm birth

- The preterm birth rate was 10.41% in 2024, unchanged from 2023 (Table 3 and Figure 3). The percentage of infants born preterm (births at less than 37 completed weeks of gestation) fell 8% from 2007 (the most recent year for which national data are available based on the obstetric estimate of gestation) to 2014, rose 7% from 2014 to 2019, declined 1% in 2020, rose 4% in 2021, and has been essentially stable from 2021 to 2024 (3,11). See Table 4 for state-specific rates for 2024.
- The early preterm (less than 34 completed weeks of gestation) birth rate declined 1% from 2023 to 2024 (2.76% to 2.72%), while the rate for late preterm (34–36 weeks) births increased 1% (7.64% to 7.69%) (Table 3). The late preterm rates for 2021 (7.67%), 2023, and 2024 are the highest reported since at least 2007 (3).
- The preterm birth rate increased 1% for Black mothers from 2023 to 2024 (14.65% to 14.86%) and was not significantly changed for other race and Hispanic-origin groups, including American Indian and Alaska Native (12.23% to 12.59%), Asian (9.08% to 9.16%), Native Hawaiian and Other Pacific Islander (12.52% to 12.50%), White (9.44% to 9.49%), and Hispanic (10.14% to 10.07%) women (Table 3).

Table 4

Total number of births, by state of residence, provisional 2024, and percentage of cesarean delivery and preterm births, by state of residence: United States, each state and territory, final 2023 and provisional 2024

[By place of residence. Data are based on a continuous file of records received from the states]
Area | Totalnumber of births, 2024 | Total cesarean | | Low-risk cesarean^1^ | | Late preterm^2^ | | Preterm^3^
Area | Totalnumber of births, 2024 | 2024 | 2023 | 2024 | 2023 | 2024 | 2023 | 2024 | 2023
| | Percent
United States^4^ | 3,622,673 | 32.4 | 32.3 | 26.6 | 26.6 | 7.69 | 7.64 | 10.41 | 10.41
Alabama | 57,857 | 34.7 | 34.2 | 28.0 | 28.3 | 9.39 | 9.51 | 12.74 | 12.91
Alaska | 8,928 | 23.3 | 24.0 | 19.7 | 20.5 | 7.49 | 7.87 | 10.04 | 10.27
Arizona | 78,680 | 29.5 | 29.0 | 24.2 | 23.4 | 7.24 | 7.32 | 9.66 | 9.87
Arkansas | 35,272 | 34.1 | 33.8 | 27.9 | 26.9 | 9.04 | 8.89 | 12.13 | 12.09
California | 401,515 | 31.9 | 31.5 | 26.2 | 25.9 | 6.80 | 6.79 | 9.08 | 9.16
Colorado | 64,277 | 27.9 | 27.5 | 22.6 | 23.1 | 7.44 | 7.20 | 9.96 | 9.70
Connecticut | 34,582 | 35.9 | 35.0 | 30.6 | 30.0 | 7.14 | 6.66 | 9.83 | 9.34
Delaware | 10,421 | 33.5 | 31.5 | 28.1 | 24.2 | 7.33 | 7.63 | 10.54 | 10.44
District of Columbia | 7,601 | 36.3 | 34.1 | 31.6 | 29.7 | 8.03 | 7.27 | 11.74 | 10.77
Florida | 224,267 | 36.3 | 36.2 | 30.1 | 29.9 | 7.78 | 7.75 | 10.70 | 10.72
Georgia | 126,350 | 34.9 | 35.8 | 28.2 | 29.8 | 8.55 | 8.59 | 11.80 | 11.82
Hawaii | 14,757 | 27.1 | 27.4 | 23.3 | 23.7 | 7.45 | 7.51 | 10.01 | 10.05
Idaho | 23,237 | 24.6 | 24.4 | 20.2 | 19.8 | 6.94 | 6.52 | 9.09 | 8.68
Illinois | 125,665 | 30.8 | 31.0 | 24.3 | 24.2 | 7.64 | 7.84 | 10.38 | 10.76
Indiana | 80,153 | 31.0 | 30.7 | 24.9 | 25.0 | 8.09 | 8.21 | 10.93 | 11.04
Iowa | 36,391 | 29.9 | 30.2 | 23.3 | 24.5 | 7.54 | 7.70 | 10.09 | 10.36
Kansas | 33,972 | 30.1 | 30.3 | 24.2 | 24.8 | 7.76 | 7.97 | 10.27 | 10.45
Kentucky | 52,846 | 34.5 | 34.3 | 26.5 | 27.2 | 8.82 | 8.42 | 11.73 | 11.28
Louisiana | 52,831 | 36.1 | 36.1 | 28.9 | 28.3 | 10.24 | 9.85 | 13.96 | 13.36
Maine | 11,595 | 30.9 | 31.1 | 24.6 | 25.5 | 7.22 | 7.24 | 9.71 | 9.57
Maryland | 65,781 | 35.6 | 35.0 | 30.7 | 30.3 | 7.63 | 7.38 | 10.49 | 10.24
Massachusetts | 68,178 | 34.0 | 33.5 | 28.5 | 27.5 | 6.61 | 6.73 | 8.89 | 9.06
Michigan | 99,486 | 32.7 | 33.2 | 27.4 | 28.4 | 7.76 | 7.49 | 10.67 | 10.31
Minnesota | 62,009 | 30.3 | 30.2 | 26.8 | 26.6 | 7.26 | 6.96 | 9.74 | 9.44
Mississippi | 33,453 | 37.9 | 37.9 | 29.7 | 30.1 | 10.93 | 10.84 | 15.01 | 14.96
Missouri | 67,925 | 30.5 | 30.2 | 24.5 | 24.0 | 8.14 | 8.24 | 10.96 | 11.04
Montana | 11,314 | 26.2 | 26.0 | 21.1 | 21.5 | 7.23 | 7.17 | 9.42 | 9.37
Nebraska | 24,729 | 29.7 | 29.4 | 24.5 | 22.9 | 8.39 | 8.40 | 11.08 | 11.12
Nevada | 32,330 | 32.9 | 33.5 | 27.7 | 28.1 | 8.11 | 8.01 | 10.98 | 11.07
New Hampshire | 11,761 | 31.2 | 32.9 | 26.6 | 27.5 | 6.04 | 6.23 | 7.93 | 8.32
New Jersey | 101,361 | 32.9 | 33.1 | 26.7 | 27.3 | 7.01 | 6.94 | 9.39 | 9.28
New Mexico | 20,602 | 28.7 | 28.4 | 24.4 | 23.6 | 7.23 | 7.44 | 9.85 | 10.11
New York | 204,864 | 33.8 | 33.9 | 29.2 | 29.6 | 7.00 | 7.14 | 9.49 | 9.62
North Carolina | 122,692 | 30.8 | 30.7 | 24.9 | 24.9 | 7.78 | 7.68 | 10.68 | 10.74
North Dakota | 9,627 | 27.0 | 26.1 | 20.2 | 19.7 | 7.00 | 8.02 | 9.40 | 10.31
Ohio | 126,689 | 32.1 | 31.4 | 26.5 | 25.7 | 7.97 | 7.67 | 10.98 | 10.70
Oklahoma | 47,940 | 32.7 | 33.1 | 25.4 | 25.7 | 8.23 | 8.18 | 11.01 | 11.03
Oregon | 38,154 | 29.5 | 28.9 | 25.1 | 24.0 | 6.70 | 6.73 | 8.90 | 8.98
Pennsylvania | 127,079 | 31.3 | 31.3 | 26.0 | 25.5 | 7.20 | 7.03 | 9.77 | 9.71
Rhode Island | 10,005 | 33.9 | 33.2 | 28.4 | 28.0 | 6.47 | 7.24 | 8.96 | 9.57
South Carolina | 58,742 | 32.5 | 32.6 | 25.6 | 25.2 | 8.54 | 8.32 | 11.66 | 11.61
South Dakota | 11,445 | 24.8 | 24.4 | 17.9 | 19.1 | 8.35 | 9.74 | 11.20 | 12.52
Tennessee | 83,745 | 31.8 | 32.3 | 25.7 | 26.5 | 8.07 | 8.40 | 10.90 | 11.34
Texas | 390,506 | 34.5 | 34.5 | 27.9 | 27.8 | 8.20 | 8.15 | 11.09 | 11.13
Utah | 46,655 | 24.7 | 24.3 | 20.6 | 20.5 | 7.19 | 6.98 | 9.52 | 9.37
Vermont | 5,026 | 26.3 | 27.5 | 20.7 | 23.7 | 6.21 | 5.79 | 8.19 | 7.66
Virginia | 93,646 | 32.1 | 32.3 | 26.1 | 26.2 | 7.30 | 7.06 | 10.06 | 9.80
Washington | 83,044 | 30.5 | 30.0 | 26.3 | 26.2 | 6.77 | 6.51 | 9.00 | 8.70
West Virginia | 16,979 | 35.2 | 34.9 | 29.4 | 29.2 | 9.97 | 9.89 | 13.39 | 13.09
Wisconsin | 59,624 | 27.6 | 27.3 | 22.7 | 22.6 | 7.50 | 7.37 | 10.00 | 9.92
Wyoming | 6,085 | 27.5 | 28.3 | 20.8 | 22.8 | 7.87 | 7.80 | 10.55 | 9.77
Puerto Rico | 18,046 | 49.8 | 50.6 | 47.1 | 48.9 | 9.01 | 8.89 | 12.23 | 12.22
Virgin Islands | 803 | 39.7 | 40.0 | 33.1 | 30.9 | 7.12 | 10.54 | 10.18 | 13.11
Guam | --- | --- | 26.6 | --- | 28.1 | --- | 10.34 | --- | 13.33
American Samoa | --- | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 546 | 27.8 | 28.8 | 21.8 | 24.5 | 5.50 | 7.44 | 7.16 | 10.38

--- Data not available.

^1^Singleton, term (37 weeks or more of gestation based on obstetric estimate), vertex (head-first), cesarean deliveries to women having a first birth per 100 women delivering singleton, term, vertex first births.

^2^Births at 34–36 completed weeks of gestation based on the obstetric estimate.

^3^Births before 37 completed weeks of gestation based on the obstetric estimate.

^4^Excludes data for the territories.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

## References

1 Driscoll AK, Osterman MJK, Hamilton BE, Valenzuela CP, Martin JA. Quarterly provisional estimates for selected birth indicators, quarter 1, 2022–quarter 4, 2024. In: Vital Statistics Rapid Release Program Internet]. Hyattsville (MD): National Center for Health Statistics (US); 2025 Jan. Available from: https://www.cdc.gov/nchs/nvss/vsrr/natality-dashboard.htm.
2 Hamilton BE, Martin JA, Osterman MJK. Births: Provisional data for 2023. 2024 Apr. In: Vital Statistics Rapid Release Reports [Internet]. Hyattsville (MD): National Center for Health Statistics (US); 2024 Apr. Report No. 35. DOI: 10.15620/cdc/151797.
3 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final data for 2023. Natl Vital Stat Rep. 2025 Mar;74(1):1–87. DOI: 10.15620/cdc/175204.
4 National Center for Health Statistics. User guide to the 2023 natality public use file. Hyattsville (MD): National Center for Health Statistics; 2024. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2023.pdf.
5 National Center for Health Statistics. Quarterly provisional estimates–technical notes–natality, quarter 4, 2024. Hyattsville (MD): National Center for Health Statistics; 2024.Available from: https://www.cdc.gov/nchs/nvss/vsrr/natality-technical-notes.htm.
6 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist 62(210):58782–90. 1997. Available from: https://www.govinfo.gov/content/pkg/FR-1997-10-30/pdf/97-28653.pdf.
7 U.S. Census Bureau. Monthly national population estimates by age, sex, race, and Hispanic origin for the United States: April 1, 2010, to July 1, 2023 (with short-term projections to December 2024). Monthly postcensal resident population. Available from: https://www2.census.gov/programs-surveys/popest/datasets/2020-2023/national/asrh/nc-est2023-alldata-r-file10.csv.
8 Martin JA, Hamilton BE, Osterman MJ, Driscoll AK, Mathews TJ. Births: Final data for 2015. Natl Vital Stat Rep. 2017 Jan;66(1):1–70. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr66/nvsr66_01.pdf.
9 National Center for Health Statistics. Vital statistics of the United States, 2003. Vol 1. Natality. Hyattsville (MD): National Center for Health Statistics; 2003. Available from: https://www.cdc.gov/nchs/products/vsus/vsus_1980_2003.htm.
10 Ventura SJ, Hamilton BE, Matthews TJ. National and state patterns of teen births in the United States, 1940– 2013. Natl Vital Stat Rep. 2014 Aug;63(4):1–34. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr63/nvsr63_04.pdf.
11 Martin JA, Osterman MJK, Kirmeyer SE, Gregory ECW. Measuring gestational age in vital statistics data: Transitioning to the obstetric estimate. Natl Vital Stat Rep. 2015 Jun 1;64(5):1–20. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr64/nvsr64_05.pdf.

## Acknowledgments

This report was prepared in the Division of Vital Statistics under the general direction of Paul D. Sutton, Director; Robert N. Anderson, Chief, Statistical Analysis and Surveillance Branch; and Joyce A. Martin, Team Leader, Perinatal Research and Statistics Team. Rajesh Virkar, Chief of the Systems, Programming, and Statistical Resources Branch, and Legesse Alemu and Annie S. Liu provided computer programming support and statistical tables. Legesse Alemu and Annie S. Liu also prepared the natality file. The Data Acquisition, Classification, and Evaluation Branch staff evaluated the quality of and acceptance procedures for the state data files on which this report is based. Danielle M. Ely of the Reproductive Statistics Branch provided content review.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science